# Conclusions

Under the conditions of this 2-year dietary study, there was equivocal evidence of carcinogenic activity^a^ of diets deficient in zinc in male Hsd:Sprague Dawley^®^ SD^®^ rats based on higher incidences of adenoma of the pancreas and increased incidences of animals with multiple pancreatic adenomas. There was no evidence of carcinogenic activity of diets deficient in zinc (3.5 or 7 ppm) in female Hsd:Sprague Dawley^®^ SD^®^ rats. There was no evidence of carcinogenic activity of diets containing excess zinc (250 or 500 ppm) in male or female Hsd:Sprague Dawley^®^ SD^®^ rats.

a See Explanation of Levels of Evidence of Carcinogenic Activity. See a summary of the Peer Review Panel comments and the public discussion on this Technical Report in Appendix I.

Exposure to diets containing excess zinc resulted in increased incidences of nonneoplastic lesions of the pancreas in male and female rats. Exposure to diets deficient in zinc resulted in increased incidences of nonneoplastic lesions of the testes in male rats.