# Discussion

Zinc is a natural component of the Earth’s crust that is an essential element required by humans and animals for multiple biological processes. It is also used extensively for many applications in industry. Dietary zinc was nominated by the Agency for Toxic Substances and Disease Registry (ATSDR) for carcinogenesis and genetic toxicity studies based on the increasing size of the population exposed to zinc through dietary supplements and due to a lack of carcinogenicity data in the literature. There was an additional nomination by private individuals to investigate the tumorigenicity of zinc deficiency due to data demonstrating DNA damage as a result of some vitamin and mineral deficiencies. Zinc carbonate was selected as the source of dietary zinc due to its degree of availability and its use as a source of supplemental zinc in rodent diets and vitamin supplements^261-263^. The current Technical Report presents the findings and conclusions of the 2-year feed study of rats exposed to varying levels of dietary zinc.

Generally, in the literature, a zinc-deficient diet in laboratory animals ranged from 0 to 9 ppm [2.34 ± 2.37 (mean ± SD)] a zinc-adequate diet ranged from 9 to 100 ppm (56 ± 25.8), and a zinc-excess diet ranged from 1,000 to 5,000 ppm (3,000 ± 1,732). In the current study, doses were chosen to allow for the chronic evaluation of the influence of varying nutritional intakes of zinc below and above the optimal physiological range. The control group of 38 ppm was chosen as a dietary level of zinc that is considered adequate for normal growth and survival in rats. The exposure concentrations for the zinc-deficient diets (3.5 and 7 ppm) were based on literature indicating a minimum dietary zinc requirement for survival. The exposure concentrations for excess zinc in the diet (250 and 500 ppm) were selected to examine the effects of excess zinc in the diet below levels that would result in interference with other essential metals (i.e., copper and iron) and were not in excess of reported LD_50_ values of 186 to 623 mg zinc/kg body weight per day (approximately equivalent to 3,162 and 10,591 ppm, respectively) for several zinc compounds in rodents^109^.

In the current 2-year study, there were no chemical-related effects on survival. Male rats maintained on the 3.5 ppm zinc-deficient diet had an increased survival rate compared to the controls, but this is likely due to low survival of the control group as a result of nephropathy.

Aside from the first time point measured (day 19), there were no changes in blood zinc concentrations as a result of dietary modulation of zinc levels in the current study when measured for up to a year. This is likely a result of the tight regulation of zinc serum and tissue levels in animals and humans and the many factors that can contribute to zinc homeostasis. Metallothionein-bound zinc has been shown to fluctuate depending on the zinc status of animals, indicating a role for metallothionein in the sequestration of excess zinc or as a reservoir in cases of zinc deficiency^264^. The increased toxicity of zinc in metallothionein-null mice provides evidence for this hypothesis.^264^. Additionally, studies in animals have indicated that adjustments are made in zinc absorption and endogenous intestinal excretion to maintain zinc homeostasis^265-268^. These alterations in excretion have also been demonstrated in humans, where large decreases in plasma zinc concentration as a result of low zinc in the diet can be prevented through rapid decreases of up to 75% in endogenous fecal and urinary zinc excretion^268^. Following excess dietary zinc intakes in humans, it was also observed that net zinc absorption reaches a plateau with doses of 20 mg/day^269^. Combined with evidence that plasma or serum zinc concentrations are only useful as biomarkers following severely deficient zinc diets or during extreme zinc supplementation^269^, these literature studies provide evidence that blood zinc concentrations may have remained unchanged in the present study due to failure to overwhelm normal homeostatic control of zinc. The present study is the longest to date that examines plasma levels of zinc with varying levels of zinc in the diet and, though it does not demonstrate dramatic changes in plasma zinc levels when measured for up to a year, it does provide long-term perspective on the complex homeostatic control of zinc levels following varying levels of zinc in the diet. Overall, it is clear that the regulation of zinc is complex and given the evidence shown in the current study, it is likely that the low incidences of nonneoplastic and neoplastic lesions may be due to the tight regulation of zinc homeostasis itself.

Zinc has been shown in the literature to interact with both copper and iron, resulting in changes in hematologic parameters^270; 271^. Zinc, copper, and iron plasma concentrations were repetitively measured in special study rats throughout the first year of the current study (day 19, and 3, 6, 9, and 12 months) to monitor zinc blood concentration changes and examine the potential influence of zinc on these other essential metals. No changes were observed in whole blood levels of males or females fed zinc-deficient diets (3.5 and 7 ppm) in comparison to the zinc sufficient controls (38 ppm). However, early increases (day 19) in zinc blood concentrations were observed with concurrent decreases (below the limit of detection) in copper blood concentrations in males and females provided diets containing excessive amounts of zinc (250 and 500 ppm); blood concentrations of both zinc and copper returned to concentrations similar to those of controls by 3 months. These early alterations in zinc and copper concentrations indicate initial disturbances in the normal homeostatic regulation of zinc. Return of near-normal zinc and copper concentrations following an initial increase after 4 weeks of exposure has also been demonstrated as an adaptive response to long-term high zinc intake in the serum, liver, and kidney of rats^272^. Similarly, rats fed 7.5 to 240 mg zinc (as zinc sulfate)/kg for 5 weeks had significant increases in serum zinc concentrations (189 ± 10 μg/dL compared to 128 ± 8 μg/dL in controls) alongside decreases in serum copper (45 ± 10 μg/dL compared to 114 ± 9 μg/dL in controls) in the top exposure group^61^. Inhibition of intestinal copper absorption induced by ingestion of high levels of zinc can be attributed to the competitive interaction of zinc and copper for metallothionein within the intestinal lumen^62; 273^. This effect has also been demonstrated in humans, where copper deficiency has been observed in susceptible individuals who are exposed to high levels of zinc for treatment of malnourishment or sickle cell anemia^130; 274^. Though most of the studies in the literature support an inverse relationship between zinc and copper levels, conflicting data demonstrate that different levels of dietary zinc (up to 180 mg/kg) and copper do not significantly influence absorption of each other when fed to rats over a period of a week^275^. Likewise, in humans, plasma copper levels were not significantly decreased following 100 to 220 mg of zinc sulfate per day for durations of either 6 weeks or 6 months^123; 276^. There are several possible reasons for these differences in the literature, and the influence of zinc on copper metabolism can be altered by many factors, including the ratio of zinc to copper in the diet, absorption and excretion of zinc in the regulation of zinc homeostasis, individual susceptibilities and species differences, the source of zinc in the diet, and the duration of dietary zinc exposure^277^. These factors may also play a role in the apparent recovery of the zinc-to-copper ratio presented in the current studies following the initial day 19 measurements.

In males fed diets that were deficient in dietary zinc (3.5 and 7 ppm), there were higher incidences of pancreatic acinar cell adenoma (P = 0.065 and P = 0.069, respectively). The number of males with multiple adenomas was significantly increased at 3.5 ppm. These neoplasms in males were accompanied by a higher incidence of pancreatic acinar cell hyperplasia in the 3.5 ppm group. Additionally, there was a single pancreatic acinar cell carcinoma in the 38 ppm male control group. Because this study was conducted on a controlled diet, historical controls are not available. The available historical control report^226^ for the Hsd:Sprague Dawley^®^ SD^®^ rat had 0/50 and 5/50 incidences of adenoma in the males compared to the current control incidence of 11/49. Acinar hyperplasia, acinar adenoma, and acinar carcinoma are proliferative lesions of the exocrine pancreas and represent a continuum of effect^278^. Though the increased incidences were not significant in the current study, the higher incidence of acinar cell hyperplasia provides supporting evidence when combined with increased incidences of acinar cell adenoma. Taken together, the higher incidences of adenoma and statistically increased incidence of multiple adenomas was considered to be equivocal evidence of carcinogenic activity.

In the current study, the incidences of acinar atrophy of the pancreas were significantly increased in males and females fed a diet with excess zinc (500 ppm). Atrophy of the pancreatic acini was characterized by small, shrunken ducts surrounded by a few depleted acinar cells, interstitial fibrous connective tissue, and mononuclear cell infiltrates, all of which resulted in an overall focal reduction in acinar tissue. In the literature, zinc toxicity from high levels of zinc has been associated with pancreatic lesions in pigs, including epithelial cell necrosis, diffuse acinar atrophy, and marked interstitial fibrosis^279^. The majority of zinc excretion occurs through the pancreas and as a result, the pancreas has also been identified as a target organ of zinc toxicity in mice through an unknown mechanism^280^. Deficiencies of other metals such as copper have also demonstrated pancreatic effects. Rats administered copper chelators through the diet to induce copper deficiency developed total acinar cell atrophy and fatty infiltration of the pancreatic acinar tissue^281^. Additionally, high levels of dietary zinc have been shown to interact with the absorption of copper^62^, an interaction that is supported by data from the current study in which male and female rats in the zinc excess 500 ppm dose groups had decreased blood concentrations of copper.

Dietary zinc exposure for 2 years had some effects on the male reproductive system as indicated by a significantly increased incidence of bilateral germinal epithelium atrophy in the testis of males fed the zinc-deficient diet (3.5 ppm). However, overall combined incidences of unilateral and bilateral germinal epithelium atrophy were not significantly increased due to higher incidences of unilateral germinal epithelium atrophy in the controls. Germinal epithelium atrophy was characterized by a thin germinal epithelium layer as a result of reduced numbers of germ cells, and most of the affected tubules were reduced in size and lined only by Sertoli cells. Although there were not pronounced effects of zinc deficiency in the current study, the importance of zinc in reproduction is illustrated through numerous studies in both animals and humans that have demonstrated decreased testosterone, reduced gonadal growth, and testicular damage (increased apoptosis and atrophy) due to zinc deficiency^146; 282-287^. Kumari et al.^286^ have shown that severe testicular degeneration and a significant loss of germ and somatic cells can occur as early as 4 weeks in rats fed a zinc-deficient diet (1 ppm). This testicular atrophy induced by zinc deficiency has also been shown to be irreversible, with no recovery after zinc was reintroduced into the diet^149; 282^. Testicular atrophy has also been observed frequently in humans with zinc deficient states, which include sickle cell anemia, chronic alcoholism, and idiopathic male sterility^146^. The testicular atrophy and arrested spermatogenesis have been attributed to defective cholesterol metabolism and thus low serum testosterone levels that result from zinc deficiency^146; 150^. Germinal epithelium atrophy can also be attributed to an ageing effect in rats, and the increased incidence of this lesion in the 3.5 ppm group may be a result of increased survival. However, given the association between zinc deficiency and testicular damage in the literature, it is likely that the testicular effects seen here are due to zinc deficiency.

Both zinc deficiency and excess have been reported in the literature to increase DNA damage in human and rodent cells in vitro^209-213; 223^. Published data have also shown increases in micronuclei and DNA damage in rats fed a zinc-deficient diet (<1 ppm) for 3 to 6 weeks, but the dietary zinc levels in these short-term studies were markedly less than the levels in the current NTP 2-year bioassay, which may account for the early detection of genetic damage^214-216^. In the current NTP rodent study, neither deficiency nor excess zinc in the diet for up to 12 months induced micronuclei in red blood cells, but results from NTP comet assays showed evidence of DNA damage in both leukocytes and colon epithelial cells in male and female rats after long-term exposure. In leukocytes, increases in DNA damage were observed primarily in the male and female rats fed a zinc-deficient diet after 9 or 12 months of exposure. In male rats fed a diet with excess zinc, DNA damage was increased in leukocytes at the 12-month sample time. In colon cells analyzed after 12 months of exposure, evidence of DNA damage was seen in the rats on zinc-deficient diets as well as the rats maintained on a diet with excess zinc. The types of damage observed in the two sets of rats may have been different, however. In this study, a zinc-deficient diet was associated with a significant decrease in DNA migration in the comet assay in colon samples compared to the control diet, an observation consistent with DNA cross-linking^254^, which has been shown to reduce the ability of DNA to migrate in the comet assay. Additionally, excess zinc in the diet was associated with significant increases in migration compared to the control diet, consistent with DNA fragmentation. Despite the evidence for DNA damage seen in colon epithelial cells of male and female rats exposed to high or low levels of dietary zinc, no preneoplastic lesions or neoplasms were observed in the colon. It is not known whether the observed DNA damage was induced in stem cells in the base of the colonic crypts or in epithelial cells that were fully differentiated. If the latter, then no opportunity would exist for development and expansion of a mutated clone to eventually produce a tumor. Interpretation of the DNA damage observations in colon cells may be further complicated by actions of the gut microbiome, but at this time, information on how this interaction might affect the consequences of zinc levels in the diet is not available. However, the indications of DNA damage associated with non-optimal zinc levels in a variety of in vitro and in vivo studies may serve as an alert to the potential for DNA damage in other cell types, which might give rise to adverse health consequences, especially if zinc levels remain altered for long periods of time.