# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TR-592.

## Two-year Study

### Survival

Estimates of 2-year survival probabilities for male and female rats are shown in Table 2 and in the Kaplan-Meier survival curves (Figure 1). Survival of 3.5 ppm males was significantly greater than that of controls. Almost half of the early deaths in control males were due to nephropathy. There were no significant differences in survival between controls and other exposed groups of males or females.

Table 2 Survival of Rats in the Two-year Feed Study of Dietary Zinc

| 3.5 ppm | 7 ppm | 38 ppm (Control) | 250 ppm | 500 ppm
Male
Animals initially in study | 60 | 60 | 60 | 60 | 60
Special study animals^a^ | 10 | 9 | 10 | 10 | 10
Moribund | 12 | 10 | 11 | 15 | 7
Natural deaths | 7 | 13 | 19 | 14 | 22
Animals surviving to study termination | 31 | 28^d^ | 20^e^ | 21 | 21^d^
Percent probability of survival at end of study^b^ | 62 | 53 | 36 | 42 | 40
Mean survival (days)^c^ | 638 | 623 | 611 | 610 | 614
Survival analysis^f^ | P = 0.009N | P = 0.144N | P = 0.008N | – | –
Survival analysis^g^ | – | – | P = 0.650N | P = 0.755N | P = 0.670N
Female
Animals initially in study | 60 | 60 | 60 | 60 | 60
Special study animals^a^ | 10 | 9 | 9 | 9 | 9
Moribund | 11 | 12 | 21 | 19 | 14
Natural deaths | 7 | 5 | 5 | 5 | 6
Animals surviving to study termination | 32 | 34 | 25 | 27 | 31
Percent probability of survival at end of study | 64 | 67 | 50 | 53 | 62
Mean survival (days) | 621 | 634 | 607 | 598 | 606
Survival analysis | P = 0.171N | P = 0.085N | P = 0.134N | – | –
Survival analysis | – | – | P = 0.346N | P = 0.920N | P = 0.369N

^a^ Euthanized at 12 months; censored in the survival analyses.

^b^ Kaplan-Meier determinations.

^c^ Mean of all deaths (uncensored, censored, and terminal euthanasia).

^d^ Includes one animal that died during the last week of the study.

^e^ Includes two animals that died during the last week of the study.

^f^ The result of the life table trend test^232^ is in the control column, and the results of the life table pairwise comparisons^231^ with the controls are in the 3.5 and 7 ppm exposure group columns. A negative trend or lower mortality in an exposure group is indicated by N.

^g^ The result of the life table trend test^232^ is in the control column, and the results of the life table pairwise comparisons^231^ with the controls are in the 250 and 500 ppm exposure group columns. A negative trend or lower mortality in an exposure group is indicated by N.

Figure 1

Kaplan-Meier Survival Curves for Rats Exposed to Dietary Zinc for Two Years

### Body Weights, Feed and Compound Consumption, and Clinical Findings

Mean body weights of 3.5 ppm males were 10% to 20% less than those of the controls between days 15 and 148; after that, mean body weights of 3.5 ppm males stayed within 10% of controls for the remainder of the study (Figure 2 and Table 3). Mean body weights of all other groups of males were within 10% of controls throughout the study. In females, similar decreases in mean body weights occurred in the 3.5 ppm group, but the decreases were less severe and of shorter duration than those seen in males (Figure 2 and Table 4). Mean body weights of 7 and 500 ppm females were within 10% of controls throughout the study; 250 ppm females had a terminal mean body weight 10% higher than that of the controls. Feed consumption by zinc deficient and zinc excess groups of males and females was generally similar to that by the control groups throughout the study (Table F-1 through Table F-4) with the exception of the 3.5 ppm males where feed consumption was as much as 25% less than that by controls by week 3 of the study and slowly recovered to control levels by study week 21. As mentioned in the [underlined: Materials and Methods], dietary concentrations were approximately 3% lower than the stated doses of 3.5, 7, 38 (control), 250, and 500 ppm because the theoretical value of zinc content (59.6%) was used instead of the measured zinc content in zinc carbonate to calculate the amount of zinc in the dose formulations. This resulted in average daily doses of 0.1, 0.3, 1.4 (control), 8.7, and 17.6 mg dietary zinc/kg body weight to males, and 0.1, 0.3, 1.5 (control), 9.9, and 19.9 mg/kg to females. No clinical observations related to deficient or excess dietary zinc exposure were observed in males or females.

Figure 2

Growth Curves for Rats Exposed to Dietary Zinc for Two Years

Table 3 Mean Body Weights and Survival of Male Rats in the Two-year Feed Study of Dietary Zinc

Day | 3.5 ppm | | 7 ppm | | | | 38 ppm (Control) | | 250 ppm | | | 500 ppm
Day | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 115 | 100 | 60 | 115 | 100 | 60 | 115 | 60 | 115 | 100 | 60 | 115 | 100 | 60
8 | 150 | 93 | 60 | 159 | 98 | 60 | 162 | 60 | 163 | 100 | 60 | 164 | 101 | 60
15 | 176 | 85 | 60 | 203 | 98 | 60 | 207 | 60 | 208 | 100 | 60 | 210 | 101 | 60
22 | 202 | 81 | 60 | 245 | 98 | 60 | 250 | 60 | 250 | 100 | 60 | 252 | 101 | 60
29 | 225 | 80 | 60 | 278 | 98 | 60 | 283 | 60 | 282 | 100 | 60 | 284 | 100 | 60
36 | 250 | 80 | 60 | 304 | 98 | 60 | 311 | 60 | 309 | 99 | 60 | 311 | 100 | 60
43 | 271 | 82 | 60 | 324 | 98 | 60 | 332 | 60 | 330 | 99 | 60 | 332 | 100 | 60
50 | 289 | 83 | 60 | 340 | 97 | 60 | 349 | 60 | 345 | 99 | 60 | 349 | 100 | 60
57 | 306 | 84 | 60 | 354 | 97 | 60 | 363 | 60 | 359 | 99 | 60 | 362 | 100 | 60
64 | 319 | 85 | 60 | 366 | 97 | 60 | 376 | 60 | 372 | 99 | 60 | 373 | 99 | 60
71 | 330 | 86 | 60 | 377 | 98 | 59 | 386 | 60 | 381 | 99 | 60 | 382 | 99 | 60
78 | 341 | 86 | 60 | 386 | 98 | 59 | 395 | 60 | 390 | 99 | 60 | 393 | 99 | 60
85 | 350 | 87 | 60 | 392 | 98 | 59 | 402 | 60 | 398 | 99 | 60 | 399 | 99 | 60
92 | 361 | 88 | 60 | 401 | 98 | 59 | 410 | 60 | 406 | 99 | 60 | 406 | 99 | 60
120 | 392 | 89 | 60 | 429 | 97 | 59 | 441 | 60 | 435 | 99 | 60 | 435 | 99 | 60
148 | 417 | 90 | 60 | 450 | 97 | 59 | 462 | 60 | 454 | 98 | 60 | 457 | 99 | 60
176 | 436 | 91 | 60 | 468 | 97 | 59 | 481 | 60 | 474 | 98 | 60 | 479 | 99 | 60
204 | 455 | 92 | 60 | 483 | 97 | 59 | 497 | 59 | 492 | 99 | 60 | 494 | 99 | 60
232 | 469 | 91 | 60 | 499 | 97 | 59 | 514 | 59 | 505 | 98 | 60 | 510 | 99 | 60
260 | 487 | 92 | 60 | 512 | 97 | 59 | 530 | 59 | 520 | 98 | 60 | 523 | 99 | 60
288 | 502 | 93 | 59 | 521 | 96 | 59 | 540 | 59 | 532 | 99 | 60 | 538 | 100 | 60
316 | 511 | 93 | 59 | 530 | 96 | 59 | 552 | 59 | 541 | 98 | 60 | 548 | 99 | 60
344 | 526 | 93 | 59 | 545 | 96 | 59 | 567 | 59 | 555 | 98 | 59 | 562 | 99 | 60
372^a^ | 541 | 93 | 49 | 557 | 96 | 50 | 583 | 49 | 569 | 98 | 48 | 580 | 100 | 48
400 | 552 | 93 | 49 | 566 | 95 | 50 | 597 | 49 | 583 | 98 | 48 | 593 | 99 | 48
428 | 565 | 93 | 49 | 577 | 95 | 49 | 608 | 49 | 588 | 97 | 47 | 606 | 100 | 45
456 | 581 | 94 | 49 | 588 | 95 | 48 | 616 | 49 | 597 | 97 | 46 | 619 | 100 | 45
484 | 587 | 95 | 48 | 595 | 96 | 48 | 621 | 49 | 611 | 98 | 44 | 628 | 101 | 45
512 | 594 | 94 | 46 | 605 | 96 | 45 | 633 | 47 | 614 | 97 | 44 | 637 | 101 | 45
540 | 596 | 94 | 45 | 609 | 96 | 45 | 636 | 44 | 619 | 97 | 44 | 646 | 102 | 44
568 | 603 | 94 | 44 | 610 | 95 | 44 | 639 | 41 | 624 | 98 | 41 | 648 | 101 | 43
596 | 605 | 95 | 44 | 614 | 96 | 41 | 638 | 40 | 618 | 97 | 40 | 652 | 102 | 42
624 | 612 | 95 | 44 | 611 | 95 | 41 | 644 | 37 | 620 | 96 | 38 | 657 | 102 | 40
652 | 604 | 94 | 42 | 610 | 95 | 39 | 642 | 33 | 628 | 98 | 33 | 648 | 101 | 34
680 | 597 | 94 | 40 | 613 | 97 | 35 | 633 | 28 | 634 | 100 | 26 | 644 | 102 | 31
708 | 614 | 95 | 32 | 602 | 93 | 28 | 647 | 20 | 623 | 96 | 24 | 644 | 100 | 25
Mean for Weeks
1–13 | 256 | 85 | – | 296 | 98 | – | 302 | – | 300 | 99 | – | 302 | 100 | –
14–52 | 456 | 91 | – | 484 | 97 | – | 499 | – | 491 | 98 | – | 495 | 99 | –
53–102 | 589 | 94 | – | 597 | 95 | – | 626 | – | 610 | 97 | – | 631 | 101 | –

^a^ Special study animals were removed during week 53.

Table 4 Mean Body Weights and Survival of Female Rats in the Two-year Feed Study of Dietary Zinc

Day | | 3.5 ppm | | 7 ppm | | | | 38 ppm (Control) | | 250 ppm | | | | 500 ppm
Day | | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | | Wt. (% of Controls) | | No. of Survivors | | Av. Wt. (g) | | Wt. (% of Controls) | No. of Survivors
1 | | 97 | 100 | 60 | 97 | 101 | 60 | 97 | 60 | 97 | | 100 | | 60 | | 97 | | 100 | 60
8 | | 121 | 96 | 60 | 128 | 101 | 60 | 126 | 60 | 129 | | 102 | | 60 | | 128 | | 101 | 60
15 | | 137 | 92 | 60 | 150 | 100 | 60 | 150 | 60 | 151 | | 101 | | 60 | | 149 | | 99 | 60
22 | | 153 | 89 | 60 | 172 | 100 | 60 | 171 | 60 | 174 | | 101 | | 60 | | 163 | | 95 | 60
29 | | 168 | 88 | 60 | 191 | 101 | 60 | 190 | 60 | 192 | | 101 | | 60 | | 185 | | 97 | 60
36 | | 182 | 89 | 60 | 206 | 101 | 60 | 205 | 60 | 207 | | 101 | | 60 | | 201 | | 98 | 60
43 | | 192 | 90 | 60 | 216 | 101 | 60 | 214 | 60 | 218 | | 102 | | 60 | | 211 | | 99 | 60
50 | | 200 | 90 | 60 | 223 | 100 | 60 | 223 | 60 | 226 | | 101 | | 60 | | 219 | | 98 | 60
57 | | 208 | 91 | 60 | 229 | 100 | 60 | 230 | 60 | 232 | | 101 | | 60 | | 226 | | 99 | 60
64 | | 213 | 91 | 60 | 233 | 99 | 60 | 235 | 60 | 237 | | 101 | | 60 | | 232 | | 99 | 60
71 | | 219 | 91 | 60 | 241 | 100 | 60 | 240 | 60 | 242 | | 101 | | 59 | | 238 | | 99 | 60
78 | | 224 | 92 | 60 | 244 | 100 | 60 | 244 | 60 | 246 | | 101 | | 59 | | 241 | | 99 | 60
85 | | 228 | 92 | 60 | 248 | 100 | 60 | 248 | 60 | 252 | | 101 | | 59 | | 246 | | 99 | 60
92 | | 232 | 92 | 60 | 251 | 100 | 60 | 253 | 60 | 254 | | 101 | | 59 | | 250 | | 99 | 60
120 | | 247 | 93 | 60 | 266 | 100 | 60 | 267 | 60 | 270 | | 101 | | 59 | | 265 | | 99 | 60
148 | | 256 | 94 | 60 | 276 | 101 | 60 | 273 | 60 | 277 | | 102 | | 59 | | 274 | | 101 | 60
176 | | 265 | 94 | 60 | 283 | 100 | 60 | 282 | 60 | 290 | | 103 | | 59 | | 281 | | 100 | 60
204 | | 272 | 94 | 60 | 289 | 100 | 59 | 290 | 60 | 296 | | 102 | | 58 | | 291 | | 100 | 60
232 | | 281 | 95 | 60 | 300 | 102 | 59 | 295 | 60 | 304 | | 103 | | 58 | | 299 | | 101 | 60
260 | | 286 | 95 | 60 | 304 | 101 | 59 | 300 | 59 | 307 | | 102 | | 58 | | 304 | | 101 | 59
288 | | 290 | 95 | 60 | 306 | 100 | 59 | 305 | 59 | 311 | | 102 | | 57 | | 308 | | 101 | 58
316 | | 296 | 96 | 60 | 316 | 102 | 59 | 308 | 58 | 318 | | 103 | | 57 | | 314 | | 102 | 58
344 | | 300 | 94 | 59 | 326 | 102 | 59 | 319 | 58 | 325 | | 102 | | 57 | | 323 | | 101 | 57
372^a^ | | 302 | 93 | 48 | 336 | 103 | 50 | 327 | 48 | 333 | | 102 | | 48 | | 334 | | 102 | 46
400 | | 309 | 92 | 48 | 342 | 102 | 50 | 336 | 48 | 342 | | 102 | | 48 | | 341 | | 101 | 45
428 | | 316 | 92 | 48 | 352 | 102 | 50 | 344 | 48 | 351 | | 102 | | 48 | | 350 | | 102 | 45
456 | | 321 | 92 | 47 | 356 | 102 | 49 | 350 | 47 | 363 | | 104 | | 47 | | 359 | | 103 | 45
484 | | 324 | 92 | 46 | 363 | 103 | 47 | 354 | 46 | 371 | | 105 | | 46 | | 365 | | 103 | 44
512 | | 334 | 92 | 46 | 369 | 102 | 47 | 363 | 46 | 376 | | 104 | | 43 | | 372 | | 103 | 43
540 | | 336 | 91 | 43 | 376 | 101 | 47 | 371 | 44 | 386 | | 104 | | 42 | | 379 | | 102 | 43
568 | | 341 | 91 | 43 | 379 | 101 | 47 | 376 | 42 | 389 | | 103 | | 38 | | 384 | | 102 | 41
596 | | 350 | 93 | 43 | 384 | 102 | 45 | 378 | 38 | 393 | | 104 | | 37 | | 389 | | 103 | 40
624 | | 351 | 93 | 41 | 388 | 102 | 44 | 379 | 35 | 405 | | 107 | | 36 | | 395 | | 104 | 38
652 | | 357 | 95 | 38 | 388 | 103 | 41 | 377 | 34 | 401 | | 106 | | 35 | | 400 | | 106 | 34
680 | | 363 | 98 | 36 | 388 | 105 | 37 | 370 | 30 | 404 | | 109 | | 31 | | 410 | | 111 | 34
708 | | 355 | 96 | 33 | 383 | 104 | 34 | 370 | 25 | 406 | | 110 | | 28 | | 402 | | 109 | 32
Mean for Weeks
1–13 | 180 | | 91 | – | 198 | 100 | – | 198 | – | | 200 | | 101 | | – | | 195 | 98 | –
14–52 | 273 | | 94 | – | 292 | 101 | – | 289 | – | | 295 | | 102 | | – | | 291 | 101 | –
53–102 | 335 | | 93 | – | 370 | 102 | – | 361 | – | | 378 | | 105 | | – | | 375 | 104 | –

^a^ Special study animals were removed during week 53.

### Hematology and Trace Metals

Whole blood was collected from special study rats for hematology and trace metal concentrations on day 19, and at 3, 6, 9, and 12 months. On day 19, and at 3 and 6 months, the hematocrit, hemoglobin concentration, mean cell volume, or mean cell hemoglobin were significantly decreased in 500 ppm males, depending on the time point (Table D-1). These mild decreases may have been due to mild alterations in erythropoiesis, and were ameliorated by 9 months. Other erythron changes were very mild or inconsistent, may have been due to biological variation, and were not considered toxicologically relevant. At 12 months, leukocyte and lymphocyte counts were decreased in 3.5 and 7 ppm males, and the reason for these decreases was not certain. Several other statistically significant changes were observed in the leukon, but they were mild, inconsistent, and not considered toxicologically relevant.

On day 19, zinc concentrations were significantly increased in 250 and 500 ppm males and females, while copper concentrations were decreased to below the limit of detection in 250 and 500 ppm males and 500 ppm females (Table 5 and Table D-2). Aside from these changes in zinc and copper concentrations at the first time point measured (day 19), there were no changes in blood zinc concentrations as a result of dietary modulation of zinc levels in the current study when measured for up to a year. Iron concentrations were inconsistently significantly altered in females at several time points. At day 19, iron concentration was minimally increased in 250 ppm females; iron concentrations were mildly decreased in 500 ppm females at months 3 and 6. These changes in iron concentrations were not considered to be biologically relevant.

Table 5 Zinc and Copper Concentrations in Blood of Rats in the Two-year Feed Study of Dietary Zinc^a^

| 3.5 ppm | 7 ppm | 38 ppm (Control) | 250 ppm | 500 ppm
Male
n | 10 | 9 | 10 | 10 | 10
Zinc (µg/mL)
Day 19 | 6.235 ± 0.557 | 6.541 ± 0.387b | 6.668 ± 0.392 | 8.662 ± 0.403** | 9.840 ± 0.382**
Month 3 | 6.287 ± 0.263 | 6.766 ± 0.342 | 6.630 ± 0.148 | 6.887 ± 0.162 | 6.659 ± 0.156
Month 6 | 6.151 ± 0.199 | 6.148 ± 0.220 | 6.860 ± 0.366 | 6.536 ± 0.143 | 6.302 ± 0.178
Month 9 | 5.822 ± 0.154 | 6.041 ± 0.250 | 6.028 ± 0.197 | 6.078 ± 0.128 | 6.057 ± 0.136
Month 12 | 5.273 ± 0.132 | 5.217 ± 0.112 | 5.379 ± 0.158 | 5.604 ± 0.251 | 5.722 ± 0.150
Copper (µg/mL)
Day 19 | 0.452 ± 0.026 | 0.441 ± 0.021^b^ | 0.438 ± 0.056 | ND | ND
Month 3 | 0.604 ± 0.030 | 0.628 ± 0.022 | 0.634 ± 0.024 | 0.584 ± 0.021 | 0.553 ± 0.038
Month 6 | 0.543 ± 0.042 | 0.527 ± 0.065 | 0.532 ± 0.042 | 0.480 ± 0.034^c^ | 0.440 ± 0.035
Month 9 | 0.831 ± 0.040 | 0.844 ± 0.066 | 0.795 ± 0.041 | 0.862 ± 0.088 | 0.712 ± 0.040
Month 12 | 0.745 ± 0.031 | 0.675 ± 0.023 | 0.710 ± 0.025 | 0.705 ± 0.054 | 0.714 ± 0.028
Female
n | 10 | 10 | 10 | 9 | 10
Zinc (µg/mL)
Day 19 | 3.928 ± 0.169 | 4.502 ± 0.131 | 4.458 ± 0.188 | 6.358 ± 0.580b** | 7.754 ± 0.202**
Month 3 | 5.187 ± 0.176 | 5.301 ± 0.153 | 5.505 ± 0.138 | 5.120 ± 0.057 | 5.448 ± 0.185
Month 6 | 4.982 ± 0.124 | 5.052 ± 0.133 | 4.864 ± 0.072 | 4.903 ± 0.203 | 4.608 ± 0.091
Month 9 | 4.638 ± 0.213 | 4.998 ± 0.120^c^ | 5.021 ± 0.149 | 5.136 ± 0.131 | 5.200 ± 0.173^c^
Month 12 | 4.595 ± 0.377 | 4.537 ± 0.146^c^ | 4.668 ± 0.197^c^ | 4.380 ± 0.209 | 4.733 ± 0.143^c^
Copper (µg/mL)
Day 19 | 0.590 ± 0.034 | 0.669 ± 0.022 | 0.663 ± 0.029 | 0.331 ± 0.044^b^** | 0.204 ± 0.018**
Month 3 | 0.655 ± 0.030 | 0.733 ± 0.023 | 0.769 ± 0.049 | 0.733 ± 0.041 | 0.697 ± 0.073
Month 6 | 0.184 ± 0.020 | 0.236 ± 0.069 | 0.289 ± 0.040 | 0.432 ± 0.079 | 0.539 ± 0.070**
Month 9 | 0.690 ± 0.031 | 0.743 ± 0.041^c^ | 0.791 ± 0.037 | 0.713 ± 0.019 | 0.685 ± 0.059^c^
Month 12 | 0.382 ± 0.040 | 0.399 ± 0.032^c^ | 0.457 ± 0.042^c^ | 0.417 ± 0.065 | 0.447 ± 0.061^c^

** Significantly different (P ≤ 0.01) from the control group by Shirley’s test.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 10.

^c^ n = 9.

ND = All values below the limit of detection at this dose level.

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions of the pancreas, testis, pituitary gland, skin, and thyroid gland. Summaries of the incidences of neoplasms and nonneoplastic lesions and statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group are presented in Appendix A for male rats and Appendix B for female rats.

Pancreas: Incidences of acinar adenoma were increased, but not significantly, in 7 and 3.5 ppm males (Table 6, Table A-1, and Table A-2). The increases in acinar adenoma in these groups were primarily due to increases in the number of animals with multiple acinar adenomas (significant increase at 3.5 ppm). One 38 ppm control male had an acinar carcinoma in addition to multiple acinar adenomas. Acinar hyperplasia was increased in the 3.5 ppm and 500 ppm males, but neither increase was significant. Significantly increased incidences of acinar atrophy occurred in 500 ppm males and females (Table 6, Table A-3, and Table B-3). Pancreatic acinar adenomas were generally 5 mm or greater in diameter and were composed of proliferative, enlarged acini that caused compression on surrounding adjacent lobules (Figure 3 and Figure 4). Adenomas were occasionally encapsulated, and islet cells were usually not present in acinar adenomas. Areas of acinar hyperplasia were generally smaller than adenomas, and tended to cause less compression. It was sometimes difficult to distinguish between areas of hyperplasia and adenomas, and the two lesions were considered to represent two different points on a single spectrum of change. Atrophy of pancreatic acini was characterized by small, shrunken ducts surrounded by a few depleted acinar cells, interstitial fibrous connective tissue, and mononuclear cell infiltrates, all of which resulted in overall focal reduction in acinar tissue (Figure 5).

Table 6 Incidences of Neoplasms and Nonneoplastic Lesions of the Exocrine Pancreas in Rats in the Two-year Feed Study of Dietary Zinc

| 3.5 ppm | 7 ppm | 38 ppm (Control) | 250 ppm | 500 ppm
Male
Number Examined Microscopically | 50 | 48 | 49 | 48 | 48
Acinus, Atrophy^a^ | 3 (1.3)^b^ | 4 (1.3) | 3 (2.3) | 3 (1.3) | 13** (1.5)
Acinus, Hyperplasia | 32 (2.3) | 23 (2.7) | 23 (2.0) | 21 (2.5) | 28 (2.3)
Acinus, Adenoma, Multiple | 13* | 10 | 5 | 8 | 4
Acinus, Adenoma (includes multiple)
Overall rate^c^ | 21/50 (42%) | 19/48 (40%) | 11/49 (22%) | 13/48 (27%) | 10/48 (21%)
Adjusted rate^d^ | 46.5% | 46.5% | 28.4% | 34.7% | 26.1%
Terminal rate^e^ | 14/31 (45%) | 16/27 (59%) | 8/18 (44%) | 11/21 (52%) | 9/20 (45%)
First incidence (days) | 467 | 701 | 652 | 648 | 729
Poly-3 test^f^ | P = 0.065 | P = 0.069 | P = 0.064 | – | –
Poly-3 test^g^ | – | – | P = 0.462N | P = 0.363 | P = 0.512N
Acinus, Carcinoma | 0 | 0 | 1 | 0 | 0
Acinus, Adenoma or Carcinoma
Overall rate | 21/50 (42%) | 19/48 (40%) | 11/49 (22%) | 13/48 (27%) | 10/48 (21%)
Adjusted rate | 46.5% | 46.5% | 28.4% | 34.7% | 26.1%
Terminal rate | 14/31 (45%) | 16/27 (59%) | 8/18 (44%) | 11/21 (52%) | 9/20 (45%)
First incidence (days) | 467 | 701 | 652 | 648 | 729
Poly-3 test | P = 0.065 | P = 0.069 | P = 0.064 | – | –
Poly-3 test | – | – | P = 0.462N | P = 0.363 | P = 0.512N
Female
Number Examined Microscopically | 48 | 49 | 50 | 49 | 49
Acinus, Atrophy | 4 (1.0) | 2 (1.0) | 2 (1.5) | 5 (1.2) | 10* (1.4)
Acinus, Hyperplasia | 1 (1.0) | 5 (1.2) | 2 (1.0) | 0 | 1 (1.0)
Acinus, Adenoma | 0 | 0 | 1 | 0 | 0

* Significantly different (P ≤ 0.05) from the control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4= marked.

^c^ Number of animals with neoplasm per number of animals with pancreas examined microscopically.

^d^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^e^ Observed incidence at terminal euthanasia.

^f^ Beneath the control incidence is the P value associated with the trend test between the control group and the 3.5 and 7 ppm exposure groups. Beneath the 3.5 or 7 ppm exposure group incidence are the P values corresponding to pairwise comparisons between the controls and that exposure group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia.

^g^ Beneath the control incidence is the P value associated with the trend test between the control group and the 250 and 500 ppm exposure groups. Beneath the 250 or 500 ppm exposure group incidence are the P values corresponding to pairwise comparisons between the controls and that exposure group. A negative trend or a lower incidence in an exposure group is indicated by N.

Figure 3

Large Acinus Adenoma from the Pancreas of a Male Rat Exposed to 3.5 ppm Dietary Zinc for Two Years (H&E)

The adenoma comprises most of the pancreatic tissue observed. A small amount of normal pancreas is present in the upper and lower right-hand corners (arrows).

Figure 4

Higher Magnification of Figure 3 Showing the Transition (Arrows) between the Adenoma (Lefthand Side) and the Normal Pancreas (Righthand Side) (H&E)

Figure 5

Mild Acinus Atrophy in the Pancreas of a Male Rat Exposed to 500 ppm Dietary Zinc for Two Years (H&E)

Increased pale space (arrows) is apparent between remaining acini in the affected area and contains fibrous connective tissue and inflammatory cells.

Testis: The incidence of bilateral germinal epithelium atrophy was significantly increased in 3.5 ppm males (Table 7 and Table A-3). The combined incidence of unilateral and bilateral germinal epithelium atrophy was higher in the 3.5 ppm group, but not significantly. In addition to germinal epithelium atrophy, there was one occurrence of bilateral germ cell degeneration in the testis in each of the 3.5, 250, and 500 ppm groups. Germinal epithelium atrophy was characterized by thinning of the germinal epithelium layer due to reduced numbers of germ cells, with most affected tubules being smaller than normal and lined by only Sertoli cells. Germ cell degeneration was characterized by shrunken germ cells with nuclear condensation and brightly eosinophilic cytoplasm, and occasional vacuolization and phagocytosis of germ cells by Sertoli cells.

Table 7 Incidences of Nonneoplastic Lesions of the Testis in Male Rats in the Two-year Feed Study of Dietary Zinc

| 3.5 ppm | 7 ppm | 38 ppm (Control) | 250 ppm | 500 ppm
Number Examined Microscopically | 50 | 50 | 50 | 50 | 50
Bilateral, Germinal Epithelium, Atrophy^a^ | 7* (2.4)^b^ | 1 (3.0) | 0 | 0 | 1 (3.0)
Germinal Epithelium, Atrophy | 3 (2.3) | 0 | 5 (2.0) | 3 (2.7) | 4 (2.8)
Germinal Epithelium, Atrophy (includes bilateral) | 10 (2.4) | 1 (3.0) | 5 (2.0) | 3 (2.7) | 5 (2.8)
Bilateral, Germ Cell, Degeneration | 1 (2.0) | 0 | 0 | 1 (2.0) | 1 (2.0)

* Significantly different (P ≤ 0.05) from the control group by the Poly-3 test.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Other Tissues: Several lesions occurred with statistically significant differences from controls that were not considered biologically relevant or related to exposure. There was a positive trend in the incidences of pituitary gland adenoma of the pars distalis in the male zinc deficient groups [38 ppm (control), 2/50; 7 ppm, 4/50; 3.5 ppm, 8/50; Table A-1 and Table A-2]. In light of the low survival in the control group, the commonality of pituitary gland adenoma in aged rats, and the fact that the incidences of this neoplasm in the zinc excess groups (250 ppm, 7/50; 500 ppm, 6/49) were not significantly different from that in the control rats, this was considered biological variability, and not due to zinc deficiency in the diet. Significantly decreased incidences of epithelial neoplasms of the skin occurred in 3.5 ppm males [38 ppm (control), 5/50; 7 ppm, 3/50; 3.5 ppm, 0/50; Table A-1 and Table A-2]; and significantly decreased incidences of thyroid gland C-cell hyperplasia occurred in 500 ppm females [38 ppm (control), 18/50; 250 ppm, 14/50; 500 ppm, 5/48; Table B-3]. The biological significance of these decreased incidences is unknown, but they were not considered related to exposure to dietary zinc.

## Genetic Toxicology

The percentage of micronucleated immature erythrocytes [also known as reticulocytes or polychromatic erythrocytes (PCEs)] was measured in peripheral blood of rats during the first year of the 2-year study (Table C-1 through Table C-4). Although data on micronucleus frequencies were also collected for the mature erythrocyte population automatically, this cell population is not appropriate for evaluating micronucleus induction in rats due to the rat spleen’s ability to efficiently sequester and destroy damaged reticulocytes soon after they emerge from the bone marrow. Therefore, evaluation of the effects of the deficient and excess zinc diets on chromosome integrity was limited to the immature erythrocyte population.

At the first sample time, 19 days after the study began, female rats maintained on the zinc-deficient diet showed a statistically significant (P ≤ 0.025) increase in micronucleated reticulocytes at both dose levels (3.5 and 7 ppm), although the trend test was not significant (P > 0.025). However, the mean micronucleated reticulocyte values observed for these two treatment groups were well within the laboratory historical control range. In addition, no increases were seen at any subsequent sampling time, and for all these reasons, the increased frequencies of micronucleated reticulocytes seen on day 19 in female rats were not judged to be biologically significant. No increases in micronucleated red blood cells were observed at any other sampling time for up to 12 months in either sex.

The percentage of PCEs among total erythrocytes was calculated at each sample time for each sex, and minor, statistically significant, sporadic alterations showing no pattern over time or association with specific diet were observed: zinc-deficient male rats at 19 days; both zinc-deficient and zinc-excess groups of female rats at 6 months. These were considered normal fluctuations and all values were within historical control ranges.

In blood leukocytes (Table C-5) and colonic epithelium (Table C-6), indications of effects on DNA integrity were observed. In blood leukocyte samples obtained from male rats at 12 months, significant increases in percent tail DNA were observed in both the zinc-deficient and the zinc-excess groups. No significant changes in percent tail DNA were observed in peripheral blood samples at any of the earlier sampling times in either dietary group of male rats. Increased levels of DNA damage were also observed in blood leukocytes of female rats fed the zinc-deficient diet at both the 9- and 12-month sampling times. No significant changes in percent tail DNA were observed in female blood samples at any other sampling times in either dietary group. In colon cell samples obtained after 12 months of exposure, a significant increase in percent tail DNA was observed in male rats (trend, P = 0.019) fed a diet with excess zinc, and a small, but not significant, decrease in percent tail DNA was observed in males maintained on the zinc-deficient diets. A significant increase in percent tail DNA was seen in female rats fed a diet supplemented with excess zinc, and a significant decrease in percent tail DNA was observed in females maintained on the zinc-deficient diets. This same pattern of DNA damage was seen in the male rat colon cell samples, although the decreases in males fed a zinc-deficient diet were not statistically significant.

Overall, indications of increased levels of DNA damage related to excess dietary levels of zinc were seen in blood leukocytes (males only) and colonic epithelial cell samples of male and female rats. In addition, colon cell samples for rats maintained on a zinc-deficient diet showed a significant decrease in DNA migration at 12 months. This reduction in DNA migration could indicate the presence of damage in the form of DNA crosslinking^255^. Experiments with known DNA crosslinkers have shown that these chemicals impede DNA migration compared to control exposures^254^.