# Materials and Methods

## Procurement and Characterization of Dietary Zinc

Zinc carbonate basic {[ZnCO_3_]_2_∙[Zn(OH)_2_]_3_} was obtained from Sigma-Aldrich (St. Louis, MO) in one lot (1217764) that was used in the 2-year study to create dietary levels of zinc. Analyses to determine the identity, purity, and storage stability were conducted by the analytical chemistry laboratory at Research Triangle Institute (RTI) (Research Triangle Park, NC) and the study laboratory at Battelle Columbus (Columbus, OH) and its sister laboratory Battelle Toxicology Northwest (BTNW) (Richland, WA) (Appendix D). Reports on analyses performed in support of the dietary zinc study are on file at the National Institute of Environmental Health Sciences.

Briefly, zinc carbonate basic (lot 1217764) was a fine white powder. The lot was analyzed by RTI using inductively coupled plasma/optical emission spectroscopy (ICP/OES), X-ray diffraction (XRD) spectroscopy, Fourier-transform infrared (FTIR) spectroscopy, qualitative X-ray fluorescence (XRF) spectroscopy, elemental analyses (conducted by Quantitative Technologies, Inc., Whitehouse, NJ), thermogravimetric analysis (TGA), ashing, and ion chromatography (IC) (conducted by Quantitative Technologies, Inc.) for anionic and cationic impurities. The moisture content of lot 1217764 was determined by RTI using weight loss on drying and by Galbraith Laboratories, Inc. (Knoxville, TN), using Karl Fischer titration^225^.

Analyses by ICP-OES showed the zinc (Zn) content to be 56.6%, which is slightly lower than the theoretical value of 59.6% based on the molecular formula of zinc carbonate basic. Analysis by ICP-OES indicated levels mostly below the limits of quantitation of the analytical method (<0.01%) except for calcium (0.0916% w/w) and magnesium (1.32% w/w). Elemental analyses for carbon and hydrogen yielded 3.58% (4.38% theoretical) and 1.07% (1.10% theoretical) weight percentages, respectively. Weight loss on drying determined a water content of 0.30% and Karl Fisher titration indicated 2.52% water. TGA measurements indicated that the test article was not hydrated and also suggested the presence of nonvolatile components such as zinc oxide (ZnO). Measured concentrations of possible anionic and cationic impurities were negligible and in agreement with values reported on the vendor’s certificate of analysis.

Due to lack of reference cards for zinc carbonate basic in the database, spectra for the test article were compared with reference cards for other zinc and zinc carbonate compounds in the database including ZnO (CASRN 1314-13-2), zinc hydroxide [Zn(OH)_2_] (CASRN 20427-58-1), zinc carbonate hydroxide hydrate [Zn_4_(CO_3_)_2_(OH)_6_ H2O] (CASRN 12539-71-8), hydrozincite [Zn_5_(CO_3_)_2_(OH)_6_] (CASRN 12122-17-1), and smithsonite (ZnCO_3_), and no match was found. However, the XRD pattern of the test article contained peaks matching the reference card of ZnO, suggesting the presence of ZnO as a minor component. ZnO and zinc carbonate hydroxide with the same nominal formula as the zinc carbonate basic test article {[ZnCO_3_]_2_ [Zn(OH)_2_]_3_} (CASRN 3486-35-9) were procured and analyzed by XRD. The peak diffraction angles and relative peak height distributions of the test article and zinc carbonate hydroxide generally corresponded with each other, suggesting that the compounds may have been equivalent. [Note: At the time of these analyses zinc carbonate basic and zinc carbonate hydroxide had independent CAS Registry numbers. However, currently these chemicals share the same CAS number (5263-02-5), suggesting that zinc carbonate basic and zinc carbonate hydroxide may be the same.] Each overlapping peak for the zinc oxide spectra was paralleled with an increase in the peak abundance of the zinc carbonate basic test article relative to procured zinc carbonate hydroxide. Taken collectively, XRD analyses suggest that the test chemical is structurally similar or equivalent to the procured zinc carbonate hydroxide, but with zinc oxide as a minor component. In addition, FTIR spectroscopy for the test article closely matched the reference spectrum of zinc carbonate basic with a ZnO signature.

Based on the data collected using multiple techniques, the test article seemed to be composed predominantly of zinc carbonate basic with some ZnO present. Weight percentages for two major components of the test article, zinc (56.6%) and carbon (3.58%), were found to be somewhat lower than the theoretical values (59.6% and 4.38%, respectively), suggesting that zinc compounds other than zinc carbonate basic may have been present in the test article. Heavy metal levels (e.g., arsenic, cadmium, chromium, mercury, lead, and thallium) were determined to be below the limit of quantitation of 0.01%. Taken together, regardless of the structure, the test article was suitable for use as the zinc source in dietary zinc deficiency and excess toxicity studies with the percent of zinc at 56.6.

Stability studies of the bulk chemical were performed by RTI using ICP/OES. These studies indicated that the test material was stable as a bulk chemical for 15 days when stored in capped plastic bottles at temperatures up to 60°C. To ensure stability, the bulk chemical was stored at room temperature in capped amber glass bottles. Periodic reanalyses of the bulk chemical were performed by the study laboratory at least every 6 months during the 2-year study with inductively coupled plasma/atomic emission spectroscopy (ICP/AES), and no degradation of the bulk chemical was detected.

The test article (stored at ambient temperature) and the frozen (nominal −20°C) reference sample were analyzed by BTNW using ICP/AES and by H&M Analytical Services, Inc. (Allentown, NJ), using developmental XRD. Results of these analyses indicated that the bulk test article and frozen reference samples of the same lot were consistent with each other during the course of the study.

## Background Zinc Content of Base Diet

Aliquots of four batches (with nine manufacture dates from June 29, 2009, to April 11, 2011) of the base diet (AIN-93M Modified Low Zinc Feed; Zeigler Brothers, Inc., Gardners, PA), were analyzed by BTNW to prescreen for possible background zinc in the blank vehicle using ICP/AES. All batches of the zinc-deficient base diet were determined to contain less than 1 mg Zn/kg diet (<1 ppm) and were considered acceptable to be used for formulation preparations.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared monthly by mixing zinc carbonate basic with AIN-93M Modified Low Zinc Feed. The theoretical value of zinc content (59.6%) was used to calculate the amount of zinc in the dose formulations, therefore the doses used in this study are approximately 3% lower than what is stated. A premix was prepared by hand and then blended with additional feed in a Patterson-Kelly twin-shell blender for approximately 15 minutes. Formulations were stored in sealed plastic bag-lined buckets at room temperature for up to 42 days. The 38 ppm formulation was used as the control formulation for the 2-year study.

Homogeneity studies of 3.5, 7, 38, 250, 500, and 1,000 ppm formulations and of 3.5, 38 (control), and 500 ppm dose formulations were performed by RTI and BTNW, respectively. These studies were conducted with ICP/AES or ICP/OES and measured Zn in digested samples of the formulations. ICP/OES was also used in stability studies of 3.5 and 7 ppm dose formulations that were performed by RTI. Homogeneity was confirmed, and stability was confirmed for at least 42 days for dose formulations stored in sealed plastic bags under freezer, refrigerated, and room temperature conditions; stability was also confirmed for at least 7 days under simulated animal room conditions.

Periodic analyses of the dose formulations of zinc carbonate basic were conducted by BTNW using ICP/AES. During the 2-year study, the dose formulations were analyzed every 2 to 3 months and animal room samples were also analyzed (Table E-2). Of the dose formulations analyzed and used during the study, 102 of 110 were within 10% of the target concentrations; all 20 animal room samples were within 10% of the target concentrations.

## Animal Source

Male and female Hsd:Sprague Dawley^®^ SD^®^ rats were obtained from Harlan, Inc. (Indianapolis, IN), now Envigo (Livermore, CA), for the 2-year study.

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. The rat study was conducted in an animal facility accredited by the Association for the Assessment and Accreditation of Laboratory Animal Care International. The study was approved by the Battelle Columbus Operations Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Two-year Study

### Study Design

Groups of 50 male and 50 female rats were fed diets containing 38 (control), 3.5, 7, 250, or 500 ppm dietary zinc for 104 to 106 weeks. Generally, in the literature, a zinc-deficient diet in laboratory animals ranged from 0 to 9 ppm [2.34 ± 2.37 (mean ± SD), n = 24], a zinc-adequate diet ranged from 9 to 100 ppm (56 ± 25.8, n = 16), and a zinc-excess diet ranged from 1,000 to 5,000 ppm (3,000 ± 1,732, n = 4).

Historically, NTP has used a diet^226^ with measured mean zinc levels from 24 lots ranging from 43.3 to 78.5 ppm, resulting in a mean zinc level of 53.6 ± 8.3 ppm. Additionally, a study with zinc carbonate^187^ demonstrated no significant difference in growth rates in rats fed control diets with zinc levels ranging from 40 to 100 ppm. In the present study, 38 ppm was chosen as the control level of dietary zinc because it is considered adequate for normal growth and survival in rats.

Due to the critical role zinc plays in maintenance of life and the importance as illustrated in the literature with animals fed extremely zinc-deficient or excess zinc diets failing to survive, groups receiving no (<1 ppm) or higher levels (>1,000 ppm) of supplemental zinc were not included in this study. This allowed for the chronic evaluation of the influence of varying nutritional intakes of zinc below and above the optimal physiological range. As a result, the exposure concentrations for the zinc-deficient diets (3.5 and 7 ppm) were based on literature indicating a minimum dietary zinc requirement for survival. The exposure concentrations for excess dietary zinc (250 and 500 ppm) were selected to examine the effects of excess zinc in the diet below levels that would result in interference with other essential metals (i.e., copper and iron) and were not in excess of reported LD_50_ values of 186 to 623 mg zinc/kg body weight per day (approximately equivalent to 3,162 and 10,591 ppm, respectively) for several zinc compounds in rodents^109^. Ten male and 10 female special study rats were exposed to the same concentrations for 53 weeks and used for micronuclei evaluations, comet assays, hematology, and trace metal concentrations.

Rats were quarantined for 9 days before the beginning of the study. Five male and five female rats were randomly selected for parasite evaluation and gross observation for evidence of disease. The animals were 5 to 6 weeks old at the beginning of the study. The health of the animals was monitored during the study according to the protocols of the NTP Sentinel Animal Program (Appendix H). All test results were negative.

Male rats were housed two per cage and female rats were housed four per cage. Rats were fed AIN-93M, a purified low-zinc rodent maintenance diet, with modified levels of zinc for the duration of the study. To accommodate the low zinc concentration needed for the study, egg white solids were used as the major protein source instead of casein. Information on feed composition and contaminants is provided in Appendix G. Feed and water were available ad libitum. Feed consumption was measured over a 7-day period and recorded for the first 14 weeks and at approximately 4-week intervals thereafter. Racks were changed and rotated every 2 weeks. Further details of animal maintenance are given in Table 1.

Table 1 Experimental Design and Materials and Methods in the Two-year Feed Study of Dietary Zinc

Two-year Study
Study Laboratory
Battelle Columbus Operations (Columbus, OH)
Strain and Species
Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats
Animal Source
Harlan, Inc. (Indianapolis, IN), now Envigo (Livermore, CA)
Time Held Before Study
9 days
Average Age When Study Began
5 to 6 weeks
Date of First Exposure
September 3 (males) or 4 (females), 2009
Duration of Exposure
104 to 105 weeks (females); 105 to 106 weeks (males)
Necropsy Dates
August 29 to September 2 (females) or September 6 to 9 (males), 2011
Average Age at Necropsy
109 to 111 weeks
Size of Study Groups
50 males and 50 females (core study) 10 males and 10 females (special study)
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights.
Animals per Cage
2 (males) or 4 (females)
Diet
Irradiated AIN-93M Modified Low Zinc Feed (Zeigler Brothers, Inc., Gardners, PA), available ad libitum
Water
Deionized tap water (Columbus, OH, municipal supply) via 16-ounce glass bottles (Wheaton Science Products, Millville, NJ) with screw caps and Teflon^®^-coated septa (Qorpak, Bridgeville, PA, and VWR, West Chester, PA) and stainless steel, double-ball bearing sipper tubes (Ancare Corp., Bellmore, NY), available ad libitum
Cages
Polycarbonate (Lab Products, Inc., Seaford, DE), changed twice weekly, rotated every 2 weeks
Bedding
Irradiated Sani-Chips (P.J. Murphy Forest Products Corporation, Montville, NJ), changed twice weekly
Rack Filters
Spun-bonded polyester (Snow Filtration Company, Cincinnati, OH), changed every 2 weeks
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed and rotated every 2 weeks
Animal Room Environment
Temperature: 72° ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour
Exposure Concentrations
3.5, 7, 38 (control), 250, or 500 ppm in feed, available ad libitum
Type and Frequency of Observation
Observed twice daily; animals were weighed initially, weekly for the next 14 weeks, every 4 weeks thereafter, and at the end of the study; clinical findings were recorded on study day 29, at 4-week intervals thereafter, and at the end of the study. Feed consumption was determined over a 7-day period for the first 14 weeks of the study, and at approximately 4-week intervals thereafter.
Method of Euthanasia
Core study rats: carbon dioxide asphyxiation
Special study rats: carbon dioxide/oxygen anesthesia, exsanguination at 12 months
Necropsy
Necropsies were performed on all core study rats.
Hematology
Blood was collected from the retroorbital plexus of special study rats on day 19 and after 3, 6, 9, and 12 months of exposure. The following parameters were measured: hematocrit; hemoglobin concentration; erythrocyte, reticulocyte, and platelet counts; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials. Manual hematocrit and blood smear evaluation were also performed.
Histopathology
Complete histopathology was performed on all core study rats. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eye, Harderian gland, heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spleen, stomach (forestomach and glandular), testis (with epididymis), thymus, thyroid gland, trachea, urinary bladder, and uterus.
Trace Metal Concentrations
Blood was collected from the retroorbital plexus of special study rats on day 19 and after 3, 6, 9, and 12 months of exposure for determination of zinc, copper, and iron concentrations.

### Clinical Examinations, Trace Metal Analysis, and Pathology

All animals were observed twice daily. Clinical findings were recorded every 4 weeks starting on study day 29 and at the end of the study. The animals were weighed initially, weekly for the first 14 weeks, at 4-week intervals thereafter, and at the end of the study.

On study day 19 and after 3, 6, 9, and 12 months of exposure, blood was collected from the retroorbital plexus of special study rats for hematology and trace metal concentrations. Prior to sample collection, each rat’s eyes were wiped with a paper towel soaked with deionized water. Rats were anesthetized with a CO_2_/O_2_ mixture, and blood for hematology and trace metal concentrations was collected into tubes containing K_3_EDTA and K_2_EDTA, respectively. In order to prevent environmental zinc contamination, the sample tubes remained unopened until the time of sample collection. The following hematologic parameters were measured using an Advia 120 analyzer (Bayer Diagnostics Division, Tarrytown, NY, or Siemans Healthcare Diagnostics, Tarrytown, NY): hematocrit; hemoglobin concentration; erythrocyte, reticulocyte, and platelet counts; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; leukocyte count and differentials. A manual hematocrit was performed and the erythrocyte and platelet morphology was assessed on blood smears. Blood samples for trace metal concentrations were frozen at −70°C and within 48 hours of collection, shipped frozen on dry ice to RTI for analysis. Samples were thawed, digested, and analyzed using ICP/OES on an Optima 4300DV (PerkinElmer, Waltham, MA). Concentrations of zinc, copper, and iron were determined at wavelengths of 213.857, 327.393, and 259.939 nm, respectively (Appendix D).

Complete necropsies and microscopic examinations were performed on all core study rats. At necropsy, all organs and tissues were examined for grossly visible lesions, and all major tissues were fixed and preserved in 10% neutral buffered formalin (except eyes were first fixed in Davidson’s solution and testes, epididymides, and vaginal tunics were first fixed in modified Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin for microscopic examination. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. Tissues examined microscopically are listed in Table 1.

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The report, slides, paraffin blocks, residual wet tissues, and pathology data were sent to the NTP Archives for inventory, slide/block match, wet tissue audit, and storage. The slides, individual animal data records, and pathology tables were evaluated by an independent quality assessment (QA) laboratory. The individual animal records and tables were compared for accuracy, the slide and tissue counts were verified, and the histotechnique was evaluated. For the 2-year study, a QA pathologist evaluated slides from all tumors and the pancreas and pituitary gland from all animals, as well as the adrenal medulla, liver, spleen, and testis of males.

The QA report and the reviewed slides were submitted to the NTP Pathology Working Group (PWG) coordinator, who reviewed the selected tissues and addressed any inconsistencies in the diagnoses made by the laboratory and QA pathologists. Representative histopathology slides containing examples of lesions related to chemical administration, examples of disagreements in diagnoses between the laboratory and QA pathologists, or lesions of general interest were presented by the coordinator to the PWG for review. The PWG consisted of the QA pathologist and other pathologists experienced in rodent toxicologic pathology. This group examined the tissues without any knowledge of dose groups. When the PWG consensus differed from the opinion of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist(s), and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman^227^ and Boorman et al.^228^ For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of McConnell et al.^229^.

## Statistical Methods

Because the goal of this study was to examine the effects of diets either deficient in zinc or containing excess zinc, two sets of statistical analyses were conducted. One set of analyses tested the effects of the zinc deficient diet by comparing the diet containing sufficient zinc (38 ppm), assigned as the control group, to 7 ppm and 3.5 ppm and testing for trends with increasing deficiency across these three dose groups. The second set of analyses tested effects of diets containing excess zinc by comparing the diet containing sufficient zinc (38 ppm), assigned as the control group, to 250 ppm and 500 ppm and testing for trends with increasing excess across these three dose groups.

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier^230^ and is presented in the form of graphs. Special study animals euthanized at 12 months and animals found dead of other than natural causes were censored; animals dying from natural causes were not censored. Statistical analyses for possible dose-related effects on survival used Cox’s^231^ method for testing two groups for equality and Tarone’s^232^ life table test to identify dose-related trends. All reported P values for the survival analyses are two sided.

### Calculation of Incidence

The incidences of neoplasms or nonneoplastic lesions are presented in Table A-1, Table A-3, Table B-1, and Table B-3 as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. For calculation of statistical significance, the incidences of most neoplasms (Table A-2 and Table B-2) and all nonneoplastic lesions are given as the numbers of animals affected at each site examined microscopically. However, when macroscopic examination was required to detect neoplasms in certain tissues (e.g., mesentery, pleura, peripheral nerve, skeletal muscle, tongue, tooth, and Zymbal’s gland) before microscopic evaluation, the denominators consist of the number of animals that had a gross abnormality. When neoplasms had multiple potential sites of occurrence (e.g., leukemia or lymphoma), the denominators consist of the number of animals on which a necropsy was performed. Table A-2 and Table B-2 also give the survival-adjusted neoplasm rate for each group and each site-specific neoplasm. This survival-adjusted rate (based on the Poly-3 method described below) accounts for differential mortality by assigning a reduced risk of neoplasm, proportional to the third power of the fraction of time on study, only to site-specific, lesion-free animals that do not reach terminal euthanasia.

### Analysis of Neoplasm and Nonneoplastic Lesion Incidences

The Poly-k test^233-235^ was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to take survival differences into account. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight. This value is one if the animal had a lesion at that site or if it survived until terminal euthanasia; if the animal died prior to terminal euthanasia and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the kth power.

This method yields a lesion prevalence rate that depends only upon the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time^233^. Unless otherwise specified, a value of k = 3 was used in the analysis of site-specific lesions. This value was recommended by Bailer and Portier^233^ following an evaluation of neoplasm onset time distributions for a variety of site-specific neoplasms in control F344 rats and B6C3F1/N mice^236^. Bailer and Portier^233^ showed that the Poly-3 test gave valid results if the true value of k was anywhere in the range from 1 to 5. A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams^237^.

Tests of significance included pairwise comparisons of each dosed group with controls and a test for an overall dose-related trend. Continuity-corrected Poly-3 tests were used in the analysis of lesion incidence, and reported P values are one sided. The significance of lower incidences or decreasing trends in lesions is represented as 1–P with the letter N added (e.g., P = 0.99 is presented as P = 0.01N).

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and control groups in the analysis of continuous variables. Body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^238^ and Williams^239; 240^. Hematology and trace metal concentration data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^241^ (as modified by Williams^242^) and Dunn^243^. Jonckheere’s test^244^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^245^ were examined by NTP personnel, and implausible values were eliminated from the analysis.

## Quality Assurance Methods

This 2-year study was conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations^246^. In addition, as records from the study were submitted to the NTP Archives, the study was audited retrospectively by an independent QA contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Technical Report.

## Genetic Toxicology

The genetic toxicity of dietary zinc was assessed by testing the ability of the chemical to increase the frequency of micronucleated erythrocytes in rat peripheral blood and to induce DNA damage in blood and colon epithelial cells. Micronuclei (literally “small nuclei” or Howell-Jolly bodies) are biomarkers of induced structural or numerical chromosomal alterations and are formed when acentric fragments or whole chromosomes fail to incorporate into either of two daughter nuclei during cell division^247; 248^. The alkaline (pH > 13) comet assay^249^ (also known as the single cell gel electrophoresis assay) detects DNA damage in any of a variety of eukaryotic cell types^250-253^; cell division is not required. The type of DNA damage detected includes nicks, adducts, strand breaks, and abasic sites that are converted to DNA strand breaks after treatment of cells in an alkali (pH > 13) solution. Transient DNA strand breaks generated by the process of DNA excision repair may also be detected. DNA damage caused by crosslinking agents has been detected as a reduction of DNA migration^254; 255^. The fate of the DNA damage detected by the comet assay is varied; most of the damage is rapidly repaired resulting in no sustained impact on the tissue but some may result in cell death or may be incorrectly passaged by the repair machinery and result in a fixed mutation or chromosomal alteration. The protocols for these studies and the results are given in Appendix C.

The genetic toxicity studies have evolved from an earlier effort by NTP to develop a comprehensive database permitting a critical anticipation of a chemical’s carcinogenicity in experimental animals based on numerous considerations, including the molecular structure of the chemical and its observed effects in short-term in vitro and in vivo genetic toxicity tests (structure-activity relationships). The short-term tests were originally developed to clarify proposed mechanisms of chemical-induced DNA damage based on the relationship between electrophilicity and mutagenicity^256^ and the somatic mutation theory of cancer^257; 258^. However, it should be noted that not all cancers arise through genotoxic mechanisms.

DNA reactivity carries the potential for carcinogenicity. In this study with dietary zinc, no bacterial mutagenicity studies were conducted. Instead, genotoxicity, in the form of chromosomal damage (micronuclei) and DNA damage (measured using the comet assay), was evaluated in special study rats after 12 months of exposure via feed.

The predictivity for rodent carcinogenicity of clearly positive results in long-term peripheral blood micronucleus tests is high; a weak response in one sex only or negative results in both sexes of one species in this assay do not correlate well with either negative or positive results in rodent carcinogenicity studies^259^. NTP has not yet conducted an evaluation of the relationship between DNA damage assessed in the comet assay with rodent carcinogenicity, although others have demonstrated a correlation^260^. However, because of the theoretical and observed associations between induced genetic damage and adverse effects in somatic and germ cells, the determination of in vivo genetic effects is important to overall understanding of the risks associated with exposure to a particular chemical.