# Introduction

Zinc carbonate basic (CASRN No. 5263-02-5; chemical formula: C_2_H_6_O_12_Zn_5;_ molecular weight: ~549.0; synonym: zinc hydroxide carbonate) was used as the dietary zinc source in this study.

For the purposes of this Technical Report, an extensive review of the literature pertaining to zinc was considered beyond the scope of this report and only the studies on oral exposures of zinc in experimental animals and in humans are highlighted here. Several more detailed reviews, as well as a full toxicologic profile for zinc and zinc compounds, can be found in the literature^1-3^.

## Chemical and Physical Properties

Zinc, a blue-white metal, is a naturally occurring element and is ubiquitous in the environment. Zinc is stable in dry air, but exposure to moist air results in the formation of zinc oxide or basic carbonate. Due to the reactivity of zinc metal, it is not found as a free element in nature but as a variety of different compounds including zinc chloride, zinc oxide, and zinc sulfate^1; 4; 5^.

## Production, Use, and Human Exposure

Zinc is a natural element of the earth’s crust. In the United States, the concentrations of zinc in soils and earth surface materials range from less than 5 to 2,900 mg/kg, with a mean of 60 mg/kg^6^. The existence of zinc in the environment (air, water, soil) is natural. However, anthropogenic sources of zinc, such as mining and metallurgic operations involving zinc and the use of commercial products containing zinc, result in higher environmental levels of zinc. Of the 1,662 hazardous waste sites that have been proposed for inclusion on the United States Environmental Protection Agency (USEPA) National Priorities List, zinc has been identified in at least 985 sites^3^. However, the number of these sites that have specifically been evaluated for zinc is unknown. The majority of the zinc produced today comes from the mineral sphalerite (ZnS)^4^. Smithsonite, also known as zinc carbonate, and hemimorphite are also important sources of zinc from nature^4^. As of 2015, approximately 850,000 metric tons of zinc were produced in the United States from domestic ores; the world production from mines is approximately 13,400,000 metric tons^7^. Zinc is also imported into the United States; in 2013, 713,000 metric tons were imported as refined zinc and 3,000 metric tons were imported as ores and concentrates^7^.

Zinc exposure in humans is mainly through ingestion of food, drinking water, polluted air, and tobacco products and through occupational exposure. Zinc is an essential element in humans and animals due to its requirement for membrane stability, enzyme activities, and in protein and nucleic acid metabolism^1^. The National Academy of Sciences has established recommended daily allowances (RDAs) for men and women at 11 mg per day and 8 mg per day, respectively^2^. The RDAs increase for women during pregnancy to 11 mg per day for adult women and 12 mg per day for women between ages 14 and 18. These RDAs increase a further 1 mg per day during lactation. For humans, the average intake of zinc from food and water ranges from 5.2 to 16.2 mg per day, and an additional 1 mg per day may be provided through dietary supplements^8; 9^. Zinc deficiencies occur when the dietary intake of zinc falls well below these RDAs. A tolerable upper intake level of 40 mg per day for adult men and women is based on the potential for elevated zinc intakes to interfere with copper absorption^10^. Food is a major source of zinc within the general population and animal products tend to have the highest zinc levels of the most commonly consumed foods^11; 12^. Meats, poultry, and fish have levels of 24.5 mg zinc/kg on average whereas grains and potatoes contain an average of 7 mg/kg^13^. From 1982 to 1984, the Food and Drug Administration (FDA) conducted an extensive survey of diets in individuals across the United States and estimated the daily zinc intake (mg per day) across eight age and sex groups: 6- to 11-month-old infants, 5.24; 2-year-old children, 7.37; 14- to 16-year-old girls, 9.90; 14- to 16-year-old boys, 15.61; 25- to 30-year-old women, 9.56; 25- to 30-year-old men, 16.15; 60- to 65-year-old women, 8.51; and 60- to 85-year-old men, 12.64^9^. These results are comparable to other studies evaluating the daily intake of zinc, including the United States Department of Agriculture’s Continuing Survey of Food Intakes by Individuals and the National Health and Nutrition Examination Survey III. Many foods are also fortified with zinc as a public measure to combat zinc deficiencies in the population^14-16^. In 1987, the amount of zinc (zinc chloride, zinc gluconate, zinc oxide, zinc sulfate) used by food manufacturers in the United States for fortification ranged from 10 to 102,150 kg^15^. In a literature review, the National Research Council concluded that zinc measurements in drinking water were typically below 5 mg/L^17^. Dietary supplements are also a source of zinc in the human diet and it can come in many forms, including zinc gluconate, zinc sulfate, and zinc acetate.

Zinc has also been used in the prevention and treatment of the common cold in humans, as lozenges (approximately 13.3 mg of zinc), sprays, or intranasal gels with doses ranging from 80 to 92 mg of zinc acetate or zinc gluconate per day^18^. There is some evidence that zinc may be effective in reducing the duration and severity of symptoms related to the common cold^18-21^. However, the data supporting this evidence are conflicting, with some studies reporting no therapeutic effect for cold treatment^22^. The use of zinc in certain preparations for cold treatment has also been associated with olfactory nasal epithelium tissue damage and the development of permanent anosmia^23-25^. The National Occupational Exposure Survey conducted from 1980 to 1983 estimated that a total of 269 workers (including 22 women) are exposed to elemental zinc and 133,608 workers (including 17,586 women) are exposed to other forms of zinc in the workplace annually^26^. Occupational groups where the workers are exposed to either elemental zinc or zinc compounds include those in the fabricated metal products industry, in machine operations, janitors and cleaners, and those producing stone, clay, and glass products^26^.

Zinc is widely used in industry as a protective coating for other metals, such as iron or steel. Methods of protective coating typically include galvanization, zinc plating, and painting with zinc-bearing paints^3^. As a weak metal, zinc is typically alloyed with other metals (e.g., aluminum, copper, titanium, and magnesium) to increase its strength. Industry consumption of zinc in 2002 was reported as 265,000 metric tons for galvanizing, 103,000 metric tons for zinc-based alloys, and 86,800 metric tons for brass and bronze production^27^. It is also used in dental, medical, and household applications. Zinc salts are used in pharmaceuticals as solubilizing agents in drugs such as insulin^28-30^. Medically, zinc compounds are administered as supplements in the treatment of zinc deficiency^31^.

Many of the zinc compounds are used across a wide range of industries that include, but are not limited to rubber production (zinc oxide, zinc chloride, zinc hydroxide), animal feed supplementation (zinc oxide, zinc sulfate), as a fertilizer additive (zinc oxide, zinc sulfate), in cosmetics and drugs as an antifungal (zinc oxide), as a paint pigment (zinc oxide, zinc sulfide, zinc chromate), in dental cements (zinc oxide, zinc chloride, zinc sulfide, zinc phosphate), as a wood preservative (zinc chloride, zinc acetate), in batteries (zinc chloride), in galvanizing and metal work (zinc chloride, zinc sulfate, zinc cyanide, zinc phosphate), in textile production (zinc chloride, zinc acetate), and in television screens and watches (zinc sulfide)^4; 32; 33^. Zinc chloride is also a primary ingredient in smoke bombs used for crowd dispersal, in fire-fighting exercises, and by the military^1^. Of the zinc compounds, zinc oxide is the most widely used.

## Regulatory Status

Zinc compounds, including zinc carbonate, are listed in the “Toxic Chemicals Subject to Section 313 of the Emergency Planning and Community Right-to-Know Act of 1986”^34^. Zinc acetate, zinc oxide, and zinc sulfide are permitted through Federal regulations for use as components of adhesives, coatings or rubber-packaging materials that are intended for contact with food^35-37^. The zinc compounds zinc chloride, zinc oxide, zinc stearate, and zinc sulfate are used as food additives and are Generally Recognized as Safe by the FDA when they are used “in accordance with good manufacturing practices”^36; 38-42^. Additionally, the FDA permits zinc oxide for use as a color additive in drugs and cosmetics with certain restrictions^43^. The Agency for Toxic Substances and Disease Registry^3^ has derived an oral Minimal Risk Level of 0.3 mg zinc/kg body weight per day, based on a study by Yadrick et al.^44^ that demonstrated decreased erythrocyte superoxide dismutase and serum ferritin changes in women who were given supplements containing zinc gluconate for 10 weeks. The USEPA has derived an oral reference dose of 0.3 mg/kg per day for zinc based on a decrease in erythrocyte copper-zinc superoxide dismutase activity in human volunteers^45^.

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

The absorption of zinc (^65^ZnCl_2_) occurs through both passive diffusion and a carrier-mediated process throughout the entire intestine, with the largest proportion of zinc absorption occurring from the duodenum^46; 47^. The intestinal absorption of low levels of zinc appears to be a carrier mediated process that involves a cysteine-rich intestinal protein^48-51^. Zinc absorption by this process can become saturated when the zinc concentration becomes too high in the intestine due to the limited binding capacity of cysteine-rich intestinal protein for zinc. Two zinc transporter protein families have since been identified and include the ZnT (solute-linked carrier 30) proteins that are responsible for lowering intracellular zinc and the Zip (Zrt- and Irt-like) proteins that promote zinc transport^52^. Metallothionein, a metal-binding protein present within the mucosal cells, can be induced by zinc and contributes to zinc homeostasis^53^. When zinc binds to metallothionein, it remains in the mucosal cell lining until the bound zinc is excreted from the rat through sloughing off of these cells within the gastrointestinal tract^54^. Studies have shown that zinc absorption in rats can be increased when the metallothionein levels are lower^55^. In male Wistar rats fed a diet with 0.81 mg zinc/kg body weight as zinc chloride or zinc carbonate, the amount of labeled zinc absorbed ranged from 40.0% to 48.4%^56^. Zinc absorption rates can be affected by the presence of phytate, the salt from phytic acid and the principal storage form of phosphorous in many plant tissues^57^. As a common constituent of plant-derived foods like cereals or legumes, zinc absorption rates can be decreased by diets containing phytate or high amounts of phosphorus due to the binding of zinc and phosphate, which results in the coprecipitation of zinc with calcium phosphate in the intestines^58; 59^. This has been demonstrated in rats fed radiolabeled zinc and phytate supplemented diets that excreted significantly more zinc in the feces compared to rats fed the same diet without phytate^60^.

The interaction of zinc with other metals, such as copper, cadmium, and cobalt, has also been extensively studied^3^. Dietary intake of zinc has been shown to interfere with copper absorption; mainly when the levels of zinc are significantly higher than those of copper^61^. This is due to their competition for the same metallothionein protein, of which, copper has the higher affinity^62^. In vitro, cadmium also competes with zinc for binding to metallothionein^63^, and has been demonstrated to interfere with the distribution of tissue zinc and lead to accumulation of zinc in the liver and kidney^64^. In rats, administration of 7 ppm zinc acetate in the diet resulted in a reduction in cadmium-induced carcinogenesis of the prostate gland and the testes^65^. Additionally, zinc chloride had a protective effect against cobalt-induced testis toxicity when the zinc and cobalt were co-administered to mice^66^.

Significantly increased levels of zinc were distributed across the heart, spleen, kidneys, liver, bone, and blood from rats that were fed 191 mg zinc/kg body weight per day as zinc acetate over 3 months^67^. Of these tissues, the largest increases in zinc were observed in bone (258% of the control) and blood (520% of the control). Mice that were given 76.9 mg/kg per day as zinc sulfate^68^ or 38 mg/kg per day as zinc nitrate^69^ for approximately 1 month, also demonstrated elevated zinc levels in the kidneys and the liver. Zinc can be found in the blood as either a diffusible or nondiffusible form^11^. Approximately two-thirds of zinc in its diffusible form is freely exchangeable and is loosely bound to albumin^70^. The diffusible form of zinc can also bind to amino acids, particularly histidine and cysteine, and form a complex that can be transported passively across tissue membranes to bind to proteins such as metallothionein^71^. A small amount of the nondiffusible form of zinc binds tightly with α2µ-globulin in the liver and circulates in the plasma^70; 71^. When zinc is bound to α2µ-globulin, it is not freely exchangeable with other zinc ligands such as zinc-albumin and the zinc-amino acid complexes in the serum.

Rats demonstrated a linear increase in fecal excretion of zinc that was proportional to the amount of zinc supplemented into their diet (32 mg zinc/kg body weight per day as zinc oxide for 7 to 42 days or 50 to 339 mg/kg for 21 days)^72; 73^. Diets supplemented with different forms of zinc (zinc chloride, zinc sulfate, zinc phosphate, or zinc citrate) did not result in any differences in fecal excretion, total excretion, or retention of zinc when fed to rats^74^. Zinc is mainly excreted in the bile of rats as a complex with reduced glutathione^75^. Excretion of zinc can be influenced by several factors including the ingestion of a zinc-deficient or malnourished diet, which can increase the urinary excretion of zinc as a result of tissue breakdown and catabolism that occurs during starvation^76^.

### Humans

Several studies measuring the oral absorption rates of several forms of zinc have been performed in humans. In humans, the absorption of zinc from short-term exposures to zinc supplements can range from 8% to 81% and is influenced by the amount of zinc ingested and the amount and type of food ingested^59; 77-82^. High-protein diets have been shown to facilitate zinc absorption^82^, while the calcium and phosphate present in dairy products decreases zinc absorption and plasma zinc concentration^83^. Zinc-deficient individuals have an increased absorption rate of administered zinc^84; 85^. As is seen with rats, phytate in the diet can also reduce the reabsorption of zinc that is secreted in the gastrointestinal tract in humans^59^. The absorption of zinc can also be influenced by endogenous substances such as amino acids that, when complexed with zinc, enhance the absorption of zinc from all intestinal segments^86^.

Zinc is one of the most abundant trace metals in humans and is normally found distributed across all tissues. Approximately 90% of the total amount of zinc in the body is in the muscle and bone (approximately 60% and 30%, respectively)^87^. Considerable concentrations of zinc can be measured within many tissues including the liver, gastrointestinal tract, kidney, skin, lung, brain, heart, pancreas, prostate, retina, and sperm^67; 88; 89^. The levels of zinc within these tissues can vary across individuals and the distribution of zinc within some of these tissues appears to be influenced by age^88; 90^. For example, zinc concentrations have been shown to increase in the liver, pancreas, and prostate and decrease in the uterus and aorta with age. The National Human Adipose Tissue Survey, conducted in the United States in 1982, measured zinc concentrations in adipose tissue that ranged from 1.1 to 6.0 μg/g^3^. Similarly, the mean whole blood zinc concentrations for residents of Baajoz, Spain, were reported as 6.95 ± 1.08 mg/L^91^. The blood and serum levels for adolescents (15 years old) in the Swedish cities of Trollhättan and Uppsala had median zinc concentrations of 0.99 and 6.1 mg/L, respectively^92^. Peak zinc plasma levels occur 2 to 3 hours following a single oral dose (0.7 mg/kg as zinc sulfate)^50; 93^. The concentration of zinc in fingernails and toenails from populations in the United States, Canada, and Japan were 105, 109, and 94 µg/g, respectively^94^. These levels were similar to the geometric mean of zinc concentrations in the toenails and scalp hair of children in Germany that had measurements of 129 and 108 mg/kg, respectively^95^. A study measuring total concentrations of zinc in 29 different tissues from human cadavers found the lowest concentration of zinc in males and females occurred in the adipose tissue (1.5 ± 2.2 mg/kg wet weight), while the highest average concentrations were found in the skull for males (54.3 mg/kg wet weight) and in the skeletal muscle of females (59.0 mg/kg wet weight)^96^.

During pregnancy, zinc transfer across perfused placentas is slow, with only 3% of the maternal zinc entering the fetal compartment over 2 hours^97^. A study of maternal and cord blood from mothers in Singapore demonstrated that maternal zinc levels (4.97 ± 1.15 mg/L) are normally higher than cord blood levels (1.58 ± 0.45 mg/L)^98^. These maternal and cord blood mean zinc levels are similar to those that were measured in Indian women, which were 6.33 and 2.53 mg/L, respectively^99^. Lactation also serves as an exposure route of infants to zinc^100^. Zinc levels in human milk have been found to increase and peak in the first 2 days postpartum (12.0 ± 4 mg/L) and then decline during the period of lactation (5.0 ± 1.4 mg/L at 6 days postpartum) to levels that are only 12% of what they were initially^101; 102^. Conversely, lactating Polish women at 10 to 30 days postpartum had mean levels of zinc in blood plasma of 0.76 ± 0.20 mg/L, which increased from the levels that were measured at 0 to 4 days postpartum (0.51 ± 0.13 mg/L).

In humans, ingested zinc is mainly excreted through the intestine and feces^60; 77; 87^. Other minor excretion routes include the urine^87^, saliva, hair, and sweat^103-107^. The excretion of zinc in the feces and urine reflects zinc intake, with excretion increasing as intake increases^84; 87^. Zinc mean concentrations were measured in the feces of urban Hispanics (75 mg/kg wet weight) and rural African Americans (94 mg/kg wet weight) in the United States^3^, as well as in the ear wax (88 and 103 mg/kg dry weight), blood plasma (0.79 and 1.7 mg/kg dry weight), sweat (0.50 and 1.58 mg/kg dry weight), and skin (15.6 and 1,000 mg/kg dry weight) from two individuals from California^108^.

## Toxicity

### Experimental Animals

The major targets of zinc toxicity in animals include the gastrointestinal and hematopoietic systems. Other targets for zinc toxicity in animals include the liver, the pancreas, and the kidney. The LD_50_s for several zinc compounds (zinc acetate, zinc nitrate, zinc chloride, and zinc sulfate) range from 186 to 623 mg zinc/kg per day in both rats and mice^109^. Zinc acetate is the most lethal to rats followed by zinc nitrate, zinc chloride, and then zinc sulfate. In mice, zinc acetate is also the most lethal followed by zinc nitrate, zinc sulfate, and then zinc chloride^109^.

Mice given 1,110 mg zinc/kg per day as zinc sulfate in the diet for 13 weeks developed ulcers in the forestomach, in contrast to rats that exhibited no gastrointestinal effects following a diet with half that amount (565 mg/kg per day) given over 13 weeks^110^. Gastrointestinal effects were also observed in ferrets that ingested 390 mg/kg per day as zinc oxide for 2 weeks and included intestinal hemorrhaging and a 75% reduction in food intake^111^. These effects were not demonstrated in ferrets from the same study that were fed 195 mg/kg per day for up to 21 days.

The liver may be a target of zinc exposure; however, the studies performed to this date are inconclusive due to many factors that include low numbers of animals or use of an inappropriate animal model. Rats fed 191 mg zinc/kg per day as zinc acetate demonstrated no histopathology of the liver or any changes in serum enzyme levels, which included measurements of serum glutamic oxaloacetic transaminase, serum glutamic pyruvic transaminase, and alkaline phosphatase^67^. Similarly, mink that were fed 327 mg zinc/kg per day as zinc sulfate for 144 days did not display any liver histopathology^112^. Hepatic effects (necrotic hepatocytes and large quantities of hemosiderin in Kupffer cells) were observed in sheep that were administered time-weighted-average doses of 19 mg zinc/kg per day as zinc oxide over 49 to 72 days^113^. Hexobarbital sleeping times were decreased in rats that received 40 mg zinc/kg per day as zinc sulfate, demonstrating a potential induction of microsomal enzymes^114^. Increased serum cholesterol was observed in two separate studies in rats that were administered either 2.8 or 10 mg zinc/kg per day as zinc acetate in the diet over 2 to 7 months^115; 116^. However, other studies have not shown an effect on total cholesterol, high-density lipoprotein (HDL) cholesterol, or serum triglycerides in rats fed 3 or 25 mg zinc/kg per day of an unspecified zinc compound^117^.

Administration of 1,110 mg zinc/kg per day as zinc sulfate in female mice for 13 weeks resulted in increased absolute and relative kidney weights as well as unspecified regressive kidney lesions; these effects were not seen in the mice and rats from the same studies that received 104 or 565 mg zinc/kg per day, respectively^110^. In another study, epithelial cell damage of the glomerulus and proximal convoluted tubules was observed in rats exposed for 3 months to 191 mg zinc/kg per day as zinc acetate^67^.

### Humans

In humans, zinc deficiency has been associated with several health outcomes. These outcomes include but are not limited to dermatitis, anorexia, growth retardation, inefficient wound healing, hypogonadism and impaired reproductive capacity, and increased incidences of congenital malformations from zinc deficient mothers^118; 119^.

Ingestion of zinc sulfate has been associated with gastrointestinal issues, such as vomiting, diarrhea, abdominal cramps, and nausea^120-123^. These gastrointestinal effects have also been seen with zinc gluconate, which induced severe nausea and vomiting following ingestion of 6.8 mg/kg^124^. Ingestion of zinc oxide through exposure to beverages prepared or stored with galvanized metals has been associated with gastrointestinal distress (nausea, vomiting, and diarrhea)^122; 125^.

Copper deficiencies can result from long-term consumption of zinc. Intermediate (6 to 13 weeks) or long-term exposures to zinc compounds (0.7 to 0.9 mg/kg per day) can lead to minor subclinical changes in copper-sensitive enzymes, such as superoxide dismutase^44; 126-128^. Anemia has been reported in several studies with individuals who have taken zinc supplements over a long period of time (1 to 8 years)^129-137^. Female subjects who ingested supplements containing 50 mg zinc per day as zinc gluconate for 10 weeks displayed a significant reduction in erythrocyte superoxide dismutase activity, hematocrit, and serum ferritin when compared to their pretreatment levels^44^. Decreases in erythrocyte superoxide dismutase activity were also reported in males administered 50 mg zinc per day as zinc gluconate for 6 weeks^126^. Several other studies with men and women (0.68 to 0.83 mg/kg per day) given zinc supplements for 4 to 6 weeks, reported significant increases and decreases in copper-sensitive enzymes (i.e., erythrocyte superoxide dismutase)^44; 126-128^. This is in contrast to another study that demonstrated no significant changes in hematologic or immunologic parameters or in copper-sensitive enzymes as a result of zinc exposure (0.43 mg supplemental zinc/kg per day) in healthy men^138; 139^.

There are several conflicting studies that examine hepatic effects through serum lipid profiles in humans that were exposed to either zinc sulfate or zinc gluconate from 3 to 12 months. Reduced high density lipoprotein (HDL) cholesterol was seen following ingestion of either 2.3 to 4.3 mg/kg per day for 5 to 6 weeks^140; 141^ or 0.71 mg/kg per day for 12 weeks^142^. Additionally, young women taking 1.6 mg zinc/kg per day for 2 months had decreased HDL cholesterol^143^. However, no effects on HDL cholesterol were seen in young men or women taking zinc for 6 weeks (2.0 or 2.4 mg/kg per day, respectively), but low-density lipoprotein (LDL) cholesterol was significantly decreased in the women^144^. No effects on HDL, LDL, or triglyceride levels were seen in men taking 0.43 mg per day as zinc glycine chelate^139^. Black et al.^142^ also reported no changes in serum cholesterol, triglyceride, or LDL cholesterol. Chronic exposure (8 years) to 2 mg/kg per day in subjects older than 68 years also had no effects on triglycerides or cholesterol levels^132^.

## Reproductive and Developmental Toxicity

### Experimental Animals

The role of zinc in reproduction has been extensively studied. In the male, the concentration of zinc is high in multiple species in the adult testis and the prostate gland, which have the highest zinc concentration compared to any other organ^145; 146^. Zinc deficiency can lead to gonadal dysfunction, decreased testicular weight, and diminished seminiferous tubules^146^. These effects are thought to stem from impaired angiotensin converting enzyme activity^146-148^, which ultimately leads to decreased steroidogenesis and inhibited spermatogenesis^146; 149; 150^. The effects on spermatogenesis in the zinc-deficient rat are frequently manifested as defects in spermatozoa^146; 151^. Testis atrophy, attributed to low availability or increased urinary excretion of zinc, is frequently observed in zinc deficient states that include sickle cell anemia, chronic alcoholism, idiopathic male sterility, or the toxic effects of di-(2-ethyl hexyl) phthalate or other phthalic acid esters^146; 152-154^. In females across multiple species, zinc deficiency, as a result of low levels of zinc in the diet (0 to 2 ppm), can interfere with the synthesis and secretion of follicle-stimulating hormone and luteinizing hormone, contributing to observed abnormal ovarian development^146^ and disruption of the estrous cycle in rats^146; 155; 156^. A reduction in the receptivity of females to mating also appears to be a result of zinc deficiencies (<1 ppm)^155; 157^.

Low levels of dietary zinc (0 to 7.5 ppm) during gestation in rats have been associated with adverse outcomes, including increased fetal resorption rates, reduced or inhibited fetal growth, high incidences of congenital malformations, prolonged gestation, stillbirths, and difficulty in parturition^146; 155; 157-163^. Zinc has been shown to be essential to fetal skeletal development in rats, with zinc deficient dams (0 to 1.3 ppm) exhibiting severe anomalies in long bones, vertebrae, and ribs^155; 164^. Gross congenital malformations induced in the fetuses of zinc deficient mothers fed diets with zinc levels ranging from 0 to 9 ppm encompassed a wide range of organ systems that included skeletal, brain, central nervous system, eye, heart, lung and urogenital systems^155; 158; 165; 166^. Excess maternal dietary zinc (0.2% to 0.5% of the diet) has demonstrated similar developmental outcomes to zinc deficiency (reduced fetal growth and weight, increased stillbirths, and increased fetal resorptions); however, congenital malformations were not observed in most studies^163; 167-170^. There are also some indications of fetal endocrine effects as a result of maternal excess zinc exposure (30 mg/kg per day as zinc chloride), with Johnson et al.^163^ reporting an increase in anogenital distance in the male offspring.

### Humans

As in animals, zinc is an essential component of reproduction and development in humans and has been extensively studied and reviewed^146; 171; 172^. The importance of zinc in human reproduction is demonstrated by the high levels of zinc in reproductive tissues and in its fluctuations in reproductive processes. Within the testis, the concentration of zinc in seminal plasma is much greater than in blood plasma and is thought to be important for both spermatogenesis and spermatozoa maintenance^173^. This is demonstrated with studies showing positive correlations between zinc concentrations in blood and seminal plasma and sperm-cell density, as well as lower zinc concentrations in infertile men^174; 175^. In women, plasma zinc concentrations fluctuate depending on menstrual cycle and pregnancy status, and low serum zinc concentrations have been associated with several pregnancy risk factors^146; 171; 176; 177^.

Epidemiological data in humans support some of the experimental observations in animals where zinc deficiencies have been associated with adverse developmental outcomes. This is supported by the effects seen in pregnant women suffering from acrodermatitis enteropathica. Acrodermatitis enteropathica is an autosomal recessive disease that results in impaired zinc absorption in the mothers, leading to high frequencies of fetal deaths, and congenital abnormalities in the form of neural tube defects^10; 146; 159; 176; 178; 179^. There appears to be a relationship between zinc supplementation during pregnancy and small decreases in preterm birth^146; 180-183^; however, these data are conflicting as several recent systematic reviews report that prenatal zinc supplementation does not affect fetal growth^179; 183; 184^. Further, no significant evidence was found for an association between plasma zinc concentration in pregnant women and fetal growth^185^. There is no clear evidence for associations between low maternal zinc levels and other fetal outcomes including fetal loss, congenital malformations, intra-uterine growth retardation, prolonged labor, and preterm or postterm deliveries^10; 146; 163; 183; 184; 186^.

## Carcinogenicity

### Experimental Animals

The potential carcinogenicity of zinc has been evaluated in only a few animal studies. Several studies have demonstrated early proliferative changes within the esophageal tissue of rats fed zinc-deficient diets (≤1 ppm) for 1 to 3 months that included hyperkeratosis, parakeratosis, and expansion of the number of cell layers^149; 187; 188^. However, aside from the formation of esophageal cancer in one rat (out of 25) on a zinc-deficient diet (2.5 to 3 ppm) in a single study^189^, these proliferative lesions seen with chronic zinc deficiency fail to progress to carcinogenesis without the addition of a known carcinogen. The majority of these studies investigating the influence of a zinc-deficient diet (2 to 4 ppm) on the promotion of tumorigenesis found nearly 100% gastrointestinal tumor incidences when the zinc-deficient animals were also exposed to a known carcinogen such as N-nitrosomethylbenzylamine^189-192^. Researchers have also found that when zinc is replenished in zinc-deficient rats, apoptosis of the esophageal epithelial cells is induced, possibly reducing the increased potential for cancer progression from the early proliferative changes^193^.

Chronic zinc-deficiency has also been shown to influence the carcinogenicity of oral cadmium when administered to male rats, where rats maintained on a 7 ppm zinc diet showed decreases in the carcinogenic potential of cadmium in the prostate, testes, and hematopoietic system^65^. A 1-year carcinogenicity study with 0, 1,000, or 5,000 ppm zinc sulfate (0, 170, 850 mg/kg per day) in the drinking water or zinc oleate in the diet (5,000 ppm for 3 months, then 2,500 ppm for the next 3 months, followed by 1,250 ppm for the remainder of the study) of mice found no significant differences in the incidences of hepatocellular carcinoma, malignant lymphoma, or lung adenoma^194^. However, the incidences of hepatocellular carcinoma in the zinc sulfate supplemented diet were increased compared to the controls (30.4% vs. 12.5%). In contrast, Halme^195^ found that 10 to 20 mg zinc/L drinking water increased the frequencies of tumors in both tumor-resistant and tumor-susceptible mouse strains, although tumor type and statistics were not reported for this study. Hypertrophy of the adrenal cortex and pancreatic islets was reported, in the absence of corresponding tumors, in a study with mice given 500 mg zinc/L drinking water as zinc sulfate over 14 months^196^. These available animal studies have not adequately established a link between long-term exposure to zinc compounds and increased cancer incidence.

### Humans

Studies examining the influence of dietary zinc deficiency on cancer outcomes in humans yield conflicting results and appear to depend on several factors, including geographical region. In Eastern European, Asian, and African countries, dietary zinc deficiency has been associated with the high incidences of esophageal cancer through human epidemiological studies^197-199^. This association is supported by Abnet et al.^200^, who found a strong association between high tissue zinc concentrations measured in Chinese individuals and a reduced risk of developing esophageal squamous cell carcinoma. Studies within the United States have also shown conflicting associations between low nutrition status, including dietary zinc deficiency, and development of cancer^201; 202^. Mellow et al.^203^ found significantly decreased plasma zinc levels [65.7 ± 3.3 µg/dL (mean ± SEM) compared to healthy controls (80.5 ± 2.4 µg/dL)] in individuals who developed squamous cancers of the head and neck. However, an ecological study of Americans between 1970 and 1974 found a reduced risk for breast, colon, and esophageal cancer, and an increased risk of ovarian and prostate cancer^204^. A systematic review of 19 epidemiological studies investigating zinc intake and its association with other gastric cancers, such as esophageal, gastric, and colorectal cancer, also showed inconsistent associations^205^. Dietary zinc deficiency has also been shown to influence the carcinogenicity of other chemicals in humans, such as methylbenzylnitrosamine, although here the directionality of the influence appears to depend on the carcinogenic agent itself^191; 198; 206^.

## Genetic Toxicity

Metals that display genotoxicity often do so via generation of oxygen radicals. In bacterial assays purported to be sensitive to compounds that induce DNA alterations via oxygen radical generation, however, zinc was inactive. Zinc sulfate was not mutagenic in Salmonella typhimurium strain TA102 when tested in the absence of exogenous metabolic activation (S9 mix)^207^ and zinc chloride demonstrated no ability to induce DNA damage in a DNA repair-deficient strain of Escherichia coli, in the absence of S9 mix^208^.

In mammalian cell systems, the data for zinc are mixed but it appears that in cells or animals exposed to abnormally high or low levels of zinc, genotoxic effects are observed more often than not. In human lymphoblastoid cells and primary human oral keratinocytes, zinc in the form of zinc sulfate or zinc carnosine, when present in excess, induced increases in micronuclei as well as DNA damage measured by the comet assay^209; 210^. In both cell lines and both assays, abnormally low levels of zinc were also associated with elevated levels of DNA damage, while normal levels of zinc had no effect on these endpoints.

In additional studies, zinc deficiency was shown to increase DNA damage in rat glioma cells^211^, human prostate gland epithelial cells^212^, and human lung fibroblasts^213^. Oxidative DNA damage was shown to be a contributing factor in the DNA damage observed in zinc deficient human lung fibroblasts^213^.

In vivo, DNA damage measured by the comet assay was increased in peripheral blood cells of Sprague Dawley rats fed a zinc-deficient diet (<1 ppm zinc) for 3 weeks^214^ and DNA damage was subsequently reduced to near baseline levels when rats were provided a zinc-adequate diet (30 ppm) for 10 days. Evidence of oxidative damage (induction of the DNA base excision repair enzyme, 8-oxoguanine glycosylase), was seen in rats fed the zinc-deficient diet. In this study, hepatic zinc concentrations were reduced by 30% in the animals fed the zinc-deficient diet; reintroduction of zinc in the diet of these animals restored hepatic zinc to normal levels.

In male Sprague Dawley rats fed a zinc-deficient diet (<1 ppm zinc) for 28 days, single-strand DNA breaks detected by the alkaline elution assay were significantly increased in liver, but DNA from the spleen was not affected^215^, although both organs were confirmed to be zinc deficient. Serum zinc concentrations in these rats ranged from 30% to 40% of control.

The effect of a zinc-deficient diet on micronucleus levels in polychromatic erythrocytes (PCEs) from bone marrow was evaluated in male Sprague Dawley rats^216^. Significant increases in micronuclei were detected after 4 and 6 weeks of a zinc-deficient diet (approximately 0.5 ppm zinc), but not after 2 weeks. Serum levels of zinc were reduced by approximately 70% in rats fed the zinc-deficient diet. DNA from bone marrow cells was also evaluated for evidence of oxidative damage from rats that received a zinc-deficient diet for 6 weeks, or rats that received two daily intraperitoneal injections of Tempol (100 µmol/kg), a superoxide scavenger, for 10 days before sacrifice at the end of 6 weeks of zinc deficiency. Oxidative damage to DNA was increased in rats fed a zinc-deficient diet and was suppressed by treatment with Tempol.

Chromosomal aberrations were not increased in bone marrow cells of male or female Swiss albino mice fed a diet deficient in zinc (2.8 ppm zinc) for 8 weeks compared to the levels in mice fed a zinc-adequate diet (51.6 ppm zinc)^217^. Plasma levels of zinc were approximately 50% lower in mice exposed to the zinc-deficient diet. Male C57Bl mice fed a standard diet supplemented with 5 ppm zinc chloride for 1 month showed no increases in chromosomal aberrations in bone marrow cells^218^; zinc levels in tissues or serum were not determined in this study.

The effect of a zinc-deficient diet on DNA damage was examined in nonhuman primates^219^. Female rhesus monkeys were fed low-zinc diets (2 or 4 ppm) or a zinc-adequate diet (50 ppm) 2 weeks before mating and during pregnancy and lactation. Oxidative DNA damage in the form of DNA strand breakage was evaluated in livers of offspring using the alkaline unwinding assay on postnatal day 30. DNA damage was higher in offspring of monkeys fed zinc-deficient diets, and levels of 8-oxo-2′-deoxyguanosine, measured by high-performance liquid chromatography, were also higher in these animals. Plasma levels of zinc were similar among offspring of monkeys fed diets with 2, 4, or 50 ppm zinc.

Comparatively little is known about the effects of excess zinc or zinc deficiency on the genomic integrity of the germ line. Excess dietary zinc in the form of zinc sulfate, at levels approaching the LD_50_, did not induce sex-linked recessive lethal mutations in germ cells of male Drosophila melanogaster^220^. Furthermore, chromosome structure and number were not altered in metaphase II oocytes of Golden hamsters fed a zinc-deficient diet (2 ppm) for 8 days (two estrus cycles) compared to Golden hamsters fed a zinc-supplemented diet (89.3 ppm), although 8% fewer oocytes were recovered from the animals exposed to low levels of zinc^221^. Serum levels of zinc were approximately 50% lower in the animals fed the zinc-deficient diet.

In a small clinical study of nine healthy male subjects, DNA damage in peripheral blood cells was serially measured using the comet assay while subjects were sequentially fed a controlled diet with normal zinc levels (13 days), followed by a diet deficient in zinc (41 days), and then finally a diet with sufficient zinc levels once again (27 days)^222^. While on the zinc-deficient diet, subjects showed increasing but small elevations in DNA damage levels; restoring sufficient zinc to the diet resulted in reductions in DNA damage levels back to baseline after 27 days.

The mechanisms by which excess zinc or zinc deficiency affect genomic integrity have not been thoroughly investigated. Results from one study using a biochemical approach indicated that excess zinc impaired the activity of enzymes in the base excision repair pathway, which is important for removing chemically modified bases, such as oxidized bases, from DNA^223^.

In summary, results from in vitro studies suggest that an optimal level of zinc protects cells from DNA damage arising from oxidative stress that occurs if zinc levels are too low or too high. Likewise, in vivo studies consistently suggest that dietary zinc deficiency may increase DNA damage detected by the comet assay. However, the effects of non-optimal levels of dietary zinc on micronucleus or chromosomal aberration frequencies were variable.

## Study Rationale

Dietary zinc was nominated by the ATSDR for carcinogenicity and genotoxicity testing based on the increasing size of the population exposed to excess zinc through dietary supplements and the lack of studies examining the carcinogenicity of zinc. There was an additional nomination by private individuals to investigate the tumorigenicity of zinc deficiency as a result of data showing that deficiency of some vitamins and minerals can cause DNA damage. NTP conducted a 2-year study to evaluate chronic toxicity and carcinogenic activity of varying levels of zinc in the diet.

Plasma levels of zinc, in addition to other clinical endpoints, were evaluated at multiple timepoints to assess zinc homeostasis during the study.

A synthetic diet (AIN-93M) was used to control zinc exposure. Although zinc oxide and zinc sulfate are the most common forms of zinc in fortified foods or supplements for humans^14; 15^, zinc carbonate was selected for study because it is the zinc salt recommended by the American Institute of Nutrition for the AIN-93M rodent diet^224^.