# Appendix I Summary of Peer Review Panel Comments

On July 13, 2017, the draft Technical Report on the toxicology and carcinogenesis studies of dietary zinc received public review by the National Toxicology Program’s Technical Reports Peer Review Panel. The review meeting was held at the National Institute of Environmental Health Sciences, Research Triangle Park, NC.

Dr. M. E. Wyde, NIEHS, introduced the draft NTP Technical Report on dietary zinc by noting that zinc is an essential trace element with various other critical biological functions. Dr. Wyde also noted that in many men over 18 and women over 14, zinc intake is below the estimated average requirement and with the popularity of zinc as a dietary supplement, many are also ingesting excess zinc. Dietary zinc deficiency was nominated by private individuals. Excess zinc exposure was nominated by the Agency for Toxic Substances and Disease Registry. Zinc carbonate was selected to be the test article in 2-year feed studies in rats. Genotoxicity testing was also conducted. Dr. Wyde stated that the management of zinc levels was a critical element of the study design, particularly elimination of extraneous sources of zinc.

The proposed conclusions were equivocal evidence of carcinogenic activity of diets deficient in zinc in male Hsd:Sprague Dawley^®^ SD^®^ rats, no evidence of carcinogenic activity of diets deficient in zinc in female Hsd:Sprague Dawley^®^ SD^®^ rats, and no evidence of carcinogenic activity of diets containing excess zinc in male or female Hsd:Sprague Dawley^®^ SD^®^ rats.

Dr. Ludewig, the first reviewer, found the study design and conduct appropriate, with the data well-described and analyzed. She said the study was interesting in that it involved both an excess and a deficiency of dietary zinc. She agreed with the proposed conclusions. She questioned references to blood levels of the metals, in that metals are usually measured in plasma or serum, not whole blood. She also requested clarification of LOD and LOQ with respect to measured copper levels. She said she would have added selenium to the analysis and would have liked to see metal determinations in the organs. She also would have liked to have seen a discussion about kinetics with respect to the reference to ‘no effects on zinc levels in blood,’ especially for the zinc deficient group. She asked for further explanation of the adenomas in the pituitary gland and discussion of clear cell foci in the liver. She found the atrophy of the pancreas in the excess zinc exposure to be surprising, because the pancreas is the major organ to get rid of excess zinc- suggesting that excretion is completely changed in those animals. She requested more discussion of the literature on zinc deficiency and Alzheimer’s disease.

Dr. A. E. Brix, NIEHS, EPL, Inc., said there were no good historical controls due to the unique diet the animals were fed, and that the pituitary adenomas in the deficiency diet were probably due to the lower survival in controls than in the other two groups. Regarding the clear cell foci, she noted that typically results are not brought forward into the body of the report if they do not attain statistical significance unless they are very unusual or important. Clear cell foci can be a common background lesion, she added. She said that historical controls are not kept for nonneoplastic lesions, but the incidences of clear cell foci seen in this study are in line with what we would expect to see. Regarding the atrophy of the pancreas, she observed that it is commonly seen in old rats.

Dr. Wyde noted that metal levels were measured in blood, and the statement in the report pointed out by Dr. Ludewig was a mistake and would be corrected. Regarding the copper data, the staff agreed that more discussion should be added to the report. Regarding the zinc excretion, he said the staff would check the literature to see if there would be further information that could be added to the report on that issue.

Dr. Dybdal, the second reviewer, agreed that the study was well-designed. She was impressed with the efforts that were made to manage and track environmental zinc exposure. She felt that the report was well-written, including the presentation of the nonneoplastic lesions. She agreed with the proposed conclusions.

Dr. Miles, the third reviewer, also felt that the study was comprehensive and well-designed. She said that there appeared to be a sex difference. She recommended inclusion, in the introduction, of additional information on phytate. She asked why the colon, rather than the duodenum, was selected for the comet assay, since the duodenum is the area reportedly responsible for the majority of zinc absorption. She agreed with the proposed conclusions.

Dr. Wyde agreed to add more information on phytates to the introduction. He said that several other tissues were considered for the comet assay, but the colon was one of the few that yielded results.

Dr. Peterson, the fourth reviewer, said the study design was excellent, with a single study evaluating both high and low concentrations. He approved of the care taken to avoid environmental contamination and agreed with the proposed conclusions.

Dr. Conner noted that there is a body of literature about zinc deficiency in animals. He recommended some discussion of cell proliferation in the esophagus associated with zinc deficiency in rodents. He found it interesting that no effect on the esophagus had been observed in the NTP study. He discussed the difficulty of removing zinc from the environment and diet, and questioned how successfully it had been done in the study, given the blood levels seen.

Dr. Dybdal recommended caution about the early literature Dr. Conner referenced due to confounding factors.

Dr. Wyde said he was also surprised that nothing was seen in the esophagus.

Dr. Gordon said that there should have been more discussion and emphasis in the report about how the environment and diet were controlled for zinc contamination. Dr. Wyde said that diet batches were analyzed carefully for zinc content throughout the study. He agreed to check the report and add to it as necessary.

Dr. Ludewig felt that the diet had been well described. She said she was surprised by the statement that zinc carbonate had been chosen due to its bioavailability. Having checked the literature, she felt that the choice was justified, but not due to ‘greater’ bioavailability. Dr. Wyde agreed to change the language in the report to reflect Dr. Ludewig’s comment.

Dr. Cattley called for the conclusions to be projected. Dr. Dybdal moved to accept the conclusions as written. Dr. Conner seconded the motion. The panel voted (6 yes) to accept the conclusions as written.