# Appendix H Sentinel Animal Program

## H.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicological evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or dosed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

Blood samples were collected and allowed to clot, and the serum was separated. All samples were processed appropriately with serology testing performed by IDEXX BioResearch [formerly Research Animal Diagnostic Laboratory (RADIL), University of Missouri] (Columbia, MO) for determination of the presence of pathogens. The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Blood was collected from five animals per sex per time point except the 18-month collection included only four male rats and three female rats.

Method and Test | Time of Collection
Rats
Two-year Study
Multiplex Fluorescent Immunoassay (MFI)
CAR Bacillus | Study termination
H-1 (Toolan’s H-1 virus) | 4 weeks, 6, 12, and 18 months, study termination
KRV (Kilham rat virus) | 4 weeks, 6, 12, and 18 months, study termination
Mycoplasma pulmonis | 4 weeks, 6, 12, and 18 months, study termination
Parvo NS-1 | 4 weeks and 6 months
PVM (pneumonia virus of mice) | 4 weeks, 6, 12, and 18 months, study termination
RCV/SDA (rat coronavirus/sialodacryoadenitis virus) | 4 weeks, 6, 12, and 18 months, study termination
RMV (rat minute virus) | 4 weeks, 6, 12, and 18 months, study termination
RPV (rat parvovirus) | 4 weeks, 6, 12, and 18 months, study termination
RTV (rat theliovirus) | 4 weeks, 6, 12, and 18 months, study termination
Sendai | 4 weeks, 6, 12, and 18 months, study termination
TMEV (Theiler’s murine encephalomyelitis virus) | 4 weeks, 6 months
Immunofluorescence Assay
CAR Bacillus | Study termination
M. pulmonis | 12 months and study termination
KRV | 12 months
Pneumocystis carinii | Study termination

## H.2 Results

All test results were negative.