# Appendix G Ingredients and Nutrient Composition of AIN-93M Modified Low Zinc Feed

Table G-1 Ingredients of AIN-93M Modified Low Zinc Feed

Ingredients | Percent by Weight
Corn starch | 46.00
Dextrin | 15.50
Egg white solids | 14.40
Sugar granual | 10.00
Solka Floc-40 | 5.00
Soy oil mixer: -No A | 4.00
Salt mix AIN-93M MX Zn Deficient | 3.50
Vitamin mix AIN-93M Zn Deficient - CO | 1.00
L-Lysine 98.5% | 0.35
Choline bitartrate | 0.25

Table G-2 Vitamins, Minerals, and Amino Acids in AIN-93M Modified Low Zinc Feed

| Amount | Source
Vitamins
A | 4.0 IU/kg | Stabilized Vitamin A palmitate
D_3_ | 1.0 IU/kg | –
E | 86.44 IU/kg | –
K | 0.75 ppm | –
Thiamine | 6 ppm | Thiamine HCL
Riboflavin | 6 ppm | –
Niacin | 31 ppm | –
α-Pantothenic acid | 16 ppm | α-Calcium pantothenate
Folic acid | 2 ppm | –
Pyridoxine | 7 ppm | Pyridoxine hydrochloride
Biotin | 0.2 ppm | α-Biotin
B_12_ | 25 ppb | –
Minerals
Calcium | 1.0% | –
Total phosphorus | 0.20% | –
Potassium | 0.36% | –
Magnesium | 0.05% | Magnesium oxide
Sodium | 0.10% | –
Sulfur | 0.03% | –
Iron | 48.33 ppm | Ferric citrate
Zinc | 0.002 ppm | –
Manganese | 10.5 ppm | Manganese carbonate
Copper | 6 ppm | Cupric carbonate
Iodine | 0.2 ppm | Potassium iodate
Selenium | 0.15 ppm | Sodium selenite
Amino Acids (% of total diet as published)
Arginine | 0.6926 | –
Lysine | 1.0059 | –
Methionine | 0.4608 | –
Cystine | 0.2938 | –
Tryptophan | 0.1829 | –
Histidine | 0.2693 | –
Leucine | 1.0325 | –
Isoleucine | 1.7229 | –
Phenalalanine | 0.7459 | –
Tyrosine | 0.4766 | –
Threonine | 0.5285 | –
Valine | 0.8899 | –
Essential Fatty Acids (% of total diet as published)
Linoleic | 2 | –

Table G-3 Nutrient Composition of AIN-93M Modified Low Zinc Feed

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by weight) | 12.3 ± 0.18 | 12.1–12.6 | 6
Crude fat (% by weight) | 3.85 ± 0.37 | 3.3–4.3 | 6
Crude fiber (% by weight) | 3.01 ± 0.15 | 2.8–3.2 | 6
Ash (% by weight) | 3.29 ± 0.08 | 3.1–3.3 | 6
Vitamins
Vitamin A (IU/kg) | 4,513 ± 95 | 3,360–5,640 | 6
Thiamine (ppm) | 5.3 ± 0.93 | 4.2–6.5 | 6
Minerals
Calcium (%) | 0.523 ± 0.024 | 0.489–0.557 | 6
Phosphorus (%) | 0.216 ± 0.0104 | 0.204–0.230 | 6

Table G-4 Contaminant Levels in AIN-93M Modified Low Zinc Feed^a^

| Mean ± Standard Deviation^b^ | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.03 ± 0.007 | 0.18–0.037 | 6
Cadmium (ppm) | 0.01 ± 0.0 | 0.04–0.01 | 6
Lead (ppm) | 0.01 ± 0.003 | 0.01–0.019 | 6
Mercury (ppm) | < 0.02 | – | 6
Selenium (ppm) | 0.46 ± 0.174 | 0.376–0.817 | 6

^a^ All samples were irradiated.

^b^ For values less than the limit of detection, the detection limit is given as the mean.