# Appendix F Feed and Compound Consumption in the Two-year Feed Study of Dietary Zinc

Table F-1 Feed and Compound Consumption by Male Rats in the Two-year Feed Study of a Zinc-Deficient Diet

Week | Control 38 ppm | | | 3.5 ppm | | | 7 ppm
Week | Feed^a^ (g/day) | Body Weight (g) | Dose^b^ (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg)
1 | 17.4 | 115 | 5.8 | 15.6 | 115 | 0.5 | 17.0 | 115 | 1.0
2 | 16.5 | 162 | 3.9 | 13.1 | 150 | 0.3 | 16.1 | 159 | 0.7
3 | 17.1 | 207 | 3.1 | 12.9 | 176 | 0.3 | 16.5 | 203 | 0.6
4 | 18.6 | 250 | 2.8 | 14.2 | 202 | 0.2 | 18.1 | 245 | 0.5
5 | 18.4 | 283 | 2.5 | 15.0 | 225 | 0.2 | 17.9 | 278 | 0.5
6 | 18.4 | 311 | 2.2 | 15.7 | 250 | 0.2 | 17.8 | 304 | 0.4
7 | 18.0 | 332 | 2.1 | 15.7 | 271 | 0.2 | 17.6 | 324 | 0.4
8 | 18.0 | 349 | 2.0 | 16.0 | 289 | 0.2 | 17.7 | 340 | 0.4
9 | 17.4 | 363 | 1.8 | 15.5 | 306 | 0.2 | 17.1 | 354 | 0.3
10 | 17.4 | 376 | 1.8 | 15.3 | 319 | 0.2 | 16.7 | 366 | 0.3
11 | 17.4 | 386 | 1.7 | 15.0 | 330 | 0.2 | 16.8 | 377 | 0.3
12 | 17.5 | 395 | 1.7 | 15.4 | 341 | 0.2 | 16.7 | 386 | 0.3
13 | 16.4 | 402 | 1.6 | 14.9 | 350 | 0.1 | 16.0 | 392 | 0.3
14 | 16.2 | 410 | 1.5 | 14.2 | 361 | 0.1 | 15.6 | 401 | 0.3
17 | 17.6 | – | – | 15.9 | – | – | 17.1 | – | –
18 | 17.4 | 441 | 1.5 | 15.9 | 392 | 0.1 | 17.2 | 429 | 0.3
21 | 17.3 | – | – | 16.0 | – | – | 17.0 | – | –
22 | 17.2 | 462 | 1.4 | 15.7 | 417 | 0.1 | 16.7 | 450 | 0.3
25 | 17.4 | – | – | 16.0 | – | – | 16.8 | – | –
26 | 17.1 | 481 | 1.4 | 15.7 | 436 | 0.1 | 16.6 | 468 | 0.2
29 | 17.8 | – | – | 16.8 | – | – | 17.7 | – | –
30 | 17.1 | 497 | 1.3 | 15.9 | 455 | 0.1 | 17.4 | 483 | 0.3
33 | 17.6 | – | – | 16.2 | – | – | 17.3 | – | –
34 | 17.3 | 514 | 1.3 | 16.1 | 469 | 0.1 | 17.4 | 499 | 0.2
37 | 17.3 | – | – | 16.8 | – | – | 17.1 | – | –
38 | 17.6 | 530 | 1.3 | 16.8 | 487 | 0.1 | 17.5 | 512 | 0.2
41 | 17.8 | – | – | 16.9 | – | – | 17.5 | – | –
42 | 18.3 | 540 | 1.3 | 17.6 | 502 | 0.1 | 18.1 | 521 | 0.2
45 | 18.4 | – | – | 18.2 | – | – | 18.3 | – | –
46 | 17.6 | 552 | 1.2 | 16.6 | 511 | 0.1 | 17.0 | 530 | 0.2
49 | 18.0 | – | – | 17.4 | – | – | 18.0 | – | –
50 | 17.5 | 567 | 1.2 | 17.1 | 526 | 0.1 | 17.8 | 545 | 0.2
53 | 18.0 | – | – | 17.0 | – | – | 17.7 | – | –
54 | 17.8 | 583 | 1.2 | 17.0 | 541 | 0.1 | 17.3 | 557 | 0.2
57 | 18.4 | – | – | 17.2 | – | – | 17.3 | – | –
58 | 18.5 | 597 | 1.2 | 17.7 | 552 | 0.1 | 17.1 | 566 | 0.2
61 | 17.6 | – | – | 17.3 | – | – | 17.5 | – | –
62 | 18.0 | 608 | 1.1 | 17.8 | 565 | 0.1 | 17.6 | 577 | 0.2
65 | 18.3 | – | – | 17.3 | – | – | 17.4 | – | –
66 | 18.4 | 616 | 1.1 | 17.5 | 581 | 0.1 | 17.5 | 588 | 0.2
69 | 17.4 | – | – | 16.8 | – | – | 17.4 | – | –
70 | 17.3 | 621 | 1.1 | 17.1 | 587 | 0.1 | 16.9 | 595 | 0.2
73 | 17.5 | – | – | 17.3 | – | – | 17.4 | – | –
74 | 17.8 | 633 | 1.1 | 17.7 | 594 | 0.1 | 17.6 | 605 | 0.2
77 | 17.2 | – | – | 17.0 | – | – | 17.5 | – | –
78 | 17.2 | 636 | 1.0 | 17.7 | 596 | 0.1 | 17.5 | 609 | 0.2
81 | 17.6 | – | – | 17.1 | – | – | 17.1 | – | –
82 | 17.2 | 639 | 1.0 | 17.5 | 603 | 0.1 | 16.8 | 610 | 0.2
85 | 17.7 | – | – | 17.1 | – | – | 17.6 | – | –
86 | 17.7 | 638 | 1.1 | 17.1 | 605 | 0.1 | 17.7 | 614 | 0.2
89 | 17.1 | – | – | 16.8 | – | – | 16.8 | – | –
90 | 17.5 | 644 | 1.0 | 17.3 | 612 | 0.1 | 17.1 | 611 | 0.2
93 | 17.5 | – | – | 17.0 | – | – | 16.8 | – | –
94 | 17.3 | 643 | 1.0 | 17.1 | 604 | 0.1 | 16.5 | 610 | 0.2
97 | 16.6 | – | – | 16.3 | – | – | 16.4 | – | –
98 | 15.9 | 633 | 1.0 | 16.0 | 597 | 0.1 | 16.6 | 613 | 0.2
101 | 17.5 | – | – | 16.1 | – | – | 16.2 | – | –
102 | 16.8 | 647 | 1.0 | 16.4 | 602 | 0.1 | 15.8 | 603 | 0.2
Mean for Weeks
1–13 | 17.6 | 302 | 2.5 | 14.9 | 256 | 0.2 | 17.1 | 296 | 0.5
14–52 | 17.5 | 499 | 1.3 | 16.4 | 456 | 0.1 | 17.3 | 484 | 0.3
53–102 | 17.5 | 626 | 1.1 | 17.1 | 589 | 0.1 | 17.1 | 597 | 0.2

^a^ Grams of feed consumed per animal per day.

^b^ Milligrams of dietary zinc consumed per kilogram body weight per day.

Table F-2 Feed and Compound Consumption by Male Rats in the Two-year Feed Study of a Zinc-Excess Diet

Week | Control 38 ppm | | | 250 ppm | | | 500 ppm
Week | Feed^a^ (g/day) | Body Weight (g) | Dose^b^ (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg)
1 | 17.4 | 115 | 5.8 | 17.3 | 115 | 37.7 | 17.7 | 115 | 77.3
2 | 16.5 | 162 | 3.9 | 16.4 | 163 | 25.2 | 16.6 | 164 | 50.5
3 | 17.1 | 207 | 3.1 | 16.7 | 208 | 20.1 | 17.0 | 210 | 40.5
4 | 18.6 | 250 | 2.8 | 18.1 | 250 | 18.1 | 18.6 | 252 | 36.9
5 | 18.4 | 283 | 2.5 | 18.0 | 282 | 15.9 | 18.2 | 284 | 32.1
6 | 18.4 | 311 | 2.2 | 18.1 | 309 | 14.7 | 18.3 | 311 | 29.5
7 | 18.0 | 332 | 2.1 | 17.7 | 330 | 13.4 | 18.1 | 332 | 27.3
8 | 18.0 | 349 | 2.0 | 17.5 | 345 | 12.7 | 18.1 | 349 | 26.0
9 | 17.4 | 363 | 1.8 | 17.1 | 359 | 11.9 | 17.3 | 362 | 23.9
10 | 17.4 | 376 | 1.8 | 17.0 | 372 | 11.4 | 17.0 | 373 | 22.8
11 | 17.4 | 386 | 1.7 | 16.9 | 381 | 11.1 | 17.0 | 382 | 22.2
12 | 17.5 | 395 | 1.7 | 17.0 | 390 | 10.9 | 17.3 | 393 | 22.0
13 | 16.4 | 402 | 1.6 | 16.0 | 398 | 10.0 | 16.6 | 399 | 20.8
14 | 16.2 | 410 | 1.5 | 15.7 | 406 | 9.7 | 15.9 | 406 | 19.6
17 | 17.6 | – | – | 16.7 | – | – | 17.0 | – | –
18 | 17.4 | 441 | 1.5 | 17.0 | 435 | 9.8 | 16.8 | 435 | 19.3
21 | 17.3 | – | – | 16.8 | – | – | 16.7 | – | –
22 | 17.2 | 462 | 1.4 | 16.9 | 454 | 9.3 | 17.3 | 457 | 18.9
25 | 17.4 | – | – | 17.0 | – | – | 17.0 | – | –
26 | 17.1 | 481 | 1.4 | 17.1 | 474 | 9.0 | 17.0 | 479 | 17.8
29 | 17.8 | – | – | 17.4 | – | – | 17.6 | – | –
30 | 17.1 | 497 | 1.3 | 17.1 | 492 | 8.7 | 17.0 | 494 | 17.2
33 | 17.6 | – | – | 17.2 | – | – | 17.4 | – | –
34 | 17.3 | 514 | 1.3 | 16.9 | 505 | 8.4 | 17.8 | 510 | 17.5
37 | 17.3 | – | – | 17.5 | – | – | 17.9 | – | –
38 | 17.6 | 530 | 1.3 | 17.9 | 520 | 8.6 | 18.0 | 523 | 17.2
41 | 17.8 | – | – | 17.8 | – | – | 18.4 | – | –
42 | 18.3 | 540 | 1.3 | 18.5 | 532 | 8.7 | 18.4 | 537 | 17.1
45 | 18.4 | – | – | 18.2 | – | – | 18.7 | – | –
46 | 17.6 | 552 | 1.2 | 17.7 | 541 | 8.2 | 17.7 | 548 | 16.2
49 | 18.0 | – | – | 17.9 | – | – | 18.6 | – | –
50 | 17.5 | 567 | 1.2 | 17.6 | 555 | 7.9 | 18.1 | 562 | 16.1
53 | 18.0 | – | – | 17.6 | – | – | 17.8 | – | –
54 | 17.8 | 583 | 1.2 | 17.4 | 569 | 7.6 | 17.6 | 580 | 15.2
57 | 18.4 | – | – | 18.0 | – | – | 18.3 | – | –
58 | 18.5 | 597 | 1.2 | 17.8 | 583 | 7.6 | 18.4 | 593 | 15.5
61 | 17.6 | – | – | 17.7 | – | – | 18.2 | – | –
62 | 18.0 | 608 | 1.1 | 17.2 | 588 | 7.3 | 18.6 | 606 | 15.3
65 | 18.3 | – | – | 16.7 | – | – | 17.9 | – | –
66 | 18.4 | 616 | 1.1 | 17.4 | 597 | 7.3 | 18.3 | 619 | 14.8
69 | 17.4 | – | – | 17.1 | – | – | 18.2 | – | –
70 | 17.3 | 621 | 1.1 | 17.4 | 611 | 7.1 | 17.8 | 628 | 14.2
73 | 17.5 | – | – | 17.6 | – | – | 18.4 | – | –
74 | 17.8 | 633 | 1.1 | 17.5 | 614 | 7.1 | 18.4 | 637 | 14.4
77 | 17.2 | – | – | 17.9 | – | – | 18.0 | – | –
78 | 17.2 | 636 | 1.0 | 17.3 | 619 | 7.0 | 18.1 | 646 | 14.0
81 | 17.6 | – | – | 18.0 | – | – | 19.0 | – | –
82 | 17.2 | 639 | 1.0 | 17.3 | 624 | 6.9 | 18.8 | 648 | 14.5
85 | 17.7 | – | – | 17.9 | – | – | 18.6 | – | –
86 | 17.7 | 638 | 1.1 | 18.3 | 618 | 7.4 | 18.5 | 652 | 14.2
89 | 17.1 | – | – | 17.1 | – | – | 17.8 | – | –
90 | 17.5 | 644 | 1.0 | 17.5 | 620 | 7.1 | 17.7 | 657 | 13.5
93 | 17.5 | – | – | 17.4 | – | – | 17.3 | – | –
94 | 17.3 | 643 | 1.0 | 17.8 | 628 | 7.1 | 17.7 | 648 | 13.7
97 | 16.6 | – | – | 15.9 | – | – | 16.5 | – | –
98 | 15.9 | 633 | 1.0 | 16.0 | 623 | 6.4 | 16.8 | 644 | 13.1
101 | 17.5 | – | – | 16.7 | – | – | 16.6 | – | –
102 | 16.8 | 647 | 1.0 | 16.6 | 623 | 6.7 | 16.9 | 644 | 13.1
Mean for Weeks
1–13 | 17.6 | 302 | 2.5 | 17.2 | 300 | 16.4 | 17.5 | 302 | 33.2
14–52 | 17.5 | 499 | 1.3 | 17.3 | 491 | 8.8 | 17.5 | 495 | 17.7
53–102 | 17.5 | 626 | 1.1 | 17.4 | 610 | 7.2 | 17.9 | 631 | 14.4

^a^ Grams of feed consumed per animal per day.

^b^ Milligrams of dietary zinc consumed per kilogram body weight per day.

Table F-3 Feed and Compound Consumption by Female Rats in the Two-year Feed Study of a Zinc-Deficient Diet

Week | Control 38 ppm | | | 3.5 ppm | | | 7 ppm
Week | Feed^a^ (g/day) | Body Weight (g) | Dose^b^ (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg)
1 | 13.6 | 97 | 5.4 | 12.8 | 97 | 0.5 | 13.9 | 97 | 1.0
2 | 12.1 | 126 | 3.6 | 10.3 | 121 | 0.3 | 12.2 | 128 | 0.7
3 | 12.1 | 150 | 3.1 | 10.8 | 137 | 0.3 | 12.0 | 150 | 0.6
4 | 12.6 | 171 | 2.8 | 11.3 | 153 | 0.3 | 13.0 | 172 | 0.5
5 | 12.6 | 190 | 2.5 | 11.3 | 168 | 0.2 | 12.4 | 191 | 0.5
6 | 12.1 | 205 | 2.2 | 11.6 | 182 | 0.2 | 12.4 | 206 | 0.4
7 | 12.3 | 214 | 2.2 | 11.5 | 192 | 0.2 | 12.2 | 216 | 0.4
8 | 12.3 | 223 | 2.1 | 11.6 | 200 | 0.2 | 12.1 | 223 | 0.4
9 | 11.6 | 230 | 1.9 | 11.4 | 208 | 0.2 | 11.7 | 229 | 0.4
10 | 11.7 | 235 | 1.9 | 11.1 | 213 | 0.2 | 11.8 | 233 | 0.4
11 | 11.5 | 240 | 1.8 | 11.4 | 219 | 0.2 | 11.9 | 241 | 0.3
12 | 11.5 | 244 | 1.8 | 11.1 | 224 | 0.2 | 11.7 | 244 | 0.3
13 | 11.5 | 248 | 1.8 | 11.2 | 228 | 0.2 | 11.3 | 248 | 0.3
14 | 11.3 | 253 | 1.7 | 10.5 | 232 | 0.2 | 11.3 | 251 | 0.3
17 | 11.5 | – | – | 11.1 | – | – | 11.6 | – | –
18 | 11.9 | 267 | 1.7 | 11.3 | 247 | 0.2 | 11.7 | 266 | 0.3
21 | 10.9 | – | – | 10.6 | – | – | 11.4 | – | –
22 | 11.2 | 273 | 1.6 | 10.7 | 256 | 0.1 | 11.4 | 276 | 0.3
25 | 11.2 | – | – | 10.9 | – | – | 11.2 | – | –
26 | 11.3 | 282 | 1.5 | 10.7 | 265 | 0.1 | 11.0 | 283 | 0.3
29 | 11.9 | – | – | 11.2 | – | – | 11.5 | – | –
30 | 11.4 | 290 | 1.5 | 10.7 | 272 | 0.1 | 11.4 | 289 | 0.3
33 | 11.6 | – | – | 11.5 | – | – | 12.1 | – | –
34 | 11.5 | 295 | 1.5 | 11.9 | 281 | 0.1 | 11.8 | 300 | 0.3
37 | 11.7 | – | – | 11.4 | – | – | 11.4 | – | –
38 | 11.6 | 300 | 1.5 | 11.8 | 286 | 0.1 | 11.7 | 304 | 0.3
41 | 11.6 | – | – | 11.7 | – | – | 11.8 | – | –
42 | 12.2 | 305 | 1.5 | 12.0 | 290 | 0.1 | 12.3 | 306 | 0.3
45 | 12.2 | – | – | 12.3 | – | – | 12.4 | – | –
46 | 11.6 | 308 | 1.4 | 11.5 | 296 | 0.1 | 12.1 | 316 | 0.3
49 | 12.1 | – | – | 11.6 | – | – | 12.2 | – | –
50 | 12.1 | 319 | 1.4 | 11.6 | 300 | 0.1 | 12.1 | 326 | 0.3
53 | 12.0 | – | – | 11.6 | – | – | 12.4 | – | –
54 | 11.9 | 327 | 1.4 | 11.4 | 302 | 0.1 | 12.1 | 336 | 0.3
57 | 12.6 | – | – | 12.4 | – | – | 12.4 | – | –
58 | 11.7 | 336 | 1.3 | 12.0 | 309 | 0.1 | 11.4 | 342 | 0.2
61 | 11.9 | – | – | 11.4 | – | – | 12.1 | – | –
62 | 12.1 | 344 | 1.3 | 11.5 | 316 | 0.1 | 12.0 | 352 | 0.2
65 | 12.2 | – | – | 11.6 | – | – | 11.8 | – | –
66 | 12.3 | 350 | 1.3 | 11.8 | 321 | 0.1 | 11.8 | 356 | 0.2
69 | 11.6 | – | – | 11.8 | – | – | 12.4 | – | –
70 | 11.9 | 354 | 1.3 | 11.2 | 324 | 0.1 | 11.9 | 363 | 0.2
73 | 12.5 | – | – | 11.9 | – | – | 12.1 | – | –
74 | 12.1 | 363 | 1.3 | 12.1 | 334 | 0.1 | 12.3 | 369 | 0.2
77 | 11.6 | – | – | 12.8 | – | – | 12.0 | – | –
78 | 11.7 | 368 | 1.2 | 11.6 | 336 | 0.1 | 12.4 | 376 | 0.2
81 | 12.3 | – | – | 12.1 | – | – | 11.8 | – | –
82 | 11.7 | 376 | 1.2 | 12.2 | 341 | 0.1 | 11.8 | 379 | 0.2
85 | 11.9 | – | – | 12.5 | – | – | 12.1 | – | –
86 | 12.3 | 378 | 1.2 | 12.2 | 350 | 0.1 | 12.2 | 384 | 0.2
89 | 12.7 | – | – | 12.3 | – | – | 12.8 | – | –
90 | 12.2 | 379 | 1.2 | 12.0 | 351 | 0.1 | 11.9 | 388 | 0.2
93 | 12.4 | – | – | 12.3 | – | – | 13.0 | – | –
94 | 12.6 | 377 | 1.3 | 12.0 | 357 | 0.1 | 12.3 | 388 | 0.2
97 | 11.6 | – | – | 11.9 | – | – | 12.6 | – | –
98 | 11.7 | 370 | 1.2 | 12.5 | 363 | 0.1 | 11.7 | 388 | 0.2
101 | 11.4 | – | – | 12.0 | – | – | 12.5 | – | –
102 | 12.1 | 370 | 1.2 | 11.6 | 355 | 0.1 | 11.9 | 383 | 0.2
Mean for Weeks
1–13 | 12.1 | 198 | 2.5 | 11.3 | 180 | 0.2 | 12.2 | 198 | 0.5
14–52 | 11.6 | 289 | 1.5 | 11.3 | 273 | 0.1 | 11.7 | 292 | 0.3
53–102 | 12.0 | 361 | 1.3 | 12.0 | 335 | 0.1 | 12.1 | 370 | 0.2

^a^ Grams of feed consumed per animal per day.

^b^ Milligrams of dietary zinc consumed per kilogram body weight per day.

Table F-4 Feed and Compound Consumption by Female Rats in the Two-year Feed Study of a Zinc-Excess Diet

Week | Control 38 ppm | | | 250 ppm | | | 500 ppm
Week | Feed^a^ (g/day) | Body Weight (g) | Dose^b^ (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg)
1 | 13.6 | 97 | 5.4 | 14.1 | 97 | 36.5 | 13.8 | 97 | 71.3
2 | 12.1 | 126 | 3.6 | 12.3 | 129 | 23.9 | 12.0 | 128 | 46.8
3 | 12.1 | 150 | 3.1 | 12.1 | 151 | 20.0 | 11.8 | 149 | 39.6
4 | 12.6 | 171 | 2.8 | 13.1 | 174 | 18.9 | 12.3 | 163 | 37.7
5 | 12.6 | 190 | 2.5 | 12.6 | 192 | 16.4 | 12.3 | 185 | 33.2
6 | 12.1 | 205 | 2.2 | 12.7 | 207 | 15.3 | 12.2 | 201 | 30.4
7 | 12.3 | 214 | 2.2 | 12.2 | 218 | 14.0 | 12.1 | 211 | 28.6
8 | 12.3 | 223 | 2.1 | 12.5 | 226 | 13.8 | 12.1 | 219 | 27.6
9 | 11.6 | 230 | 1.9 | 12.1 | 232 | 13.0 | 12.4 | 226 | 27.4
10 | 11.7 | 235 | 1.9 | 12.0 | 237 | 12.6 | 11.9 | 232 | 25.7
11 | 11.5 | 240 | 1.8 | 12.1 | 243 | 12.5 | 12.0 | 238 | 25.2
12 | 11.5 | 244 | 1.8 | 11.9 | 246 | 12.1 | 11.7 | 241 | 24.3
13 | 11.5 | 248 | 1.8 | 11.7 | 252 | 11.6 | 11.9 | 246 | 24.2
14 | 11.3 | 253 | 1.7 | 11.3 | 254 | 11.1 | 11.6 | 250 | 23.2
17 | 11.5 | – | – | 11.9 | – | – | 11.8 | – | –
18 | 11.9 | 267 | 1.7 | 12.1 | 270 | 11.2 | 11.9 | 265 | 22.5
21 | 10.9 | – | – | 11.2 | – | – | 12.0 | – | –
22 | 11.2 | 273 | 1.6 | 11.4 | 277 | 10.3 | 11.5 | 274 | 21.0
25 | 11.2 | – | – | 11.9 | – | – | 11.8 | – | –
26 | 11.3 | 282 | 1.5 | 11.9 | 290 | 10.3 | 11.5 | 281 | 20.5
29 | 11.9 | – | – | 12.3 | – | – | 12.0 | – | –
30 | 11.4 | 290 | 1.5 | 11.9 | 296 | 10.1 | 11.4 | 291 | 19.6
33 | 11.6 | – | – | 11.9 | – | – | 11.8 | – | –
34 | 11.5 | 295 | 1.5 | 12.2 | 304 | 10.0 | 12.0 | 299 | 20.1
37 | 11.7 | – | – | 11.8 | – | – | 12.0 | – | –
38 | 11.6 | 300 | 1.5 | 12.0 | 307 | 9.8 | 11.9 | 304 | 19.6
41 | 11.6 | – | – | 12.3 | – | – | 12.2 | – | –
42 | 12.2 | 305 | 1.5 | 13.0 | 311 | 10.4 | 12.0 | 308 | 19.5
45 | 12.2 | – | – | 12.8 | – | – | 12.7 | – | –
46 | 11.6 | 308 | 1.4 | 12.6 | 318 | 9.9 | 12.3 | 314 | 19.6
49 | 12.1 | – | – | 12.3 | – | – | 12.0 | – | –
50 | 12.1 | 319 | 1.4 | 12.4 | 325 | 9.5 | 12.2 | 323 | 18.9
53 | 12.0 | – | – | 12.5 | – | – | 12.3 | – | –
54 | 11.9 | 327 | 1.4 | 12.5 | 333 | 9.4 | 12.3 | 334 | 18.4
57 | 12.6 | – | – | 12.8 | – | – | 13.4 | – | –
58 | 11.7 | 336 | 1.3 | 11.9 | 342 | 8.7 | 12.1 | 341 | 17.8
61 | 11.9 | – | – | 12.3 | – | – | 12.7 | – | –
62 | 12.1 | 344 | 1.3 | 12.3 | 351 | 8.8 | 12.8 | 350 | 18.3
65 | 12.2 | – | – | 12.6 | – | – | 12.4 | – | –
66 | 12.3 | 350 | 1.3 | 12.6 | 363 | 8.7 | 12.0 | 359 | 16.7
69 | 11.6 | – | – | 12.0 | – | – | 12.6 | – | –
70 | 11.9 | 354 | 1.3 | 12.2 | 371 | 8.2 | 12.7 | 365 | 17.4
73 | 12.5 | – | – | 12.5 | – | – | 13.6 | – | –
74 | 12.1 | 363 | 1.3 | 12.7 | 376 | 8.4 | 12.7 | 372 | 17.1
77 | 11.6 | – | – | 12.8 | – | – | 13.0 | – | –
78 | 11.7 | 368 | 1.2 | 12.5 | 386 | 8.1 | 12.9 | 379 | 17.0
81 | 12.3 | – | – | 12.9 | – | – | 14.0 | – | –
82 | 11.7 | 376 | 1.2 | 13.3 | 386 | 8.6 | 13.4 | 384 | 17.4
85 | 11.9 | – | – | 13.3 | – | – | 13.1 | – | –
86 | 12.3 | 378 | 1.2 | 12.4 | 393 | 7.9 | 12.3 | 389 | 15.8
89 | 12.7 | – | – | 13.7 | – | – | 13.3 | – | –
90 | 12.2 | 379 | 1.2 | 13.6 | 405 | 8.4 | 12.8 | 395 | 16.2
93 | 12.4 | – | – | 13.3 | – | – | 13.0 | – | –
94 | 12.6 | 377 | 1.3 | 12.2 | 401 | 7.6 | 12.1 | 400 | 15.1
97 | 11.6 | | | 13.2 | – | – | 13.0 | – | –
98 | 11.7 | 370 | 1.2 | 13.7 | 404 | 8.5 | 12.7 | 410 | 15.5
101 | 11.4 | – | – | 13.7 | – | – | 12.7 | – | –
102 | 12.1 | 370 | 1.2 | 12.7 | 406 | 7.8 | 12.4 | 402 | 15.4
Mean for Weeks
1–13 | 12.1 | 198 | 2.5 | 12.4 | 200 | 17.0 | 12.2 | 195 | 34.0
14–52 | 11.6 | 289 | 1.5 | 12.1 | 295 | 10.3 | 11.9 | 291 | 20.5
53–102 | 12.0 | 361 | 1.3 | 12.8 | 378 | 8.5 | 12.8 | 375 | 16.9

^a^ Grams of feed consumed per animal per day.

^b^ Milligrams of dietary zinc consumed per kilogram body weight per day.