# Appendix E Chemical Characterization and Dose Formulation Studies

## E.1 Procurement and Characterization of Dietary Zinc

Zinc carbonate basic {[ZnCO_3_]_2_ ∙ [Zn (OH)_2_]_3_} was obtained from Sigma-Aldrich (St. Louis, MO) in one lot (1217764) that was used in the 2-year study to create dietary levels of zinc. Analyses to determine the identity, purity, and storage stability were conducted by the analytical chemistry laboratory at Research Triangle Institute (RTI) (Research Triangle Park, NC) and the study laboratory at Battelle Columbus (Columbus, OH) and its sister laboratory at Battelle Toxicology Northwest (BTNW) (Richland, WA). Reports on analyses performed in support of the dietary zinc study are on file at the National Institute of Environmental Health Sciences.

Zinc carbonate basic (lot 1217764) was a fine white powder. The lot was analyzed by RTI using inductively coupled plasma/optical emission spectroscopy (ICP/OES) for zinc and a panel of secondary elements (a total of 18 including zinc) using Thermo Jarrell Ash Atomscan-16 ICP-OES (Franklin, MA, USA). The instrument was calibrated with standards prepared from National Institute of Standards and Technology (NIST)-traceable, single element standards for each element. NIST-traceable yttrium and gold was used as the internal standard and to stabilize mercury during analysis. Zinc carbonate basic aliquots were dissolved in high-purity nitric acid (J.T. Baker, Phillipsburg, NJ), internal standard was added and diluted with deionized water prior to analyses. The zinc content (at the primary zinc wavelength of 213.856 nm) was calculated to be 56.6%, which is lower than the theoretical value of 59.6% based on the molecular formula of zinc carbonate basic suggesting other zinc-based compounds may have been present. Of the other elements, heavy metal levels (e.g., arsenic, cadmium, chromium, mercury, lead, and thallium) were determined to be below the limit of quantitation of 0.01% and levels of calcium and magnesium were 0.0916% and 1.32%, respectively.

The moisture content of lot 1217764 was determined by RTI using weight loss on drying and by Galbraith Laboratories, Inc. (Knoxville, TN), using Karl Fischer titration. Purity of the test article was assessed using elemental analyses conducted by Quantitative Technologies, Inc. (Whitehouse, NJ), and Galbraith Laboratories, Inc. Ion chromatography (IC) was conducted by Quantitative Technologies, Inc., to measure the concentrations of a number of possible anionic and cationic impurities in the test article.

Weight loss on drying determined a water content of 0.30% and Karl Fisher titration indicated 2.52% water. Elemental analyses yielded for carbon (3.58%) and hydrogen (1.07%) were slightly different than the theoretical (carbon, 4.38%; hydrogen, 1.10%) suggesting the presence of other zinc-based compounds. IC analysis revealed the presence of minor ionic impurities, including chloride (429 µg/g), sulfate (1,871 µg/g), and sodium (698 µg/g), that were consistent with the vendor’s certificate of analysis.

RTI conducted several additional analyses using x-ray diffraction (XRD) spectroscopy, Fourier-transform infrared (FTIR) spectroscopy, thermogravimetric analysis (TGA), and qualitative X-ray fluorescence (XRF) spectroscopy. XRD was performed using a Shimadzu XRD-6000 instrument (Shimadzu Scientific Instruments, Kyoto, Japan), with a step size of 0.02° and a two-theta angle range of 5° to 65°. FTIR was performed on pelletized aliquots of the test article using a ThermoFisher Nicolet 6700 instrument (ThermoFisher Scientific, Waltham, MA). TGA was performed on a Q50 TGA instrument (TA Instruments, New Castle, DE) with nitrogen as both the sample and balance gasses and ramping at 5°C/minute to 400°C. Qualitative XRF was performed using a Thermo ARL Quant’X instrument (Thermo Fisher Scientific) to determine if elements with atomic weights ranging from sodium to uranium were present. After preliminary detection of zinc, copper, magnesium, and sulfur, XRF instrumental conditions were optimized to analyze for these four elements using either no filter, a cellulose filter, or a thin or thick palladium filter.

XRD patterns collected from the zinc carbonate basic test article were searched against a database from the International Center for Diffraction Data (ICDD, Newton Square, PA) Powder Diffraction File (PDF4+) for potential matches. The diffraction patterns did not yield a conclusive match as zinc carbonate basic because a zinc carbonate basic reference spectrum does not exist in the database. The database returned 43 possible matches, but only three scored with match figures of merit less than 5.0 (a perfect match has figure of merit equal to 1.0). These potential matches included zinc oxide (ZnO; PDF4+ reference 03-065-3411, figure of merit 3.0), zinc hydroxide [Zn(OH)_2_; PDF4+ reference 00-048-1066, figure of merit 3.5], and zinc carbonate hydroxide hydrate [Zn_4_(CO_3_)_2_(OH)_6_ H_2_O, PDF4+ reference 00-003-0787, figure of merit 4.0]. The ICDD PDF4+ database was also queried to produce the closest possible chemical formula match to zinc carbonate basic and returned reference spectra for both hydrozincite [Zn_5_(CO_3_)_2_(OH)_6_, PDF4+ reference 00-014-0256] and smithsonite (ZnCO_3_, PDF4+ reference 00-001-1036). Peak diffraction angles and relative intensities from the zinc carbonate basic were closely compared against these five reference compounds but a match was not found. In contrast, all of the peak diffraction angles for zinc oxide corresponded with matching peak diffraction angles from the test lot, but relative peak height intensity distributions of the most abundant peaks for zinc oxide did not correlate with the zinc carbonate basic test lot. Taken collectively, these data suggest that zinc oxide is likely present in the sample, but as a possible minor component.

Because none of the database reference cards produced an unequivocal match with the observed diffraction pattern from the zinc carbonate basic lot, zinc carbonate hydroxide (CASRN 3486-35-9) with the same nominal formula as the zinc carbonate basic lot (both are [ZnCO_3_]_2_ [Zn(OH)_2_]_3_) was procured and analyzed by XRD. (It was difficult to identify and procure potential reference compounds with the same nominal formula, so only this one additional compound was obtained.) Zinc carbonate hydroxide had the same nominal formula as the test article but had a different CAS number at the time of purchase. However, the zinc carbonate hydroxide vendor now offers this compound under the same CAS number as the zinc carbonate basic (5263-02-5). This change in CAS numbers suggests that zinc carbonate hydroxide and the test zinc carbonate basic article may be the same material. Zinc oxide was also procured and analyzed. Diffraction patterns from zinc carbonate hydroxide and zinc carbonate basic generally correspond with each other (Figure E-1). These same diffraction patterns are overlaid with data obtained from zinc oxide. Each of the overlapping peaks for the procured zinc oxide is paralleled with an increase in the peak abundance in the zinc carbonate basic test article spectrum relative to the procured zinc carbonate hydroxide spectrum. Taken collectively, XRD data suggest that the test article is structurally similar or equivalent to the procured zinc carbonate hydroxide, but with zinc oxide as a minor component.

The FTIR spectrum from the zinc carbonate basic lot agrees with a reference spectrum^295^. For additional comparison, FTIR spectra were obtained for aliquots of the zinc carbonate hydroxide and zinc oxide compounds. Visual inspection of the FTIR spectra from the zinc carbonate basic test article and zinc carbonate hydroxide and comparison of prominent peaks further suggests that these compounds are structurally very similar to each other and to the zinc carbonate basic reference spectrum. A strong zinc oxide stretch peak (approximately 450 cm^-1^) was also observed from the test chemical spectrum and the spectra from the procured zinc carbonate hydroxide and zinc oxide compounds, suggesting that zinc oxide is a plausible minor component in the lot.

A single peak was observed in TGA depicting simultaneous decarbonation and dehydroxylation of zinc carbonate basic as represented in the equation^296^.

Zn_5_(CO_3_)_2_(OH)_6_ → 5ZnO + 2CO_2_ + 3H_2_O

Because zinc carbonate basic degrades to zinc oxide upon heating, theoretical weight loss due to loss of water and carbon dioxide for the above equation is 25.9%. However, the observed weight loss was 23.3%, suggesting that nonvolatile impurities may be present in the test lot.

A preliminary XRF scan was obtained to determine whether elements with atomic weights ranging from sodium to uranium were present. From these scans, zinc, calcium, magnesium, and sulfur were observed, and the test article was reanalyzed using optimal instrumental conditions for these elements. Peaks were observed for calcium and sulfur by using the optimal cellulose filter condition for these elements and for magnesium and sulfur by using the optimal no filter condition for these elements. Sulfur is a plausible impurity in the zinc carbonate test article because zinc sulfate compounds can be used in the synthesis of zinc carbonate hydroxides^297; 298^ and because zinc carbonates are effective sulfide scavengers^299^.

Stability studies of the bulk chemical were performed by RTI using the ICP/OES method previously described. These studies indicated that zinc carbonate basic was stable as a bulk chemical for 15 days when stored in capped plastic bottles at temperatures up to 60°C. To ensure stability, the bulk chemical was stored at room temperature in capped amber glass bottles. Prior to study start, the study laboratory analyzed the bulk chemical and the frozen reference standard using XRD (H&M Analytical Services, Inc., Allentown, NJ) and ICP/atomic emission spectroscopy (AES) (IRIS Intrepid, Thermo Electron Corporation, Waltham, MA) using the method described above for ICP/OES. Results of these analyses showed that the bulk test article and frozen reference samples of the same lot were consistent with each other. Periodic analyses of the bulk chemical and the frozen reference standard were performed by the study laboratory at least every 6 months during the 2-year study with ICP/AES, and no degradation of the bulk chemical was detected.

## E.2 Background Zinc Content of Base Diet

Aliquots of four batches (with nine manufacture dates from June 29, 2009, to April 11, 2011) of the base diet (AIN-93M Modified Low Zinc Feed; Zeigler Brothers, Inc., Gardners, PA), were analyzed by BTNW to prescreen for possible background zinc in the blank vehicle using ICP/AES. All batches of the zinc-deficient base diet were determined to contain less than 1 mg Zn/kg diet and were considered acceptable to be used for formulation preparations.

For ICP/AES or ICP/OES, each feed sample (approximately 10 g) was weighed, 1 mL of internal standard solution Y and 100 mL of concentrated nitric acid were added, and the mixture was stirred with a magnetic stir bar until the feed material was thoroughly wetted. The samples were covered or capped loosely and allowed to sit overnight at room temperature in a fume hood.

Samples were restirred with the magnetic stir bars and 5 mL were transferred from each container to separate centrifuge tubes containing 2 mL of deionized water. The centrifuge tubes were capped with vented microwave digestion caps and the samples were subjected to three stages of microwave digestion: a 1 minute ramp to 60°C with a 20 minute hold, then a 2 minute ramp to 80°C with a 20 minute hold, and finally a 2 minute ramp to 100°C with a 10 minute hold. After cooling for 15 minutes, hydrogen peroxide was added, the tubes were recapped with vented caps, and the samples were subjected to a second three-stage digestion as described above. After the second digestion and cooling for 15 minutes, the samples were diluted with deionized water, capped with solid (unvented) caps, mixed well, and analyzed for zinc (213.856 nm) and internal standard solution Y (371.030 nm) on an IRIS Intrepid, Intrepid II, or Thermo Jarrell Ash AtomScan-16 spectrometer (Thermo Electron Corporation, Waltham, MA) or on an Optima 4300 DV spectrometer (PerkinElmer, Waltham, MA).

## E.3 Preparation and Analysis of Dose Formulations

The dose formulations were prepared monthly by mixing zinc carbonate basic with AIN-93M feed (Table E-1). The theoretical value of zinc content (59.6%) was used to calculate the amount of zinc in the dose formulations, therefore the doses used in this study are approximately 3% lower than what is stated. A premix was prepared by hand and then blended with additional feed in a Patterson-Kelly twin-shell blender for approximately 15 minutes. Formulations were stored in sealed plastic bag-lined buckets at room temperature for up to 42 days. The 38 ppm formulation was used as the control formulation for the 2-year study.

Homogeneity studies of 3.5, 7, 38, 250, 500, and 1,000 ppm formulations and of 3.5, 38, and 500 ppm dose formulations were performed by RTI and BTNW, respectively. These studies were conducted with ICP/AES or ICP/OES and measured Zn in digested samples of the formulations. ICP-OES was also used in stability studies of 3.5 and 7 ppm dose formulations that were performed by RTI. Homogeneity was confirmed, and stability was confirmed for at least 42 days for dose formulations stored in sealed plastic bags under freezer, refrigerated, and room temperature conditions; stability was also confirmed for at least 7 days under simulated animal room conditions. Periodic analyses of the dose formulations of zinc carbonate basic were conducted by BTNW using ICP/AES.

During the 2-year study, the dose formulations were analyzed every 2 to 3 months and animal room samples were also analyzed (Table E-2). Of the dose formulations analyzed and used during the study, 102 of 110 were within 10% of the target concentrations; all 20 animal room samples were within 10% of the target concentrations.

Table E-1 Preparation and Storage of Dose Formulations in the Two-year Feed Study of Dietary Zinc

Preparation
Appropriate amounts of blank AIN-93M Modified Low Zinc Feed and zinc carbonate basic test article (adjusted for the theoretical Zn content of 59.6%) were weighed into separate weighing containers. The test article was transferred with rinses to a mortar and pestle and thoroughly ground. The ground mixtures were transferred with rinses into a stainless steel container, and the remaining blank premix feed was incrementally added to obtain a final premix size of 1 kg; the contents of the stainless steel container were thoroughly mixed at each step using a spatula. Each premix was layered into the remaining blank feed and blended in a Patterson-Kelly twin-shell blender for approximately 15 minutes. The dose formulations were prepared monthly during the study.
Chemical Lot Number
1217764
Maximum Storage Time
42 days
Storage Conditions
Stored in sealed plastic bag-lined buckets at room temperature
Study Laboratory
Battelle Columbus Operations (Columbus, OH)

Table E-2 Results of Analyses of Dose Formulations Administered to Rats in the Two-year Feed Study of Dietary Zinc

Date Prepared | Date Analyzed | Target Concentration^a^ (ppm) | Determined Concentration^b^ (ppm) | Difference from Target (%)
August 21, 2009 | August 28, 2009 | 3.5 | 3.49 | 0
| | 3.5 | 3.53 | +1
| | 7 | 6.67 | –5
| | 7 | 6.75 | –4
| | 38 | 35.9 | –6
| | 38 | 35.9 | –6
| | 250 | 234 | –6
| | 250 | 234 | –6
| | 500 | 472 | –6
| | 500 | 468 | –6
| October 22, 2009^c^ | 3.5 | 3.48 | –1
| | 7 | 6.83 | –2
| | 38 | 36.7 | –3
| | 250 | 232 | –7
| | 500 | 465 | –7
October 16, 2009 | October 22, 2009 | 3.5 | 3.51 | 0
| | 3.5 | 3.57 | +2
| | 7 | 7.02 | 0
| | 7 | 6.86 | –2
| | 38 | 37.3 | –2
| | 38 | 36.6 | –4
| | 250 | 242 | –3
| | 250 | 244 | –2
| | 500 | 483 | –3
| | 500 | 482 | –4
January 8, 2010 | January 14–15, 2010 | 3.5 | 3.40 | –3
| | 3.5 | 3.45 | –1
| | 7 | 6.98 | 0
| | 7 | 6.96 | –1
| | 38 | 36.6 | –4
| | 38 | 36.4 | –4
| | 250 | 242 | –3
| | 250 | 244 | –2
| | 500 | 481 | –4
| | 500 | 481 | –4
March 8, 2010 | March 12, 2010 | 3.5 | 3.56 | +2
| | 3.5 | 3.59 | +3
| | 7 | 6.90 | –1
| | 7 | 6.92 | –1
| | 38 | 35.8 | –6
| | 38 | 36.5 | –4
| | 250 | 236 | –6
| | 250 | 239 | –4
| | 500 | 480 | –4
| | 500 | 481 | –4
| April 23, 2010^c^ | 3.5 | 3.40 | –3
| | 7 | 6.86 | –2
| | 38 | 36.6 | –4
| | 250 | 238 | –5
| | 500 | 478 | –4
May 28, 2010 | June 4, 2010 | 3.5 | 3.67 | +5
| | 3.5 | 3.53 | +1
| | 7 | 6.72 | –4
| | 7 | 6.65 | –5
| | 38 | 35.2 | –7
| | 38 | 35.2 | –7
| | 250 | 228 | –9
| | 250 | 228 | –9
| | 500 | 458 | –8
| | 500 | 462 | –8
July 23, 2010 | August 2, 2010 | 3.5 | 3.72 | +6
| | 3.5 | 3.70 | +6
| | 7 | 7.22 | +3
| | 7 | 6.95 | –1
| | 38 | 38.6 | +2
| | 38 | 37.4 | –2
| | 250 | 244 | –2
| | 250 | 236 | –6
| | 500 | 467 | –7
| | 500 | 471 | –6
October 15, 2010 | October 22, 2010 | 3.5 | 3.43 | –2
| | 3.5 | 3.42 | –2
| | 7 | 6.56 | –6
| | 7 | 6.57 | –6
| | 38 | 35.6 | –6
| | 38 | 35.5 | –7
| | 250 | 239 | –4
| | 250 | 239 | –4
| | 500 | 468 | –6
| | 500 | 470 | –6
| December 8, 2010^c^ | 3.5 | 3.84 | +10
| | 7 | 7.22 | +3
| | 38 | 36.5 | –4
| | 250 | 240 | –4
| | 500 | 481 | –4
December 10, 2010 | December 16, 2010 | 3.5 | 3.92 | +12^d^
| | 3.5 | 3.94 | +13^d^
| | 7 | 6.99 | 0
| | 7 | 7.33 | +5
| | 38 | 37.7 | –1
| | 38 | 38.2 | +1
| | 250 | 245 | –2
| | 250 | 243 | –3
| | 500 | 479 | –4
| | 500 | 485 | –3
March 4, 2011 | March 15, 2011 | 3.5 | 4.05 | +16^d^
| | 3.5 | 4.00 | +14^d^
| | 7 | 7.32 | +5
| | 7 | 7.56 | +8
| | 38 | 38.3 | +1
| | 38 | 38.6 | +2
| | 250 | 249 | 0
| | 250 | 247 | –1
| | 500 | 485 | –3
| | 500 | 488 | –2
April 29, 2011 | May 6, 2011 | 3.5 | 3.88 | +11^d^
| | 3.5 | 3.92 | +12^d^
| | 7 | 7.06 | +1
| | 7 | 7.26 | +4
| | 38 | 37.9 | 0
| | 38 | 38.0 | 0
| | 250 | 245 | –2
| | 250 | 243 | –3
| | 500 | 473 | –5
| | 500 | 471 | –6
| June 17, 2011^c^ | 3.5 | 3.83 | +9
| | 7 | 7.15 | +2
| | 38 | 36.8 | –3
| | 250 | 241 | –4
| | 500 | 475 | –5
July 22, 2011 | July 27, 2011 | 3.5 | 3.87 | +11^d^
| | 3.5 | 3.93 | +12^d^
| | 7 | 7.15 | +2
| | 7 | 7.27 | +4
| | 38 | 38.2 | +1
| | 38 | 38.9 | +2
| | 250 | 249 | 0
| | 250 | 247 | –1
| | 500 | 477 | –5
| | 500 | 478 | –4

^a^ The theoretical value of zinc content (59.6%) was used to calculate the amount of zinc in the dose formulations, therefore the doses used in this study are approximately 3% lower than what is stated.

^b^ Results of duplicate analyses.

^c^ Animal room samples.

^d^ Formulation was outside the acceptable range of ± 10% of target concentration, but used at NTP’s direction.

Figure E-1

X-ray Diffraction Patterns of Zinc Carbonate Basic Test Article (gray) and Zinc Carbonate Basic (black)