# Appendix D Hematology Results and Trace Metal Methods and Results

## D.1 Materials and Methods for Trace Metal Concentrations

### D.1.1 Study Design

Ten male and 10 female special study rats were exposed to 3.5, 7, 38 (control), 250, or 500 ppm zinc in the diet. Blood was collected on day 19 and at 3, 6, 9, and 12 months following exposure for determination of trace metal concentrations. All samples were frozen at −70°C and shipped to the analytical chemistry laboratory (Research Triangle Institute (RTI), Research Triangle Park, NC).

### D.1.2 Analysis of Blood for Zinc, Copper, and Iron

Samples were analyzed for zinc concentrations in blood with a validated analytical method using Inductively Coupled Plasma Optical Emission Spectrometry (ICP-OES). The validation was accomplished using calibration standards prepared in an acid matrix that matched the digested blood samples and the performance of the assay in blood was demonstrated using matrix standards run on male and female rat blood. All standards used were National Institute of Standards and Technology–traceable. To mitigate the potential for contamination, high-purity, Ultrex grade acids and oxidants and approximately 18 MΩ quality deionized (DI) water were used. In addition, all new labware (pipette tips and centrifuge tubes) and reusable labware were cleaned prior to use with DI water and 20% (v/v) nitric acid, respectively, and dried under HEPA-filtered air. All sample preparation activities took place in a HEPA-filtered environment, and a high percentage of method blanks approximating 20% of the study sample numbers were processed with each sample batch to continuously monitor the analyte background contribution from the reagents and procedure to ensure the background levels were controlled (see below).

The analytical method was validated over the zinc concentration range of 0.030 to 1.00 µg/mL in the acid digestion matrix (10% v/v nitric acid), which translates to 2.40 to 80.0 µg/mL of blood using 125 µL of blood in the assay. The following criteria were met for linearity (correlation coefficient, r ≥ 0.99), precision [relative standard deviation (RSD) ≤15% except at the experimental limit of quantitation (ELOQ) where RSD ≤ 20%], and accuracy relative error (RE) ≤ ± 10% (except at the ELOQ RE ≤ ± 20%). The ELOQ and estimated limit of detection (LOD) for zinc were 2.40 and 0.6 µg/mL of blood, respectively. During validation, this ELOQ was conservatively established to exceed the observed analyte background levels. Dilution verification was conducted to demonstrate that concentrations outside the validated range could be accurately quantitated after dilution. Stability of zinc in blood digests prepared for analysis stored under ambient and refrigerated conditions were demonstrated for up to 2 hours and 32 days, respectively. Stability of zinc in blood that had undergone three freeze-thaw cycles and stored at −70°C for up to 61 days was also established. The assay was qualified to quantitate copper and iron, respectively, over the concentration range of 0.010 to 0.100 and 1.00 to 20.0 µg/mL of acid digestion matrix (10% v/v nitric acid), which translates to 0.800 to 8.00 and 80.0 to 1,600 µg/mL in blood for copper and iron, respectively. The ELOQ and LOD in blood for copper were 0.800 and 0.2 µg/mL respectively, and the ELOQ for iron was 80 µg/mL.

All study samples were stored frozen at −70°C until analysis. Prior to preparation, samples were allowed to thaw at room temperature in a plastic hood. A 125 µL-aliquot of blood was transferred into a digestion tube along with 1 mL each of nitric acid and DI water. All tubes were tightly capped with digestion caps and digested in two sequences using a microwave (maximum power 800 watts) at 50% power as given below. During sequence 1, temperature was ramped to 60ºC in 5 minutes and held for 20 minutes followed by ramping to 75ºC in 5 minutes and held at 10 minutes. Samples were allowed to cool to room temperature, 1 mL of hydrogen peroxide was added to each tube, and subjected to a second sequence of digestion as follows; temperature was ramped to 75ºC in 5 minutes, held for 10 minutes, ramped to 90ºC in 5 minutes, held for 20 minutes, and ramped to 100ºC in 5 minutes and held for 10 minutes. After the digestion was complete, samples were allowed to come to room temperature and brought to a final volume of 10 mL with DI water. An aliquot of the supernatant was transferred to a vial for analysis by ICP-OES.

All samples were analyzed using ICP-OES on a Perkin-Elmer Optima 4300DV (Waltham, MA). Analyses wave lengths were set for zinc at 213.857 nm, copper at 327.393 nm, and iron at 259.939 nm using a cyclonic spray chamber with three scans/analysis at radio frequency power of 1,450 watts. The concentration of each analyte was calculated using its individual response, the regression equation, and dilution when applicable. Samples with responses greater than the highest calibration standard were diluted with the diluent to get a response within the range. The concentrations of zinc, copper, and iron were expressed as µg/mL of blood. Concentrations less than the LOD were reported as not detected.

A large number of control samples (approximately 50% of the number of study samples) were prepared and analyzed with each batch of study samples, including method blanks, method controls, quality control (QC) samples and certified reference material (CRM) (International Atomic Energy Agency CRM IAEA-A-13, trace elements in freeze dried animal blood). Calibration standards of zinc (0 to 1.00 µg/mL), copper (0 to 0.100 µg/mL) and iron (0 to 20 µg/mL) were prepared with a minimum of six concentrations in acid digestion matrix (10% v/v nitric acid). The performance of the calibration curve was evaluated prior to the analysis of each sample set. A successful calibration was indicated by an acceptable correlation coefficient (r > 0.99) and error within ± 20% of the nominal concentration for the lowest standard and within ± 10% of the nominal concentration for all other standards.

With each batch of 25 study samples, five method blanks, two method controls, and three CRMs were bracketed by two QC sets. Method blanks were prepared in a manner identical to the study samples but excluding blood to monitor for assay background levels. Method controls were included to determine analyte recovery in the absence of the blood matrix. Method controls were prepared in a manner identical to the study samples excluding blood but adding analytes to give final representative blood concentrations of 16, 4, and 400 μg/mL, for zinc, copper, and iron, respectively. CRM samples were prepared with each sample batch in a manner identical to the study samples where final concentrations were 13.0, 4.3, and 2,400 mg analyte/kg blood for zinc, copper and iron, respectively.

The mean percent recoveries for CRM were ≥93.1 for zinc, ≥73.5 for copper, and ≥86.6 for iron, of the recommended concentration in CRM. The mean percent recoveries for method controls were ≥91.3 for zinc, ≥85.8 for copper and ≥92.5 for iron of the nominal value. Analyte levels in method blanks were below the ELOQ for both copper and iron. For zinc, levels were below the ELOQ for all (n = 97) except three samples; the average values (± standard deviation) with and without the three samples above ELOQ were, 0.662 (0.650) and 0.570 (0.369) µg/mL blood, respectively.

Data from study samples were considered valid if they were bracketed by valid QC sets. A QC set passed when the measured concentration for the QC standard was within 10% of its nominal value. If the QC standard failed, it was necessary to reanalyze the bracketed samples. Any samples with a response greater than the calibration range required dilution into range and reanalysis. All analyte values above the LOD were reported.

### D.1.3 Statistical Analyses

Data were analyzed using the nonparametric multiple comparison methods of Shirley^241^ (as modified by Williams^242^) and Dunn^243^. Jonckheere’s test^244^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^245^ were examined by NTP personnel, and implausible values were eliminated from the analysis. All values above the LOD and below the ELOQ were used as reported. In groups with at least 20% of the values above the LOD, the samples that were below the LOD were replaced with half of the LOD value in order to provide non-zero values for statistical analyses.

Table D-1 Hematology Data for Rats in the Two-year Feed Study of Dietary Zinc^a^

| Control 38 ppm | 3.5 ppm | 7 ppm | 250 ppm | 500 ppm
Male
n | 10 | 10 | 9 | 10 | 10
Hematocrit (auto) (%)
Day 19 | 44.7 ± 0.6^b^ | 44.1 ± 0.5^c^ | 42.0 ± 0.4**^d^ | 42.4 ± 0.7*^b^ | 41.7 ± 0.8**
Month 3 | 50.0 ± 0.6 | 49.1 ± 0.5 | 49.8 ± 0.7 | 50.2 ± 0.4^b^ | 49.0 ± 0.7
Month 6 | 49.0 ± 0.5 | 48.9 ± 0.7 | 48.3 ± 0.6 | 47.9 ± 0.4 | 47.2 ± 0.3*
Month 9 | 47.9 ± 0.5 | 47.9 ± 0.4^b^ | 47.0 ± 0.5 | 47.9 ± 0.6 | 48.1 ± 0.3^b^
Month 12 | 49.8 ± 0.4 | 48.6 ± 0.6^c^ | 48.3 ± 0.7 | 50.3 ± 0.5 | 49.6 ± 0.2
Hematocrit (manual) (%)
Day 19 | 43.2 ± 0.7^b^ | 43.3 ± 0.7^c^ | 41.6 ± 0.5^d^ | 41.9 ± 0.7^b^ | 40.7 ± 0.7
Month 3 | 54.0 ± 0.9 | 51.9 ± 0.8 | 58.0 ± 3.2 | 54.2 ± 1.0^b^ | 52.9 ± 1.3^b^
Month 6 | 49.2 ± 0.5 | 48.8 ± 0.8 | 48.2 ± 0.6 | 48.3 ± 0.5 | 48.0 ± 0.4
Month 9 | 48.7 ± 0.7 | 49.2 ± 0.6^b^ | 48.3 ± 0.5^c^ | 48.2 ± 0.3 | 49.2 ± 0.5^b^
Month 12 | 48.8 ± 0.4 | 48.9 ± 0.6^c^ | 49.0 ± 0.7 | 49.3 ± 0.4 | 48.7 ± 0.4
Hemoglobin (g/dL)
Day 19 | 13.6 ± 0.2^b^ | 13.9 ± 0.1^c^ | 13.0 ± 0.1*^d^ | 13.1 ± 0.2^b^ | 12.7 ± 0.2**
Month 3 | 15.3 ± 0.2 | 15.1 ± 0.1 | 15.2 ± 0.2 | 15.3 ± 0.1^b^ | 15.0 ± 0.2
Month 6 | 15.6 ± 0.2 | 15.2 ± 0.2 | 15.2 ± 0.1 | 15.1 ± 0.2 | 14.9 ± 0.1*
Month 9 | 15.3 ± 0.1 | 15.5 ± 0.2^b^ | 15.3 ± 0.2 | 15.2 ± 0.2 | 15.2 ± 0.1^b^
Month 12 | 15.6 ± 0.1 | 15.4 ± 0.2^c^ | 15.5 ± 0.2 | 15.6 ± 0.1 | 15.3 ± 0.1
Erythrocytes (10^6^/μL)
Day 19 | 7.21 ± 0.09^b^ | 7.23 ± 0.10^c^ | 6.78 ± 0.07**^d^ | 6.91 ± 0.12^b^ | 7.14 ± 0.14
Month 3 | 8.82 ± 0.08 | 8.53 ± 0.10 | 8.73 ± 0.09 | 8.87 ± 0.06^b^ | 8.93 ± 0.12
Month 6 | 8.69 ± 0.09 | 8.50 ± 0.12 | 8.55 ± 0.09 | 8.42 ± 0.08 | 8.56 ± 0.07
Month 9 | 8.52 ± 0.09 | 8.49 ± 0.08^b^ | 8.35 ± 0.05 | 8.50 ± 0.09 | 8.70 ± 0.12^b^
Month 12 | 8.77 ± 0.09 | 8.65 ± 0.08^c^ | 8.64 ± 0.09 | 8.80 ± 0.09 | 8.83 ± 0.11
Reticulocytes (10^3^/μL)
Day 19 | 356.5 ± 11.2^b^ | 230.0 ± 16.3**^c^ | 312.4 ± 11.6*^d^ | 358.9 ± 11.4^b^ | 325.4 ± 15.0
Month 3 | 199.0 ± 15.8 | 177.3 ± 4.6 | 180.3 ± 6.2 | 193.5 ± 7.3^b^ | 182.7 ± 8.3
Month 6 | 188.1 ± 9.9 | 185.3 ± 7.6 | 190.7 ± 10.7 | 175.3 ± 6.3 | 161.1 ± 6.4
Month 9 | 190.2 ± 8.3 | 177.4 ± 5.7b | 186.7 ± 9.0 | 186.8 ± 12.2 | 171.9 ± 8.8^b^
Month 12 | 216.6 ± 10.0 | 178.2 ± 9.5*^c^ | 205.9 ± 9.4 | 206.1 ± 13.1 | 179.7 ± 9.7*
Mean cell volume (fL)
Day 19 | 62.0 ± 0.4^b^ | 60.9 ± 0.4^c^ | 62.0 ± 0.4^d^ | 61.4 ± 0.2^b^ | 58.4 ± 0.6**
Month 3 | 56.7 ± 0.4 | 57.5 ± 0.2 | 57.1 ± 0.5 | 56.6 ± 0.3^b^ | 54.9 ± 0.5**
Month 6 | 56.5 ± 0.4 | 57.5 ± 0.3 | 56.5 ± 0.4 | 56.9 ± 0.3 | 55.2 ± 0.5
Month 9 | 56.2 ± 0.4 | 56.5 ± 0.4^b^ | 56.3 ± 0.5 | 56.4 ± 0.4 | 55.3 ± 0.6^b^
Month 12 | 56.8 ± 0.4 | 56.2 ± 0.4^c^ | 55.9 ± 0.6 | 57.2 ± 0.4 | 56.2 ± 0.6
Mean cell hemoglobin (pg)
Day 19 | 18.9 ± 0.2^b^ | 19.2 ± 0.1^c^ | 19.2 ± 0.1^d^ | 19.0 ± 0.1^b^ | 17.8 ± 0.2**
Month 3 | 17.4 ± 0.1 | 17.7 ± 0.1 | 17.4 ± 0.1 | 17.3 ± 0.1^b^ | 16.8 ± 0.2**
Month 6 | 17.9 ± 0.1 | 17.9 ± 0.1 | 17.8 ± 0.1 | 18.0 ± 0.1 | 17.4 ± 0.2*
Month 9 | 18.0 ± 0.1 | 18.3 ± 0.2^b^ | 18.3 ± 0.2 | 17.9 ± 0.1 | 17.5 ± 0.2^b^
Month 12 | 17.8 ± 0.2 | 17.9 ± 0.1^c^ | 17.9 ± 0.2 | 17.8 ± 0.2 | 17.3 ± 0.2
Mean cell hemoglobin concentration (g/dL)
Day 19 | 30.5 ± 0.2^b^ | 31.5 ± 0.1**^c^ | 30.9 ± 0.1^d^ | 30.9 ± 0.1^b^ | 30.5 ± 0.2
Month 3 | 30.7 ± 0.2 | 30.8 ± 0.2 | 30.5 ± 0.2 | 30.5 ± 0.1^b^ | 30.5 ± 0.1
Month 6 | 31.7 ± 0.3 | 31.1 ± 0.1 | 31.4 ± 0.2 | 31.6 ± 0.1 | 31.6 ± 0.1
Month 9 | 32.0 ± 0.2 | 32.4 ± 0.2^b^ | 32.5 ± 0.2 | 31.8 ± 0.1 | 31.6 ± 0.2^b^
Month 12 | 31.3 ± 0.2 | 31.8 ± 0.1^c^ | 32.0 ± 0.1** | 31.0 ± 0.1 | 30.8 ± 0.1*
Platelets (10^3^/μL)
Day 19 | 1,074 ± 40^b^ | 930 ± 42^c^ | 1,032 ± 57^d^ | 974 ± 73^b^ | 984 ± 38
Month 3 | 765 ± 46 | 752 ± 50 | 830 ± 44 | 769 ± 34^b^ | 752 ± 29
Month 6 | 763 ± 52 | 777 ± 29 | 786 ± 20 | 806 ± 50 | 811 ± 23
Month 9 | 713 ± 36 | 799 ± 38^b^ | 653 ± 49 | 709 ± 67 | 702 ± 61^b^
Month 12 | 491 ± 51 | 546 ± 24^c^ | 521 ± 64 | 486 ± 21 | 546 ± 36
Leukocytes (10^3^/μL)
Day 19 | 14.56 ± 0.62^b^ | 13.20 ± 1.08^c^ | 12.93 ± 0.48^d^ | 12.52 ± 0.63^b^ | 12.38 ± 0.91
Month 3 | 10.95 ± 0.57 | 11.17 ± 0.53 | 11.63 ± 0.60 | 11.09 ± 0.49^b^ | 9.95 ± 0.52
Month 6 | 10.96 ± 0.56 | 11.53 ± 0.94 | 11.84 ± 0.83 | 10.54 ± 0.33 | 9.81 ± 0.43
| 10.54 ± 0.60 | 11.48 ± 0.44^b^ | 11.94 ± 0.58 | 12.07 ± 0.87 | 10.33 ± 0.65^b^
Month 12 | 11.93 ± 0.51 | 8.84 ± 0.42**^c^ | 9.77 ± 0.44* | 12.03 ± 0.71 | 11.16 ± 0.63
Segmented neutrophils (10^3^/μL)
Day 19 | 1.43 ± 0.19^b^ | 1.72 ± 0.17^c^ | 1.60 ± 0.07^d^ | 1.24 ± 0.12^b^ | 1.21 ± 0.12
Month 3 | 1.23 ± 0.15 | 1.42 ± 0.16 | 0.98 ± 0.07 | 1.07 ± 0.07^b^ | 0.96 ± 0.07
Month 6 | 1.44 ± 0.15 | 1.85 ± 0.50 | 1.63 ± 0.31 | 1.38 ± 0.12 | 1.33 ± 0.08
Month 9 | 1.60 ± 0.12 | 1.44 ± 0.11^b^ | 1.82 ± 0.16 | 2.36 ± 0.55 | 1.59 ± 0.20^b^
Month 12 | 2.24 ± 0.22 | 2.18 ± 0.36^c^ | 1.83 ± 0.13 | 1.74 ± 0.16 | 1.75 ± 0.17
Lymphocytes (10^3^/μL)
Day 19 | 12.48 ± 0.48^b^ | 10.91 ± 0.88^c^ | 10.76 ± 0.43*^d^ | 10.73 ± 0.52^b^ | 10.62 ± 0.78
Month 3 | 9.24 ± 0.46 | 9.31 ± 0.38 | 10.20 ± 0.53 | 9.64 ± 0.43^b^ | 8.65 ± 0.45
Month 6 | 9.10 ± 0.49 | 9.15 ± 0.60 | 9.75 ± 0.66 | 8.70 ± 0.30 | 7.99 ± 0.35
Month 9 | 8.33 ± 0.53 | 9.39 ± 0.36^b^ | 9.40 ± 0.51 | 8.92 ± 0.59 | 8.17 ± 0.40^b^
Month 12 | 8.83 ± 0.39 | 6.04 ± 0.32**^c^ | 7.17 ± 0.35** | 9.39 ± 0.51 | 8.67 ± 0.45
Monocytes (10^3^/μL)
Day 19 | 0.55 ± 0.03^b^ | 0.40 ± 0.03**^c^ | 0.44 ± 0.03*^d^ | 0.44 ± 0.05^b^ | 0.42 ± 0.05
Month 3 | 0.32 ± 0.03 | 0.27 ± 0.03 | 0.28 ± 0.04 | 0.25 ± 0.02^b^ | 0.20 ± 0.02**
Month 6 | 0.30 ± 0.02 | 0.32 ± 0.04 | 0.33 ± 0.06 | 0.30 ± 0.03 | 0.32 ± 0.03
Month 9 | 0.38 ± 0.04 | 0.39 ± 0.04^b^ | 0.45 ± 0.04 | 0.55 ± 0.10 | 0.36 ± 0.05^b^
Month 12 | 0.58 ± 0.05 | 0.39 ± 0.04**^c^ | 0.53 ± 0.07 | 0.59 ± 0.10 | 0.49 ± 0.05
Basophils (10^3^/μL)
Day 19 | 0.05 ± 0.00^b^ | 0.04 ± 0.01^c^ | 0.04 ± 0.00^d^ | 0.04 ± 0.00^b^ | 0.04 ± 0.01
Month 3 | 0.03 ± 0.00 | 0.04 ± 0.00 | 0.04 ± 0.01 | 0.04 ± 0.00^b^ | 0.03 ± 0.00
Month 6 | 0.02 ± 0.01 | 0.04 ± 0.01 | 0.03 ± 0.00 | 0.03 ± 0.00 | 0.03 ± 0.00
Month 9 | 0.04 ± 0.00 | 0.05 ± 0.00^b^ | 0.05 ± 0.00 | 0.06 ± 0.01 | 0.04 ± 0.01^b^
Month 12 | 0.02 ± 0.01 | 0.02 ± 0.00^c^ | 0.03 ± 0.00 | 0.04 ± 0.01 | 0.03 ± 0.00
Eosinophils (10^3^/μL)
Day 19 | 0.05 ± 0.01^b^ | 0.12 ± 0.03*^c^ | 0.09 ± 0.02^d^ | 0.09 ± 0.02^b^ | 0.09 ± 0.02
Month 3 | 0.13 ± 0.01 | 0.14 ± 0.03 | 0.12 ± 0.01 | 0.10 ± 0.01^b^ | 0.10 ± 0.01
Month 6 | 0.11 ± 0.02 | 0.18 ± 0.04 | 0.10 ± 0.02 | 0.13 ± 0.01 | 0.15 ± 0.01
Month 9 | 0.20 ± 0.03 | 0.21 ± 0.03^b^ | 0.22 ± 0.05 | 0.19 ± 0.03 | 0.18 ± 0.03^b^
Month 12 | 0.26 ± 0.05 | 0.22 ± 0.03^c^ | 0.21 ± 0.02 | 0.27 ± 0.06 | 0.22 ± 0.04
Female
n | 10 | 10 | 9 | 9 | 10
Hematocrit (auto) (%)
Day 19 | 42.4 ± 0.6 | 45.3 ± 0.8**^e^ | 43.7 ± 0.6 | 42.8 ± 0.5^d^ | 41.9 ± 0.5
Month 3 | 44.2 ± 0.7 | 45.4 ± 0.5 | 46.3 ± 0.3^d^ | 45.4 ± 0.6 | 44.0 ± 0.6
Month 6 | 42.8 ± 0.7 | 44.8 ± 0.5* | 43.5 ± 1.1^d^ | 44.2 ± 0.4 | 42.8 ± 0.5
Month 9 | 42.2 ± 0.7 | 43.2 ± 0.6 | 43.8 ± 0.5 | 44.5 ± 0.8 | 42.5 ± 0.5^b^
Month 12 | 44.9 ± 1.1^b^ | 45.9 ± 0.9 | 46.2 ± 0.6 | 46.2 ± 0.6 | 44.6 ± 0.7^c^
Hematocrit (manual) (%)
Day 19 | 42.4 ± 0.5 | 45.6 ± 0.7**^e^ | 43.9 ± 0.6* | 43.7 ± 0.6^d^ | 42.2 ± 0.6
Month 3 | 44.6 ± 0.9 | 46.4 ± 0.7 | 47.0 ± 0.5^d^ | 46.0 ± 0.7 | 45.3 ± 0.5
Month 6 | 44.0 ± 0.7 | 45.0 ± 0.5 | 44.9 ± 1.1^d^ | 44.6 ± 0.4 | 43.6 ± 0.5
Month 9 | 44.6 ± 0.7^c^ | 45.0 ± 0.6 | 45.6 ± 0.5 | 45.8 ± 0.7 | 44.2 ± 0.3^b^
Month 12 | 44.3 ± 1.1^b^ | 46.5 ± 1.0 | 45.8 ± 0.7 | 45.8 ± 0.7 | 43.8 ± 0.8^c^
Hemoglobin (g/dL)
Day 19 | 13.5 ± 0.2 | 14.2 ± 0.1**^e^ | 13.8 ± 0.2 | 13.6 ± 0.2^d^ | 13.0 ± 0.2
Month 3 | 14.1 ± 0.2 | 14.5 ± 0.1 | 14.5 ± 0.1^d^ | 14.3 ± 0.1 | 13.9 ± 0.2
Month 6 | 13.8 ± 0.2 | 14.7 ± 0.2** | 13.9 ± 0.4^d^ | 14.5 ± 0.1 | 13.7 ± 0.2
Month 9 | 14.0 ± 0.2 | 14.3 ± 0.2 | 14.3 ± 0.2 | 14.5 ± 0.3 | 13.8 ± 0.2^b^
Month 12 | 14.0 ± 0.3^b^ | 14.4 ± 0.3 | 14.4 ± 0.2 | 14.4 ± 0.2 | 13.9 ± 0.2^c^
Erythrocytes (10^6^/μL)
Day 19 | 6.97 ± 0.10 | 7.46 ± 0.12*^e^ | 7.11 ± 0.14^d^ | 7.08 ± 0.07^d^ | 7.10 ± 0.08
Month 3 | 7.84 ± 0.09 | 8.05 ± 0.08 | 8.14 ± 0.10^d^ | 8.00 ± 0.06 | 7.87 ± 0.08
Month 6 | 7.52 ± 0.09 | 7.77 ± 0.09 | 7.39 ± 0.34^d^ | 7.76 ± 0.08 | 7.56 ± 0.08
Month 9 | 7.57 ± 0.10 | 7.66 ± 0.08 | 7.71 ± 0.09 | 7.87 ± 0.13 | 7.62 ± 0.07^b^
Month 12 | 7.67 ± 0.18^b^ | 7.73 ± 0.28 | 7.84 ± 0.13 | 7.97 ± 0.13 | 7.73 ± 0.11^c^
Reticulocytes (103/μL)
Day 19 | 194.3 ± 18.2 | 216.4 ± 13.8^e^ | 214.0 ± 14.1 | 221.3 ± 18.3^d^ | 213.9 ± 20.4
Month 3 | 163.3 ± 11.6 | 187.4 ± 14.7 | 204.5 ± 9.4*^d^ | 188.0 ± 15.6 | 171.0 ± 10.8
Month 6 | 166.5 ± 17.0 | 191.6 ± 15.3 | 293.4 ± 125.6^d^ | 164.1 ± 15.5 | 157.0 ± 14.3
Month 9 | 143.9 ± 8.0 | 176.2 ± 10.3 | 171.0 ± 5.9 | 169.2 ± 17.8 | 144.1 ± 12.3^b^
Month 12 | 172.2 ± 19.0^b^ | 258.9 ± 66.5 | 201.8 ± 9.2 | 215.4 ± 26.9 | 158.7 ± 13.2^c^
Mean cell volume (fL)
Day 19 | 60.8 ± 0.2 | 60.7 ± 0.3^e^ | 61.5 ± 0.^b^ | 60.5 ± 0.5^d^ | 58.9 ± 0.4*
Month 3 | 56.3 ± 0.5 | 56.5 ± 0.4 | 56.9 ± 0.4 | 56.7 ± 0.5 | 55.9 ± 0.5
Month 6 | 56.9 ± 0.6 | 57.6 ± 0.4 | 59.6 ± 2.0 | 56.9 ± 0.3 | 56.6 ± 0.5
Month 9 | 55.7 ± 0.4 | 56.4 ± 0.5 | 56.8 ± 0.5^b^ | 56.5 ± 0.5 | 55.7 ± 0.6^b^
Month 12 | 58.6 ± 0.6^b^ | 59.8 ± 1.6 | 59.1 ± 0.4^b^ | 58.0 ± 0.3 | 57.8 ± 0.7^c^
Mean cell hemoglobin (pg)
Day 19 | 19.3 ± 0.1 | 19.0 ± 0.2^e^ | 19.4 ± 0.2 | 19.2 ± 0.1^d^ | 18.3 ± 0.1**
Month 3 | 18.0 ± 0.2 | 18.0 ± 0.1 | 17.9 ± 0.2^d^ | 17.9 ± 0.1 | 17.7 ± 0.2
Month 6 | 18.4 ± 0.2 | 19.0 ± 0.2 | 19.0 ± 0.5^d^ | 18.7 ± 0.2 | 18.1 ± 0.2
Month 9 | 18.4 ± 0.2 | 18.6 ± 0.2 | 18.6 ± 0.2 | 18.4 ± 0.1 | 18.1 ± 0.2^b^
Month 12 | 18.2 ± 0.2^b^ | 18.8 ± 0.4 | 18.4 ± 0.2 | 18.1 ± 0.1 | 18.0 ± 0.2^c^
Mean cell hemoglobin concentration (g/dL)
Day 19 | 31.8 ± 0.2 | 31.3 ± 0.3^e^ | 31.5 ± 0.2 | 31.8 ± 0.2^d^ | 31.0 ± 0.1**
Month 3 | 32.0 ± 0.1 | 31.8 ± 0.2 | 31.4 ± 0.1*^d^ | 31.5 ± 0.1* | 31.6 ± 0.1
Month 6 | 32.3 ± 0.2 | 32.9 ± 0.2 | 32.0 ± 0.3^d^ | 32.8 ± 0.1* | 32.0 ± 0.2
Month 9 | 33.0 ± 0.2 | 33.0 ± 0.2 | 32.7 ± 0.1 | 32.6 ± 0.2 | 32.6 ± 0.1^b^
Month 12 | 31.1 ± 0.1^b^ | 31.4 ± 0.2 | 31.1 ± 0.1 | 31.2 ± 0.2 | 31.1 ± 0.1^c^
Platelets (103/μL)
Day 19 | 953 ± 53 | 932 ± 55^e^ | 937 ± 47 | 1,006 ± 53^d^ | 1,092 ± 82
Month 3 | 902 ± 38 | 881 ± 35 | 831 ± 37^d^ | 863 ± 63 | 800 ± 55
Month 6 | 813 ± 46 | 764 ± 23 | 816 ± 52^d^ | 775 ± 42 | 786 ± 52
Month 9 | 844 ± 49 | 761 ± 18 | 724 ± 43 | 767 ± 41 | 753 ± 49^b^
Month 12 | 749 ± 63^b^ | 577 ± 47 | 594 ± 22 | 617 ± 61 | 601 ± 43^c^
Leukocytes (10^3^/μL)
Day 19 | 9.18 ± 0.78 | 9.98 ± 0.71^e^ | 10.50 ± 0.44* | 10.05 ± 0.73^d^ | 9.11 ± 0.67
Month 3 | 9.22 ± 0.80 | 9.20 ± 0.38 | 9.84 ± 0.63^d^ | 8.76 ± 0.47 | 7.66 ± 0.40
Month 6 | 7.44 ± 0.57 | 7.74 ± 0.38 | 8.70 ± 0.72^d^ | 8.16 ± 0.20 | 8.09 ± 0.49
Month 9 | 8.70 ± 0.52 | 10.03 ± 0.85 | 8.45 ± 0.64 | 8.31 ± 0.37 | 7.88 ± 0.35^b^
Month 12 | 7.17 ± 0.85^b^ | 6.98 ± 0.61 | 5.88 ± 0.73 | 7.25 ± 0.43 | 6.78 ± 0.48^c^
Segmented neutrophils (10^3^/μL)
Day 19 | 0.78 ± 0.10 | 1.02 ± 0.15^e^ | 1.08 ± 0.09 | 0.89 ± 0.08^d^ | 0.79 ± 0.09
Month 3 | 0.93 ± 0.23 | 0.85 ± 0.09 | 0.90 ± 0.11_d_ | 0.87 ± 0.11 | 0.71 ± 0.08
Month 6 | 1.22 ± 0.19 | 0.74 ± 0.05* | 0.98 ± 0.18^d^ | 1.05 ± 0.09 | 1.23 ± 0.19
Month 9 | 1.49 ± 0.24 | 1.64 ± 0.34 | 1.20 ± 0.30 | 1.36 ± 0.23 | 1.16 ± 0.09^b^
Month 12 | 1.41 ± 0.21^b^ | 1.43 ± 0.32 | 1.06 ± 0.13 | 1.12 ± 0.20 | 1.13 ± 0.16^c^
Lymphocytes (10^3^/μL)
Day 19 | 8.01 ± 0.73 | 8.50 ± 0.58^e^ | 9.00 ± 0.36 | 8.70 ± 0.73^d^ | 7.89 ± 0.57
Month 3 | 7.94 ± 0.58 | 8.01 ± 0.39 | 8.59 ± 0.57^d^ | 7.51 ± 0.40 | 6.67 ± 0.35
Month 6 | 5.84 ± 0.47 | 6.68 ± 0.34 | 7.39 ± 0.63^d^ | 6.68 ± 0.19 | 6.46 ± 0.39
Month 9 | 6.65 ± 0.50 | 7.83 ± 0.54 | 6.75 ± 0.59 | 6.46 ± 0.21 | 6.25 ± 0.34^b^
Month 12 | 5.32 ± 0.71^b^ | 5.18 ± 0.39 | 4.47 ± 0.59 | 5.81 ± 0.29 | 5.12 ± 0.28^c^
Monocytes (10^3^/μL)
Day 19 | 0.27 ± 0.04 | 0.31 ± 0.05^e^ | 0.28 ± 0.03 | 0.31 ± 0.03^d^ | 0.31 ± 0.04
Month 3 | 0.23 ± 0.03 | 0.23 ± 0.02 | 0.23 ± 0.02^d^ | 0.28 ± 0.03 | 0.15 ± 0.01
Month 6 | 0.24 ± 0.03 | 0.21 ± 0.02 | 0.25 ± 0.04^d^ | 0.29 ± 0.03 | 0.26 ± 0.02
Month 9 | 0.33 ± 0.03 | 0.38 ± 0.05 | 0.31 ± 0.03 | 0.32 ± 0.02 | 0.32 ± 0.04^b^
Month 12 | 0.29 ± 0.07^b^ | 0.24 ± 0.04 | 0.20 ± 0.06 | 0.23 ± 0.06 | 0.33 ± 0.04^c^
Basophils (10^3^/μL)
Day 19 | 0.02 ± 0.00 | 0.03 ± 0.01^e^ | 0.03 ± 0.00 | 0.03 ± 0.00^d^ | 0.02 ± 0.00
Month 3 | 0.03 ± 0.01 | 0.02 ± 0.00 | 0.03 ± 0.00^d^ | 0.02 ± 0.00 | 0.02 ± 0.00
Month 6 | 0.02 ± 0.00 | 0.01 ± 0.00 | 0.02 ± 0.00^d^ | 0.02 ± 0.00 | 0.02 ± 0.00
Month 9 | 0.04 ± 0.00 | 0.04 ± 0.00 | 0.04 ± 0.01 | 0.03 ± 0.00 | 0.03 ± 0.00**^b^
Month 12 | 0.02 ± 0.01^b^ | 0.01 ± 0.00 | 0.01 ± 0.00 | 0.01 ± 0.00 | 0.02 ± 0.00^c^
Eosinophils (10^3^/μL)
Day 19 | 0.10 ± 0.01 | 0.12 ± 0.04^e^ | 0.11 ± 0.02 | 0.12 ± 0.03^d^ | 0.10 ± 0.03
Month 3 | 0.09 ± 0.01 | 0.08 ± 0.01 | 0.10 ± 0.01^d^ | 0.08 ± 0.01 | 0.10 ± 0.02
Month 6 | 0.13 ± 0.02 | 0.11 ± 0.02 | 0.07 ± 0.01*^d^ | 0.13 ± 0.02 | 0.13 ± 0.02
Month 9 | 0.19 ± 0.03 | 0.15 ± 0.02 | 0.14 ± 0.02 | 0.14 ± 0.02 | 0.13 ± 0.02^b^
Month 12 | 0.14 ± 0.03^b^ | 0.12 ± 0.02 | 0.15 ± 0.03 | 0.08 ± 0.02 | 0.18 ± 0.03^c^

* Significantly different (P ≤ 0.05) from the control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 9.

^c^ n = 8.

^d^ n = 10.

^e^ n = 7.

Table D-2 Trace Metal Concentrations in Blood of Rats in the Two-year Feed Study of Dietary Zinc^a^

| Control 38 ppm | 3.5 ppm | 7 ppm | 250 ppm | 500 ppm
Male
n | 10 | 10 | 9 | 10 | 10
Zinc (µg/mL)
Day 19 | 6.668 ± 0.392 | 6.235 ± 0.557 | 6.541 ± 0.387^b^ | 8.662 ± 0.403** | 9.840 ± 0.382**
Month 3 | 6.630 ± 0.148 | 6.287 ± 0.263 | 6.766 ± 0.342 | 6.887 ± 0.162 | 6.659 ± 0.156
Month 6 | 6.860 ± 0.366 | 6.151 ± 0.199 | 6.148 ± 0.220 | 6.536 ± 0.143 | 6.302 ± 0.178
Month 9 | 6.028 ± 0.197 | 5.822 ± 0.154 | 6.041 ± 0.250 | 6.078 ± 0.128 | 6.057 ± 0.136
Month 12 | 5.379 ± 0.158 | 5.273 ± 0.132 | 5.217 ± 0.112 | 5.604 ± 0.251 | 5.722 ± 0.150
Copper (µg/mL)
Day 19 | 0.438 ± 0.056 | 0.452 ± 0.026 | 0.441 ± 0.021^b^ | ND | ND
Month 3 | 0.634 ± 0.024 | 0.604 ± 0.030 | 0.628 ± 0.022 | 0.584 ± 0.021 | 0.553 ± 0.038
Month 6 | 0.532 ± 0.042 | 0.543 ± 0.040 | 0.527 ± 0.065 | 0.480 ± 0.034^c^ | 0.440 ± 0.035
Month 9 | 0.795 ± 0.041 | 0.831 ± 0.040 | 0.844 ± 0.066 | 0.862 ± 0.088 | 0.712 ± 0.040
Month 12 | 0.710 ± 0.025 | 0.745 ± 0.031 | 0.675 ± 0.023 | 0.705 ± 0.054 | 0.714 ± 0.028
Iron (µg/mL)
Day 19 | 453.1 ± 8.6 | 462.0 ± 6.5 | 447.6 ± 4.9^b^ | 442.7 ± 6.6 | 434.9 ± 8.1
Month 3 | 490.7 ± 8.6 | 495.0 ± 7.4 | 497.8 ± 5.6 | 484.1 ± 7.7 | 479.6 ± 5.7
Month 6 | 486.1 ± 6.2 | 492.8 ± 6.6 | 475.2 ± 5.0 | 482.9 ± 4.4 | 480.0 ± 5.0
Month 9 | 476.2 ± 7.1 | 478.6 ± 6.9 | 477.8 ± 6.0 | 470.5 ± 5.4 | 471.7 ± 7.6
Month 12 | 473.1 ± 8.7 | 458.8 ± 5.9 | 462.2 ± 8.9 | 473.2 ± 8.6 | 476.0 ± 6.1
Female
n | 10 | 10 | 10 | 9 | 10
Zinc (µg/mL)
Day 19 | 4.458 ± 0.188 | 3.928 ± 0.169 | 4.502 ± 0.131 | 6.358 ± 0.580^b^** | 7.754 ± 0.202**
Month 3 | 5.505 ± 0.138 | 5.187 ± 0.176 | 5.301 ± 0.153 | 5.120 ± 0.057 | 5.448 ± 0.185
Month 6 | 4.864 ± 0.072 | 4.982 ± 0.124 | 5.052 ± 0.133 | 4.903 ± 0.203 | 4.608 ± 0.091
Month 9 | 5.021 ± 0.149 | 4.638 ± 0.213 | 4.998 ± 0.120^c^ | 5.136 ± 0.131 | 5.200 ± 0.173^c^
Month 12 | 4.668 ± 0.197^c^ | 4.595 ± 0.377 | 4.537 ± 0.146^c^ | 4.380 ± 0.209 | 4.733 ± 0.143^c^
Copper (µg/mL)
Day 19 | 0.663 ± 0.029 | 0.590 ± 0.034 | 0.669 ± 0.022 | 0.331 ± 0.044^b^** | 0.167 ± 0.027**
Month 3 | 0.769 ± 0.049 | 0.665 ± 0.030 | 0.733 ± 0.023 | 0.733 ± 0.041 | 0.699 ± 0.072
Month 6 | 0.275 ± 0.045 | 0.159 ± 0.025 | 0.236 ± 0.069 | 0.432 ± 0.079 | 0.546 ± 0.064**
Month 9 | 0.791 ± 0.037 | 0.690 ± 0.031 | 0.743 ± 0.041^c^ | 0.713 ± 0.019 | 0.685 ± 0.059^c^
Month 12 | 0.457 ± 0.042^c^ | 0.382 ± 0.032 | 0.399 ± 0.032^c^ | 0.417 ± 0.065 | 0.451 ± 0.058^c^
Iron (µg/mL)
Day 19 | 411.1 ± 9.9 | 400.6 ± 13.6 | 436.0 ± 10.2 | 444.9 ± 9.4^b^ | 423.6 ± 5.4
Month 3 | 448.0 ± 5.0 | 461.3 ± 7.3 | 445.4 ± 9.6 | 430.8 ± 7.1 | 419.9 ± 6.7**
Month 6 | 420.3 ± 6.7 | 428.0 ± 9.2 | 418.9 ± 16.0 | 398.3 ± 17.8 | 378.8 ± 8.2**
Month 9 | 405.1 ± 5.3 | 378.2 ± 7.7* | 409.8 ± 7.0^c^ | 411.9 ± 6.6 | 389.4 ± 9.6^c^
Month 12 | 402.8 ± 8.6^c^ | 376.8 ± 13.8 | 385.6 ± 14.9^c^ | 383.7 ± 17.5 | 412.1 ± 12.9^c^

* Significantly different (P ≤ 0.05) from the control group by Dunn’s or Shirley’s test.

** Significantly different (P ≤ 0.01) from the control group by Shirley’s test.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data. ND = All values below the limit of detection at this dose level.

^b^ n = 10.

^c^ n = 9.