# Appendix C Genetic Toxicology

## C.1 Rat Peripheral Blood Micronucleus Test Protocol

A detailed discussion of this assay is presented by Witt et al.^288^ and Torous et al.^289^. At day 19, and at months 3, 6, 9, and 12 in the 2-year study of dietary zinc, small blood samples (~120 µL) were obtained from male and female Hsd:Sprague Dawley^®^ SD^®^ special study rats in EDTA tubes. Samples were immediately refrigerated, and then shipped with cold packs by overnight courier to the analytical laboratory where they were immediately fixed in ultracold methanol (MicroFlow^®^ Basic Kits, Litron Laboratories, Rochester NY^290^) and stored in a −80°C freezer until analysis. Flow cytometric analysis was conducted using a FACSCalibur flow cytometer (Becton Dickinson, San Jose, CA). Immature erythrocytes or reticulocytes (polychromatic erythrocytes, PCEs) were identified by the presence of an active transferrin receptor (CD71+) on the cell surface; mature erythrocytes were identified as CD71 negative. For these rat blood samples, the analysis was restricted to the youngest reticulocytes (i.e., the subpopulation of immature erythrocytes with the highest CD71 expression) to focus on the population of reticulocytes that were least altered by the efficient action of the rat spleen in sequestering and destroying micronucleated red blood cells^291^. Using flow cytometry, micronucleated cells are detected using the DNA staining dye propidium iodide (PI) in conjunction with RNase treatment. Therefore, micronucleated reticulocytes express high levels of CD71 (CD71+) and PI-associated fluorescence. CD71+ reticulocytes without micronuclei show no PI-associated fluorescence. Twenty thousand CD71+ reticulocytes were scored per animal for presence of micronuclei, and approximately 1×10^6^ mature erythrocytes were counted for the presence of micronuclei and to determine of the percentage of reticulocytes (% PCEs) as a measure of chemical-induced bone marrow toxicity.

In this assay, the animal is the experimental unit and approximately 20,000 reticulocytes and/or 1×10^6^ erythrocytes are evaluated per animal for presence of micronuclei. In addition, the % PCEs was determined in approximately 1×10^6^ erythrocytes. The optimum number of cells to score for micronuclei using flow cytometric approaches was determined in earlier studies^292^. Data from each treatment group are summarized as the mean frequency of micronucleated reticulocytes per 1,000 reticulocytes, plus or minus the standard error of the mean. With the large number of cells counted by flow cytometry, it is assumed that the number of micronucleated cells is normally distributed. Levene’s test is used to determine if variances among treatment groups were equal. When they are, linear regression analysis is used to test for linear trend and pairwise differences with the control group are evaluated using Williams’ test, after linearizing the data by averaging data points that violate a linear trend. When variances are unequal, nonparametric methods are used to analyze the data: Jonckheere’s test is used to evaluate linear trend and Dunn’s test is used to assess the significance of pairwise differences with the control group. To maintain the overall significance level at P ≤ 0.05, the trend as well as the pairwise differences from the control group are declared statistically significant if P ≤ 0.025. Ultimately, the scientific staff determines the final call after considering the results of statistical analyses, reproducibility of any effects observed where applicable, and the magnitudes of those effects.

## C.2 Comet Assay Protocol for DNA Damage Assessment

The same rats sampled for the peripheral blood micronucleus assay were sampled for assessment of DNA damage in cells from the blood and colon. The general tissue sample preparation procedures have been described in detail previously^293^. In brief, blood samples (~50 µL) were obtained at the same five time points that were used to assess micronucleus frequencies^250; 253; 294^. Blood samples were placed into tubes containing 1 mL of mincing solution (Mg^+2^ and Ca^+2^ free Hank’s Balanced Salt Solution with 20 mM EDTA pH 7.4 to 7.7 and 10% v/v fresh DMSO), flash frozen in liquid nitrogen and stored at −80°C prior to shipping. At 12 months, the colon was removed, opened, rinsed thoroughly with cold mincing solution to remove food and debris, and gently scraped to release epithelial cells into 1 mL of mincing solution. Colon samples were flash frozen in liquid nitrogen and stored at −80°C along with the blood samples prior to shipping on dry ice to the genetic toxicology laboratory. Upon arrival at the genetic toxicology laboratory, frozen samples were stored in a −80°C freezer until thawing and processing for DNA damage analysis.

Thawed cell samples were diluted with phosphate buffered saline (PBS), mixed with 0.5% low melting point agarose at 37°C, layered onto slides, and placed in cold lysing solution (2.5 M NaCl, 100 mM Na_2_EDTA, 10 mM Tris, pH 10, with freshly added 10% DMSO and 1% Triton X-100) overnight. After rinsing in 0.4 M Trizma base, pH 7.5, slides were treated with cold alkali (300 mM NaOH, 1 mM Na_2_EDTA, pH > 13) for 20 minutes to allow DNA unwinding, then electrophoresed at 4° to 10°C for 20 minutes at 1.0 V/cm, 300 mA. Slides were then neutralized with 0.4 M Trizma base (pH 7.5) for 5 minutes, incubated for 5 minutes in ice-cold 100% ethanol and allowed to air dry. Slides were stained with SYBR^®^ Gold and 100 cells were scored per leukocyte or colon sample per animal using Comet Assay IV Imaging Software, Version 4.11 (Perceptive Instruments, Ltd., Suffolk, UK). For each cell, the extent of DNA migration was characterized using the percent tail DNA endpoint measurement (intensity of all tail pixels divided by the total intensity of all pixels in the comet, expressed as a percentage).

Five animals per sex per treatment group were analyzed, except no females were analyzed on day 19. Levene’s test was used to determine if variances among treatment groups were equal. When they were, linear regression analysis was used to test for linear trend and pairwise differences with the control group were evaluated using Williams’ test, after linearizing the data by averaging data points that violated a linear trend. When variances were unequal, nonparametric methods were used to analyze the data: Jonckheere’s test was used to evaluate linear trend and Dunn’s test was used to assess the significance of pairwise differences with the control group. To maintain the overall significance level at 0.05, the trend as well as the pairwise differences from the control group were declared statistically significant if P ≤ 0.025. One-tailed tests were used to generate P values for percent tail DNA for the blood samples, and two-tailed tests for both trend and pairwise tests were used to generate P values for percent tail DNA for the colon samples. Ultimately, the scientific staff determined the final call after considering the results of statistical analyses, reproducibility of any effects observed where applicable, and the magnitudes of those effects.

## C.3 Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The summary table in the [underlined: Abstract] of this Technical Report presents a result that represents a scientific judgment of the overall evidence for activity of the chemical in an assay.

## C.4 Results

The percentage of micronucleated immature erythrocytes (reticulocytes) was measured in peripheral blood at five sequential time points during the first year of the 2-year rat study (Table C-1 through Table C-4). Although data on micronucleus frequencies were also collected for the mature erythrocyte population automatically, this cell population is not appropriate for evaluating micronucleus induction in rats due to the rat spleen’s ability to efficiently sequester and destroy damaged reticulocytes soon after they emerge from the bone marrow. Therefore, evaluation of the effects of the deficient and excess zinc diets on chromosome integrity was limited to the immature erythrocyte population.

At the first sample time, 19 days after the study began, female rats maintained on the zinc-deficient diet showed a statistically significant (P ≤ 0.025) increase in micronucleated reticulocytes at both dose levels (3.5 and 7 ppm), although the trend test was not significant (P > 0.025). However, the mean micronucleated reticulocyte values observed for these two treatment groups were well within the laboratory historical control range, and in fact, were within the range of values seen in female rats maintained on either deficient or excess zinc diets at all time points. In addition, no increases were seen at any subsequent sampling time, and for all these reasons, the increased frequencies of micronucleated reticulocytes seen on day 19 in female rats were not judged to be biologically significant. No increases in micronucleated red blood cells were observed at any other sampling time for up to 12 months in either sex.

The percentage of PCEs among total erythrocytes was calculated at each sample time for each sex, and minor, statistically significant, sporadic alterations showing no pattern over time or association with specific diet were observed: zinc-deficient male rats at 19 days; both zinc-deficient and zinc-excess groups of female rats at 6 months. These were considered normal fluctuations and all values were within historical control ranges.

In blood leukocytes (Table C-5) and colonic epithelium (Table C-6), indications of effects on DNA integrity were observed. In blood leukocyte samples obtained from male rats at 12 months, significant increases in percent tail DNA were observed in both the zinc-deficient and the zinc-excess groups. No significant changes in percent tail DNA were observed in peripheral blood samples at any of the earlier sampling times in either dietary group of male rats. Increased levels of DNA damage were also observed in blood leukocytes of female rats fed the zinc-deficient diet at both the 9- and 12-month sampling times. No significant changes in percent tail DNA were observed in female rat blood samples at any other sampling times in either dietary group.

In colon cell samples obtained after 12 months of exposure, a significant increase in percent tail DNA was observed in male rats (trend, P = 0.019) fed a diet with excess zinc, and a small, but not significant, decrease in percent tail DNA was observed in males maintained on the zinc-deficient diet. A significant increase in percent tail DNA was observed in female rats fed a diet supplemented with excess zinc, and a significant decrease in percent tail DNA was observed in females maintained on the zinc-deficient diet. This same pattern of DNA damage was seen in the male rat colon cell samples, although the decreases observed in males fed a zinc-deficient diet were not statistically significant.

Overall, indications of increased levels of DNA damage related to excess dietary levels of zinc were seen in blood leukocytes and colonic epithelial cell samples of male and female rats. In addition, colon cell samples for rats maintained on a zinc-deficient diet showed a significant decrease in DNA migration at 12 months, an observation that is consistent with DNA cross-linking.

Table C-1 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Male Rats Following Exposure to a Zinc-Deficient Diet for Up to 12 months^a^

Dose (ppm) | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/ 1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/ 1,000 NCEs^b^ | P Value | PCEs (%)^b^ | P Value
Day 19
38^d^ | 5 | 0.860 ± 0.215 | | 0.349 ± 0.066 | | 2.6 ± 0.1
7 | 5 | 0.890 ± 0.070 | 0.457 | 0.327 ± 0.037 | 0.695 | 2.3 ± 0.2 | 0.426
3.5 | 5 | 0.742 ± 0.077 | 1.000 | 0.241 ± 0.065 | 0.780 | 1.4 ± 0.1 | < 0.001
| | P = 0.584^e^ | | P = 0.902 | | P < 0.001
Month 3
38 | 5 | 0.846 ± 0.054 | | 0.069 ± 0.011 | | 1.3 ± 0.3
7 | 5 | 0.570 ± 0.089 | 0.927 | 0.060 ± 0.006 | 0.600 | 1.1 ± 0.1 | 0.494
3.5 | 5 | 0.690 ± 0.043 | 0.965 | 0.067 ± 0.017 | 0.633 | 1.0 ± 0.1 | 0.388
| | P = 0.912 | | P = 0.548 | | P = 0.305
Month 6
38 | 5 | 0.800 ± 0.132 | | 0.056 ± 0.013 | | 0.8 ± 0.0
7 | 5 | 0.830 ± 0.145 | 0.446 | 0.037 ± 0.006 | 1.000 | 1.0 ± 0.1 | 0.139
3.5 | 5 | 0.840 ± 0.176 | 0.505 | 0.045 ± 0.003 | 1.000 | 1.0 ± 0.1 | 0.166
| | P = 0.425 | | P = 0.479 | | P = 0.317
Month 9
38 | 5 | 0.994 ± 0.136 | | 0.073 ± 0.008 | | 0.9 ± 0.1
7 | 5 | 1.030 ± 0.101 | 0. 663 | 0.122 ± 0.015 | 0.053 | 1.1 ± 0.1 | 0.236
3.5 | 5 | 0.760 ± 0.081 | 0.748 | 0.106 ± 0.024 | 0.065 | 0.9 ± 0.0 | 0.282
| | P = 0.923 | | P = 0.106 | | P = 0.712
Month 12
38 | 5 | 1.140 ± 0.062 | | 0.086 ± 0.033 | | 1.2 ± 0.1
7 | 5 | 0.950 ± 0.101 | 0.972 | 0.044 ± 0.006 | 1.000 | 1.0 ± 0.1 | 0.223
3.5 | 5 | 0.700 ± 0.022 | 0.989 | 0.044 ± 0.003 | 1.000 | 0.9 ± 0.1 | 0.064
| | P = 1.000 | | P = 0.968 | | P = 0.046

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Dertinger et al.^290^, MacGregor et al.^291^, and Witt et al.^288^. NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the control group; values are significant at P ≤ 0.025 by Williams’ or Dunn’s test.

^d^ 38 ppm is the control group.

^e^ Dose-related trend; significant at P ≤ 0.025 by linear regression or Jonckheere’s test.

Table C-2 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Male Rats Following Exposure to a Zinc-Excess Diet for Up to 12 months^a^

Dose (ppm) | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/ 1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/ 1,000 NCEs^b^ | P Value | PCEs (%)^b^ | P Value
Day 19
38^d^ | 5 | 0.860 ± 0.215 | | 0.349 ± 0.066 | | 2.6 ± 0.1
250 | 5 | 0.660 ± 0.070 | 1.000 | 0.243 ± 0.083 | 0.871 | 3.3 ± 0.1 | 0.166
500 | 5 | 0.780 ± 0.152 | 1.000 | 0.134 ± 0.024 | 0.928 | 2.4 ± 0.1 | 0.196
| | P = 0.521^e^ | | P = 0.987 | | P = 0.557
Month 3
38 | 5 | 0.846 ± 0.054 | | 0.069 ± 0.011 | | 1.3 ± 0.3
250 | 5 | 0.850 ± 0.122 | 0.640 | 0.057 ± 0.017 | 0.671 | 1.0 ± 0.1 | 0.402
500 | 5 | 0.710 ± 0.058 | 0.727 | 0.055 ± 0.010 | 0.757 | 1.0 ± 0.1 | 0.224
| | P = 0.867 | | P = 0.768 | | P = 0.172
Month 6
38 | 5 | 0.800 ± 0.132 | | 0.056 ± 0.013 | | 0.8 ± 0.0
250 | 5 | 0.840 ± 0.083 | 0.614 | 0.029 ± 0.003 | 1.000 | 0.9 ± 0.1 | 0.403
500 | 5 | 0.640 ± 0.048 | 0.702 | 0.031 ± 0.004 | 1.000 | 0.9 ± 0.0 | 0.337
| | P = 0.873 | | P = 0.866 | | P = 0.264
Month 9
38 | 5 | 0.994 ± 0.136 | | 0.073 ± 0.008 | | 0.9 ± 0.1
250 | 5 | 1.470 ± 0.200 | 0.068 | 0.177 ± 0.043 | 0.104 | 1.0 ± 0.1 | 0.467
500 | 5 | 1.210 ± 0.111 | 0.082 | 0.074 ± 0.008 | 0.777 | 1.0 ± 0.0 | 0.562
| | P = 0.192 | | P = 0.396 | | P = 0.603
Month 12
38 | 5 | 1.140 ± 0.062 | | 0.086 ± 0.033 | | 1.2 ± 0.1
250 | 5 | 0.910 ± 0.068 | 0.846 | 0.055 ± 0.007 | 1.000 | 1.2 ± 0.1 | 0.788
500 | 5 | 0.990 ± 0.113 | 0.908 | 0.036 ± 0.004 | 1.000 | 1.1 ± 0.1 | 0.537
| | P = 0.875 | | P = 0.988 | | P = 0.429

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Dertinger et al.^290^, MacGregor et al.^291^, and Witt et al.^288^. NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the control group; values are significant at P ≤ 0.025 by Williams’ or Dunn’s test.

^d^ 38 ppm is the control group.

^e^ Dose-related trend; significant at P ≤ 0.025 by linear regression or Jonckheere’s test.

Table C-3 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Female Rats Following Exposure to a Zinc-Deficient Diet for Up to 12 months^a^

Dose (ppm) | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/ 1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/ 1,000 NCEs^b^ | P Value | PCEs (%)^b^ | P Value
Day 19
38^d^ | 5 | 0.623 ± 0.085 | | 0.126 ± 0.041 | | 0.9 ± 0.2
7 | 5 | 0.970 ± 0.086 | 0.011 | 0.232 ± 0.026 | 0.100 | 1.3 ± 0.2 | 0.117
3.5 | 5 | 0.860 ± 0.064 | 0.013 | 0.180 ± 0.054 | 0.120 | 1.3 ± 0.1 | 0.092
| | P = 0.045^e^ | | P = 0.201 | | P = 0.074
Month 3
38 | 5 | 0.840 ± 0.095 | | 0.073 ± 0.009 | | 0.7 ± 0.1
7 | 5 | 0.750 ± 0.061 | 0.637 | 0.052 ± 0.016 | 0.717 | 1.2 ± 0.1 | 0.022
3.5 | 5 | 0.840 ± 0.103 | 0.584 | 0.064 ± 0.010 | 0.775 | 0.9 ± 0.1 | 0.578
| | P = 0.500 | | P = 0.691 | | P = 0.267
Month 6
38 | 5 | 0.830 ± 0.108 | | 0.043 ± 0.008 | | 0.6 ± 0.1
7 | 5 | 1.110 ± 0.154 | 0.076 | 0.049 ± 0.015 | 0.427 | 0.7 ± 0.0 | 0.120
3.5 | 5 | 1.120 ± 0.123 | 0.084 | 0.042 ± 0.006 | 0.504 | 0.9 ± 0.1 | 0.012
| | P = 0.067 | | P = 0.520 | | P = 0.008
Month 9
38 | 5 | 1.020 ± 0.064 | | 0.024 ± 0.003 | | 0.8 ± 0.1
7 | 5 | 0.960 ± 0.171 | 0.564 | 0.040 ± 0.009 | 0.106 | 0.9 ± 0.1 | 0.555
3.5 | 5 | 1.040 ± 0.126 | 0.538 | 0.036 ± 0.009 | 0.126 | 0.9 ± 0.1 | 0.390
| | P = 0.456 | | P = 0.135 | | P = 0.306
Month 12
38 | 5 | 1.220 ± 0.046 | | 0.054 ± 0.010 | | 1.0 ± 0.3
7 | 5 | 1.290 ± 0.155 | 0.740 | 0.043 ± 0.007 | 0.650 | 1.0 ± 0.1 | 0.729
3.5 | 5 | 0.788 ± 0.154 | 0.820 | 0.046 ± 0.015 | 0.736 | 2.7 ± 0.2 | 0.211
| | P = 0.976 | | P = 0.687 | | P = 0.164

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Dertinger et al.^290^, MacGregor et al.^291^, and Witt et al.^288^. NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the control group; values are significant at P ≤ 0.025 by Williams’ or Dunn’s test.

^d^ 38 ppm is the control group.

^e^ Dose-related trend; significant at P ≤ 0.025 by linear regression or Jonckheere’s test.

Table C-4 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Female Rats Following Exposure to a Zinc-Excess Diet for Up to 12 months^a^

Dose (ppm) | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/ 1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/ 1,000 NCEs^b^ | P Value | PCEs (%)^b^ | P Value
Day 19
38^d^ | 5 | 0.623 ± 0.085 | | 0.126 ± 0.041 | | 0.9 ± 0.2
250 | 5 | 0.700 ± 0.076 | 0.368 | 0.124 ± 0.014 | 0.506 | 1.3 ± 0.3 | 0.185
500 | 5 | 0.620 ± 0.068 | 0.438 | 0.149 ± 0.025 | 0.349 | 1.6 ± 0.3 | 0.097
| | P = 0.511^e^ | | P = 0.285 | | P = 0.073
Month 3
38 | 5 | 0.840 ± 0.095 | | 0.073 ± 0.009 | | 0.7 ± 0.1
250 | 5 | 0.820 ± 0.064 | 0.572 | 0.090 ± 0.016 | 0.576 | 1.2 ± 0.2 | 0.041
500 | 5 | 0.780 ± 0.130 | 0.660 | 0.044 ± 0.015 | 0.633 | 1.1 ± 0.2 | 0.048
| | P = 0.667 | | P = 0.902 | | P = 0.096
Month 6
38 | 5 | 0.830 ± 0.108 | | 0.043 ± 0.008 | | 0.6 ± 0.1
250 | 5 | 1.030 ± 0.128 | 0.279 | 0.071 ± 0.018 | 0.289 | 1.0 ± 0.1 | 0.019
500 | 5 | 0.860 ± 0.164 | 0.334 | 0.043 ± 0.009 | 1.000 | 1.1 ± 0.1 | 0.007
| | P = 0.439 | | P = 0.521 | | P = 0.006
Month 9
38 | 5 | 1.020 ± 0.064 | | 0.024 ± 0.003 | | 0.8 ± 0.1
250 | 5 | 0.869 ± 0.145 | 1.000 | 0.030 ± 0.007 | 0.224 | 0.9 ± 0.2 | 0.741
500 | 5 | 0.820 ± 0.108 | 1.000 | 0.028 ± 0.001 | 0.271 | 0.8 ± 0.1 | 0.861
| | P = 0.831 | | P = 0.265 | | P = 0.836
Month 12
38 | 5 | 1.220 ± 0.046 | | 0.054 ± 0.010 | | 1.0 ± 0.3
250 | 5 | 0.975 ± 0.156 | 0.842 | 0.030 ± 0.005 | 0.890 | 1.3 ± 0.3 | 0.443
500 | 5 | 0.925 ± 0.131 | 0.911 | 0.030 ± 0.006 | 0.943 | 0.9 ± 0.1 | 0.532
| | P = 0.963 | | P = 0.972 | | P = 0.809

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Dertinger et al.^290^, MacGregor et al.^291^, and Witt et al.^288^. NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the control group; values are significant at P ≤ 0.025 by Williams’ or Dunn’s test.

^d^ 38 ppm is the control group.

^e^ Dose-related trend; significant at P ≤ 0.025 by linear regression or Jonckheere’s test.

Table C-5 DNA Damage in the Blood of Rats Administered Varying Levels of Zinc in the Diet for up to 12 months^a^

Exposure Concentration (ppm) | Percent Tail DNA^b^ | P Value^c^
Male
Day 19
38 (Control) | 2.24 ± 0.30
3.5 | 2.89 ± 0.26 | 0.101
7 | 1.91 ± 0.37 | 0.644
| P = 0.098^d^
250 | 1.92 ± 0.31 | 0.723
500 | 1.77 ± 0.31 | 0.805
| P = 0.861
Month 3
38 (Control) | 3.25 ± 0.37
3.5 | 2.35 ± 0.52 | 0.910
7 | 2.28 ± 0.32 | 0.848
| P = 0.928
250 | 2.50 ± 0.41 | 0.771
500 | 2.35 ± 0.68 | 0.849
| P = 0.892
Month 6
38 (Control) | 1.46 ± 0.19
3.5 | 1.94 ± 0.29 | 0.120
7 | 1.44 ± 0.27 | 0.510
| P = 0.098
250 | 2.37 ± 0.24 | 0.028
500 | 3.08 ± 1.05 | 0.104
| P = 0.041
Month 9
38 (Control) | 6.67 ± 1.05
3.5 | 5.80 ± 0.78 | 0.521
7 | 8.00 ± 1.29 | 0.442
| P = 0.710
250 | 5.61 ± 0.65 | 0.660
500 | 6.12 ± 0.94 | 0.746
| P = 0.667
Month 12
38 (Control) | 5.25 ± 0.59
3.5 | 8.90 ± 0.39 | 0.011
7 | 7.78 ± 1.07 | 0.056
| P = 0.007
250 | 8.15 ± 0.41 | 0.045
500 | 8.86 ± 1.80 | 0.025
| P = 0.019
Female
Month 3
38 (Control) | 4.04 ± 0.75
3.5 | 6.79 ± 1.46 | 0.049
7 | 3.80 ± 0.67 | 0.532
| P = 0.043
250 | 4.05 ± 0.58 | 0.649
500 | 3.04 ± 0.41 | 0.736
| P = 0.877
Month 6
38 (Control) | 2.86 ± 0.26
3.5 | 2.84 ± 0.21 | 1.000
7 | 4.00 ± 0.93 | 0.596
| P = 0.500
250 | 3.71 ± 0.58 | 0.202
500 | 3.00 ± 0.31 | 0.245
| P = 0.409
Month 9
38 (Control) | 3.16 ± 0.43
3.5 | 8.82 ± 1.19 | 0.001
7 | 4.80 ± 1.15 | 0.013
| P = 0.001
250 | 3.13 ± 0.36 | 0.551
500 | 3.00 ± 0.21 | 0.638
| P = 0.663
Month 12
38 (Control) | 7.97 ± 1.36
3.5 | 17.32 ± 1.33 | 0.001
7 | 6.22 ± 2.15 | 0.642
| P = 0.005
250 | 7.32 ± 1.70 | 0.589
500 | 7.24 ± 1.07 | 0.677
| P = 0.647

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Recio et al.^293^.

^b^ Mean ± standard error. n = 5.

^c^ Pairwise comparison with the control group; exposed group values are significant at P ≤ 0.025 by Williams’ or Dunn’s test.

^d^ Exposure concentration-related trend; significant at P ≤ 0.025 by linear regression or Jonckheere’s test.

Table C-6 DNA Damage in the Colon of Rats Administered Varying Levels of Zinc in the Diet for 12 months^a^

Exposure Concentration (ppm) | Percent Tail DNA^b^ | P Value^c^
Male
38 (Control) | 12.54 ± 2.52
3.5 | 8.20 ± 0.70 | 0.066
7 | 7.03 ± 1.18 | 0.056
| P = 0.104^d^
250 | 14.84 ± 1.60 | 0.395
500 | 19.36 ± 1.17 | 0.026
| P = 0.019
Female
38 (Control) | 14.13 ± 0.99
3.5 | 4.47 ± 1.74 | 0.004
7 | 9.16 ± 1.01 | 0.154
| P = 0.001
250 | 13.45 ± 1.40 | 1.000
500 | 19.04 ± 0.81 | 0.009
| P = 0.017

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Recio et al.^293^.

^b^ Mean ± standard error. n = 5.

^c^ Pairwise comparison with the control group; exposed group values are significant at P ≤ 0.025 by Williams or Dunn’s test.

^d^ Exposure concentration-related trend; significant at P ≤ 0.025 by linear regression or Jonckheere’s test.