# Appendix B Summary of Lesions in Female Rats in the Two-year Feed Study of Dietary Zinc

Table B-1 Summary of the Incidence of Neoplasms in Female Rats in the Two-year Feed Study of Dietary Zinc^a^

| Control 38 ppm | 3.5 ppm | 7 ppm | 250 ppm | 500 ppm
Disposition Summary
Animals initially in study | 60 | 60 | 60 | 60 | 60
Special study animals | 9 | 10 | 9 | 9 | 9
Early deaths
Moribund | 21 | 11 | 12 | 19 | 14
Natural deaths | 5 | 7 | 5 | 5 | 6
Survivors
Terminal euthanasia | 25 | 32 | 34 | 27 | 31
Animals examined microscopically | 50 | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (49) | (50) | (50) | (49)
Intestine large, cecum | (50) | (49) | (50) | (49) | (48)
Intestine, large, colon | (50) | (49) | (50) | (50) | (49)
Intestine large, rectum | (50) | (50) | (50) | (50) | (49)
Intestine small, duodenum | (50) | (49) | (50) | (49) | (49)
Leiomyoma | – | – | 1 (2%) | 1 (2%) | –
Intestine small, ileum | (50) | (49) | (50) | (49) | (49)
Intestine small, jejunum | (50) | (49) | (50) | (49) | (49)
Liver | (50) | (50) | (50) | (50) | (50)
Cholangioma | 1 (2%) | – | 1 (2%) | – | –
Pancreas | (50) | (48) | (49) | (49) | (49)
Schwannoma malignant | – | – | – | – | 1 (2%)
Acinus, adenoma | 1 (2%) | – | – | – | –
Salivary glands | (50) | (49) | (50) | (48) | (49)
Stomach, forestomach | (50) | (50) | (50) | (50) | (49)
Stomach, glandular | (50) | (50) | (50) | (50) | (49)
Tooth | (1) | (1) | (0) | (6) | (0)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50) | (50)
Heart | (50) | (50) | (50) | (50) | (50)
Endocardium, schwannoma malignant | – | – | 1 (2%) | – | –
Myocardium, schwannoma malignant | – | 1 (2%) | – | – | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50) | (50)
Carcinoma | – | – | – | 1 (2%) | –
Adrenal medulla | (50) | (50) | (50) | (50) | (50)
Pheochromocytoma benign | – | – | 1 (2%) | 2 (4%) | –
Pheochromocytoma malignant | 1 (2%) | – | – | – | –
Islets, pancreatic | (50) | (50) | (50) | (49) | (49)
Adenoma | – | – | – | 1 (2%) | –
Parathyroid gland | (42) | (43) | (41) | (42) | (43)
Pituitary gland | (50) | (50) | (50) | (50) | (50)
Pars distalis, adenoma | 11 (22%) | 13 (26%) | 9 (18%) | 3 (6%) | 8 (16%)
Pars distalis, carcinoma | 1 (2%) | – | 1 (2%) | – | –
Thyroid gland | (50) | (49) | (50) | (50) | (48)
Bilateral, C-cell, adenoma | – | – | – | 1 (2%) | –
C-cell, adenoma | 1 (2%) | 2 (4%) | 1 (2%) | – | 3 (6%)
C-cell, carcinoma | 1 (2%) | – | – | 2 (4%) | –
General Body System
None | – | – | – | – | –
Genital System
Clitoral gland | (49) | (50) | (50) | (49) | (50)
Ovary | (50) | (50) | (50) | (50) | (49)
Granulosa cell tumor malignant | – | – | – | – | 1 (2%)
Uterus | (50) | (50) | (49) | (50) | (50)
Adenocarcinoma | 1 (2%) | – | 1 (2%) | – | 1 (2%)
Hemangioma | – | – | – | 1 (2%) | –
Leiomyoma | 1 (2%) | 1 (2%) | – | – | –
Polyp stromal | 3 (6%) | 2 (4%) | 1 (2%) | | 2 (4%)
Schwannoma malignant | – | 1 (2%) | – | – | –
Squamous cell carcinoma | – | – | 1 (2%) | – | –
Cervix, schwannoma malignant | – | – | – | – | 1 (2%)
Hematopoietic System
Bone marrow | (50) | (49) | (50) | (50) | (50)
Lymph node | (1) | (0) | (0) | (0) | (1)
Pancreatic, schwannoma malignant | | | | | 1 (100%)
Lymph node, mandibular | (50) | (49) | (49) | (48) | (48)
Lymph node, mesenteric | (50) | (49) | (50) | (50) | (49)
Hemangiosarcoma | – | – | – | – | 1 (2%)
Spleen | (50) | (50) | (50) | (50) | (49)
Thymus | (48) | (50) | (48) | (49) | (49)
Thymoma malignant | – | – | – | – | 1 (2%)
Integumentary System
Mammary gland | (50) | (50) | (50) | (50) | (50)
Adenocarcinoma | 4 (8%) | 4 (8%) | 4 (8%) | 2 (4%) | 4 (8%)
Adenocarcinoma, multiple | – | – | – | 2 (4%) | –
Adenoma | 3 (6%) | 2 (4%) | – | 3 (6%) | 1 (2%)
Fibroadenoma | 23 (46%) | 20 (40%) | 21 (42%) | 22 (44%) | 13 (26%)
Fibroadenoma, multiple | 6 (12%) | 11 (22%) | 12 (24%) | 9 (18%) | 14 (28%)
Fibrosarcoma | – | – | – | 1 (2%) | –
Schwannoma malignant | – | – | – | 1 (2%) | 1 (2%)
Skin | (50) | (50) | (50) | (50) | (50)
Sebaceous gland, adenoma | 1 (2%) | – | – | – | –
Subcutaneous tissue, fibroma | – | – | 1 (2%) | – | –
Subcutaneous tissue, schwannoma malignant | – | 1 (2%) | – | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50) | (50)
Carcinoma, metastatic, Zymbal’s gland | – | – | – | 1 (2%) | –
Nervous System
Brain | (50) | (50) | (50) | (50) | (50)
Cerebrum, oligodendroglioma malignant | 1 (2%) | – | – | – | –
Peripheral nerve | (0) | (0) | (0) | (1) | (1)
Spinal cord | (0) | (0) | (0) | (1) | (1)
Respiratory System
Lung | (50) | (50) | (50) | (50) | (50)
Adenocarcinoma, metastatic, mammary gland | – | – | 1 (2%) | – | –
Adenocarcinoma, metastatic, uterus | – | – | 1 (2%) | – | –
Carcinoma, metastatic, adrenal cortex | – | – | – | 1 (2%) | –
Carcinoma, metastatic, thyroid gland | 1 (2%) | – | – | – | –
Cystic keratinizing epithelioma | – | 1 (2%) | – | – | –
Squamous cell carcinoma, metastatic, uterus | – | – | 1 (2%) | – | –
Nose | (50) | (50) | (50) | (50) | (50)
Carcinoma, metastatic, Zymbal’s gland | – | – | – | 1 (2%) | –
Trachea | (50) | (50) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (49) | (50)
Harderian gland | (50) | (50) | (50) | (49) | (50)
Zymbal’s gland | (0) | (0) | (0) | (1) | (0)
Carcinoma | – | – | – | 1 (100%) | –
Urinary System
Kidney | (50) | (50) | (50) | (50) | (49)
Urinary bladder | (50) | (50) | (50) | (50) | (49)
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50) | (50)
Histiocytic sarcoma | 1 (2%) | – | – | – | 1 (2%)
Leukemia mononuclear | 1 (2%) | 1 (2%) | – | – | –
Lymphoma malignant | – | 1 (2%) | – | 1 (2%) | –
Neoplasm Summary
Total animals with primary neoplasms^c^ | 40 | 41 | 42 | 40 | 39
Total primary neoplasms | 62 | 61 | 56 | 54 | 54
Total animals with benign neoplasms | 35 | 39 | 39 | 34 | 32
Total benign neoplasms | 51 | 52 | 48 | 43 | 41
Total animals with malignant neoplasms | 11 | 8 | 8 | 11 | 11
Total malignant neoplasms | 11 | 9 | 8 | 11 | 13
Total animals with metastatic neoplasms | 1 | | 3 | 2
Total metastatic neoplasms | 1 | | 3 | 3

^a^ Number of core study animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table B-2 .Statistical Analysis of Primary Neoplasms in Female Rats in the Two-year Feed Study of Dietary Zinc

| Control 38 ppm | 3.5 ppm | 7 ppm | 250 ppm | 500 ppm
Mammary Gland: Fibroadenoma
Overall rate^a^ | 29/50 (58%) | 31/50 (62%) | 33/50 (66%) | 31/50 (62%) | 27/50 (54%)
Adjusted rate^b^ | 65.1% | 64.5% | 68.7% | 68.0% | 59.8%
Terminal rate^c^ | 14/25 (56%) | 16/32 (50%) | 22/34 (65%) | 15/27 (56%) | 15/31 (48%)
First incidence (days) | 435 | 323 | 447 | 179 | 396
Poly-3 test^d^ | P = 0.513N | P = 0.563N | P = 0.441 | – | –
Poly-3 test^e^ | P = 0.335N | – | – | P = 0.473 | P = 0.379N
Mammary Gland: Adenoma
Overall rate | 3/50 (6%) | 2/50 (4%) | 0/50 (0%) | 3/50 (6%) | 1/50 (2%)
Adjusted rate | 7.6% | 4.7% | 0.0% | 7.7% | 2.5%
Terminal rate | 3/25 (12%) | 1/32 (3%) | 0/34 (0%) | 3/27 (11%) | 1/31 3%)
First incidence (days) | 725 (T) | 659 | –^f^ | 725 (T) | 725 (T)
Poly-3 test | P = 0.384N | P = 0.468N | P = 0.099N | – | –
Poly-3 test | P = 0.229N | – | – | P = 0.659 | P = 0.296N
Mammary Gland: Fibroadenoma or Adenoma
Overall rate | 29/50 (58%) | 31/50 (62%) | 33/50 (66%) | 31/50 (62%) | 28/50 (56%)
Adjusted rate | 65.1% | 64.5% | 68.7% | 68.0% | 62.0%
Terminal rate | 14/25 (56%) | 16/32 (50%) | 22/34 (65%) | 15/27 (56%) | 16/31 (52%)
First incidence (days) | 435 | 323 | 447 | 179 | 396
Poly-3 test | P = 0.513N | P = 0.563N | P = 0.441 | – | –
Poly-3 test | P = 0.419N | – | – | P = 0.473 | P = 0.465N
Mammary Gland: Carcinoma
Overall rate | 4/50 (8%) | 4/50 (8%) | 4/50 (8%) | 4/50 (8%) | 4/50 (8%)
Adjusted rate | 9.8% | 9.4% | 8.9% | 10% | 9.9%
Terminal rate | 1/25 (4%) | 3/32 (3%) | 2/34 (6%) | 2/27 (7%) | 4/31 (13%)
First incidence (days) | 540 | 601 | 483 | 449 | 725 (T)
Poly-3 test | P = 0.553N | P = 0.623N | P = 0.589N | – | –
Poly-3 test | P = 0.566 | – | – | P = 0.632 | P = 0.637
Mammary Gland: Adenoma or Carcinoma
Overall rate | 7/50 (14%) | 6/50 (12%) | 4/50 (8%) | 7/50 (14%) | 5/50 (10%)
Adjusted rate | 17.1% | 14.0% | 8.9% | 17.5% | 12.4%
Terminal rate | 4/25 (16%) | 4/32 (13%) | 2/34 (6%) | 5/27 (19%) | 5/31 (16%)
First incidence (days) | 540 | 601 | 483 | 449 | 725 (T)
Poly-3 test | P = 0.413N | P = 0.465N | P = 0.206N | – | –
Poly-3 test | P = 0.333N | – | – | P = 0.598 | P = 0.387N
Mammary Gland: Fibroadenoma, Adenoma, or Carcinoma
Overall rate | 33/50 (66%) | 33/50 (66%) | 35/50 (70%) | 34/50 (68%) | 32/50 (64%)
Adjusted rate | 71.7% | 68.6% | 71.6% | 73.3% | 70.8%
Terminal rate | 15/25 (60%) | 18/32 (56%) | 22/34 (65%) | 17/27 (63%) | 20/31 (65%)
First incidence (days) | 435 | 323 | 447 | 179 | 396
Poly-3 test | P = 0.414N | P = 0.459N | P = 0.588N | – | –
Poly-3 test | P = 0.511N | – | – | P = 0.524 | P = 0.557N
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 11/50 (22%) | 13/50 (26%) | 9/50 (18%) | 3/50 (6%) | 8/50 (16%)
Adjusted rate | 27.1% | 30.2% | 19.8% | 7.6% | 19.1%
Terminal rate | 6/25 (24%) | 9/32 (28%) | 4/34 (12%) | 2/27 (7%) | 4/31 (13%)
First incidence (days) | 609 | 601 | 615 | 687 | 562
Poly-3 test | P = 0.408 | P = 0.472 | P = 0.293N | – | –
Poly-3 test | P = 0.217N | – | – | P = 0.020N | P = 0.273N
Pituitary Gland (Pars Distalis): Adenoma or Carcinoma
Overall rate | 12/50 (24%) | 13/50 (26%) | 10/50 (20%) | 3/50 (6%) | 8/50 (16%)
Adjusted rate | 29.6% | 30.2% | 21.8% | 7.6% | 19.1%
Terminal rate | 7/25 (28%) | 9/32 (28%) | 4/34 (12%) | 2/27 (7%) | 4/31 (13%)
First incidence (days) | 609 | 601 | 572 | 687 | 562
Poly-3 test | P = 0.510 | P = 0.571 | P = 0.280N | – | –
Poly-3 test | P = 0.144N | – | – | P = 0.011N | P = 0.195N
Thyroid Gland (C-Cell): Adenoma
Overall rate | 1/50 (2%) | 2/49 (4%) | 1/50 (2%) | 1/50 (2%) | 3/48 (6%)
Adjusted rate | 2.5% | 4.8% | 2.3% | 2.6% | 7.5%
Terminal rate | 1/25 (4%) | 2/32 (6%) | 0/34 (0%) | 0/27 (0%) | 1/31 (3%)
First incidence (days) | 725 (T) | 725 (T) | 676 | 687 | 610
Poly-3 test | P = 0.394 | P = 0.517 | P = 0.733N | – | –
Poly-3 test | P = 0.205 | – | – | P = 0.760 | P = 0.312
Thyroid Gland (C-Cell): Adenoma or Carcinoma
Overall rate | 2/50 (4%) | 2/49 (4%) | 1/50 (2%) | 3/50 (6%) | 3/48 (6%)
Adjusted rate | 5.1% | 4.8% | 2.3% | 7.5% | 7.5%
Terminal rate | 1/25 (4%) | 2/32 (6%) | 0/34 (0%) | 1/27 (4%) | 1/31 (3%)
First incidence (days) | 700 | 725 (T) | 676 | 568 | 610
Poly-3 test | P = 0.603N | P = 0.678N | P = 0.459N | – | –
Poly-3 test | P = 0.424 | – | – | P = 0.502 | P = 0.508
Uterus: Stromal Polyp
Overall rate | 3/50 (6%) | 2/50 (4%) | 1/50 (2%) | 0/50 (0%) | 2/50 (4%)
Adjusted rate | 7.5% | 4.8% | 2.2% | 0.0% | 4.9%
Terminal rate | 1/25 (4%) | 2/32 (6%) | 0/34 (0%) | 0/27 (0%) | 1/31 (3%)
First incidence (days) | 677 | 725 (T) | 663 | – | 635
Poly-3 test | P = 0.388N | P = 0.474N | P = 0.266N | – | –
Poly-3 test | P = 0.386N | – | – | P = 0.121N | P = 0.490N
All Organs: Benign Neoplasms
Overall rate | 35/50 (70%) | 39/50 (78%) | 39/50 (78%) | 34/50 (68%) | 32/50 (64%)
Adjusted rate | 77.1% | 81.1% | 79.9% | 73.7% | 69.6%
Terminal rate | 17/25 (68%) | 24/32 (75%) | 25/34 (74%) | 17/27 (63%) | 18/31 (58%)
First incidence (days) | 435 | 323 | 447 | 179 | 396
Poly-3 test | P = 0.362 | P = 0.408 | P = 0.464 | – | –
Poly-3 test | P = 0.239N | – | – | P = 0.446N | P = 0.278N
All Organs: Malignant Neoplasms
Overall rate | 11/50 (22%) | 8/50 (16%) | 8/50 (16%) | 11/50 (22%) | 11/50 (22%)
Adjusted rate | 26.1% | 18.1% | 17.3% | 25.8% | 26.2%
Terminal rate | 4/25 (16%) | 5/32 (16%) | 4/34 (12%) | 3/27 (11%) | 8/31 (26%)
First incidence (days) | 540 | 350 | 483 | 449 | 362
Poly-3 test | P = 0.226N | P = 0.264N | P = 0.231N | – | –
Poly-3 test | P = 0.541 | – | – | P = 0.589N | P = 0.590
All Organs: Benign or Malignant Neoplasms
Overall rate | 40/50 (80%) | 41/50 (82%) | 42/50 (84%) | 40/50 (80%) | 39/50 (78%)
Adjusted rate | 84.3% | 82.5% | 84.0% | 82.7% | 82.5%
Terminal rate | 18/25 (72%) | 24/32 (75%) | 26/34 (77%) | 19/27 (70%) | 23/31 (74%)
First incidence (days) | 435 | 323 | 447 | 179 | 362
Poly-3 test | P = 0.457N | P = 0.511N | P = 0.592N | – | –
Poly-3 test | P = 0.462N | – | – | P = 0.526N | P = 0.517N

T = Terminal euthanasia.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for pituitary gland and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal euthanasia.

^d^ Beneath the control incidence is the P value associated with the trend test between the control group and the deficient exposure groups. Beneath the deficient exposure group incidence are the P values corresponding to pairwise comparisons between the controls and that deficient exposure group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Beneath the control incidence is the P value associated with the trend test between the control group and the excess exposure groups. Beneath the excess exposure group incidence are the P values corresponding to pairwise comparisons between the controls and that excess exposure group. A negative trend or a lower incidence in an exposure group is indicated by N.

^f^ Not applicable; no neoplasms in animal group.

Table B-3 Summary of the Incidence of Nonneoplastic Lesions in Female Rats in the Two-year Feed Study of Dietary Zinc^a^

| Control 38 ppm | 3.5 ppm | 7 ppm | 250 ppm | 500 ppm
Disposition Summary
Animals initially in study | 60 | 60 | 60 | 60 | 60
Special study animals | 9 | 10 | 9 | 9 | 9
Early deaths
Moribund | 21 | 11 | 12 | 19 | 14
Natural deaths | 5 | 7 | 5 | 5 | 6
Survivors
Terminal euthanasia | 25 | 32 | 34 | 27 | 31
Animals examined microscopically | 50 | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (49) | (50) | (50) | (49)
Intestine large, cecum | (50) | (49) | (50) | (49) | (48)
Intestine, large, colon | (50) | (49) | (50) | (50) | (49)
Parasite, metazoan | – | – | – | 1 (2%) | 1 (2%)
Intestine large, rectum | (50) | (50) | (50) | (50) | (49)
Intestine small, duodenum | (50) | (49) | (50) | (49) | (49)
Intestine small, ileum | (50) | (49) | (50) | (49) | (49)
Intestine small, jejunum | (50) | (49) | (50) | (49) | (49)
Liver | (50) | (50) | (50) | (50) | (50)
Angiectasis | – | 2 (4%) | 3 (6%) | 1 (2%) | 1 (2%)
Basophilic focus | 1 (2%) | – | – | – | 1 (2%)
Clear cell focus | 2 (4%) | 2 (4%) | 7 (14%) | 5 (10%) | 5 (10%)
Developmental malformation | – | 1 (2%) | – | – | –
Eosinophilic focus | – | 1 (2%) | 3 (6%) | 1 (2%) | 2 (4%)
Fatty change | 6 (12%) | 4 (8%) | 11 (22%) | 4 (8%) | 3 (6%)
Hematopoietic cell proliferation | 1 (2%) | 2 (4%) | – | – | –
Hepatodiaphragmatic nodule | 1 (2%) | – | – | – | –
Inflammation | 1 (2%) | – | – | – | –
Mixed cell focus | – | 1 (2%) | 2 (4%) | 4 (8%) | –
Bile duct, cyst | – | 1 (2%) | – | – | –
Bile duct, hyperplasia | – | 2 (4%) | – | – | –
Hepatocyte, hypertrophy | – | – | – | 1 (2%) | 1 (2%)
Hepatocyte, inclusion body intracytoplasmic | – | 1 (2%) | – | – | –
Hepatocyte, necrosis | – | 1 (2%) | 2 (4%) | – | 1 (2%)
Hepatocyte, vacuolization cytoplasmic | 1 (2%) | 1 (2%) | – | 2 (4%) | –
Pancreas | (50) | (48) | (49) | (49) | (49)
Thrombosis | – | 1 (2%) | – | – | –
Acinus, atrophy | 2 (4%) | 4 (8%) | 2 (4%) | 5 (10%) | 10 (20%)
Acinus, basophilic focus | – | – | 2 (4%) | – | –
Acinus, depletion secretory | – | – | – | – | 1 (2%)
Acinus, hyperplasia | 2 (4%) | 1 (2%) | 5 (10%) | – | 1 (2%)
Duct, hyperplasia, cystic | – | 1 (2%) | – | – | 1 (2%)
Salivary glands | (50) | (49) | (50) | (48) | (49)
Stomach, forestomach | (50) | (50) | (50) | (50) | (49)
Edema | 1 (2%) | – | – | – | –
Inflammation | – | – | – | 1 (2%) | –
Ulcer | 1 (2%) | 1 (2%) | | 1 (2%) | 1 (2%)
Epithelium, hyperplasia | 5 (10%) | 8 (16%) | 4 (8%) | 2 (4%) | 4 (8%)
Stomach, glandular | (50) | (50) | (50) | (50) | (49)
Erosion | 1 (2%) | – | – | – | –
Tooth | (1) | (1) | (0) | (6) | (0)
Inflammation | – | – | – | 3 (50%) | –
Malformation | – | 1 (100%) | – | – | –
Necrosis | 1 (100%) | – | – | 3 (50%) | –
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50) | (50)
Inflammation | 1 (2%) | 1 (2%) | – | 1 (2%) | 1 (2%)
Heart | (50) | (50) | (50) | (50) | (50)
Cardiomyopathy | 7 (14%) | 10 (20%) | 4 (8%) | 8 (16%) | 6 (12%)
Endocardium, fibrosis | 1 (2%) | – | – | – | –
Endocardium, hyperplasia | – | – | 1 (2%) | 1 (2%) | –
Myocardium, inflammation, chronic active | 1 (2%) | – | – | – | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50) | (50)
Degeneration, cystic | 3 (6%) | 4 (8%) | 1 (2%) | 1 (2%) | 2 (4%)
Hyperplasia | 6 (12%) | 5 (10%) | 5 (10%) | 4 (8%) | 5 (10%)
Necrosis | 1 (2%) | – | – | – | 1 (2%)
Thrombosis | – | – | 1 (2%) | 2 (4%) | –
Adrenal medulla | (50) | (50) | (50) | (50) | (50)
Hyperplasia | 6 (12%) | 4 (8%) | 3 (6%) | 3 (6%) | 2 (4%)
Islets, pancreatic | (50) | (50) | (50) | (49) | (49)
Hyperplasia | – | – | 1 (2%) | – | –
Parathyroid gland | (42) | (43) | (41) | (42) | (43)
Hyperplasia | – | 1 (2%) | – | – | –
Pituitary gland | (50) | (50) | (50) | (50) | (50)
Angiectasis | 1 (2%) | – | – | – | –
Hemorrhage | – | – | – | 1 (2%) | –
Pars distalis, angiectasis | – | 1 (2%) | – | 1 (2%) | –
Pars distalis, hyperplasia | 15 (30%) | 15 (30%) | 22 (44%) | 13 (26%) | 17 (34%)
Thyroid gland | (50) | (49) | (50) | (50) | (48)
C-cell, hyperplasia | 18 (36%) | 14 (29%) | 9 (18%) | 14 (28%) | 5 (10%)
General Body System
None | – | – | – | – | –
Genital System
Clitoral gland | (49) | (50) | (50) | (49) | (50)
Cyst | – | – | 1 (2%) | – | –
Hyperplasia | – | – | – | 1 (2%) | –
Ovary | (50) | (50) | (50) | (50) | (49)
Atrophy | 31 (62%) | 29 (58%) | 30 (60%) | 29 (58%) | 26 (53%)
Cyst | 12 (24%) | 8 (16%) | 5 (10%) | 11 (22%) | 4 (8%)
Inflammation | 1 (2%) | – | – | – | –
Bilateral, cyst | – | – | 2 (4%) | – | –
Granulosa cell, hyperplasia | 1 (2%) | – | 1 (2%) | – | –
Interstitial cell, hyperplasia | – | 2 (4%) | – | – | 1 (2%)
Uterus | (50) | (50) | (49) | (50) | (50)
Cyst | – | 1 (2%) | – | – | –
Hemorrhage | – | – | – | – | 1 (2%)
Inflammation | 1 (2%) | 1 (2%) | – | 1 (2%) | –
Metaplasia, squamous | 21 (42%) | 19 (38%) | 18 (37%) | 15 (30%) | 20 (40%)
Pigmentation, hemosiderin | 2 (4%) | – | – | – | –
Polyp, inflammatory | – | – | 1 (2%) | – | –
Thrombosis | 1 (2%) | – | – | – | –
Cervix, adenomyosis | – | – | – | 1 (2%) | –
Cervix, hypertrophy | 1 (2%) | – | – | – | –
Endometrium, hyperplasia, cystic | 9 (18%) | 13 (26%) | 5 (10%) | 7 (14%) | 7 (14%)
Hematopoietic System
Bone marrow | (50) | (49) | (50) | (50) | (50)
Atrophy | 1 (2%) | – | 1 (2%) | 2 (4%) | –
Hyperplasia | 14 (28%) | 10 (20%) | 9 (18%) | 14 (28%) | 18 (36%)
Lymph node | (1) | (0) | (0) | (0) | (1)
Mediastinal, hemorrhage | 1 (100%) | – | – | – | –
Lymph node, mandibular | (50) | (49) | (49) | (48) | (48)
Atrophy | – | 2 (4%) | 1 (2%) | 1 (2%) | –
Hyperplasia | 8 (16%) | 12 (24%) | 8 (16%) | 8 (17%) | 6 (13%)
Infiltration, cellular, plasma cell | 15 (30%) | 18 (37%) | 8 (16%) | 14 (29%) | 10 (21%)
Lymph node, mesenteric | (50) | (49) | (50) | (50) | (49)
Atrophy | – | 1 (2%) | 1 (2%) | – | –
Hyperplasia | 1 (2%) | 1 (2%) | – | – | 1 (2%)
Infiltration, cellular, plasma cell | 1 (2%) | 3 (6%) | 2 (4%) | – | 3 (6%)
Spleen | (50) | (50) | (50) | (50) | (49)
Hematopoietic cell proliferation | 25 (50%) | 28 (56%) | 31 (62%) | 39 (78%) | 34 (69%)
Hemorrhage | 1 (2%) | – | – | – | –
Inflammation | – | 1 (2%) | – | – | –
Pigmentation, hemosiderin | 39 (78%) | 38 (76%) | 43 (86%) | 42 (84%) | 33 (67%)
Lymphoid follicle, atrophy | 1 (2%) | 2 (4%) | 1 (2%) | 3 (6%) | –
Lymphoid follicle, hyperplasia | 11 (22%) | 9 (18%) | 7 (14%) | 7 (14%) | 8 (16%)
Thymus | (48) | (50) | (48) | (49) | (49)
Atrophy | 35 (73%) | 34 (68%) | 31 (65%) | 32 (65%) | 33 (67%)
Hyperplasia | – | – | 1 (2%) | – | –
Epithelial cell, hyperplasia | – | 1 (2%) | – | – | –
Integumentary System
Mammary gland | (50) | (50) | (50) | (50) | (50)
Cyst | – | – | 1 (2%) | – | –
Hyperplasia | 2 (4%) | 5 (10%) | 2 (4%) | 2 (4%) | 2 (4%)
Skin | (50) | (50) | (50) | (50) | (50)
Inflammation | – | 1 (2%) | – | – | –
Ulcer | – | – | – | – | 1 (2%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (50) | (50)
Osteopetrosis | – | – | – | 1 (2%) | –
Joint, degeneration | – | – | – | 1 (2%) | –
Maxilla, fibrosis | – | – | – | 2 (4%) | –
Nervous System
Brain | (50) | (50) | (50) | (50) | (50)
Hemorrhage | 1 (2%) | 1 (2%) | – | – | –
Hydrocephalus | – | – | – | – | 1 (2%)
Cerebrum, gliosis | 1 (2%) | – | – | – | –
Glial cell, hyperplasia | 1 (2%) | – | – | – | –
Peripheral nerve | (0) | (0) | (0) | (1) | (1)
Spinal cord | (0) | (0) | (0) | (1) | (1)
Axon, degeneration | – | – | – | 1 (100%) | 1 (100%)
Respiratory System
Lung | (50) | (50) | (50) | (50) | (50)
Cyst, squamous | – | – | – | 1 (2%) | –
Infiltration cellular, histiocyte | 37 (74%) | 38 (76%) | 40 (80%) | 38 (76%) | 35 (70%)
Inflammation | – | 1 (2%) | – | – | 1 (2%)
Metaplasia, squamous | – | – | – | – | 1 (2%)
Alveolar epithelium, hyperplasia | 1 (2%) | – | – | 1 (2%) | 1 (2%)
Nose | (50) | (50) | (50) | (50) | (50)
Inflammation | 1 (2%) | 2 (4%) | – | 2 (4%) | 4 (8%)
Metaplasia, squamous | – | – | – | – | 1 (2%)
Respiratory epithelium, hyperplasia | – | – | 1 (2%) | – | –
Trachea | (50) | (50) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (49) | (50)
Cataract | – | 1 (2%) | – | – | –
Harderian gland | (50) | (50) | (50) | (49) | (50)
Hyperplasia | – | – | – | 1 (2%) | –
Zymbal’s gland | (0) | (0) | (0) | (1) | (0)
Urinary System
Kidney | (50) | (50) | (50) | (50) | (49)
Cyst | 2 (4%) | – | – | – | –
Hydronephrosis | 1 (2%) | – | – | – | –
Infarct, chronic | – | 1 (2%) | – | – | –
Mineralization | – | 1 (2%) | – | – | 2 (4%)
Nephropathy | 27 (54%) | 28 (56%) | 21 (42%) | 31 (62%) | 29 (59%)
Bilateral, papilla, inflammation, acute | – | – | – | 1 (2%) | –
Cortex, inflammation, chronic active | 1 (2%) | – | – | – | –
Pelvis, inflammation | – | – | – | 1 (2%) | –
Pelvis, inflammation, acute | – | – | – | 1 (2%) | –
Urinary bladder | (50) | (50) | (50) | (50) | (49)
Inflammation | – | – | – | 1 (2%) | –

^a^ Number of core study animals examined microscopically at the site and the number of animals with lesion.