# Appendix A Summary of Lesions in Male Rats in the Two-year Feed Study of Dietary Zinc

Table A-1 Summary of the Incidence of Neoplasms in Male Rats in the Two-year Feed Study of Dietary Zinc^a^

| Control 38 ppm | 3.5 ppm | 7 ppm | 250 ppm | 500 ppm
Disposition Summary
Animals initially in study | 60 | 60 | 60 | 60 | 60
Early deaths
Special study animals | 10 | 10 | 9 | 10 | 10
Moribund | 11 | 12 | 10 | 15 | 7
Natural deaths | 19 | 7 | 13 | 14 | 22
Survivors
Died last week of study | 2 | – | 1 | – | 1
Terminal euthanasia | 18 | 31 | 27 | 21 | 20
Animals examined microscopically | 50 | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50) | (50)
Intestine large, cecum | (50) | (50) | (50) | (50) | (47)
Intestine, large, colon | (49) | (50) | (49) | (50) | (48)
Intestine large, rectum | (50) | (50) | (50) | (50) | (48)
Adenocarcinoma | – | – | 1 (2%) | – | –
Intestine small, duodenum | (50) | (49) | (50) | (49) | (48)
Adenocarcinoma | 1 (2%) | – | – | – | –
Intestine small, ileum | (50) | (49) | (48) | (50) | (45)
Intestine small, jejunum | (50) | (49) | (50) | (50) | (47)
Adenocarcinoma | 1 (2%) | – | 1 (2%) | 1 (2%) | 3 (6%)
Schwannoma malignant, metastatic, skin | – | – | 1 (2%) | – | –
Liver | (50) | (50) | (50) | (50) | (46)
Pheochromocytoma malignant, metastatic, adrenal medulla | – | – | – | 1 (2%) | –
Mesentery | (0) | (1) | (0) | (0) | (0)
Paraganglioma | – | 1 (100%) | – | – | –
Oral mucosa | (1) | (0) | (2) | (1) | (1)
Squamous cell carcinoma | – | – | – | 1 (100%) | –
Pancreas | (49) | (50) | (48) | (48) | (48)
Schwannoma malignant, metastatic, skin | – | – | 1 (2%) | – | –
Acinus, adenoma | 6 (12%) | 8 (16%) | 9 (19%) | 5 (10%) | 6 (13%)
Acinus, adenoma, multiple | 5 (10%) | 13 (26%) | 10 (21%) | 8 (17%) | 4 (8%)
Acinus, carcinoma | 1 (2%) | – | – | – | –
Salivary glands | (49) | (50) | (50) | (50) | (49)
Stomach, forestomach | (50) | (50) | (50) | (50) | (49)
Squamous cell carcinoma | – | 2 (4%) | – | – | –
Stomach, glandular | (50) | (50) | (50) | (50) | (49)
Tongue | (0) | (0) | (0) | (0) | (1)
Tooth | (3) | (0) | (1) | (0) | (2)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50) | (50)
Schwannoma malignant, metastatic, skin | – | – | 1 (2%) | – | –
Heart | (50) | (50) | (50) | (50) | (50)
Schwannoma malignant, metastatic, skin | – | – | 1 (2%) | – | –
Endocardium, schwannoma malignant | – | 1 (2%) | 2 (4%) | 1 (2%) | –
Epicardium, paraganglioma | – | 1 (2%) | – | – | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50) | (50)
Adrenal medulla | (50) | (50) | (50) | (50) | (50)
Pheochromocytoma benign | 5 (10%) | 3 (6%) | 8 (16%) | 10 (20%) | 3 (6%)
Pheochromocytoma complex | – | 1 (2%) | – | – | –
Pheochromocytoma malignant | 1 (2%) | – | – | 1 (2%) | 3 (6%)
Bilateral, pheochromocytoma benign | – | – | 2 (4%) | – | –
Bilateral, pheochromocytoma malignant | – | 1 (2%) | 1 (2%) | – | –
Islets, pancreatic | (50) | (50) | (50) | (49) | (49)
Adenoma | 2 (4%) | 6 (12%) | 2 (4%) | 2 (4%) | 2 (4%)
Carcinoma | 1 (2%) | – | 1 (2%) | 1 (2%) | 1 (2%)
Parathyroid gland | (47) | (41) | (44) | (40) | (42)
Pituitary gland | (50) | (50) | (50) | (50) | (49)
Schwannoma malignant, metastatic, peripheral nerve | 1 (2%) | – | – | – | –
Pars distalis, adenoma | 2 (4%) | 8 (16%) | 4 (8%) | 7 (14%) | 6 (12%)
Pars distalis, carcinoma | 1 (2%) | – | – | – | –
Pars intermedia, adenoma | – | – | 2 (4%) | – | –
Pars intermedia, carcinoma | 1 (2%) | – | – | – | –
Thyroid gland | (50) | (50) | (50) | (50) | (49)
Bilateral, C-cell, adenoma | – | – | 1 (2%) | – | –
Bilateral, C-cell, carcinoma | 1 (2%) | – | – | – | –
C-cell, adenoma | 2 (4%) | 5 (10%) | – | 2 (4%) | 2 (4%)
C-cell, carcinoma | – | 2 (4%) | 3 (6%) | 2 (4%) | 1 (2%)
General Body System
None | – | – | – | – | –
Genital System
Epididymis | (50) | (50) | (50) | (50) | (50)
Penis | (0) | (0) | (1) | (0) | (0)
Preputial gland | (50) | (50) | (50) | (50) | (50)
Carcinoma | – | – | – | 1 (2%) | –
Prostate | (50) | (50) | (50) | (50) | (50)
Seminal vesicle | (50) | (50) | (50) | (50) | (50)
Testes | (50) | (50) | (50) | (50) | (50)
Interstitial cell, adenoma | – | 2 (4%) | – | – | –
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50) | (50)
Lymph node | (6) | (1) | (4) | (3) | (2)
Lymph node, mandibular | (49) | (50) | (50) | (50) | (48)
Lymph node, mesenteric | (50) | (50) | (49) | (50) | (49)
Schwannoma malignant, metastatic, skin | – | – | 1 (2%) | – | –
Spleen | (50) | (50) | (49) | (48) | (45)
Thymus | (47) | (49) | (50) | (47) | (58)
Schwannoma malignant, metastatic, skin | – | – | 1 (2%) | – | –
Integumentary System
Mammary gland | (50) | (49) | (50) | (48) | (49)
Fibroadenoma | 3 (6%) | 3 (6%) | – | 1 (2%) | 1 (2%)
Fibroma | – | – | 2 (4%) | 1 (2%) | 1 (2%)
Schwannoma malignant | – | 1 (2%) | 1 (2%) | – | –
Skin | (50) | (50) | (50) | (50) | (50)
Basal cell adenoma | – | – | – | 1 (2%) | –
Basal cell carcinoma | 1 (2%) | – | 1 (2%) | – | 1 (2%)
Keratoacanthoma | 3(6%) | – | 2 (4%) | – | 1 (2%)
Schwannoma malignant | – | – | 1 (2%) | – | –
Schwannoma malignant, metastatic, peripheral nerve | 1 (2%) | – | – | – | –
Squamous cell carcinoma | – | – | – | – | 1 (2%)
Trichoepithelioma | 1 (2%) | – | – | – | –
Head, neural crest tumor | 1 (2%) | – | – | – | –
Sebaceous gland, adenoma | – | – | 1 (2%) | – | –
Subcutaneous tissue, carcinoma, metastatic, thyroid gland | – | – | 1 (2%) | – | –
Subcutaneous tissue, fibroma | 2 (4%) | 4 (8%) | 3 (6%) | 1 (2%) | –
Subcutaneous tissue, ibrosarcoma | 1 (2%) | 1 (2%) | – | – | –
Subcutaneous tissue, fibrosarcoma, multiple | – | 1 (2%) | – | – | –
Subcutaneous tissue, hemangioma | 1 (2%) | – | – | – | –
Subcutaneous tissue, hemangiosarcoma | 1 (2%) | – | – | – | –
Subcutaneous tissue, lipoma | – | 2 (4%) | – | 1 (2%) | 1 (2%)
Subcutaneous tissue, schwannoma malignant | – | – | – | 1 (2%) | –
Tail, papilloma | – | – | 1 (2%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50) | (50)
Cranium, schwannoma malignant, metastatic, peripheral nerve | 1 (2%) | – | – | – | –
Femur, osteosarcoma | – | – | – | – | 1 (2%)
Humerus, osteosarcoma | – | – | – | 1 (2%) | –
Skeletal muscle | (0) | (0) | (1) | (2) | (0)
Rhabdomyosarcoma | – | – | – | 1 (50%) | –
Schwannoma malignant | – | – | 1 (100%) | 1 (50%) | –
Nervous System
Brain | (48) | (50) | (50) | (50) | (50)
Granular cell tumor malignant | – | – | – | 1 (2%) | –
Schwannoma malignant, metastatic, peripheral nerve | 1 (2%) | – | – | – | –
Cerebrum, astrocytoma malignant | – | 1 (2%) | – | – | –
Cerebrum, meningioma malignant | – | – | – | 1 (2%) | –
Cerebrum, oligodendroglioma malignant | – | 1 (2%) | – | 1 (2%) | –
Peripheral nerve | (1) | (1) | (1) | (1) | (0)
Schwannoma malignant | 1 (100%) | – | – | – | –
Spinal cord | (0) | (1) | (1) | (1) | (0)
Respiratory System
Lung | (50) | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | – | 1 (2%) | – | – | –
Carcinoma, metastatic, thyroid gland | – | – | 1 (2%) | – | –
Cystic keratinizing epithelioma | – | – | 1 (2%) | – | –
Neuroblastoma, metastatic, nose | – | – | 1 (2%) | – | –
Osteosarcoma, metastatic, bone | – | – | – | – | 1 (2%)
Schwannoma malignant, metastatic, skin | – | – | 1 (2%) | – | –
Nose | (50) | (50) | (50) | (50) | (49)
Schwannoma malignant, metastatic, peripheral nerve | 1 (2%) | – | – | – | –
Olfactory epithelium, neuroblastoma | – | – | 1 (2%) | – | –
Trachea | (50) | (50) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (49) | (50) | (50) | (49)
Optic nerve, schwannoma malignant | – | – | – | 1 (2%) | –
Harderian gland | (50) | (49) | (50) | (50) | (49)
Schwannoma malignant, metastatic, peripheral nerve | 1 (2%) | – | – | – | –
Zymbal’s gland | (1) | (0) | (0) | (0) | (0)
Carcinoma | 1 (100%) | – | – | – | –
Urinary System
Kidney | (50) | (50) | (50) | (50) | (50)
Schwannoma malignant, metastatic, skin | – | – | 1 (2%) | – | –
Renal tubule, adenoma | – | – | – | 1 (2%) | 1 (2%)
Urinary bladder | (50) | (50) | (50) | (50) | (49)
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50) | (50)
Histiocytic sarcoma | 1 (2%) | – | – | – | –
Leukemia mononuclear | 1 (2%) | 2 (4%) | – | 1 (2%) | 1 (2%)
Lymphoma malignant | 1 (2%) | 1 (2%) | 1 (2%) | 3 (6%) | –
Mesothelioma malignant | 1 (2%) | – | – | – | –
Neoplasm Summary
Total animals with primary neoplasms^c^ | 32 | 38 | 39 | 35 | 28
Total primary neoplasms | 50 | 72 | 63 | 60 | 40
Total animals with benign neoplasms | 22 | 36 | 36 | 29 | 22
Total benign neoplasms | 32 | 57 | 48 | 40 | 28
Total animals with malignant neoplasms | 16 | 15 | 14 | 17 | 12
Total malignant neoplasms | 17 | 15 | 15 | 20 | 12
Total animals with metastatic neoplasms | 1 | – | 4 | 1 | 1
Total metastatic neoplasms | 6 | – | 11 | 1 | 1
Total animals with uncertain neoplasms—benign or malignant | 1 | – | – | – | –
Total uncertain neoplasms | 1 | – | – | – | –

^a^ Number of core study animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table A-2 Statistical Analysis of Primary Neoplasms in Male Rats in the Two-year Feed Study of Dietary Zinc

| Control 38 ppm | 3.5 ppm | 7 ppm | 250 ppm | 500 ppm
Adrenal Medulla: Benign Pheochromocytoma
Overall rate^a^ | 5/50 (10%) | 3/50 (6%) | 10/50 (20%) | 10/50 (20%) | 3/50 (6%)
Adjusted rate^b^ | 12.8% | 6.9% | 23.7% | 25.0% | 7.6%
Terminal rate^c^ | 2/18 (11%) | 3/31 (10%) | 6/27 (22%) | 6/21 (29%) | 2/20 (10%)
First incidence (days) | 652 | 734 (T) | 659 | 363 | 715
Poly-3 test^d^ | P = 0.230N | P = 0.298N | P = 0.160 | – | –
Poly-3 test^e^ | P = 0.311N | – | – | P = 0.133 | P = 0.351N
Adrenal Medulla: Malignant Pheochromocytoma
Overall rate | 1/50 (2%) | 1/50 (2%) | 1/50 (2%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 2.6% | 2.3% | 2.4% | 2.6% | 7.6%
Terminal rate | 1/18 (6%) | 1/31 (3%) | 1/27 (4%) | 0/21 (0%) | 1/20 (5%)
First incidence (days) | 734 (T) | 734 (T) | 734 (T) | 713 | 669
Poly-3 test | –^f^ | – | – | – | –
Poly-3 test | P = 0.209 | – | – | P = 0.760N | P = 0.315
Adrenal Medulla: Benign, Complex, or Malignant Pheochromocytoma
Overall rate | 6/50 (12%) | 5/50 (10%) | 11/50 (22%) | 11/50 (22%) | 5/50 (10%)
Adjusted rate | 15.4% | 11.5% | 26.1% | 27.5% | 12.6%
Terminal rate | 3/18 (17%) | 5/31 (16%) | 7/27 (26%) | 6/21 (29%) | 2/20 (10%)
First incidence (days) | 652 | 734 (T) | 659 | 363 | 669
Poly-3 test | P = 0.336N | P = 0.424N | P = 0.177 | – | –
Poly-3 test | P = 0.427N | – | – | P = 0.146 | P = 0.490N
Small Intestine (Jejunum): Carcinoma
Overall rate | 1/50 (2%) | 0/50 (0%) | 1/50 (2%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 2.6% | 0.0% | 2.4% | 2.6% | 7.6%
Terminal rate | 0/18 (0%) | 0/31 (0%) | 0/27 (0%) | 0/21 (0%) | 0/20 (0%)
First incidence (days) | 586 | –^g^ | 670 | 680 | 715
Poly-3 test | – | – | – | – | –
Poly-3 test | P = 0.204 | – | – | P = 0.760 | P = 0.309
Small Intestine (Duodenum or Jejunum): Carcinoma
Overall rate | 2/50 (4%) | 0/50 (0%) | 1/50 (2%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 5.1% | 0.0% | 2.4% | 2.6% | 7.6%
Terminal rate | 1/18 (6%) | 0/31 (0%) | 0/27 (0%) | 0/21 (0%) | 0/20 (0%)
First incidence (days) | 586 | – | 670 | 680 | 715
Poly-3 test | P = 0.129N | P = 0.213N | P = 0.475N | – | –
Poly-3 test | P = 0.404 | – | – | P = 0.502N | P = 0.506
Mammary Gland: Fibroadenoma
Overall rate | 3/50 (6%) | 3/50 (6%) | 0/50 (0%) | 1/50 (2%) | 1/50 (2%)
Adjusted rate | 7.7% | 6.9% | 0% | 2.6% | 2.5%
Terminal rate | 0/18 (0%) | 1/31 (3%) | 0/27 (0%) | 1/21 (5%) | 0/20 (0%)
First incidence (days) | 638 | 698 | – | 734 (T) | 541
Poly-3 test | P = 0.585N | P = 0.611N | P = 0.108N | – | –
Poly-3 test | P = 198N | – | – | P = 0.310N | P = 0.298N
Mammary Gland: Fibroma or Fibroadenoma
Overall rate | 3/50 (6%) | 3/50 (6%) | 2/50 (4%) | 2/50 (4%) | 2/50 (4%)
Adjusted rate | 7.7% | 6.9% | 4.8% | 5.2% | 5.0%
Terminal rate | 0/18 (0%) | 1/31 (3%) | 1/27 (4%) | 2/21 (10%) | 1/20 (5%)
First incidence (days) | 638 | 698 | 660 | 734 (T) | 541
Poly-3 test | P = 0.548N | P = 0.611N | P = 0.471N | – | –
Poly-3 test | P = 0.400N | – | – | P = 0.508N | P = 0.492N
Pancreas: Adenoma
Overall rate | 11/49 (22%)^h^ | 21/50 (42%) | 19/48 (40%) | 13/48 (27%) | 10/48 (21%)
Adjusted rate | 28.4% | 46.5% | 46.5% | 34.7% | 26.1%
Terminal rate | 8/18 (44%) | 14/31 (45%) | 16/27 (59%) | 11/21 (52%) | 9/20 (45%)
First incidence (days) | 652 | 467 | 701 | 648 | 729
Poly-3 test | P = 0.064 | P = 0.065 | P = 0.069 | – | –
Poly-3 test | P = 0.462N | – | – | P = 0.363 | P = 0.512N
Pancreatic Islets: Adenoma
Overall rate | 2/50 (4%) | 6/50 (12%) | 2/50 (4%) | 2/49 (4%) | 2/49 (4%)
Adjusted rate | 5.2% | 13.7% | 4.8% | 5.2% | 5.1%
Terminal rate | 2/18 (11%) | 5/31 (16%) | 1/27 (4%) | 1/21 (5%) | 1/20 (5%)
First incidence (days) | 734 (T) | 663 | 641 | 551 | 717
Poly-3 test | P = 0.103 | P = 0.178 | P = 0.663N | – | –
Poly-3 test | P = 0.594N | – | – | P = 0.694 | P = 0.688N
Pancreatic Islets: Adenoma or Carcinoma
Overall rate | 3/50 (6%) | 6/50 (12%) | 3/50 (6%) | 3/49 (6%) | 3/49 (6%)
Adjusted rate | 7.8% | 13.7% | 7.2% | 7.8% | 7.7%
Terminal rate | 2/18 (11%) | 5/31 (16%) | 2/27 (7%) | 1/21 (5%) | 2/20 (10%)
First incidence (days) | 656 | 663 | 641 | 551 | 717
Poly-3 test | P = 0.224 | P = 0.306 | P = 0.627N | – | –
Poly-3 test | P = 0.578N | – | – | P = 0.660 | P = 0.658N
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 2/50 (4%) | 8/50 (16%) | 4/50 (8%) | 7/50 (14%) | 6/49 (12%)
Adjusted rate | 5.2% | 18.3% | 9.2% | 17.7% | 15.2%
Terminal rate | 1/18 (6%) | 7/31 (23%) | 1/27 (4%) | 2/21 (10%) | 2/20 (10%)
First incidence (days) | 673 | 687 | 406 | 461 | 645
Poly-3 test | P = 0.042 | P = 0.067 | P = 0.391 | – | –
Poly-3 test | P = 0.128 | – | – | P = 0.082 | P = 0.138
Pituitary Gland (Pars Distalis): Adenoma or Carcinoma
Overall rate | 3/50 (6%) | 8/50 (16%) | 4/50 (8%) | 7/50 (14%) | 6/49 (12%)
Adjusted rate | 7.6% | 18.3% | 9.2% | 17.7% | 15.2%
Terminal rate | 1/18 (6%) | 7/31 (23%) | 1/27 (4%) | 2/21 (10%) | 2/20 (10%)
First incidence (days) | 488 | 687 | 406 | 461 | 645
Poly-3 test | P = 0.087 | P = 0.133 | P = 0.552 | – | –
Poly-3 test | P = 0.209 | – | – | P = 0.156 | P = 0.242
Skin: Keratoacanthoma
Overall rate | 3/50 (6%) | 0/50 (0%) | 2/50 (4%) | 0/50 (0%) | 1/50 (2%)
Adjusted rate | 7.8% | 0.0% | 4.8% | 0.0% | 2.5%
Terminal rate | 2/18 (11%) | 0/31 (0%) | 2/27 (7%) | 0/21 (0%) | 0/20 (0%)
First incidence (days) | 701 | – | 734 (T) | – | 707
Poly-3 test | P = 0.066N | P = 0.098N | P = 0.466N | – | –
Poly-3 test | P = 0.172N | – | – | P = 0.118N | P = 0.296N
Skin: Keratoacanthoma or Squamous Cell Carcinoma
Overall rate | 3/50 (6%) | 0/50 (0%) | 2/50 (4%) | 0/50 (0%) | 2/50 (4%)
Adjusted rate | 7.8% | 0.0% | 4.8% | 0.0% | 5.0%
Terminal rate | 2/18 (11%) | 0/31 (0%) | 2/27 (7%) | 0/21 (0%) | 0/20 (0%)
First incidence (days) | 701 | – | 734 (T) | – | 649
Poly-3 test | P = 0.066N | P = 0.098N | P = 0.466N | – | –
Poly-3 test | P = 0.386N | – | – | P = 0.118N | P = 0.487N
Skin: Keratoacanthoma, Trichoepithelioma, Basal Cell Adenoma, Basal Cell Carcinoma, or Squamous Cell Carcinoma
Overall rate | 5/50 (10%) | 0/50 (0%) | 3/50 (6%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 12.8% | 0.0% | 7.2% | 2.6% | 7.5%
Terminal rate | 3/18 (17%) | 0/31 (0%) | 3/27 (11%) | 0/21 (0%) | 0/20 (0%)
First incidence (days) | 586 | – | 734 (T) | 713 | 649
Poly-3 test | P = 0.015N | P = 0.022N | P = 0.321N | – | –
Poly-3 test | P = 0.255N | – | – | P = 0.102N | P = 0.342N
Skin (Subcutaneous Tissue): Fibroma
Overall rate | 2/50 (4%) | 4/50 (8%) | 3/50 (6%) | 1/50 (2%) | 0/50 (0%)
Adjusted rate | 5.2% | 9.0% | 7.2% | 2.6% | 0.0%
Terminal rate | 1/18 (6%) | 1/31 (3%) | 1/27 (4%) | 1/21 (5%) | 0/20 (0%)
First incidence (days) | 701 | 504 | 660 | 734 (T) | –
Poly-3 test | P = 0.0.334 | P = 0.407 | P = 0.539 | – | –
Poly-3 test | P = 0.139N | – | – | P = 0.500N | P = 0.232N
Skin (Subcutaneous Tissue): Fibroma or Fibrosarcoma
Overall rate | 3/50 (6%) | 6/50 (12%) | 3/50 (6%) | 1/50 (2%) | 0/50 (0%)
Adjusted rate | 7.7% | 13.2% | 7.2% | 2.6% | 0.0%
Terminal rate | 1/18 (6%) | 1/31 (3%) | 1/27 (4%) | 1/21 (5%) | 0/20 (0%)
First incidence (days) | 538 | 504 | 660 | 734 (T) | –
Poly-3 test | P = 0.238 | P = 0.322 | P = 0.631N | – | –
Poly-3 test | P = 0.059N | – | – | P = 0.310N | P = 0.117N
Thyroid Gland (C-Cell): Adenoma
Overall rate | 2/50 (4%) | 5/50 (10%) | 1/50 (2%) | 2/50 (4%) | 2/49 (4%)
Adjusted rate | 5.2% | 11.1% | 2.4% | 5.2% | 5.2%
Terminal rate | 1/18 (6%) | 1/31 (3%) | 0/27 (0%) | 2/21 (10%) | 1/20 (5%)
First incidence (days) | 611 | 505 | 728 | 734 (T) | 597
Poly-3 test | P = 0.164 | P = 0.281 | P = 0.477N | – | –
Poly-3 test | P = 0.602N | – | – | P = 0.692 | P = 0.695N
Thyroid Gland (C-Cell): Carcinoma
Overall rate | 1/50 (2%) | 2/50 (4%) | 3/50 (6%) | 2/50 (4%) | 1/49 (2%)
Adjusted rate | 2.6% | 4.6% | 7.2% | 5.2% | 2.6%
Terminal rate | 0/18 (0%) | 1/31 (3%) | 3/27 (11%) | 2/21 (10%) | 1/20 (5%)
First incidence (days) | 733 | 686 | 734 (T) | 734 (T) | 734 (T)
Poly-3 test | P = 0.471 | P = 0.545 | P = 0.333 | – | –
Poly-3 test | P = 0.622N | – | – | P = 0.501 | P = 0.761
Thyroid Gland (C-Cell): Adenoma or Carcinoma
Overall rate | 3/50 (6%) | 7/50 (14%) | 4/50 (8%) | 3/50 (6%) | 3/49 (6%)
Adjusted rate | 7.7% | 15.4% | 9.6% | 7.8% | 7.7%
Terminal rate | 1/18 (6%) | 2/31 (7%) | 3/27 (11%) | 3/21 (14%) | 2/20 (10%)
First incidence (days) | 611 | 505 | 728 | 734 (T) | 597
Poly-3 test | P = 0.167 | P = 0.227 | P = 0.537 | – | –
Poly-3 test | P = 0.585N | – | – | P = 0.660 | P = 0.664N
All Organs: Malignant Lymphoma
Overall rate | 1/50 (2%) | 1/50 (2%) | 1/50 (2%) | 3/50 (6%) | 0/50 (0%)
Adjusted rate | 2.6% | 2.3% | 2.4% | 7.8% | 0.0%
Terminal rate | 0/18 (0%) | 1/31 (3%) | 0/27 (0%) | 2/21 (10%) | 0/20 (0%)
First incidence (days) | 693 | 734 (T) | 701 | 677 | –
Poly-3 test | – | – | – | – | –
Poly-3 test | P = 0.369N | – | – | P = 0.305 | P = 0.496N
All Organs: Benign Neoplasms
Overall rate | 22/50 (44%) | 36/50 (72%) | 36/50 (72%) | 29/50 (58%) | 22/50 (44%)
Adjusted rate | 53.7% | 74.6% | 78.5% | 68.5% | 53.0%
Terminal rate | 12/18 (67%) | 21/31 (68%) | 22/27 (82%) | 17/21 (81%) | 12/20 (60%)
First incidence (days) | 586 | 467 | 406 | 363 | 541
Poly-3 test | P = 0.024 | P = 0.026 | P = 0.007 | – | –
Poly-3 test | P = 0.512N | – | – | P = 0.105 | P = 0.563N
All Organs: Malignant Neoplasms
Overall rate | 16/50 (32%) | 15/50 (30%) | 14/50 (28%) | 17/50 (34%) | 12/50 (24%)
Adjusted rate | 37.7% | 32.5% | 31.8% | 40.6% | 29.4%
Terminal rate | 4/18 (22%) | 7/31 (23%) | 7/27 (26%) | 7/21 (33%) | 4/20 (20%)
First incidence (days) | 488 | 285 | 490 | 330 | 597
Poly-3 test | P = 0.350N | P = 0.385N | P = 0.361N | – | –
Poly-3 test | P = 0.254N | – | – | P = 0.480 | P = 0.283N
All Organs: Benign or Malignant Neoplasms
Overall rate | 32/50 (64%) | 38/50 (76%) | 39/50 (78%) | 35/50 (70%) | 28/50 (56%)
Adjusted rate | 73.0% | 77.3% | 83.1% | 77.7% | 65.9%
Terminal rate | 14/18 (78%) | 22/31 (71%) | 23/27 (85%) | 18/21 (86%) | 13/20 (56%)
First incidence (days) | 488 | 285 | 406 | 330 | 541
Poly-3 test | P = 0.380 | P = 0.404 | P = 0.161 | – | –
Poly-3 test | P = 0.260N | – | – | P = 0.387 | P = 0.302N

T = terminal euthanasia.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal gland, pancreas, pancreatic islets, pituitary gland, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal euthanasia.

^d^ Beneath the control incidence is the P value associated with the trend test between the control group and the deficient exposure groups. Beneath the deficient exposure group incidence are the P values corresponding to pairwise comparisons between the controls and that deficient exposure group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Beneath the control incidence is the P value associated with the trend test between the control group and the excess exposure groups. Beneath the excess exposure group incidence are the P values corresponding to pairwise comparisons between the controls and that excess exposure group. A negative trend or a lower incidence in an exposure group is indicated by N.

^f^ Poly-3 test was not run.

^g^ Not applicable; no neoplasms in animal group.

^h^ A single incidence of carcinoma occurred in an animal that also had multiple adenoma.

Table A-3 Summary of the Incidence of Nonneoplastic Lesions in Male Rats in the Two-year Feed Study of Dietary Zinc^a^

| Control 38 ppm | 3.5 ppm | 7 ppm | 250 ppm | 500 ppm
Disposition Summary
Animals initially in study | 60 | 60 | 60 | 60 | 60
Early deaths
Special study animals | 10 | 10 | 9 | 10 | 10
Moribund | 11 | 12 | 10 | 15 | 7
Natural deaths | 19 | 7 | 13 | 14 | 22
Survivors
Died last week of study | 2 | – | 1 | – | 1
Terminal euthanasia | 18 | 31 | 27 | 21 | 20
Animals examined microscopically | 50 | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50) | (50)
Intestine large, cecum | (50) | (50) | (50) | (50) | (47)
Erosion | 1 (2%) | – | – | – | –
Epithelium, necrosis | – | – | – | – | 1 (2%)
Intestine, large, colon | (49) | (50) | (49) | (50) | (48)
Parasite, metazoan | – | – | – | – | 1 (2%)
Ulcer | 1 (2%) | – | – | – | –
Intestine, large, rectum | (50) | (50) | (50) | (50) | (48)
Intestine small, duodenum | (50) | (49) | (50) | (49) | (48)
Epithelium, hyperplasia | 1 (2%) | – | – | – | –
Intestine small, ileum | (50) | (49) | (48) | (50) | (45)
Intestine small, jejunum | (50) | (49) | (50) | (50) | (47)
Peyer’s patch, hyperplasia | – | – | – | – | 1 (2%)
Liver | (50) | (50) | (50) | (50) | (46)
Atrophy | – | – | – | – | 1 (2%)
Basophilic focus | – | 1 (2%) | – | 1 (2%) | –
Clear cell focus | 18 (36%) | 26 (52%) | 19 (38%) | 21 (42%) | 23 (50%)
Eosinophilic focus | 4 (8%) | – | 1 (2%) | 1 (2%) | –
Fatty change | 5 (10%) | 4 (8%) | 5 (10%) | 2 (4%) | 4 (9%)
Hematopoietic cell proliferation | – | – | – | – | 1 (2%)
Hepatodiaphragmatic nodule | – | 1 (2%) | – | 1 (2%) | –
Inflammation | – | – | – | 1 (2%) | 1 (2%)
Mixed cell focus | – | – | 1 (2%) | 1 (2%) | –
Bile duct, hyperplasia | – | – | – | 3 (6%) | –
Hepatocyte, atrophy | 1 (2%) | – | – | – | –
Hepatocyte, necrosis | 4 (8%) | – | 3 (6%) | 1 (2%) | –
Hepatocyte, vacuolization cytoplasmic | – | – | – | 1 (2%) | 1 (2%)
Serosa, inflammation, acute | – | – | 1 (2%) | – | –
Mesentery | (0) | (1) | (0) | (0) | (0)
Oral mucosa | (1) | (0) | (2) | (1) | (1)
Hyperplasia | – | – | 1 (50%) | – | 1 (100%)
Inflammation | – | – | 1 (50%) | – | –
Ulcer | 1 (100%) | – | – | – | –
Pancreas | (49) | (50) | (48) | (48) | (48)
Inflammation, acute | – | – | – | – | 1 (2%)
Inflammation, chronic active | – | – | – | – | 1 (2%)
Mineralization | 1 (2%) | – | – | – | –
Acinus, atrophy | 3 (6%) | 3 (6%) | 4 (8%) | 3 (6%) | 13 (27%)
Acinus, basophilic focus | 1 (2%) | – | 1 (2%) | – | 2 (4%)
Acinus, hyperplasia | 23 (47%) | 32 (64%) | 23 (48%) | 21 (44%) | 28 (58%)
Duct, hyperplasia, cystic | – | 1 (2%) | – | – | –
Salivary glands | (49) | (50) | (50) | (50) | (49)
Cyst | 1 (2%) | 1 (2%) | – | – | –
Stomach, forestomach | (50) | (50) | (50) | (50) | (49)
Mineralization | 2 (4%) | – | – | – | –
Ulcer | 3 (6%) | – | 1 (2%) | 2 (4%) | 2 (4%)
Epithelium, hyperplasia | 11 (22%) | 16 (32%) | 11 (22%) | 14 (28%) | 7 (14%)
Stomach, glandular | (50) | (50) | (50) | (50) | (49)
Metaplasia, squamous | – | – | 1 (2%) | – | –
Mineralization | 2 (4%) | – | 1 (2%) | 1 (2%) | 1 (2%)
Tongue | (0) | (0) | (0) | (0) | (1)
Hemorrhage | – | – | – | – | 1 (100%)
Inflammation, chronic | – | – | – | – | 1 (100%)
Ulcer | – | – | – | – | 1 (100%)
Tooth | (3) | (0) | (1) | (0) | (2)
Inflammation | – | – | – | – | 1 (50%)
Malformation | – | – | 1 (100%) | – | –
Necrosis | 3 (100%) | – | – | – | 2 (100%)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50) | (50)
Inflammation | 24 (48%) | 29 (58%) | 29 (58%) | 27 (54%) | 16 (32%)
Mineralization | 3 (6%) | – | – | – | –
Necrosis | – | – | 1 (2%) | – | –
Aorta, mineralization | – | 1 (2%) | – | – | –
Heart | (50) | (50) | (50) | (50) | (50)
Cardiomyopathy | 42 (84%) | 38 (76%) | 39 (78%) | 35 (70%) | 32 (64%)
Mineralization | 2 (4%) | – | – | 1 (2%) | –
Atrium, thrombosis | 3 (6%) | – | 4 (8%) | 3 (6%) | –
Valve, inflammation | – | – | 1 (2%) | – | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50) | (50)
Degeneration, cystic | – | 1 (2%) | – | – | –
Hyperplasia | 7 (14%) | 3 (6%) | 7 (14%) | 5 (10%) | 5 (10%)
Hypertrophy | – | 1 (2%) | – | – | –
Necrosis | 1 (2%) | – | 1 (2%) | – | –
Thrombosis | – | – | – | 1 (2%) | –
Vacuolization, cytoplasmic | 1 (2%) | 1 (2%) | – | – | –
Adrenal medulla | (50) | (50) | (50) | (50) | (50)
Hyperplasia | 16 (32%) | 21 (42%) | 14 (28%) | 15 (30%) | 11 (22%)
Bilateral, hyperplasia | 6 (12%) | 3 (6%) | 8 (16%) | 4 (8%) | 5 (10%)
Islets, pancreatic | (50) | (50) | (50) | (49) | (49)
Atrophy | – | 1 (2%) | – | – | 1 (2%)
Hyperplasia | 1 (2%) | – | 3 (6%) | – | 4 (8%)
Parathyroid gland | (47) | (41) | (44) | (40) | (42)
Hyperplasia | 6 (13%) | 2 (5%) | 2 (5%) | 6 (15%) | 5 (12%)
Pituitary gland | (50) | (50) | (50) | (50) | (49)
Inflammation | – | – | – | – | 1 (2%)
Pars distalis, hyperplasia | 12 (24%) | 17 (34%) | 17 (34%) | 13 (26%) | 15 (31%)
Pars intermedia, hyperplasia | 1 (2%) | 1 (2%) | – | 1 (2%) | –
Thyroid gland | (50) | (50) | (50) | (50) | (49)
Mineralization | – | – | – | 1 (2%) | –
Thrombosis, chronic | 1 (2%) | – | – | – | –
C-cell, hyperplasia | 16 (32%) | 16 (32%) | 13 (26%) | 10 (20%) | 12 (24%)
Follicular cell, hyperplasia | 1 (2%) | – | – | – | 1 (2%)
General Body System
None | – | – | – | – | –
Genital System
Epididymis | (50) | (50) | (50) | (50) | (50)
Degeneration | – | – | – | 2 (4%) | –
Hyperplasia | – | – | – | 1 (2%) | –
Penis | (0) | (0) | (1) | (0) | (0)
Developmental malformation | – | – | 1 (100%) | – | –
Preputial gland | (50) | (50) | (50) | (50) | (50)
Inflammation | – | – | 2 (4%) | – | –
Prostate | (50) | (50) | (50) | (50) | (50)
Inflammation | 1 (2%) | – | – | 1 (2%) | –
Epithelium, hyperplasia | 2 (4%) | – | 1 (2%) | – | –
Seminal vesicle | (50) | (50) | (50) | (50) | (50)
Inflammation | 1 (2%) | – | – | – | –
Testes | (50) | (50) | (50) | (50) | (50)
Edema | – | 2 (4%) | – | – | –
Mineralization | – | 1 (2%) | – | – | –
Bilateral, germ cell, degeneration | – | 1 (2%) | – | 1 (2%) | 1 (2%)
Bilateral, germinal epithelium, atrophy | – | 7 (14%) | 1 (2%) | – | 1 (2%)
Germinal epithelium, atrophy | 5 (10%) | 3 (6%) | – | 3 (6%) | 4 (8%)
Interstitial cell, hyperplasia | 1 (2%) | – | – | – | –
Seminiferous tubule, dilation | 1 (2%) | 1 (2%) | – | 1 (2%) | –
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50) | (50)
Atrophy | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%) | 2 (4%)
Hyperplasia | 4 (8%) | 4 (8%) | – | 1 (2%) | 1 (2%)
Myelofibrosis | – | – | – | 1 (2%) | –
Lymph node | (6) | (1) | (4) | (3) | (2)
Deep cervical, inflammation | 1 (17%) | – | – | – | –
Inguinal, ectasia | – | – | – | 1 (33%) | –
Mediastinal, atrophy | 1 (17%) | – | 2 (50%) | – | –
Mediastinal, ectasia | – | – | – | – | 1 (50%)
Mediastinal, hemorrhage | 2 (33%) | 1 (100%) | 4 (100%) | 1 (33%)
Mediastinal, hemorrhage, chronic | 1 (17%) | – | – | – | –
Mediastinal, pigmentation, hemosiderin | 1 (17%) | – | – | – | –
Pancreatic, hemorrhage | – | 1 (100%) | – | – | 1 (50%)
Pancreatic, hyperplasia | – | – | – | – | 1 (50%)
Renal, hemorrhage | 1 (17%) | – | – | 1 (33%) | –
Lymph node, mandibular | (49) | (50) | (50) | (50) | (48)
Atrophy | 2 (4%) | 1 (2%) | 2 (4%) | 2 (4%) | 2 (4%)
Ectasia | – | 1 (2%) | 1 (2%) | 1 (2%) | –
Hyperplasia | 15 (31%) | 14 (28%) | 11 (22%) | 10 (20%) | 11 (23%)
Infiltration, cellular, histiocyte | – | – | – | 1 (2%) | –
Inflammation, plasma cell | 12 (24%) | 9 (18%) | 13 (26%) | 12 (24%) | 10 (21%)
Lymph node, mesenteric | (50) | (50) | (49) | (50) | (49)
Atrophy | 2 (4%) | – | – | 1 (2%) | –
Hyperplasia | – | 2 (4%) | – | 2 (4%) | 4 (8%)
Infiltration, cellular, plasma cell | – | 1 (2%) | – | – | –
Inflammation, granulomatous | 1 (2%) | – | 1 (2%) | 1 (2%) | –
Inflammation, chronic active | 1 (2%) | – | – | – | –
Spleen | (50) | (50) | (49) | (48) | (45)
Atrophy | – | – | 1 (2%) | – | –
Hematopoietic cell proliferation | 27 (54%) | 37 (74%) | 24 (49%) | 26 (54%) | 24 (53%)
Pigmentation, hemosiderin | 44 (88%) | 43 (86%) | 49 (100%) | 40 (83%) | 34 (76%)
Capsule, inflammation | – | – | – | 1 (2%) | –
Lymphoid follicle, atrophy | 6 (12%) | 1 (2%) | 3 (6%) | 3 (6%) | 4 (9%)
Lymphoid follicle, hyperplasia | 7 (14%) | 8 (16%) | 10 (20%) | 8 (17%) | 3 (7%)
Thymus | (47) | (49) | (50) | (47) | (48)
Atrophy | 37 (79%) | 40 (82%) | 35 (70%) | 36 (77%) | 37 (77%)
Hyperplasia | – | 1 (2%) | 3 (6%) | 1 (2%) | 1 (2%)
Integumentary System
Mammary gland | (50) | (49) | (50) | (48) | (49)
Skin | (50) | (50) | (50) | (50) | (50)
Cyst epithelial inclusion | 1 (2%) | 1 (2%) | 1 (2%) | – | 2 (4%)
Dysplasia | – | – | – | 1 (2%) | –
Fibrosis | 1 (2%) | – | – | 1 (2%) | –
Inflammation | 4 (8%) | – | 2 (4%) | 1 (2%) | –
Ulcer | 3 (6%) | – | – | 1 (2%) | 2 (4%)
Epidermis, hyperplasia | 2 (4%) | 2 (4%) | 2 (4%) | 1 (2%) | –
Hair follicle, cyst | 2 (4%) | 1 (2%) | – | 5 (10%) | 2 (4%)
Hair follicle, cyst, multiple | 1 (2%) | – | – | – | –
Hair follicle, hyperplasia | – | 1 (2%) | – | – | –
Pinna, hyperplasia, squamous | – | – | – | – | 1 (2%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (50) | (50)
Fibrous osteodystrophy | 3 (6%) | – | 1 (2%) | 1 (2%) | –
Inflammation | 1 (2%) | – | – | – | –
Skeletal muscle | (0) | (0) | (1) | (2) | (0)
Nervous System
Brain | (48) | (50) | (50) | (50) | (50)
Edema | – | – | – | 1 (2%) | 1 (2%)
Inflammation | – | – | 1 (2%) | – | –
Mineralization | – | – | – | 1 (2%) | –
Cerebrum, gliosis | – | 1 (2%) | – | 1 (2%) | 1 (2%)
Cerebrum, neuron, necrosis | – | – | – | 1 (2%) | –
Ventricle, developmental malformation | 1 (2%) | – | – | – | –
Venule, mineralization | – | – | – | 1 (2%) | –
Peripheral nerve | (1) | (1) | (1) | (1) | (0)
Sciatic, degeneration | – | – | – | 1 (100%) | –
Spinal cord | (0) | (1) | (1) | (1) | (0)
Axon, degeneration | – | 1 (100%) | 1 (100%) | 1 (100%) | –
Respiratory System
Lung | (50) | (50) | (50) | (50) | (50)
Edema | 1 (2%) | – | – | – | –
Hemorrhage | – | – | – | – | 1 (2%)
Infiltration cellular, histiocyte | 18 (36%) | 21 (42%) | 21 (42%) | 14 (28%) | 14 (28%)
Inflammation | 3 (6%) | 4 (8%) | 7 (14%) | 10 (20%) | 4 (8%)
Necrosis | 1 (2%) | – | – | – | –
Alveolar epithelium, hyperplasia | – | – | – | 1 (2%) | –
Interstitium, thrombosis | 1 (2%) | – | – | – | –
Nose | (50) | (50) | (50) | (50) | (49)
Accumulation, hyaline droplet | – | 1 (2%) | – | – | –
Inflammation | 8 (16%) | – | 4 (8%) | 2 (4%) | 4 (8%)
Olfactory epithelium. atrophy | – | – | 1 (2%) | – | –
Respiratory epithelium, hyperplasia | – | – | 3 (6%) | 2 (4%) | 1 (2%)
Respiratory epithelium, metaplasia, squamous | 1 (2%) | – | – | – | –
Trachea | (50) | (50) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (49) | (50) | (50) | (49)
Atrophy | – | 1 (2%) | 1 (2%) | 1 (2%) | –
Cataract | – | 1 (2%) | – | – | –
Anterior chamber, inflammation, acute | 1 (2%) | – | 1 (2%) | – | –
Anterior chamber, bilateral, inflammation, acute | 1 (2%) | – | – | – | –
Bilateral, cornea, inflammation, acute | 2 (4%) | 1 (2%) | 2 (4%) | – | –
Bilateral, cornea inflammation, chronic active | 1 (2%) | 1 (2%) | 2 (4%) | 3 (6%) | 1 (2%)
Bilateral, cornea, necrosis | 1 (2%) | – | 1 (2%) | 1 (2%) | –
Cornea, inflammation, acute | – | 1 (2%) | – | 2 (4%) | 1 (2%)
Cornea, inflammation, chronic active | – | – | 2 (4%) | – | 1 (2%)
Cornea, necrosis | – | – | – | 3 (6%) | –
Cornea, ulcer | – | 1 (2%) | – | – | –
Lens, cataract | 1 (2%) | – | – | – | –
Harderian gland | (50) | (49) | (50) | (50) | (49)
Inflammation | – | – | 1 (2%) | – | –
Zymbal’s gland | (1) | (0) | (0) | (0) | (0)
Urinary System
Kidney | (50) | (50) | (50) | (50) | (50)
Cyst | – | 1 (2%) | 4 (8%) | 4 (8%) | –
Infarct, chronic | – | 3 (6%) | 1 (2%) | – | 3 (6%)
Nephropathy | 49 (98%) | 50 (100%) | 48 (96%) | 49 (98%) | 49 (98%)
Pelvis, inflammation, chronic active | – | – | – | 1 (2%) | –
Renal tubule, hyperplasia, atypical | – | – | 1 (2%) | – | –
Urinary bladder | (50) | (50) | (50) | (50) | (49)
Inflammation | 2 (4%) | – | – | 1 (2%) | –
Ulcer | – | – | – | 1 (2%) | –

^a^ Number of core study animals examined microscopically at the site and the number of animals with lesion.