# Overview

The National Institute for Occupational Safety and Health (NIOSH) nominated the class of metalworking fluids to the National Toxicology Program (NTP) for toxicological evaluation. Individual metalworking fluids are formulated based upon the intended use, and there are hundreds, and perhaps many more, metalworking fluid formulations currently in use. Selection of specific metalworking fluids for study based upon production volumes and use patterns was not possible because this information is proprietary thus was not available. For this reason, selection of specific metalworking fluid formulations was accomplished by initially selecting 30 prominently marketed metalworking fluids from among the three major classes of metalworking fluids: soluble oils, semisynthetic fluids, and synthetic fluids. These three classes encompass the majority of metal-working fluids in use. From the initial 30 metalworking fluids, 18 were selected for chemical analysis based on commercial availability, review of composition as listed on Material Safety Data Sheets, and elimination of redundant formulations. The number of formulations for study was reduced to nine by selecting from a minimum of three major producers following chemical screening. These nine formulations underwent further chemical analysis and genetic toxicity assessment prior to selecting four formulations, as examples from each class, for inhalation toxicity studies. In collaboration with NIOSH, the selection for the NTP studies was based on class, estimated usage, and chemical composition. CIMSTAR^®^ 3800 (semisynthetic), TRIM^®^ VX (soluble oil), Syntilo^®^ 1023 (synthetic), and TRIM^®^ SC210 (semisynthetic) were selected for 3-month inhalation studies. Based on the results of the 3-month studies, CIMSTAR^®^ 3800 and TRIM^®^ VX were selected for 2-year studies^1^. CIMSTAR^®^ 3800 3-month and 2-year studies are reported in TR 586^2^. TRIM^®^ VX 3-month and 2-year studies are reported in the current Technical Report (TR 591). Although registered trademarks, the formulations may be referred to as TRIM, CIMSTAR, and Syntilo throughout this document.