# Peer Review

The members of the Peer Review Panel who evaluated the draft NTP Technical Report on the Toxicology and Carcinogenesis Studies of TRIM^®^ VX in Wistar Han [Crl:WI (Han)] Rats and B6C3F1/N Mice (Inhalation Studies) on February 16, 2016, are listed below. Panel members served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, reviewers had five major responsibilities in reviewing the NTP studies:

- to ascertain that all relevant literature data have been adequately cited and interpreted,
- to determine if the design and conditions of the NTP studies were appropriate,
- to ensure that the Technical Report presents the experimental results and conclusions fully and clearly,
- to judge the significance of the experimental results by scientific criteria, and
- to assess the evaluation of the evidence of carcinogenic activity and other observed toxic responses.

## Peer Reviewers

- Jon C. Mirsalis, Ph.D. (Chairperson)
  SRI International
  Menlo Park, California, USA
- William J. Brock, Ph.D. (Primary Reviewer)
  Brock Scientific Consulting, LLC
  Montgomery Village, Maryland, USA
- Michael R. Elwell, D.V.M., Ph.D. (Primary Reviewer)
  Nonclinical Safety Assessment
  Covance Laboratories, Inc.
  Chantilly, Virginia, USA
- Kent E. Pinkerton, Ph.D.
  Center for Health and the Environment
  University of California
  Davis, California, USA
- Michael V. Pino, D.V.M., Ph.D.
  Veterinary Toxicologic Pathology and Preclinical Drug Development
  Albuquerque, New Mexico, USA
- Tara Sabo-Attwood, Ph.D. (Primary Reviewer)
  Department of Environmental and Global Health
  University of Florida
  Gainesville, Florida, USA
- Madhuri Singal, Ph.D.
  Global Regulatory Compliance
  Reckitt Benckiser
  Montvale, New Jersey, USA