# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  K.R. Ryan, Ph.D., Study Scientist
  R.A. Herbert, D.V.M., Ph.D., Co-Study Pathologist
  C.R. Blystone, Ph.D.
  M.C. Cora, D.V.M.
  P.M. Foster, Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  D.L. Morgan, Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  M.K. Vallant, M.S., M.T.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- ILS, Inc., Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  K.S. Janardhan, Ph.D., Co-Study Pathologist
- Coordinated NTP Pathology Working Groups
  G.D. Hill, D.V.M., Ph.D., Coordinated 2-year rats (February 20, 2014)
  L.M. Staska, D.V.M., Ph.D., Coordinated 2-year mice (May 6, 2014)
- Battelle Toxicology Northwest, Richland, Washington, USA
  Conducted studies and evaluated pathology findings
  J.A. Dill, Ph.D., Principal Investigator
  S.L. Grumbein, D.V.M., Ph.D.
  B.K. Hayden
  K.M. Patton, D.V.M., Ph.D.
  M.J. Ryan, D.V.M., Ph.D.
  L.M. Staska, D.V.M., Ph.D.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Conducted pathology review
  T. Crabbs, D.V.M.
  M.M. Gruebbel, D.V.M., Ph.D.