# References

1 Ryan KR, Cesta MF, Herbert R, Brix A, Cora M, Witt K, Kissling G, Morgan DL. Comparative pulmonary toxicity of inhaled metalworking fluids in rats and mice. Toxicol Ind Health. 2017; 33(5):385–405. 10.1177/0748233716653912 27343050
2 National Toxicology Program (NTP). Toxicology studies of CIMSTAR 3800 in F344/NTac rats and B6C3F1/N mice and toxicology and carcinogenesis studies of CIMSTAR 3800 in Wistar Han [Crl:WI (Han)] rats and B6C3F1/N mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2015. Technical Report Series No. 586.
3 Gauthier SL. Metalworking fluids: Oil mist and beyond. Appl Occup Environ Hyg. 2003; 18(11):818–824. 10.1080/10473220390237313 14555433
4 Meyer SR, Boslett WS. Working safely with metalworking fluids. Rockford, IL: Fabricators & Manufacturers Association, International; 2001.
5 Woskie SR, Virji MA, Hallock M, Smith TJ, Hammond SK. Summary of the findings from the exposure assessments for metalworking fluid mortality and morbidity studies. Appl Occup Environ Hyg. 2003; 18(11):855–864. 10.1080/10473220390237377 14555438
6 Cohen H, White EM. Metalworking fluid mist occupational exposure limits: A discussion of alternative methods. J Occup Environ Hyg. 2006; 3(9):501–507. 10.1080/15459620600867872 16857649
7 Frazier AD. Cutting fluid applications for today’s materials. In: Zintak D, editor. Improving Production with Coolants and Lubricants. Dearborn, MI: Society of Manufacturing Engineers; 1982. p. 19–24.
8 Pryce DW, White J, English JS, Rycroft RJ. Soluble oil dermatitis: A review. J Soc Occup Med. 1989; 39(3):93–98. 10.1093/occmed/39.3.93 2531255
9 Gordon T. Metalworking fluid—the toxicity of a complex mixture. J Toxicol Environ Health A. 2004; 67(3):209–219. 10.1080/15287390490266864 14681076
10 Arrandale VH, Liss GM, Tarlo SM, Pratt MD, Sasseville D, Kudla I, Holness DL. Occupational contact allergens: Are they also associated with occupational asthma? Am J Ind Med. 2012; 55(4):353–360. 10.1002/ajim.22015 22238032
11 Zugerman C. Cutting fluids. Their use and effects on the skin. Occup Med. 1986; 1(2):245–258. 2956708
12 Anderson SE, Brown KK, Butterworth LF, Fedorowicz A, Jackson LG, Frasch HF, Beezhold D, Munson AE, Meade BJ. Evaluation of irritancy and sensitization potential of metalworking fluid mixtures and components. J Immunotoxicol. 2009; 6(1):19–29. 10.1080/15476910802604291 19519159
13 Centers for Disease Control and Prevention (CDC). International Chemical Safety Card: 4-Chloro-m-cresol. Atlanta, GA: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention; 2014. https://web.archive.org/web/20160821065534/https://www.cdc.gov/niosh/ipcsneng/neng0131.html
14 Code of Federal Regulations (CFR). 40:§ 747.115.
15 Newhouse R. Modern metal-forming lubrication. In: Zintak D, editor. Improving Production with Coolants and Lubricants. Dearborn, MI: Society of Manufacturing Engineers; 1982. p. 25–29.
16 Independent Lubricant Manufacturers Association (ILMA). Report on the volume of lubricants manufactured in the United States and Canada by independent lubricant manufacturers in 1999, August 11, 2000. Alexandria, VA; 2000.
17 Master Chemical Corporation (MCC). Cutting and grinding fluids data and information: TRIM® VX. Perrysburg, OH: MCC; 2014. [Last Updated: February 24, 2014].
18 National Institute for Occupational Safety and Health (NIOSH). National Occupational Exposure Survey (1981-1983), unpublished provisional data as of July 1, 1990. Cincinnati, OH: NIOSH. 1990.
19 National Institute for Occupational Safety and Health (NIOSH). What you need to know about occupational exposure to metalworking fluids. Cincinnati, OH: U.S. Department of Health and Human Services, Public Health Service, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 2013. DHHS Publication No. 98-116.
20 National Institute for Occupational Safety and Health (NIOSH). Metal working fluids: Recommendation for chronic inhalation studies. Cincinnati, OH: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention; 2001.
21 Greaves IA, Eisen EA, Smith TJ, Pothier LJ, Kriebel D, Woskie SR, Kennedy SM, Shalat S, Monson RR. Respiratory health of automobile workers exposed to metal-working fluid aerosols: Respiratory symptoms. Am J Ind Med. 1997; 32(5):450–459. 10.1002/(SICI)1097-0274(199711)32:5<450::AID-AJIM4>3.0.CO;2-W 9327068
22 Kriebel D, Eberiel D, Eisen EA, Moure-Eraso R, Kumar S, Sama SR, Smith M, Virgi MA, Woskie SR, Hammond SK et al. Field investigations of the acute respiratory effects of machining fluids: Final report to the National Joint Committee for Occupational Safety and Health for the United Auto Workers and General Motors, June 1. 1994.
23 Robins T, Sexias N, Franzblau A, Burge H, Abrams L, Minick S. Respiratory effects of machining fluid aerosols. Final report to the UAW-GM Occupational Health Advisory Board. 1994.
24 Bennett EO, Bennett DL. Minimizing human exposure to chemicals in metalworking fluids. J Am Soc Lubr Eng. 1987; 43(3):167–175.
25 Simpson AT, Stear M, Groves JA, Piney M, Bradley SD, Stagg S, Crook B. Occupational exposure to metalworking fluid mist and sump fluid contaminants. Ann Occup Hyg. 2003; 47(1):17–30. 12505903
26 Geier J, Lessmann H, Dickel H, Frosch PJ, Koch P, Becker D, Jappe U, Aberer W, Schnuch A, Uter W. Patch test results with the metalworking fluid series of the German Contact Dermatitis Research Group (DKG). Contact Dermatitis. 2004; 51(3):118–130. 10.1111/j.0105-1873.2004.00416.x 15479200
27 Suuronen K, Aalto-Korte K, Piipari R, Tuomi T, Jolanki R. Occupational dermatitis and allergic respiratory diseases in Finnish metalworking machinists. Occup Med (Lond). 2007; 57(4):277–283. 10.1093/occmed/kqm011 17392449
28 National Institute for Occupational Safety and Health (NIOSH). Criteria for a recommended standard: Occupational exposure to metalworking fluids. Cincinnati, OH: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention; 1998. DHHS Publication No. 98-102.
29 Occupational Safety and Health Administration (OSHA). Metalworking fluids: Safety and health best practices manual. Washington, DC: U.S. Department of Labor, Occupational Safety and Health Administration; 2001. https://www.osha.gov/SLTC/metalworkingfluids/metalworkingfluids_manual.html [Accessed: April 22, 2015]
30 Schaper M, Detwiler K. Evaluation of the acute respiratory effects of aerosolized machining fluids in mice. Fundam Appl Toxicol. 1991; 16(2):309–319. 10.1016/0272-0590(91)90115-K 2055361
31 Schaper MM, Detwiler-Okabayashi KA. An approach for evaluating the respiratory irritation of mixtures: Application to metalworking fluids. Arch Toxicol. 1995; 69(10):671–676. 10.1007/s002040050230 8572923
32 Lim CH, Yu IJ, Kim HY, Lee SB, Marshak DR, Lee JH, Kim KJ. Effect of water-soluble metal working fluid aerosols on respiratory system after 13 weeks of repeated inhalation exposure in F344 rats. Toxicol Ind Health. 2005; 21(7-8):207–213. 10.1191/0748233705th230oa 16342471
33 Thorne PS, DeKoster JA. Pulmonary effects of machining fluids in guinea pigs and mice. Am Ind Hyg Assoc J. 1996; 57(12):1168–1172. 10.1080/15428119691014297 8976591
34 DeLorme MP, Gao X, Doyon-Reale N, Barraclough-Mitchell H, Bassett DJ. Inflammatory effects of inhaled endotoxin-contaminated metal working fluid aerosols in rats. J Toxicol Environ Health A. 2003; 66(1):7–24. 10.1080/15287390306458 12587288
35 Lim CH, Yu IJ, Kim HY, Lee SB, Kang MG, Marshak DR, Moon CK. Respiratory effect of acute and subacute exposure to endotoxin-contaminated metal working fluid (MWF) aerosols on Sprague-Dawley rats. Arch Toxicol. 2005; 79(6):321–329. 10.1007/s00204-004-0640-6 15692821
36 Lim CH, Yu IJ, Kim HY, Lee SB, Kang MG, Marshak DR, Moon CK. Inflammatory and immunological responses to subchronic exposure to endotoxin-contaminated metalworking fluid aerosols in F344 rats. Environ Toxicol. 2005; 20(2):212–218. 10.1002/tox.20097 15793813
37 Mirer FE. New evidence on the health hazards and control of metalworking fluids since completion of the OSHA advisory committee report. Am J Ind Med. 2010; 53(8):792–801. 10.1002/ajim.20853 20623659
38 Meredith SK, McDonald JC. Work-related respiratory disease in the United Kingdom, 1989-1992: Report on the SWORD project. Occup Med (Lond). 1994; 44(4):183–189. 10.1093/occmed/44.4.183 7949060
39 Bernstein DI, Lummus ZL, Santilli G, Siskosky J, Bernstein IL. Machine operator’s lung. A hypersensitivity pneumonitis disorder associated with exposure to metalworking fluid aerosols. Chest. 1995; 108(3):636–641. 10.1378/chest.108.3.636 7656609
40 Kreiss K, Cox-Ganser J. Metalworking fluid-associated hypersensitivity pneumonitis: A workshop summary. Am J Ind Med. 1997; 32(4):423–432. 10.1002/(SICI)1097-0274(199710)32:4<423::AID-AJIM16>3.0.CO;2-5 9258399
41 Rose C, Robins T, Harkaway P. Biopsy-confirmed hypersensitivity pneumonitis in automobile production workers exposed to metalworking fluids—Michigan, 1994-1995. MMWR Morb Mortal Wkly Rep. 1996; 45(28):606–610. 8676853
42 Rosenman KD, Reilly MJ, Watt FC, Kalinowski DJ. 1993 annual report on occupational asthma in Michigan. Michigan, US: Michigan State University and Michigan Department of Public Health; 1994.
43 Bogaert P, Tournoy KG, Naessens T, Grooten J. Where asthma and hypersensitivity pneumonitis meet and differ: Noneosinophilic severe asthma. Am J Pathol. 2009; 174(1):3–13. 10.2353/ajpath.2009.071151 19074616
44 Eisen EA, Holcroft CA, Greaves IA, Wegman DH, Woskie SR, Monson RR. A strategy to reduce healthy worker effect in a cross-sectional study of asthma and metalworking fluids. Am J Ind Med. 1997; 31(6):671–677. 10.1002/(SICI)1097-0274(199706)31:6<671::AID-AJIM1>3.0.CO;2-U 9131220
45 Rosenman KD, Reilly MJ, Kalinowski D. Work-related asthma and respiratory symptoms among workers exposed to metal-working fluids. Am J Ind Med. 1997; 32(4):325–331. 10.1002/(SICI)1097-0274(199710)32:4<325::AID-AJIM1>3.0.CO;2-T 9258384
46 Hendy MS, Beattie BE, Burge PS. Occupational asthma due to an emulsified oil mist. Br J Ind Med. 1985; 42(1):51–54. 10.1136/oem.42.1.51 3965015
47 Robertson AS, Weir DC, Burge PS. Occupational asthma due to oil mists. Thorax. 1988; 43(3):200–205. 10.1136/thx.43.3.200 3406905
48 Savonius B, Keskinen H, Tuppurainen M, Kanerva L. Occupational asthma caused by ethanolamines. Allergy. 1994; 49(10):877–881. 10.1111/j.1398-9995.1994.tb00791.x 7709998
49 Kennedy SM. Acquired airway hyperresponsiveness from nonimmunogenic irritant exposure. Occup Med. 1992; 7(2):287–300. 1615364
50 Michel O, Ginanni R, Le Bon B, Content J, Duchateau J, Sergysels R. Inflammatory response to acute inhalation of endotoxin in asthmatic patients. Am Rev Respir Dis. 1992; 146(2):352–357. 10.1164/ajrccm/146.2.352 1489124
51 Sprince NL, Thorne PS, Popendorf W, Zwerling C, Miller ER, DeKoster JA. Respiratory symptoms and lung function abnormalities among machine operators in automobile production. Am J Ind Med. 1997; 31(4):403–413. 10.1002/(SICI)1097-0274(199704)31:4<403::AID-AJIM5>3.0.CO;2-W 9093654
52 Kriebel D, Sama SR, Woskie S, Christiani DC, Eisen EA, Hammond SK, Milton DK, Smith M, Virji MA. A field investigation of the acute respiratory effects of metal working fluids. I. Effects of aerosol exposures. Am J Ind Med. 1997; 31(6):756–766. 10.1002/(SICI)1097-0274(199706)31:6<756::AID-AJIM13>3.0.CO;2-X 9131232
53 Gilman JPW, Vesselinovitch SD. Cutting oils and squamous-cell carcinoma. II. An experimental study of the carcinogenicity of two types of cutting oils. Br J Ind Med. 1955; 12(3):244–248. 10.1136/oem.12.3.244 13240030
54 Gupta KP, Mehrotra NK. Tumor initiation in mouse skin by cutting oils. Environ Res. 1989; 49(2):225–232. 10.1016/S0013-9351(89)80068-4 2502387
55 Jepsen JR, Stoyanov S, Unger M, Clausen J, Christensen HE. Cutting fluids and their effects on the skin of mice. An experimental study with special reference to carcinogenicity. Acta Pathol Microbiol Scand [A]. 1977; 85(5):731–738. 920187
56 McKee RH, Scala RA, Chauzy C. An evaluation of the epidermal carcinogenic potential of cutting fluids. J Appl Toxicol. 1990; 10(4):251–256. 10.1002/jat.2550100405 2391406
57 Wang D, Huang WQ, Wang HW. Mutagenicity and carcinogenicity studies of homemade “rust-proof cutting fluid”. Teratog Carcinog Mutagen. 1988; 8(1):35–43. 10.1002/tcm.1770080105 2897723
58 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of triethanolamine (CAS No. 102-71-6) in F344/N rats and B6C3F1 mice (dermal studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1999. Technical Report Series No. 449. NIH Publication No. 00-3365.
59 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of triethanolamine (CAS No. 102-71-6) in B6C3F1 mice (dermal study). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2004. Technical Report Series No. 518. NIH Publication No. 04-4452.
60 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of diethanolamine (CAS No. 111-42-2) in F344/N rats and B6C3F1 mice (dermal studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1999. Technical Report Series No. 478. NIH Publication No. 99-3968.
61 Cruickshank CND, Gourevitch A. Skin cancer of the hand and forearm. Br J Ind Med. 1952; 9(1):74–79. 10.1136/oem.9.1.74 14895807
62 Järvholm B, Easton D. Models for skin tumour risks in workers exposed to mineral oils. Br J Cancer. 1990; 62(6):1039–1041. 10.1038/bjc.1990.435 2257210
63 Järvholm B, Fast K, Lavenius B, Tomsic P. Exposure to cutting oils and its relation to skin tumors and premalignant skin lesions on the hands and forearms. Scand J Work Environ Health. 1985; 11(5):365–369. 10.5271/sjweh.2211 4071002
64 Cruickshank CND, Squire JR. Skin cancer in the engineering industry from the use of mineral oil. Br J Ind Med. 1950; 7(1):1–11. 10.1136/oem.7.1.1 15403146
65 Järvholm B, Lavenius B. Mortality and cancer morbidity in workers exposed to cutting fluids. Arch Environ Health. 1987; 42(6):361–366. 10.1080/00039896.1987.9934360 3439814
66 Roush GC, Kelly JA, Meigs JW, Flannery JT. Scrotal carcinoma in Connecticut metalworkers: Sequel to a study of sinonasal cancer. Am J Epidemiol. 1982; 116(1):76–85. 10.1093/oxfordjournals.aje.a113404 7102658
67 International Agency for Research on Cancer (IARC). Mineral oils: Untreated and mildly-treated oils (group 1). Highly-refined oils (group 3). In: IARC Monographs on the Evaluation of Carcinogenic Risks to Humans Overall Evaluations of Carcinogenicity: An Updating of IARC Monographs Volumes 1 to 42; Suppl 7. Lyon, France: IARC; 1987. p. 252-254.
68 Tolbert PE, Eisen EA, Pothier LJ, Monson RR, Hallock MF, Smith TJ. Mortality studies of machining-fluid exposure in the automobile industry: II. Risks associated with specific fluid types. Scand J Work Environ Health. 1992;18:351–360. 10.5271/sjweh.1562 1485160
69 Eisen EA, Tolbert PE, Hallock MF, Monson RR, Smith TJ, Woskie SR. Mortality studies of machining fluid exposure in the automobile industry. III: A case-control study of larynx cancer. Am J Ind Med. 1994; 26(2):185–202. 10.1002/ajim.4700260205 7977395
70 Bardin JA, Eisen EA, Tolbert PE, Hallock MF, Hammond SK, Woskie SR, Smith TJ, Monson RR. Mortality studies of machining fluid exposure in the automobile industry. V: A case-control study of pancreatic cancer. Am J Ind Med. 1997; 32(3):240–247. 10.1002/(SICI)1097-0274(199709)32:3<240::AID-AJIM9>3.0.CO;2-0 9219653
71 Costello S, Friesen MC, Christiani DC, Eisen EA. Metalworking fluids and malignant melanoma in autoworkers. Epidemiology. 2011; 22(1):90–97. 10.1097/EDE.0b013e3181fce4b8 20975563
72 Behrens T, Pohlabeln H, Mester B, Langner I, Schmeisser N, Ahrens W. Exposure to metal-working fluids in the automobile industry and the risk of male germ cell tumours. Occup Environ Med. 2012; 69(3):224–226. 10.1136/oemed-2011-100070 22131554
73 Langner I, Schmeisser N, Mester B, Behrens T, Gottlieb A, Ahrens W. Case-control study of male germ cell tumors nested in a cohort of car-manufacturing workers: Findings from the occupational history. Am J Ind Med. 2010; 53(10):1006–1018. 10.1002/ajim.20865 20860055
74 Friesen MC, Costello S, Thurston SW, Eisen EA. Distinguishing the common components of oil- and water-based metalworking fluids for assessment of cancer incidence risk in autoworkers. Am J Ind Med. 2011; 54(6):450–460. 10.1002/ajim.20932 21328414
75 Gomes-Carneiro MR, Felzenszwalb I, Paumgartten FJR. Mutagenicity testing (+/-)-camphor, 1,8-cineole, citral, citronellal, (-)-menthol and terpineol with the Salmonella/microsome assay. Mutat Res. 1998; 416(1-2):129–136. 10.1016/S1383-5718(98)00077-1 9725999
76 Hill MA, Watson CR, Moss OR. NEWCAS - An interactive computer program for particle size analysis. Richland, WA: Pacific Northwest Laboratory; 1977. PNL-2405, UC-32.
77 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. 10.1177/019262338201000210 28094716
78 Boorman GA, Montgomery CA Jr, Eustis SL, Wolfe MJ, McConnell EE, Hardisty JF. Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA, Weisburger EK, editors. Handbook of Carcinogen Testing. Park Ridge, NJ: Noyes Publications; 1985. p. 345–357.
79 McConnell EE, Solleveld HA, Swenberg JA, Boorman GA. Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. J Natl Cancer Inst. 1986; 76(2):283–289. 3456066
80 Kaplan EL, Meier P. Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958; 53(282):457–481.10.1080/01621459.1958.10501452
81 Cox DR. Regression models and life-tables. J R Stat Soc [Ser A]. 1972; B34(2):187–220.
82 Tarone RE. Tests for trend in life table analysis. Biometrika. 1975; 62(3):679–690.10.1093/biomet/62.3.679
83 Bailer AJ, Portier CJ. Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988; 44(2):417–431. 10.2307/2531856 3390507
84 Portier CJ, Bailer AJ. Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam Appl Toxicol. 1989; 12(4):731–737. 10.1016/0272-0590(89)90004-3 2744275
85 Piegorsch WW, Bailer AJ. Statistics for environmental biology and toxicology, Section 6.3.2. London, UK: Chapman and Hall; 1997.
86 Portier CJ, Hedges JC, Hoel DG. Age-specific models of mortality and tumor onset for historical control animals in the National Toxicology Program’s carcinogenicity experiments. Cancer Res. 1986; 46(9):4372–4378. 3731095
87 Bieler GS, Williams RL. Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993; 49(3):793–801. 10.2307/2532200 8241374
88 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121.10.1080/01621459.1955.10501294
89 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. 10.2307/2528930 5547548
90 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. 10.2307/2556164 5037867
91 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. 10.2307/2529789 884197
92 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. 10.2307/2531254 3719054
93 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252.10.1080/00401706.1964.10490181
94 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1/2):133–145.10.2307/2333011
95 Dixon WJ, Massey FJ. Introduction to statistical analysis. 2nd ed. New York, NY: McGraw Hill Book Company Inc; 1957.10.2307/2332898
96 Haseman JK. Value of historical controls in the interpretation of rodent tumor data. Drug Inf J. 1992; 26(2):191–200.10.1177/009286159202600210
97 Haseman JK, Rao GN. Effects of corn oil, time-related changes, and inter-laboratory variability on tumor occurrence in control Fischer 344 (F344/N) rats. Toxicol Pathol. 1992; 20(1):52–60. 10.1177/019262339202000107 1411131
98 Haseman JK. Data analysis: statistical analysis and use of historical control data. Regul Toxicol Pharm. 1995; 21(1):52-59.10.1006/rtph.1995.1009
99 Code of Federal Regulations (CFR). 21:Part 58.
100 Heddle JA, Hite M, Kirkhart B, Mavournin K, MacGregor JT, Newell GW, Salamone MF. The induction of micronuclei as a measure of genotoxicity. A report of the U.S. Environmental Protection Agency Gene-Tox Program. Mutat Res. 1983; 123(1):61–118. 10.1016/0165-1110(83)90047-7 6888413
101 Schmid W. The micronucleus test. Mutat Res. 1975; 31(1):9–15. 10.1016/0165-1161(75)90058-8 48190
102 Miller JA, Miller EC. Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt HH, Watson JD, Winsten JA, editors. Origins of Human Cancer. Cold Spring Harbor, NY: Cold Spring Harbor Laboratory; 1977. p. 605–627.
103 Crawford BD. Perspectives on the somatic mutation model of carcinogenesis. In: Mehlman MA, Flamm WG, Lorentzen RJ, editors. Advances in Modern Environmental Toxicology Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton, NJ: Princton Scientific Publishing Co. Inc.; 1985. p. 13–59.
104 Straus DS. Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981;67:233–241. 7021938
105 Ashby J, Tennant RW. Definitive relationships among chemical structure, carcinogenicity and mutagenicity for 301 chemicals tested by the U.S. NTP. Mutat Res. 1991; 257(3):229–306. 10.1016/0165-1110(91)90003-E 1707500
106 Tennant RW, Margolin BH, Shelby MD, Zeiger E, Haseman JK, Spalding J, Caspary W, Resnick M, Stasiewicz S, Anderson B, et al. Prediction of chemical carcinogenicity in rodents from in vitro genetic toxicity assays. Science. 1987; 236(4804):933–941. 10.1126/science.3554512 3554512
107 Zeiger E, Haseman JK, Shelby MD, Margolin BH, Tennant RW. Evaluation of four in vitro genetic toxicity tests for predicting rodent carcinogenicity: Confirmation of earlier results with 41 additional chemicals. Environ Mol Mutag. 1990; 16 Suppl 18:1-14.10.1002/em.2850160502
108 Shelby MD, Erexson GL, Hook GJ, Tice RR. Evaluation of a three‐exposure mouse bone marrow micronucleus protocol: Results with 49 chemicals. Environ Mol Mutag. 1993; 21(2):160-179.10.1002/em.2850210210
109 Shelby MD, Witt KL. Comparison of results from mouse bone marrow chromosome aberration and micronucleus tests. Environ Mol Mutag. 1995; 25(4):302-313.10.1002/em.2850250407
110 Witt KL, Knapton A, Wehr CM, Hook GJ, Mirsalis J, Shelby MD, MacGregor JT. Micronucleated erythrocyte frequency in peripheral blood of B6C3F1 mice from short-term, prechronic, and chronic studies of the NTP carcinogenesis bioassay program. Environ Mol Mutag. 2000; 36(3):163-194.10.1002/1098-2280(2000)36:3<163::AID-EM1>3.0.CO;2-P
111 National Toxicology Program (NTP). Evaluation of the prechronic toxicity (C20523) of metal working fluids: Trim VX (TRIMVX) in Wistar Han, rat exposed via respiratory exposure whole body. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2016. Chemical Effects in Biological Systems (CEBS) No. C20523.
112 National Toxicology Program (NTP). Evaluation of the chronic toxicity and carcinogenicity (C20523) of metal working fluids: Trim VX (TRIMVX) in Wistar Han, rat exposed via respiratory exposure whole body. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2016. Chemical Effects in Biological Systems (CEBS) No. C20523. https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-02408-0008-0000-4 [Accessed: May 11, 2016]
113 National Toxicology Program (NTP). 3-Month Evaluation of the Toxicity (C20523) of Metal Working Fluids: Trim® VX (TRIMVX) in B6C3F1 Mice via Whole Body Respiratory Exposure. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2016. Chemical Effects in Biological Systems (CEBS) No. C20523. https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-02408-0005-0000-1 [Accessed: May 11, 2016]
114 National Toxicology Program (NTP). Evaluation of the chronic toxicity and carcinogenicity (C20523) of metal working fluids: Trim VX (TRIMVX) in B6C3F1, mouse exposed via respiratory exposure whole body. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2016. Chemical Effects in Biological Systems (CEBS) No. C20523. https://tools.niehs.nih.gov/cebs3/ntpViews/?studyNumber=002-02408-0009-0000-5 [Accessed: May 11, 2016]
115 Dalbey WE. Subchronic inhalation exposures to aerosols of three petroleum lubricants. AIHAJ. 2001; 62(1):49–56. 11258868
116 Selgrade MK, Hatch GE, Grose EC, Stead AG, Miller FJ, Graham JA, Stevens MA, Hardisty JF. Pulmonary effects due to subchronic exposure to oil fog. Toxicol Ind Health. 1990; 6(1):123–143. 10.1177/074823379000600108 2349572
117 Haschek WM, Rousseaux CG, Wallig MA. Nomenclature: Terminology for morphologic alterations. In: Fundamentals of Toxicologic Pathology, 2nd ed. San Diego, CA: Academic Press; 2010. p. 67-79.10.1016/B978-0-12-370469-6.00004-0
118 Jaakkola MS, Suuronen K, Luukkonen R, Jarvela M, Tuomi T, Alanko K, Makela EA, Jolanki R. Respiratory symptoms and conditions related to occupational exposures in machine shops. Scand J Work Environ Health. 2009; 35(1):64–73. 10.5271/sjweh.1299 19190832
119 Oudyk J, Haines AT, D’Arcy J. Investigating respiratory responses to metalworking fluid exposure. Appl Occup Environ Hyg. 2003; 18(11):939–946. 10.1080/10473220390237610 14555447
120 Park DU, Jin KW, Koh DH, Kim BK, Kim KS, Park DY. Association between use of synthetic metalworking fluid and risk of developing rhinitis-related symptoms in an automotive ring manufacturing plant. J Occup Health. 2008; 50(2):212–220. 10.1539/joh.O7006 18403875
121 Guerra S, Sherrill DL, Martinez FD, Barbee RA. Rhinitis as an independent risk factor for adult-onset asthma. J Allergy Clin Immunol. 2002; 109(3):419–425. 10.1067/mai.2002.121701 11897985
122 Kaufmann W, Bader R, Ernst H, Harada T, Hardisty J, Kittel B, Kolling A, Pino M, Renne R, Rittinghausen S, et al. 1st International ESTP Expert Workshop: “Larynx squamous metaplasia”. A re-consideration of morphology and diagnostic approaches in rodent studies and its relevance for human risk assessment. Exp Toxicol Pathol. 2009; 61(6):591–603. 10.1016/j.etp.2009.01.001 19285845
123 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of diethylamine (CAS No. 109-89-7) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2011. Technical Report Series No. 566. NIH Publication No. 12-5908.
124 National Toxicology Program (NTP). Toxicity studies of triethylamine (CAS No. 121-44-8) administered by inhalation to F344/N rats and B6C3F1/N mice. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2016. Toxicity Report Series No. 78.
125 Calvert GM, Ward E, Schnorr TM, Fine LJ. Cancer risks among workers exposed to metalworking fluids: A systematic review. Am J Ind Med. 1998; 33(3):282–292. 10.1002/(SICI)1097-0274(199803)33:3<282::AID-AJIM10>3.0.CO;2-W 9481427
126 Eisen EA, Bardin J, Gore R, Woskie SR, Hallock MF, Monson RR. Exposure-response models based on extended follow-up of a cohort mortality study in the automobile industry. Scand J Work Environ Health. 2001; 27(4):240–249. 10.5271/sjweh.611 11560338
127 Renne RA, Gideon KM. Types and patterns of response in the larynx following inhalation. Toxicol Pathol. 2006; 34(3):281–285. 10.1080/01926230600695631 16698727
128 Heroiu Cataloiu A-D, Danciu CE, Popescu CR. Multiple cancers of the head and neck. Maedica (Buchar). 2013; 8(1):80–85. 24023604
129 Waters M, Stasiewicz S, Merrick BA, Tomer K, Bushel P, Paules R, Stegman N, Nehls G, Yost KJ, Johnson CH, et al. CEBS—Chemical Effects in Biological Systems: A public data repository integrating study design and toxicity data with microarray and proteomics data. Nucleic Acids Res. 2008;36:D892–D900. 10.1093/nar/gkm755 17962311
130 Fuchs J, Burg J, Hengstler JG, Bolm-Audorff U, Oesch F. DNA damage in mononuclear blood cells of metal workers exposed to N-nitrosodiethanolamine in synthetic cutting fluids. Mutat Res. 1995; 342(1-2):95–102. 10.1016/0165-1218(95)90094-2 7885399
131 National Institute for Occupational Safety and Health (NIOSH). Workplace safety and health topics: Metalworking fluids. Atlanta, GA: Centers for Disease Control and Prevention; 2013.
132 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of cobalt sulfate heptahydrate (CAS No. 10026-24-1) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1998. Technical Report Series No. 471. NIH Publication No. 98-3961.
133 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of indium phosphide (CAS No. 22398-80-7) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2001. Technical Report Series No. 499. NIH Publication No. 01-4433.
134 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of vanadium pentoxide (CAS No. 1314-62-1) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2002. Technical Report Series No. 507. NIH Publication No. 03-4441.
135 Harkema J, Nikula K, Haschek WM. Respiratory system. In: Haschek WM, Rousseaux CG, Wallig MA, editors. Haschek and Rosseaux’s Handbook of Toxicologic Pathology. 3rd ed. London, UK: Academic Press; 2013. p. 1935–2003.10.1016/B978-0-12-415759-0.00051-0
136 Renne RA, Dungworth DL, Keenan CM, Morgan KT, Hahn FF, Schwartz LW. Non-proliferative lesions of the respiratory tract in rats. In: Guides For Toxicologic Pathology. Washington, DC: STP/ARP/AFIP; 2003.
137 Gordon T, Galdanes K. Factors contributing to the acute and subchronic adverse respiratory effects of machining fluid aerosols in guinea pigs. Toxicol Sci. 1999; 49(1):86–92. 10.1093/toxsci/49.1.86 10367345
138 Monteiro-Riviere NA, Inman AO, Barlow BM, Baynes RE. Dermatotoxicity of cutting fluid mixtures:in vitro and in vivo studies. Cutan Ocul Toxicol. 2006; 25(4):235–247. 10.1080/15569520601013137 17162411
139 Weiss L, Pue C, Lewis R, Rossmoore H, Fink J, Harney J, Trout D. Respiratory illness in workers exposed to metalworking fluid contaminated with nontuberculous mycobacteria—Ohio, 2001. MMWR Morb Mortal Wkly Rep. 2002; 51(16):349–352. 12004986
140 Zeiger E, Anderson B, Haworth S, Lawlor T, Mortelmans K. Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ Mol Mutag. 1992; 19 Suppl 21:2-141. 10.1002/em.2850190603
141 Witt KL, Livanos E, Kissling GE, Torous DK, Caspary W, Tice RR, Recio L. Comparison of flow cytometry- and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res. 2008; 649(1-2):101–113. 10.1016/j.mrgentox.2007.08.004 17869571
142 Dertinger SD, Camphausen K, Macgregor JT, Bishop ME, Torous DK, Avlasevich S, Cairns S, Tometsko CR, Menard C, Muanza T, et al. Three-color labeling method for flow cytometric measurement of cytogenetic damage in rodent and human blood. Environ Mol Mutag. 2004; 44(5):427-435. 10.1002/em.20075
143 Kissling GE, Dertinger SD, Hayashi M, MacGregor JT. Sensitivity of the erythrocyte micronucleus assay: Dependence on number of cells scored and inter-animal variability. Mutat Res. 2007; 634(1-2):235–240. 10.1016/j.mrgentox.2007.07.010 17851117
144 United States Environmental Protection Agency (USEPA). Method 1664, revision A: n-Hexane Extractable Material (HEM; oil and grease) and silica gel treated n-Hexane Extractable Material (SGT HEM; non polar material) by extraction and gravimetry. Washington, DC: U.S. Environmental Protection Agency, Office of Water; 1999. EPA 821-R-89-98-002; PB99-1-21949.
145 Epping G, Van Baarlen J, Van Der Valk PD. Toxic alveolitis after inhalation of a water repellent. Int J Occup Med Environ Health. 2011; 24(4):409–413. 10.2478/s13382-011-0038-7 22002324