# Conclusions

Under the conditions of these 2-year inhalation studies, there was equivocal evidence of carcinogenic activity (see Explanation of Levels of Evidence; a summary of the Peer Review Panel comments and the public discussion on this Technical Report appears in Appendix K) of TRIM VX in male Wistar Han rats based on the combined occurrences of alveolar/bronchiolar adenoma or carcinoma of the lung. There was equivocal evidence of carcinogenic activity of TRIM VX in female Wistar Han rats based on the occurrences of alveolar/bronchiolar adenoma of the lung. There was clear evidence of carcinogenic activity of TRIM VX in male B6C3F1/N mice based on the increased combined incidences of alveolar/bronchiolar adenoma or carcinoma of the lung. There was clear evidence of carcinogenic activity of TRIM VX in female B6C3F1/N mice based on the increased combined incidences of alveolar/bronchiolar adenoma or carcinoma (primarily carcinoma) of the lung.

Exposure to TRIM VX resulted in increased incidences of nonneoplastic lesions of the lung, nose, and larynx in male and female rats and mice, the bronchial lymph node in male and female rats and male mice, and the mediastinal lymph node in male and female rats.