# Discussion

TRIM VX is a metalworking fluid used as a lubricant and coolant liquid and for cleaning tools and parts during machining operations. Occupational exposures to metalworking fluids occur primarily by dermal exposure and inhalation. Inhalation exposure to metalworking fluids has been reported to cause respiratory problems and to be associated with cancer. Metalworking fluids were nominated by the National Institute for Occupational Safety and Health (NIOSH) for study by the National Toxicology Program (NTP). In addition, NIOSH aided in the selection of metalworking fluids for inhalation toxicity testing by NTP, which was based on a combination of considerations including high production volumes and commercial availability, chemical composition, and class. In all, nine metalworking fluids underwent chemical analysis and genetic toxicity assessment prior to selection of four formulations for 3-month inhalation studies: CIMSTAR 3800 (semisynthetic), TRIM VX (soluble oil), Syntilo 1023 (synthetic), and TRIM SC210 (semisynthetic). In all four studies, the respiratory tract was the primary site of toxicity in rats and mice^1^. Based on the respiratory tract toxicity observed in these 3-month studies, CIMSTAR 3800 and TRIM VX were selected for 2-year studies. The findings from the 3-month and 2-year studies with CIMSTAR 3800 have been previously reported^2^. The current Technical Report presents the findings of the 3-month and 2-year inhalation studies of TRIM VX in Wistar Han rats and B6C3F1/N mice.

The exposure concentrations (25 to 400 mg/m^3^) used in the 3-month studies of the four metalworking fluids, including TRIM VX, were selected based on their low toxicity in previously conducted 3-month studies and because generation of higher concentrations was not feasible due to the high water content of the aerosols. TRIM VX, like many other metalworking fluids, is diluted with water before use and workers are typically exposed to aerosols composed primarily of water. Because it is technically difficult to generate and expose animals to liquid aerosols containing high water content, the metalworking fluid aerosols in NTP studies were generated from undiluted concentrates and diluted with clean air to produce the desired concentrations. Thus, the exposure concentrations used in these studies were considerably higher than those encountered in an occupational setting. The NIOSH recommended exposure limit for total particulate mass is 0.5 mg/m^3^ of metalworking fluid mist, and mists are regulated as a nuisance dust by the Occupational Safety and Health Administration with a permissible exposure limit of 15 mg/m^3^.^29^

In the 3-month studies of TRIM VX, there was no exposure-related mortality in rats or mice. Minor body weight decreases occurred in exposed groups of male rats and mice and the decreases were significant at the highest exposure concentration (400 mg/m^3^); body weights of females from both species were similar to those of the chamber controls. Biologically relevant increases in organ weights were recorded in groups exposed to 50 mg/m^3^ or greater and included the liver of male and female rats and mice, the lung of female rats and male and female mice, and the spleen of male and female mice. However, corresponding histologic changes were observed only in the lungs.

The respiratory tract was the primary site of toxicity in rats and mice following TRIM VX inhalation exposure for 3 months. In the lung, nonneoplastic lesions including chronic active inflammation, minimal to mild fibrosis, and infiltration of histiocytes generally occurred in both male and female rats and mice. Minimal to mild bronchiole hyperplasia occurred in the lung of male and female mice. Such lesions are commonly observed in the lungs of rats and mice following inhalation exposure to irritant gases, vapors, and relatively insoluble particulates. Previous studies of metalworking fluid have also found that the lung is a primary target for acute and subchronic toxicity in experimental animals^32; 34-36; 115; 116^. A number of commonly reported histologic changes in the lungs of rodents exposed to metalworking fluids include the accumulation of macrophages, infiltration of inflammatory cells, and thickening of alveolar walls^36; 115; 116^. Fibrosis can be progressive and may result in lung disease, such as interstitial lung disease, characterized by scarring (fibrosis) of the alveolar walls. Interstitial lung disease observed in metalworking fluid workers is often attributed to bacteria, endotoxins, and fungi present in the used fluids^34-36; 132^. However, the TRIM VX used in the current study did not contain these contaminants, indicating that fibrosis may be caused by the chemical constituents or physical properties of TRIM VX.

In the nasal cavity, rats had a greater spectrum of lesions than mice. Hyaline droplet accumulation of the olfactory and respiratory epithelium and suppurative inflammation occurred in all exposed groups of male and female rats and mice. Exposed male and female rats also had hyperplasia and squamous metaplasia of the respiratory epithelium and goblet cell hyperplasia in the nose. Similar lesions have been observed in the nasal cavity of rodents following inhalation exposure to gases, vapors, and particulates. Inflammation and epithelial hyperplasia that is most likely regenerative may result from irritation and damage to the nasal epithelium^117^, and goblet cell hyperplasia and hyaline droplet accumulation are likely adaptive protective responses. Nasal symptoms, such as rhinitis (inflammation of the nasal passages), are common among workers exposed to various types of metalworking fluids including soluble oils^45; 118-120^ Rhinitis may appear in conjunction with other airway diseases such as asthma, which is also reported in metalworking fluid workers^52; 121^.

There were also exposure-related lesions noted in the larynx such as significantly increased incidences of mild to marked squamous metaplasia, minimal to mild squamous hyperplasia, and chronic inflammation in male and female rats and mice. Squamous metaplasia occurred primarily at the base of the epiglottis, an area that normally consists of ciliated columnar epithelium, and when injured, these cells are often replaced by the more resistant squamous epithelium. Squamous metaplasia of the larynx has been reported in 30% to 40% of inhalation studies conducted in rodents^122^. Mild squamous metaplasia of the larynx is considered an adaptive or protective response to repeated irritation of the rodent epithelium, whereas diffuse moderate to severe metaplasia is considered an adverse effect^122^. Only a few NTP inhalation studies, including diethylamine^123^, triethylamine^124^, and CIMSTAR 3800^2^, have shown similar marked squamous metaplasia of the larynx.

Overall, the incidences and severities of nonneoplastic lesions were similar between male and female rats and mice in the 3-month studies. These findings are comparable with the previously conducted 3-month inhalation studies of CIMSTAR 3800, TRIM SC210, and Syntilo 1023^1^. However, the lung fibrosis identified at exposure concentrations as low as 50 mg/m^3^ in rats and 100 mg/m^3^ in mice was specific to TRIM VX exposure. Based on the severity of lung fibrosis in rats and mice, which is considered a secondary response to the observed inflammatory changes, 100 mg/m^3^ was chosen as the highest exposure concentration for the 2-year studies with TRIM VX. This exposure concentration was also selected to allow comparison to the 2-year studies of CIMSTAR 3800^2^.

In the 2-year studies, the survival of male and female rats and mice exposed to 10, 30, or 100 mg/m^3^ TRIM VX was similar to that of the respective chamber controls. Mean body weights of male and female rats and mice were also similar to those of the chamber controls. As with the 3-month studies of TRIM VX, the respiratory tract was the primary target for toxicity in the 2-year studies.

In male rats exposed for 2 years, there was equivocal evidence of TRIM VX carcinogenicity in the lungs. This conclusion was based on the occurrences of one alveolar/bronchiolar adenoma and two alveolar/bronchiolar carcinomas in the 100 mg/m^3^ group. There was a positive trend in the incidences of alveolar/bronchiolar carcinoma, as well as a positive trend in the combined incidences of alveolar/bronchiolar adenoma or carcinoma. Alveolar/bronchiolar carcinomas are uncommon for the Wistar Han rat strain: the incidence of carcinoma (2/50) in the 100 mg/m^3^ group exceeded the historical control incidences for inhalation studies (0/150) and all routes (0/299). The combined incidence of alveolar/bronchiolar adenoma or carcinoma (3/50) in the 100 mg/m^3^ group was at the upper end of the historical control ranges for inhalation studies (0% to 6%) and all routes (0% to 6%). In addition, the incidences of alveolar epithelium hyperplasia and alveolar/bronchiolar epithelium hyperplasia were significantly increased (P < 0.001) in all exposed groups of male rats. The severities of these nonneoplastic lesions increased slightly with increasing exposure concentration and may have contributed to the development of adenoma and carcinoma in the lung. Taken together, the low occurrence of these tumors was considered to be equivocal evidence of carcinogenic activity.

In female rats exposed to TRIM VX for 2 years, there was equivocal evidence of carcinogenic activity in the lung. This conclusion was based on the low incidence of alveolar/bronchiolar adenoma in the 100 mg/m^3^ group, which had a positive trend. The incidence of adenoma (3/50) in the 100 mg/m^3^ group, two of which consisted of multiple adenomas, exceeded the historical control incidences for inhalation studies (0/150) and all routes (0/300); however, the response was not robust and the incidence was not significantly increased compared to the chamber controls. As in male rats, the incidences of alveolar epithelium hyperplasia and alveolar/bronchiolar epithelium hyperplasia were significantly increased (P < 0.001) in all exposed groups of female rats. The severities of these nonneoplastic lesions increased from minimal to mild with increasing exposure concentration. However, there were no carcinomas observed in female rats, while two were observed in the male rats. Taken together, the low incidences of alveolar/bronchiolar adenoma were considered to be equivocal evidence of carcinogenic activity in female rats.

Additional findings in the rats included a cystic keratinizing epithelioma in one female exposed to 100 mg/m^3^ and several other nonneoplastic lesions which increased in severity and incidence with increasing exposure concentration. Alveolar epithelium hyperplasia and alveolar/ bronchiolar epithelium hyperplasia, fibrosis, histiocytic cellular infiltration, and chronic active inflammation were significantly increased in all exposed groups of males and females. There were also significantly increased incidences of alveolar epithelium squamous metaplasia, lymphohistiocytic hyperplasia of the bronchus-associated lymphoid tissue, and alveolar proteinosis in some exposed groups of males and females. These nonneoplastic lesions are commonly observed in inhalation studies of irritant gases, vapors, and particulates.

In male and female mice exposed to TRIM VX for 2 years, there was clear evidence of carcinogenic activity in the lung. In males, this was based on the significantly increased incidence of alveolar/bronchiolar adenoma or carcinoma (combined) in the 100 mg/m^3^ group, which occurred with a positive trend. Also, the combined incidence in the 100 mg/m^3^ group (46%) exceeded the historical control ranges for inhalation studies (26% to 32%) and all routes (16% to 38%). In males, the incidence of multiple alveolar/bronchiolar carcinoma was significantly increased in the 100 mg/m^3^ group. In females, the incidences of alveolar/bronchiolar carcinoma and alveolar/bronchiolar adenoma or carcinoma (combined) were significantly increased in the 100 mg/m^3^ group, and there were positive trends in the incidences of these neoplasms. In 100 mg/m^3^ females, the incidence of alveolar/ bronchiolar carcinoma (28%) and the combined incidence of alveolar/bronchiolar adenoma or carcinoma (40%) exceeded the historical control ranges for inhalation studies (2% to 10% and 6% to 18%, respectively). There were increased incidences of multiple alveolar/bronchiolar adenoma and multiple alveolar/bronchiolar carcinoma in females, but the incidences were not statistically significant. The incidences of alveolar epithelium hyperplasia and alveolar/bronchiolar epithelium hyperplasia were significantly increased (P < 0.001) in both male and female mice exposed to 100 mg/m^3^. In general, these lesions were qualitatively similar to those observed in rats. As noted for rats, the severities of these lesions increased with increasing exposure concentration and may have contributed to the development of adenoma and carcinoma in the lung.

Additional nonneoplastic lung lesions noted in male and female mice after a 2-year exposure to TRIM VX included histiocytic cellular infiltration and chronic inflammation. There were also significantly increased incidences of lung fibrosis in both sexes. These lesions were qualitatively similar to the nonneoplastic lung lesions observed in rats but were not as severe. In general, the incidences increased with increasing exposure concentration and were most severe in the 100 mg/m^3^ groups.

In the 2-year studies, lung neoplasms were accompanied by a range of inflammatory and nonneoplastic lesions of the respiratory tract. Prolonged exposure to TRIM VX appeared to cause progressive injury to the lungs in both rats and mice, as indicated by the increased incidences and severities of the nonneoplastic lesions relative to the 3-month studies, and may have contributed to the development of pulmonary neoplasms in mice. There have been no epidemiologic studies evaluating the potential carcinogenicity of TRIM VX exposure. The epidemiologic data that are available do not show an association between lung cancer and exposure to other soluble oil metalworking fluids^74; 125; 126^. However, most retrospective evaluations that associate metalworking fluid exposure and cancer in humans are limited by the facts that these products are chemical mixtures that change over time, exposure information was not always attributed to a particular class of metalworking fluid, and confounding personal behaviors such as smoking were also present.

Several other nonneoplastic lesions were noted in the nose, larynx, and lymph nodes of both rats and mice following TRIM VX exposure for 2 years; however, there was no indication of carcinogenicity at these sites. In the nasal cavity of rats, there were significantly increased incidences of olfactory epithelium glands hyperplasia, goblet cell hyperplasia, suppurative inflammation, and olfactory and respiratory epithelium hyaline droplet accumulation in all exposed groups of males and females. There were also significantly increased incidences of respiratory epithelium hyperplasia in some exposed groups of males and females and transitional epithelium hyperplasia in females. In the nasal cavity of all exposed groups of male and female mice, there were significantly increased incidences of exudate, chronic active inflammation, and olfactory and respiratory epithelium hyaline droplet accumulation. In addition, there were significantly increased incidences of atrophy and necrosis in the respiratory epithelium of some groups of male and female mice. The incidences of turbinate atrophy, turbinate perforation, and nasopharyngeal duct perforation were increased in male and female mice exposed to 30 or 100 mg/m^3^. With the exception of exudate and associated turbinate and nasopharyngeal duct perforation, these lesions are not uncommon in inhalation studies with irritating gases, aerosols, or particulates. An increased incidence of nasal carcinoma has not been reported in metalworking fluid workers.

In the larynx of rats, there were significantly increased incidences of squamous hyperplasia and squamous metaplasia of the epiglottis and mixed cell infiltration cellular in all exposed male and female groups. Similarly, in mice there were significantly increased incidences of squamous hyperplasia of the epiglottis in 30 and 100 mg/m^3^ males and females and squamous metaplasia of the epiglottis in all exposed groups of males and females. These lesions in the larynx were morphologically similar in rats and mice. In inhalation studies with laboratory rodents, squamous hyperplasia and squamous metaplasia are considered adaptive/protective responses to chronic irritation or injury to the laryngeal epithelium, rather than preneoplastic responses^127^. These lesions are not considered preneoplastic in the larynx since they have not been accompanied by laryngeal squamous cell tumors in rats or mice in NTP studies. Although cancer of the larynx is rare in rodents, squamous cell carcinoma of the larynx is one of the most common cancers of the respiratory tract in humans^128^. Epidemiologic studies have reported increased laryngeal cancer in workers exposed to straight oil metalworking fluids^69^; however, the evidence was significantly less for workers exposed to soluble oils^68; 74^.

Nonneoplastic lesions were also noted in the lymph nodes of rats and mice. In the bronchial and mediastinal lymph nodes of rats, there were significantly increased incidences of lymphohistiocytic hyperplasia in all exposed groups of males and females and the severities increased with exposure concentration. In the bronchial lymph node of male mice, there were significantly increased incidences of lymphoid hyperplasia and histiocytic cellular infiltration that were morphologically similar to the nonneoplastic lesions that occurred in the lymph nodes of male and female rats and diagnosed as lymphohistiocytic hyperplasia. These lymph nodes drain the lung, thus the changes observed most likely reflect the inflammatory lesions in the lung.

There are no published genotoxicity data for TRIM VX. In the current study, TRIM VX was not mutagenic in several bacterial strains and no indication of chromosomal damage in erythrocytes of rats or mice was observed after 3 months of exposure to TRIM VX. NTP has evaluated the mutagenicity of a variety of different metalworking fluids in bacteria and most were shown to be negative^129^. However, older formulations of metalworking fluids that contained nitrosating agents were associated with DNA damage in a single epidemiologic study^130^. Although newer formulations of metalworking fluids used after 1980 do not contain nitrosating agents, it is possible that other components of these mixtures may have genotoxic potential. To that end, several components of TRIM VX have been tested for mutagenicity and all but one were found to be inactive. The one exception is α-terpineol, which demonstrated weak activity in Salmonella typhimurium strain TA102, a strain that is sensitive to oxygen radicals^75^.

Overall, a wide spectrum of nonneoplastic lesions of the lung, nose, larynx, and lymph nodes were significantly increased across exposure groups, many of which were observed at the lowest concentration tested (10 mg/m^3^). Workers exposed to metalworking fluids report a wide variety of respiratory conditions including hypersensitivity pneumonitis, impaired lung function, and asthma. Furthermore, work-related asthma is one of the most prevalent occupational disorders and is associated with significant costs in healthcare and workers’ compensation^131^. Although there has been no previous association between metalworking fluid exposure and lung cancer, this study also suggests that chronic exposure to TRIM VX may lead to the development of lung tumors. Interestingly, evidence of systemic toxicity or carcinogenicity was minimal in animals exposed to TRIM VX, which implies that TRIM VX-related toxicity may be limited to the site of contact.

TRIM VX toxicity was evaluated as part of a larger comparative assessment of currently marketed metalworking fluids. In this paradigm, TRIM VX results can be compared to results previously obtained in a NTP carcinogenicity study of CIMSTAR 3800, a semisynthetic metalworking fluid^2^. In both 2-year studies, identical exposure concentrations (10, 30, and 100 mg/m^3^) were evaluated by inhalation in B6C3F1/N mice and Wistar Han rats. Overall, rats and mice in the TRIM VX studies had a greater spectrum of inflammatory and nonneoplastic proliferative lesions in the lung, nose, and larynx when compared to animals exposed to CIMSTAR 3800. One notable difference between the two metalworking fluids was the occurrence of fibrosis in the lungs of rats and mice in TRIM VX studies. Fibrosis was not observed in the CIMSTAR 3800 studies. In rats and mice, pulmonary fibrosis is a common response to particulate exposure and is usually associated with areas of chronic injury and inflammation^132-134^. Fibrosis is not considered to be due to direct injury to the fibroblast but is secondary to the chronic inflammatory processes in the lungs of exposed rodents and related to production and release of potentially fibrogenic mediators, fibronectin, and growth factors by alveolar macrophages and other inflammatory cells^135; 136^. The lack of fibrosis in the CIMSTAR 3800 studies may be entirely due to the lack of significant inflammatory responses in the lungs of rats and mice compared to that observed in rats and mice exposed to TRIM VX.

Furthermore, there was clear evidence for carcinogenicity in male and female mice exposed to TRIM VX and only some evidence for carcinogenicity in female mice exposed to CIMSTAR 3800 based on the incidence of lung tumors. In the rats exposed to TRIM VX, lung tumors may have been treatment related but there was no evidence for carcinogenicity in rats exposed to CIMSTAR 3800 for 2 years. There was evidence of systemic toxicity in mice exposed to CIMSTAR 3800 based on an increase in the incidences of nonneoplastic lesions and follicular cell carcinoma in the thyroid gland of females. Furthermore, there was equivocal evidence for carcinogenic activity in the prostate gland, brain, skin, and uterus of rats exposed to CIMSTAR 3800 for 2 years. In contrast, evidence for systemic toxicity or carcinogenic activity was minimal in rodents exposed to TRIM VX. To summarize, these data suggest that TRIM VX toxicity may be limited to the site of contact whereas CIMSTAR 3800 exposure may elicit a broader range of toxicity^2^.

In previous literature, metalworking fluid toxicity was speculated to be associated with chemical by-products, accumulating metals, added biocides or anticorrosives, bacterial growth, and endotoxins^32; 35; 137-139^. In the TRIM VX and CIMSTAR 3800 studies, only unused formulations were evaluated in order to eliminate the confounding effects of contaminants. Although a complete chemical analysis was not performed, several major chemical groups were identified in TRIM VX (soluble oil) and CIMSTAR 3800 (semisynthetic). Notable differences in water and oil content, and oil-soluble components (Table H-2), could account for the variances in the nonneoplastic lung responses that occurred in the TRIM VX and CIMSTAR 3800 studies.