# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TR-591.

## Rats

### Three-month Study

All rats survived to the end of the study, and the mean body weights of exposed groups of females were similar to those of the chamber controls (Table 3; Figure 1). Final mean body weights of 25 and 400 mg/m^3^ males and the mean body weight gain of 400 mg/m^3^ males were significantly less than those of the chamber controls; however, the effect in the 25 mg/m^3^ males was not considered biologically relevant. There were no chemical-related clinical observations in male or female rats^111^.

Table 3 Survival and Body Weights of Rats in the Three-month Inhalation Study of TRIM VX^a^

Concentration (mg/m^3^) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 152 ± 3 | 425±8 | 273±8
25 | 10/10 | 149 ± 3 | 387 ± 8* | 238 ± 7 | 91
50 | 10/10 | 150 ± 3 | 416 ± 9 | 267 ± 10 | 98
100 | 10/10 | 148 ± 3 | 404 ± 8 | 255 ± 8 | 95
200 | 10/10 | 149 ± 2 | 413 ± 12 | 263 ± 12 | 97
400 | 10/10 | 150 ± 3 | 380 ± 14* | 230 ± 13* | 89
Female
0 | 10/10 | 117 ± 3 | 237 ± 6 | 120 ± 5
25 | 10/10 | 116 ± 2 | 222 ± 5 | 106 ± 5 | 94
50 | 10/10 | 115 ± 2 | 230 ± 5 | 115 ± 5 | 97
100 | 10/10 | 115 ± 2 | 232 ± 6 | 118 ± 4 | 98
200 | 10/10 | 117 ± 3 | 236 ± 6 | 119 ± 7 | 99
400 | 10/10 | 116 ± 2 | 227 ± 6 | 111 ± 5 | 96

* Significantly different (P ≤ 0.05) from the chamber control group by Dunnett’s test.

^a^ Weights and weight changes are given as mean ± standard error.

^b^ Number of animals surviving at 14 weeks/number initially in group.

Figure 1

Growth Curves for Rats Exposed to TRIM VX by Inhalation for Three Months

A low number of changes were observed in the hematology parameters; however, these changes were mild and not considered toxicologically relevant (Table F-1). Several minimal to mild or sporadic alterations in the clinical chemistry parameters were also observed, but were not considered toxicologically relevant (Table F-1).

The relative liver weights of 200 and 400 mg/m^3^ males and the absolute and relative liver weights of 200 and 400 mg/m^3^ females were significantly increased by 8% to 18% compared to those of the chamber controls (Table 4 and Table G-1). There were no histopathologic changes in liver corresponding to weight changes. The absolute and relative lung weights of females exposed to 100 mg/m^3^ or greater were significantly increased (up to 20%) compared to those of the chamber controls. The absolute and relative lung weights of all exposed male groups were similar to those of the chamber controls.

Table 4 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Three-month Inhalation Study of TRIM VX^a^

| Chamber Control | 25 mg/m^3^ | 50 mg/m^3^ | 100 mg/m^3^ | 200 mg/m^3^ | 400 mg/m^3^
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 425 ± 8 | 387 ± 8* | 416 ± 9 | 404 ± 8 | 413 ± 12 | 380 ± 14*
Liver
Absolute | 12.30 ± 0.35 | 11.75 ± 0.25 | 12.52 ± 0.30 | 12.18 ± 0.47 | 12.87 ± 0.39 | 12.59 ± 0.73
Relative | 28.903 ± 0.499 | 30.416 ± 0.370 | 30.125 ± 0.452 | 30.101 ± 0.785 | 31.244 ± 0.645* | 33.002 ± 0.935**
Lung
Absolute | 2.50 ± 0.13 | 2.17 ± 0.11 | 2.44 ± 0.16 | 2.44 ± 0.14 | 2.52 ± 0.08 | 2.54 ± 0.12
Relative | 5.893 ± 0.311 | 5.622 ± 0.294 | 5.890 ± 0.430 | 6.048 ± 0.312 | 6.154 ± 0.250 | 6.715 ± 0.334
Female
Necropsy body wt | 237 ± 6 | 222 ± 5 | 230 ± 5 | 232 ± 6 | 236 ± 6 | 227 ± 6
Liver
Absolute | 7.39 ± 0.21 | 6.95 ± 0.25 | 7.14 ± 0.25 | 7.56 ± 0.15 | 8.25 ± 0.36* | 8.37 ± 0.25**
Relative | 31.311 ± 0.855 | 31.326 ± 0.758 | 31.045 ± 0.450 | 32.658 ± 0.620 | 34.940 ± 0.888** | 36.843 ± 0.390**
Lung
Absolute | 1.60 ± 0.08 | 1.40 ± 0.06 | 1.56 ± 0.07 | 1.85 ± 0.11* | 1.86 ± 0.08* | 1.85 ± 0.06*
Relative | 6.779 ± 0.279 | 6.301 ± 0.182 | 6.778 ± 0.199 | 7.930 ± 0.368** | 7.953 ± 0.378** | 8.157 ± 0.246**

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** Significantly different (P ≤ 0.01) from the chamber control by Williams’ test.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

In the lung, there were significantly increased incidences of fibrosis and chronic active inflammation in males and females exposed to 50 mg/m^3^ or greater and of histiocytic cellular infiltration in males and females exposed to 100 mg/m^3^ or greater (Table 5). Fibrosis was characterized by the expansion of alveolar ducts or septae by collagen and fibrocytes, mainly at the junction of alveolar ducts and alveoli or at the junction of terminal bronchioles and alveolar ducts. The changes were mild in the 400 mg/m^3^ group and minimal in the other exposed groups. Fibrosis was confirmed by Masson’s trichrome staining of selected lung slides. Chronic active inflammation in the lung was composed of a few lymphocytes, macrophages, or rare neutrophils in the areas of fibrosis and this change was graded as minimal in severity. When the inflammatory cells were also present in the peribronchiolar or perivascular interstitium, the change was graded as mild in severity. Histiocytic cellular infiltration was characterized by the presence of minimal to mild increases in vacuolated alveolar macrophages diffusely scattered within the alveolar spaces. Many of the macrophages were large and contained one to many, clear, round to oval cytoplasmic vacuoles; some also contained brown granular material.

Table 5 Incidences of Nonneoplastic Lesions of the Respiratory System in Rats in the Three-month Inhalation Study of TRIM VX

| Chamber Control | 25 mg/m^3^ | 50 mg/m^3^ | 100 mg/m^3^ | 200 mg/m^3^ | 400 mg/m^3^
Male
Lung^a^ | 10 | 10 | 10 | 10 | 10 | 10
Fibrosis^b^ | 0 | 0 | 10** (1.0)^c^ | 10** (1.0) | 10** (1.1) | 10** (2.0)
Infiltration Cellular, Histiocyte | 0 | 0 | 1 (1.0) | 10** (1.2) | 10** (2.0) | 10** (2.0)
Inflammation, Chronic Active | 0 | 0 | 8** (1.0) | 10** (1.0) | 10** (1.1) | 10** (2.0)
Nose | 10 | 10 | 10 | 10 | 10 | 10
Goblet Cell, Hyperplasia | 0 | 0 | 1 (1.0) | 3 (1.0) | 10** (1.0) | 8** (1.0)
Inflammation, Suppurative | 0 | 10** (1.0) | 10** (1.0) | 10** (1.0) | 10** (1.0) | 10** (1.0)
Olfactory Epithelium, Accumulation Hyaline Droplet | 1 (1.0) | 10** (1.7) | 10** (2.0) | 10** (2.3) | 10** (2.7) | 10** (2.5)
Respiratory Epithelium, Accumulation, Hyaline Droplet | 0 | 10** (1.7) | 10** (2.0) | 10** (2.3) | 10** (2.7) | 7** (2.3)
Respiratory Epithelium, Hyperplasia | 0 | 0 | 0 | 0 | 9** (1.0) | 10** (1.0)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 0 | 4* (1.0) | 7** (1.0)
Larynx | 10 | 10 | 10 | 10 | 10 | 10
Hyperplasia, Squamous | 0 | 8** (1.0) | 8** (1.4) | 7** (1.0) | 10** (1.5) | 10** (2.4)
Inflammation, Chronic Active | 0 | 10** (1.0) | 10** (1.0) | 10** (1.0) | 10** (1.0) | 10** (1.0)
Metaplasia, Squamous | 0 | 10** (2.1) | 10** (2.5) | 10** (2.5) | 10** (3.4) | 10** (3.4)
Female
Lung | 10 | 10 | 10 | 10 | 10 | 10
Fibrosis | 0 | 0 | 10** (1.0) | 10** (1.0) | 10** (1.0) | 10** (2.0)
Infiltration Cellular, Histiocyte | 0 | 0 | 1 (1.0) | 10** (1.3) | 10** (1.9) | 10** (2.0)
Inflammation, Chronic Active | 3 (1.0) | 0 | 9** (1.1) | 10** (1.0) | 10** (1.1) | 10** (2.0)
Nose | 10 | 10 | 10 | 10 | 10 | 10
Goblet Cell, Hyperplasia | 0 | 0 | 0 | 3 (1.0) | 9** (1.0) | 9** (1.0)
Inflammation, Suppurative | 0 | 10** (1.0) | 10** (1.0) | 10** (1.0) | 10** (1.0) | 10** (1.0)
Olfactory Epithelium, Accumulation, Hyaline Droplet | 0 | 10** (2.0) | 10** (2.4) | 10** (2.6) | 10** (2.6) | 10** (2.6)
Respiratory Epithelium, Accumulation, Hyaline Droplet | 0 | 10** (2.0) | 9** (2.4) | 10** (2.6) | 10** (2.6) | 10** (2.6)
Respiratory Epithelium, Hyperplasia | 0 | 0 | 0 | 1 (1.0) | 10** (1.0) | 10** (1.0)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 2 (1.0) | 5* (1.0) | 7** (1.0)
Larynx | 10 | 10 | 10 | 10 | 10 | 10
Hyperplasia, Squamous | 0 | 8** (1.0) | 4* (1.0) | 7** (1.4) | 8** (1.5) | 10** (1.8)
Inflammation, Chronic Active | 0 | 10** (1.0) | 10** (1.0) | 10** (1.0) | 10** (1.0) | 10** (1.0)
Metaplasia, Squamous | 0 | 10** (2.0) | 10** (2.1) | 10** (2.7) | 10** (3.1) | 10** (3.4)

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4=marked.

In the nose, there were significantly increased incidences of suppurative inflammation and olfactory and respiratory epithelium hyaline droplet accumulation in all exposed groups of males and females (Table 5). There were also significantly increased incidences of goblet cell and respiratory epithelium hyperplasia and squamous metaplasia in 200 and 400 mg/m^3^ males and females. Suppurative inflammation was minimal and consisted of small numbers of neutrophils in the submucosa subjacent to areas with hyaline droplet accumulation. Goblet cell hyperplasia consisted of minimally increased numbers of large goblet cells on the medial aspects of the maxilloturbinates of the Level I nasal section and in respiratory epithelium of the Level II nasal section. Hyaline droplet accumulation in the respiratory and olfactory epithelium lining the ethmoturbinates of the Level III nasal section was mild to moderate in severity and was characterized by the presence of variable-sized eosinophilic globules in the cytoplasm. Occasionally, the change was present in the epithelia of Level II. Respiratory epithelial hyperplasia was minimal, present in the ventral aspect of Level I, lateral to the vomeronasal organ at the junction of the squamous and respiratory epithelium, and was characterized by a four to five cell thick pseudostratified columnar epithelium. The change was also present in Level II and sometimes was associated with goblet cell hyperplasia. Squamous metaplasia of respiratory epithelium was of minimal severity and present at the tips of the naso- and maxillary turbinates and lateral walls in Level I. The features ranged from flattening or attenuation of cuboidal cells with loss of cilia to increased numbers of pseudostratified/stratified layers of cells.

In the larynx, there were significantly increased incidences of squamous hyperplasia, squamous metaplasia, and chronic active inflammation in all exposed groups of male and female rats (Table 5). Squamous hyperplasia in the larynx was characterized by thickening of the epithelium (more than three cell layers versus one to two cell layers in chamber controls) overlying the arytenoid cartilages. Squamous metaplasia involved the ventral epithelium at the base of the epiglottis, lateral walls of the anterior section (Level I), and dorsolateral walls and ventral diverticulum of the middle section (Level II). In these areas, the normally pseudostratified ciliated columnar epithelium lining the base of the epiglottis and the nonciliated cuboidal epithelium lining the ventral diverticulum were replaced by squamous epithelium which was sometimes keratinized. Frequently, the metaplastic squamous epithelium was also hyperplastic. Chronic active inflammation frequently accompanied squamous metaplasia and was characterized by the presence of small numbers of lymphocytes, plasma cells, macrophages, and neutrophils or eosinophils between the basal epithelium and the epiglottic cartilage or between the epithelial cells of the mucosa.

Exposure Concentration Selection Rationale: The exposure concentrations selected for the 2-year inhalation study in male and female Wistar Han rats were 10, 30, and 100 mg/m^3^. The highest exposure concentration was based on the incidence and severity of lung fibrosis in the current 3-month study. Although minimal lung fibrosis was present in rats exposed to 50 and 100 mg/m^3^, this lesion was not expected to affect survival in the 2-year study, and use of the same exposure concentrations for rats and mice would facilitate inter-species comparisons. In addition, these concentrations were used in the 2-year study of CIMSTAR 3800 in Wistar Han rats, which allows for comparisons between the two metalworking fluid studies.

### Two-year Study

#### Survival

Estimates of 2-year survival probabilities for male and female rats are shown in Table 6 and in the Kaplan-Meier survival curves (Figure 2). Survival of all exposed groups of male and female rats was similar to that of the chamber control groups.

Table 6 Survival of Rats in the Two-year Inhalation Study of TRIM VX

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Male
Animals initially in study | 50 | 50 | 50 | 50
Moribund | 12 | 10 | 14 | 15
Natural deaths | 2 | 1 | 3 | 1
Animals surviving to study termination | 36 | 39 | 33 | 34
Percent probability of survival at end of study^a^ | 72 | 78 | 66 | 68
Mean survival (days)^b^ | 696 | 710 | 669 | 673
Survival analysis^c^ | P = 0.386 | P = 0.555N | P = 0.588 | P = 0.686
Female
Animals initially in study | 50 | 50 | 50 | 50
Moribund | 19 | 15 | 15 | 16
Natural deaths | 1 | 2 | 2 | 4
Animals surviving to study termination | 30^d^ | 33^d^ | 33 | 30
Percent probability of survival at end of study | 60 | 66 | 66 | 60
Mean survival (days) | 681 | 674 | 697 | 695
Survival analysis | P = 1.000 | P = 0.680N | P = 0.568N | P = 0.947N

^a^ Kaplan-Meier determinations.

^b^ Mean of all deaths (uncensored, censored, and terminal kill).

^c^ The result of the life table trend test^82^ is in the chamber control column, and the results of the life table pairwise comparisons^81^ with the chamber controls are in the exposed group columns. A lower mortality in an exposure group is indicated by N.

^d^ Includes one animal that died during the last week of the study.

Figure 2

Kaplan-Meier Survival Curves for Rats Exposed to TRIM VX by Inhalation for Two Years

#### Body Weights and Clinical Findings

The mean body weights of all exposed groups of males and females were similar to those of the chamber control groups throughout the study (Table 7 and Table 8; Figure 3). Clinical observations included abnormal breathing in a very few males and females exposed to 30 or 100 mg/m^3^.^.112^

Table 7 Mean Body Weights and Survival of Male Rats in the Two-year Inhalation Study of TRIM VX

Day | Chamber Control | | 10 mg/m^3^ | | | 30 mg/m^3^ | | | | 100 mg/m^3^
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 129 | 50 | 128 | 99 | 50 | 127 | 99 | | 50 | 127 | 98 | 50
9 | 176 | 50 | 172 | 98 | 50 | 167 | 95 | | 50 | 169 | 96 | 50
16 | 218 | 50 | 213 | 98 | 50 | 211 | 97 | | 50 | 212 | 97 | 50
23 | 253 | 50 | 246 | 97 | 50 | 246 | 97 | | 50 | 247 | 98 | 50
30 | 283 | 50 | 277 | 98 | 50 | 277 | 98 | | 50 | 279 | 98 | 50
37 | 308 | 50 | 299 | 97 | 50 | 301 | 98 | | 50 | 302 | 98 | 50
44 | 328 | 50 | 318 | 97 | 50 | 321 | 98 | | 50 | 321 | 98 | 50
51 | 346 | 50 | 334 | 97 | 50 | 340 | 98 | | 50 | 339 | 98 | 50
58 | 361 | 50 | 347 | 96 | 50 | 352 | 98 | | 50 | 351 | 97 | 50
65 | 375 | 50 | 359 | 96 | 50 | 367 | 98 | | 50 | 363 | 97 | 50
72 | 388 | 50 | 369 | 95 | 50 | 378 | 98 | | 50 | 373 | 96 | 50
79 | 396 | 50 | 379 | 96 | 50 | 388 | 98 | | 50 | 383 | 97 | 50
86 | 406 | 50 | 386 | 95 | 50 | 397 | 98 | | 50 | 391 | 96 | 50
114 | 431 | 50 | 408 | 95 | 50 | 421 | 98 | | 50 | 415 | 96 | 50
142 | 452 | 50 | 427 | 94 | 50 | 441 | 98 | | 50 | 435 | 96 | 50
170 | 466 | 50 | 442 | 95 | 50 | 456 | 98 | | 50 | 451 | 97 | 50
198 | 481 | 50 | 453 | 94 | 50 | 470 | 98 | | 50 | 461 | 96 | 50
226 | 497 | 50 | 467 | 94 | 50 | 484 | 97 | | 49 | 478 | 96 | 50
254 | 512 | 50 | 482 | 94 | 50 | 499 | 97 | | 49 | 492 | 96 | 50
282 | 521 | 50 | 490 | 94 | 50 | 508 | 97 | | 47 | 501 | 96 | 50
310 | 534 | 50 | 500 | 94 | 50 | 519 | 97 | | 47 | 513 | 96 | 50
338 | 544 | 50 | 506 | 93 | 49 | 529 | 97 | | 47 | 519 | 95 | 50
367 | 554 | 50 | 518 | 93 | 49 | 540 | 98 | | 47 | 529 | 96 | 49
394 | 563 | 50 | 525 | 93 | 49 | 549 | 98 | | 47 | 535 | 95 | 49
422 | 573 | 49 | 534 | 93 | 49 | 557 | 97 | | 47 | 543 | 95 | 48
450 | 580 | 49 | 538 | 93 | 49 | 559 | 96 | | 47 | 546 | 94 | 48
478 | 590 | 49 | 546 | 93 | 49 | 567 | 96 | | 46 | 555 | 94 | 46
506 | 596 | 49 | 558 | 94 | 49 | 575 | 96 | | 46 | 566 | 95 | 45
534 | 603 | 48 | 568 | 94 | 49 | 583 | 97 | | 45 | 568 | 94 | 45
562 | 609 | 45 | 574 | 94 | 49 | 589 | 97 | | 42 | 569 | 93 | 42
590 | 614 | 45 | 582 | 95 | 47 | 592 | 96 | | 42 | 570 | 93 | 40
618 | 621 | 44 | 588 | 95 | 47 | 596 | 96 | | 42 | 573 | 92 | 39
646 | 622 | 42 | 589 | 95 | 47 | 591 | 95 | | 38 | 576 | 93 | 36
674 | 619 | 40 | 587 | 95 | 46 | 605 | 98 | | 36 | 582 | 94 | 36
703 | 600 | 38 | 591 | 99 | 42 | 605 | 101 | | 35 | 578 | 96 | 35
Mean for Weeks
1–13 | 305 | | 294 | 96 | | 298 | | 98 | | 297 | 97
14–52 | 493 | | 464 | 94 | | 481 | | 98 | | 474 | 96
53–101 | 596 | | 561 | 94 | | 578 | | 97 | | 561 | 94

Table 8 Mean Body Weights and Survival of Female Rats in the Two-year Inhalation Study of TRIM VX

Day | Chamber Control | | 10 mg/m^3^ | | | 30 mg/m^3^ | | | 100 mg/m^3^
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 115 | 50 | 115 | 100 | 50 | 115 | 100 | 50 | 114 | 99 | 50
9 | 138 | 50 | 139 | 101 | 50 | 139 | 101 | 50 | 138 | 100 | 50
16 | 154 | 50 | 156 | 101 | 50 | 155 | 101 | 50 | 155 | 100 | 50
23 | 168 | 50 | 170 | 101 | 50 | 171 | 101 | 50 | 169 | 100 | 50
30 | 179 | 50 | 181 | 101 | 50 | 180 | 101 | 50 | 180 | 100 | 50
37 | 188 | 50 | 190 | 101 | 50 | 191 | 102 | 50 | 191 | 101 | 50
44 | 197 | 50 | 199 | 101 | 50 | 199 | 101 | 50 | 198 | 101 | 50
51 | 205 | 50 | 206 | 101 | 50 | 206 | 101 | 50 | 204 | 99 | 50
58 | 209 | 50 | 213 | 102 | 50 | 212 | 101 | 50 | 211 | 101 | 50
65 | 215 | 50 | 218 | 101 | 50 | 218 | 101 | 50 | 216 | 101 | 50
72 | 221 | 50 | 222 | 100 | 50 | 222 | 100 | 50 | 220 | 100 | 50
79 | 224 | 50 | 226 | 101 | 50 | 226 | 101 | 50 | 223 | 100 | 50
86 | 227 | 50 | 228 | 101 | 50 | 227 | 100 | 50 | 226 | 100 | 50
114 | 239 | 50 | 241 | 101 | 49 | 239 | 100 | 50 | 240 | 100 | 50
142 | 246 | 50 | 251 | 102 | 49 | 246 | 100 | 50 | 246 | 100 | 50
170 | 256 | 50 | 258 | 101 | 49 | 251 | 98 | 50 | 252 | 99 | 50
198 | 260 | 50 | 264 | 102 | 49 | 259 | 100 | 50 | 256 | 99 | 50
226 | 267 | 50 | 273 | 102 | 49 | 264 | 99 | 50 | 265 | 99 | 50
254 | 275 | 50 | 276 | 101 | 49 | 271 | 99 | 50 | 270 | 98 | 50
282 | 279 | 50 | 283 | 102 | 49 | 277 | 99 | 50 | 277 | 99 | 50
310 | 289 | 50 | 296 | 103 | 49 | 288 | 100 | 50 | 285 | 99 | 50
338 | 296 | 50 | 299 | 101 | 49 | 294 | 99 | 50 | 291 | 98 | 50
367 | 301 | 49 | 313 | 104 | 47 | 303 | 101 | 50 | 300 | 100 | 50
394 | 313 | 49 | 322 | 103 | 47 | 312 | 100 | 50 | 307 | 98 | 50
422 | 324 | 49 | 331 | 102 | 47 | 324 | 100 | 50 | 318 | 98 | 50
450 | 334 | 49 | 341 | 102 | 47 | 333 | 100 | 50 | 321 | 96 | 49
478 | 342 | 49 | 352 | 103 | 47 | 342 | 100 | 50 | 329 | 96 | 49
506 | 353 | 49 | 362 | 103 | 46 | 353 | 100 | 50 | 339 | 96 | 49
534 | 359 | 48 | 374 | 104 | 45 | 361 | 101 | 48 | 351 | 98 | 48
562 | 361 | 45 | 381 | 106 | 45 | 365 | 101 | 48 | 355 | 98 | 48
590 | 367 | 42 | 393 | 107 | 43 | 373 | 102 | 47 | 361 | 98 | 46
618 | 372 | 37 | 402 | 108 | 41 | 380 | 102 | 43 | 368 | 99 | 42
646 | 378 | 36 | 411 | 109 | 39 | 381 | 101 | 40 | 368 | 98 | 41
674 | 389 | 34 | 420 | 108 | 35 | 388 | 100 | 38 | 372 | 96 | 39
703 | 391 | 32 | 424 | 108 | 35 | 391 | 100 | 34 | 371 | 95 | 36
Mean for Weeks
1–13 | 188 | | 189 | 101 | | 189 | 101 | | 188 | 100
14–52 | 267 | | 271 | 101 | | 265 | 99 | | 265 | 99
53–101 | 352 | | 371 | 105 | | 354 | 100 | | 343 | 97

Figure 3

Growth Curves for Rats Exposed to TRIM VX by Inhalation for Two Years

#### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and nonneoplastic lesions of the lung, nose, larynx, and bronchial and mediastinal lymph nodes. Summaries of the incidences of neoplasms and nonneoplastic lesions, statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group, and historical incidences for the neoplasms mentioned in this section are presented in Appendix A for male rats and Appendix B for female rats.

Lung: There was an increased incidence of alveolar/ bronchiolar carcinoma in 100 mg/m^3^ males that resulted in a positive trend for carcinoma alone (Table 9, Table A-1, and Table A-2). When combined with the incidence of alveolar/ bronchiolar adenoma in 100 mg/m^3^ males, there was a positive trend in the incidences; however, the combined incidence was not statistically significant compared to the chamber control group. In females, there was an increased incidence of alveolar/bronchiolar adenoma at 100 mg/m^3^ which included two animals with multiple adenomas (Table 9, Table B-1, and Table B-2). Although the incidence of alveolar/bronchiolar adenoma in the 100 mg/m^3^ females was not statistically significant, there was a positive trend in the incidences of this neoplasm. Alveolar/bronchiolar carcinomas in males and adenomas in females have not occurred in historical control Wistar Han rats (Table 9, Table A-3, and Table B-3). One 100 mg/m^3^ female had a cystic keratinizing epithelioma; this neoplasm has not occurred in historical controls from all routes of exposure (Table 9 and Table B-3).

Table 9 Incidences of Neoplasms and Nonneoplastic Lesions of the Respiratory System in Rats in the Two-year Inhalation Study of TRIM VX

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Male
Lung^a^ | 50 | 50 | 50 | 50
Alveolar Epithelium, Hyperplasia^b^ | 11 (1.2)^c^ | 43** (1.3) | 45** (1.5) | 49** (2.1)
Alveolar Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 5* (1.4)
Alveolar/bronchiolar Epithelium, Hyperplasia | 4 (1.0) | 22** (1.0) | 39** (1.2) | 46** (1.8)
Alveolus, Proteinosis | 0 | 1 (1.0) | 31** (1.2) | 45** (2.2)
Bronchus-associated Lymphoid Tissue, Hyperplasia, Lymphohistiocytic | 0 | 1 (1.0) | 4 (1.3) | 6* (1.0)
Fibrosis | 4 (1.0) | 43** (1.0) | 45** (1.4) | 49** (1.3)
Infiltration Cellular, Histiocyte | 14 (1.0) | 50** (1.4) | 50** (2.0) | 50** (2.6)
Inflammation, Chronic Active | 7 (1.0) | 46** (1.0) | 46** (2.0) | 48** (3.0)
Alveolar/bronchiolar Adenoma^d^ | 0 | 0 | 0 | 1
Alveolar/bronchiolar Carcinoma^e^
Overall rate^f^ | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 2/50 (4%)
Adjusted rate^g^ | 0.0% | 0.0% | 0.0% | 4.8%
Terminal rate^h^ | 0/36 (0%) | 0/39 (0%) | 0/33 (0%) | 2/34 (6%)
First incidence (days) | –^j^ | – | – | 729 (T)
Poly-3 test^i^ | P = 0.036 | –^k^ | – | P = 0.221
Alveolar/bronchiolar Adenoma or Carcinoma^d^
Overall rate | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 7.2%
Terminal rate | 0/36 (0%) | 0/39 (0%) | 0/33 (0%) | 3/34 (9%)
First incidence (days) | – | – | – | 729 (T)
Poly-3 test | P = 0.007 | – | – | P = 0.106
Nose | 50 | 50 | 50 | 50
Glands, Olfactory Epithelium, Hyperplasia | 0 | 43** (1.5) | 41** (1.6) | 49** (1.9)
Goblet Cell, Hyperplasia | 5 (1.4) | 36** (1.0) | 37** (1.1) | 42** (1.2)
Inflammation, Suppurative | 7 (1.1) | 46** (1.2) | 47** (1.3) | 46** (1.1)
Olfactory Epithelium, Accumulation, Hyaline Droplet | 20 (1.4) | 50** (2.8) | 50** (2.9) | 50** (3.2)
Respiratory Epithelium, Accumulation, Hyaline Droplet | 10 (1.2) | 50** (1.4) | 48** (1.4) | 50** (1.6)
Respiratory Epithelium, Hyperplasia | 2 (1.0) | 7 (1.0) | 7 (1.0) | 19** (1.1)
Transitional Epithelium, Hyperplasia | 7 (1.3) | 7 (1.0) | 8 (1.4) | 13 (1.5)
Larynx | 50 | 50 | 50 | 50
Epiglottis, Hyperplasia, Squamous | 0 | 26** (1.1) | 48** (1.8) | 50** (2.4)
Epiglottis, Metaplasia, Squamous | 3 (1.0) | 50** (1.4) | 50** (2.1) | 50** (2.6)
Infiltration Cellular, Mixed Cell | 1 (1.0) | 9* (1.1) | 27** (1.0) | 31** (1.1)
Lymph Node, Bronchial | 39 | 43 | 42 | 42
Hyperplasia, Lymphohistiocytic | 0 | 17** (1.4) | 29** (1.8) | 35** (1.9)
Lymph Node, Mediastinal | 43 | 48 | 44 | 43
Hyperplasia, Lymphohistiocytic | 0 | 20** (1.5) | 22** (1.9) | 32** (2.5)
Female
Lung | 50 | 50 | 50 | 50
Alveolar Epithelium, Hyperplasia | 8 (1.3) | 43** (1.1) | 49** (2.0) | 50** (2.4)
Alveolar Epithelium, Metaplasia, Squamous | 0 | 3 (1.3) | 9** (1.3) | 21** (1.9)
Alveolar/bronchiolar Epithelium, Hyperplasia | 2 (1.0) | 9* (1.1) | 31** (1.4) | 50** (2.8)
Alveolus, Proteinosis | 1 (1.0) | 15** (1.0) | 41** (1.4) | 48** (2.8)
Bronchus-associated Lymphoid Tissue, Hyperplasia, Lymphohistiocytic | 0 | 2 (1.0) | 7** (1.0) | 10** (1.4)
Fibrosis | 5 (1.0) | 35** (1.1) | 49** (1.5) | 50** (1.8)
Infiltration Cellular, Histiocyte | 16 (1.1) | 48** (1.3) | 50** (1.8) | 50** (2.8)
Inflammation, Chronic Active | 5 (1.0) | 46** (1.0) | 50** (2.0) | 50** (3.2)
Cystic Keratinizing Epithelioma^l^ | 0 | 0 | 0 | 1
Alveolar/bronchiolar Adenoma, Multiple | 0 | 0 | 0 | 2
Alveolar/bronchiolar Adenoma (includes multiple)^l^
Overall rate | 0/50 (0%) | 0/50 (0%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 0.0% | 0.0% | 2.3% | 6.8%
Terminal rate | 0/30 (0%) | 0/33 (0%) | 1/33 (3%) | 3/30 (10%)
First incidence (days) | – | – | 731 (T) | 731 (T)
Poly-3 test | P = 0.024 | – | P = 0.511 | P = 0.127
Nose | 50 | 50 | 49 | 50
Glands, Olfactory Epithelium, Hyperplasia | 0 | 32** (1.1) | 43** (1.1) | 46** (1.5)
Goblet Cell, Hyperplasia | 3 (1.0) | 36** (1.0) | 40** (1.1) | 47** (1.1)
Inflammation, Suppurative | 1 (1.0) | 46** (1.2) | 47** (1.2) | 48** (1.3)
Olfactory Epithelium, Accumulation, Hyaline Droplet | 14 (1.2) | 50** (2.8) | 49** (2.9) | 50** (3.0)
Respiratory Epithelium, Accumulation, Hyaline Droplet | 5 (1.2) | 50** (1.5) | 48** (1.5) | 50** (1.5)
Respiratory Epithelium, Hyperplasia | 0 | 7** (1.0) | 8** (1.0) | 25** (1.0)
Transitional Epithelium, Hyperplasia | 5 (1.2) | 11 (1.1) | 4 (1.0) | 21** (1.3)
Larynx | 50 | 50 | 50 | 50
Epiglottis, Hyperplasia, Squamous | 1 (1.0) | 24** (1.6) | 41** (1.4) | 50** (2.3)
Epiglottis, Metaplasia, Squamous | 0 | 49** (1.4) | 50** (2.2) | 50** (2.7)
Infiltration Cellular, Mixed Cell | 0 | 9** (1.0) | 18** (1.1) | 22** (1.1)
Lymph Node, Bronchial | 37 | 37 | 44 | 36
Hyperplasia, Lymphohistiocytic | 1 (1.0) | 18** (1.3) | 37** (1.6) | 31** (1.8)
Lymph Node, Mediastinal | 46 | 49 | 46 | 45
Hyperplasia, Lymphohistiocytic | 0 | 11** (1.3) | 14** (1.6) | 28** (2.2)

* Significantly different (P ≤ 0.05) from the chamber control group by the Poly-3 test.

** P ≤ 0.01.

(T) Terminal kill.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical incidence for 2-year inhalation studies with chamber control groups (mean ± standard deviation): 4/150 (2.7% ± 3.1%), range 0%–6%; all routes: 4/299 (1.3% ± 2.4%), range 0%–6%.

^e^ Historical incidence for inhalation studies: 0/150; all routes: 0/299.

^f^ Number of animals with neoplasm per number of animals with lung examined microscopically.

^g^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^h^ Observed incidence at terminal kill.

^i^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

^j^ Not applicable; no neoplasm in animal group.

^k^ Value of statistic cannot be computed.

^l^ Historical incidence for inhalation studies: 0/150; all routes: 0/300.

Alveolar/bronchiolar neoplasms were morphologically typical of those that occur spontaneously in rats. Adenomas were small, circumscribed, and nodular to slightly irregularly shaped masses that distorted and sometimes partially compressed surrounding tissue (Figure 7). They were composed of poorly defined, glandular and/or papillary like structures lined by one to a few rows of loosely to densely packed, generally uniform, well-differentiated cuboidal epithelial cells (Figure 8). In some instances, adenomas were located within large areas of marked, noncompressive, alveolar epithelial hyperplasia; however, adenoma cells were usually larger than those in areas of alveolar epithelial hyperplasia. Alveolar/bronchiolar carcinomas were generally larger, irregularly shaped, expansile and invasive masses that effaced the normal alveolar architecture and compressed the surrounding parenchyma (Figure 9). Component neoplastic cells were densely packed, pleomorphic and had a heterogeneous growth with areas of poorly defined, irregular, glandular and/or papillary structures and occasionally solid sheets, incompletely separated by fibrous trabeculae (Figure 10). The cells had oval to round, hyperchromatic to vesicular nuclei often with prominent nucleoli and variable amounts of often finely vacuolated cytoplasm. Carcinomas contained scattered foci of necrosis and/or neutrophils.

The cystic keratinizing epithelioma had the characteristic morphology of this neoplasm type. It was a large, compressive mass with an irregular, thick wall of multi-layered, well-differentiated squamous epithelium that surrounded a large central cavity packed with massive accumulations of lamellated to whorled keratin aggregates, necrotic debris, and inflammatory cells (Figure 11 and Figure 12). The squamous-type lining wall of the cystic keratinizing epithelioma was in close contact and focally contiguous with an adjacent area of alveolar epithelial squamous metaplasia. The toxicological significance of the neoplasm in this study is unknown due to the single occurrence in one female rat.

Exposure to TRIM VX resulted in increased incidences of a complex spectrum of nonneoplastic lesions in the lung. The lesions were multifocal to locally extensive and were frequently intermingled and contiguous such that it was sometimes difficult to establish clear demarcations between the various changes. There were significantly increased incidences of alveolar epithelium hyperplasia, alveolar/bronchiolar epithelium hyperplasia, fibrosis, histiocytic cellular infiltration, and chronic active inflammation in all exposed groups of males and females (Table 9, Table A-4, and Table B-4). There were significantly increased incidences of alveolar epithelium squamous metaplasia and lymphohistiocytic hyperplasia of bronchus-associated lymphoid tissue (BALT) in 100 mg/m^3^ males and 30 and 100 mg/m^3^ females. There were also significantly increased incidences of alveolus proteinosis in 30 and 100 mg/m^3^ males and all exposed groups of females. The severity of these lesions generally increased with exposure concentration.

Alveolar epithelium hyperplasia consisted of multifocal to confluent, discrete, irregularly shaped, minimal to marked proliferations of alveolar epithelial cells in which the alveolar architecture was still discernable (Figure 13). Component epithelial cells that lined the alveolar septa were well-differentiated, plump, and typically cuboidal cells (Figure 14). There was minimal focal crowding and disorganization. The hyperplastic areas blended inconspicuously with adjacent normal alveolar parenchyma and ranged from small foci composed of only a few alveoli to extensive zones that could involve most of an individual lobe, but even the largest hyperplasias did not cause compression of the adjacent parenchyma. Areas of alveolar epithelial hyperplasia were often intermingled or contiguous with areas of other treatment-related nonneoplastic lung lesions.

Alveolar/bronchiolar epithelium hyperplasia consisted of multifocal cellular proliferations in which the distal terminal bronchioles, alveolar ducts, and immediately adjacent septa (periacinar region) were lined by single to few crowded layers of tall cuboidal to columnar ciliated cells that had vesicular oval nuclei and pale eosinophilic cytoplasm (Figure 15 and Figure 16). These changes did not extend into the more proximal terminal bronchioles. Alveolar epithelium squamous metaplasia consisted of scattered, small to quite large, irregular foci in which the alveolar septa and sometimes the alveolar ducts were lined by multiple layers of well-differentiated squamous epithelium (Figure 17 and Figure 18). Superficial keratinization was generally present and in some areas was so abundant as to occlude affected alveoli. Areas of alveolar epithelium hyperplasia, alveolar/bronchiolar epithelium hyperplasia, and alveolar squamous metaplasia were often contiguous and/or admixed with each other, often without clear demarcation between these changes.

Infiltration, cellular, histiocyte consisted of multifocal variably sized areas in which the alveoli contained few to many macrophages (histiocytes). The infiltrates were mixtures of small to swollen macrophages that typically had small, round to oval nuclei and abundant, pale pink to grayish, finely granular or foamy cytoplasm (Figure 19 and Figure 20). Frequently, the cells were distended with deeply eosinophilic proteinaceous material that sometimes contained angular eosinophilic crystals. Histiocytic cell infiltrates were often closely intermingled with intra-alveolar eosinophilic protein material (proteinosis), but frequently, histiocytes also occurred in alveoli without this material. The infiltrates were often confluent with other lung lesions, especially inflammation, such that it was sometimes difficult to distinguish demarcations between the various nonneoplastic lesions. Alveolus proteinosis consisted of predominantly amorphous, pale, flocculent, wispy, light pink to deeply eosinophilic proteinaceous material primarily within the alveoli and sometimes within the alveolar ducts (Figure 21 and Figure 22). Occasional scattered clumps were dense and deeply eosinophilic. Severity ranged from minimal to marked, with higher grade lesions exhibiting copious amounts of intra-alveolar protein which filled many or most alveoli in any given lung lobe. Less extensive lesions were characterized by scattered areas of affected alveoli containing variable amounts of proteinaceous material. Frequently, the material contained deeply eosinophilic angular crystals. This material was often but not always associated with intra-alveolar histiocyte infiltrates, areas of alveolar epithelium hyperplasia, and chronic active inflammation.

Chronic active inflammation was a complex lesion that consisted of multifocal to focally extensive areas of mild to markedly intense aggregations of inflammatory cells that obscured and/or effaced the alveolar parenchyma (Figure 23). Although areas of inflammation were scattered throughout the pulmonary parenchyma, they were frequently located peripherally, adjacent to the pleural surface. The inflammatory cell infiltrates consisted primarily of macrophages, epithelioid cells, and occasional multinucleated giant cells, along with variable numbers of lymphocytes, small monocytes, and red blood cells (Figure 24). Some epithelioid macrophages and less often multinucleated giant cells contained clear, spindle-shaped clefts, resembling sterol clefts. Occasionally, few areas of inflammation consisted primarily of neutrophils or lymphocytes mixed with lesser numbers of macrophages. Variable fibrosis was consistently present within areas of inflammation.

Fibrosis of the lung was characterized by the presence of fibrous collagenous strands within the alveolar interstitium that resulted in subtle, though widespread, thickening of alveolar septa and alveolar duct walls including areas of alveolar epithelial hyperplasia (Figure 23 and Figure 24). Variable fibrous strands and bands also often extended into alveolar spaces, variably within and surrounding areas of chronic active inflammation. Fibrous sheaths were also often especially prominent around affected alveoli/alveolar ducts in areas of alveolar epithelium squamous metaplasia, especially the larger areas. Frequently, there was fibrosis of the parietal pleura characterized by focal to confluent, subtle to prominent thickening of the pleura due to increased amounts of mature collagenous tissue. In some cases, multiple, delicate fibrous tags protruded from the thickened pleural surface; these tags were covered by single layers of well-differentiated mesothelial cells. In some areas, low numbers of lymphocytes, macrophages, and/or mast cells were scattered though the fibrotic pleura. Oil-red-O histochemical staining of lung sections revealed oil droplets (presumed to be a component of TRIM VX) free within the inflammatory lesions and within alveolar macrophages and the hyperplastic alveolar epithelium (Figure 25).

Lymphohistiocytic hyperplasia of BALT was variably enlarged due to increased numbers of well-differentiated lymphocytes mixed with multifocal to coalescing clusters of large macrophages that had abundant, foamy, pale amphophilic cytoplasm (Figure 26 and Figure 27).

Nose: There were significantly increased incidences of olfactory epithelium glands hyperplasia, goblet cell hyperplasia, suppurative inflammation, and olfactory and respiratory epithelium hyaline droplet accumulation in all exposed groups of males and females (Table 9, Table A-4, and Table B-4). There were also significantly increased incidences of respiratory epithelium hyperplasia in 100 mg/m^3^ males and all exposed groups of females and transitional epithelium hyperplasia in 100 mg/m^3^ females.

Suppurative inflammation was a minimal to mild change that was most common in the ventral ethmoid turbinates of the olfactory epithelium. This lesion was characterized by infiltrates of predominantly neutrophils mixed with fewer mononuclear cells within the lamina propria and sometimes the lumens of hyperplastic olfactory epithelial glands (Figure 28). In some cases, focal neutrophil infiltrates were also noted in the lamina propria and/or epithelium of the nasoturbinates, maxilloturbinates, and/or the lateral walls in the Level I and II nasal sections.

Respiratory epithelium hyperplasia of minimal severity was a focal lesion generally confined to the distal tips of the Level II maxilloturbinates and less commonly the tips of the nasoturbinates. Hyperplasia consisted of focally increased numbers of epithelial cells lining the affected turbinates resulting in small segments of densely packed, tall columnar epithelial cells with elongated, hyperchromatic nuclei (Figure 29).

Transitional epithelium hyperplasia of minimal to mild severity was located along the tips and lateral surfaces and curvatures of the nasoturbinates and maxilloturbinates and/or the adjacent lateral meatus walls in the Level I section of the nose. Hyperplasia appeared as focal to segmental areas of hypercellularity of the epithelium due to increased numbers (proliferation) of the epithelial cells (Figure 30).

Respiratory epithelium hyaline droplet accumulation of minimal to mild severity most commonly affected the epithelium at the bases of the ventral ethmoid turbinates and along the ventral meatus floor. Affected cells were distended by large aggregates of intracytoplasmic, supranuclear, homogeneous, brightly eosinophilic globular material that partially or completely filled the cytoplasm. The affected segments of epithelium appeared folded due to crowding of the swollen epithelial cells. Olfactory epithelium hyaline droplet accumulation of mild to moderate severity was morphologically similar to that of the respiratory epithelium and involved the olfactory epithelium lining the ventral ethmoid turbinates and underlying submucosal glands (Figure 31).

Olfactory epithelium glands hyperplasia occurred in the submucosal glands in the ethmoid region of the nose especially in the more ventral ethmoid turbinates and ventral meatus. Affected glands were increased in size and there appeared to be increased numbers of gland profiles (Figure 32).

Goblet cell hyperplasia of mostly minimal severity most commonly affected the respiratory epithelium lining the mid to distal nasoturbinates and maxilloturbinates in Level II. In affected segments of the epithelium, the numbers and/or size of the mucus-containing goblet cells that are normal components of respiratory epithelium were increased. Hyperplasia was sporadic and less prominent in other areas of the respiratory epithelium regions and along the nasal septum and lateral walls in Levels I and II.

Larynx: There were significantly increased incidences of epiglottis squamous hyperplasia, epiglottis squamous metaplasia, and mixed cell infiltration cellular in all exposed male and female groups (Table 9, Table A-4, and Table B-4). Squamous metaplasia and squamous hyperplasia of the epiglottis were minimal to moderate changes that affected the epithelium in the histologic section that contains the epiglottis. Squamous metaplasia was characterized by replacement of the cuboidal to low columnar, ciliated epithelium that normally lines the base and lateral aspects of the epiglottis by multiple layers of well-differentiated, variably keratinized squamous epithelium (Figure 33). In more severe cases, the metaplastic change affected the entire epithelium lining base of the epiglottis and lower aspects of the lateral walls, and the central portion of the base in less severe cases. Squamous hyperplasia was characterized by thickening of the squamous epithelium that normally lines the arytenoid cartilages (Figure 33).

Bronchial and Mediastinal Lymph Nodes: There were significantly increased incidences of lymphohistiocytic hyperplasia in all exposed groups of males and females (Table 9, Table A-4, and Table B-4) and the severities increased with exposure concentration. The morphology of this lesion was similar to that observed in the lung. The lymph nodes were large due to expansion of the cortex and paracortex by increased numbers of well-differentiated small lymphocytes mixed with focal, multifocal to coalescing aggregates of plump macrophages with abundant, foamy, pale amphophilic cytoplasm (Figure 34). The macrophage aggregates were morphologically distinct from the pigment-laden (brown) macrophages normally present in the medullary cords and sinusoids of the chamber.

## Mice

### Three-month Study

All mice survived to the end of the study and the mean body weights of exposed groups of females were similar to those of the chamber controls (Table 10; Figure 4). Final mean body weights and mean body weight gains of 400 mg/m^3^ males were significantly less than those of the chamber controls. There were no chemical-related clinical observations in male or female mice^113^.

Table 10 Survival and Body Weights of Mice in the Three-month Inhalation Study of TRIM VX^a^

Concentration (mg/m^3^) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 24.8 ± 0.3 | 37.6 ± 0.8 | 12.8 ± 0.7
25 | 10/10 | 24.7 ± 0.3 | 35.8 ± 0.4 | 11.1 ± 0.3 | 95
50 | 10/10 | 24.7 ± 0.3 | 37.0 ± 0.7 | 12.3 ± 0.7 | 98
100 | 10/10 | 24.5 ± 0.3 | 36.1 ± 0.8 | 11.6 ± 0.7 | 96
200 | 10/10 | 24.6 ± 0.4 | 36.4 ± 0.6 | 11.8 ± 0.4 | 97
400 | 10/10 | 25.1 ± 0.3 | 34.7 ± 0.6* | 9.7 ± 0.5** | 92
Female
0 | 10/10 | 19.9 ± 0.3 | 29.8 ± 0.9 | 9.9 ± 0.8
25 | 10/10 | 20.2 ± 0.3 | 31.0 ± 0.9 | 10.8 ± 0.7 | 104
50 | 10/10 | 19.5 ± 0.3 | 30.7 ± 1.1 | 11.3 ± 0.9 | 103
100 | 10/10 | 19.7 ± 0.3 | 29.1 ± 0.8 | 9.4 ± 0.8 | 98
200 | 10/10 | 19.8 ± 0.2 | 30.1 ± 0.6 | 10.3 ± 0.5 | 101
400 | 10/10 | 20.1 ± 0.2 | 29.2 ± 0.5 | 9.2 ± 0.6 | 98

* Significantly different (P ≤ 0.05) from the chamber control group by Dunnett’s test.

** Significantly different (P ≤ 0.01) from the chamber control group by William’s test.

^a^ Weights and weight changes are given as mean ± standard error.

^b^ Number of animals surviving at 14 weeks/number initially in group.

Mild decreases (≤12%) in the erythrocyte and reticulocyte counts and packed cell volume occurred in 200 and 400 mg/m^3^ males (Table F-2). Hemoglobin concentration was also mildly decreased in 200 mg/m^3^ males. The exact etiology for the decreases in the erythron is not known; however, the possibility exists that the mild suppression is due to the systemic effects of the chronic inflammation present in the respiratory tract. There were no changes in the hematology parameters of female mice.

Figure 4

Growth Curves for Mice Exposed to TRIM VX by Inhalation for Three Months

The absolute liver weights of 200 and 400 mg/m^3^ males and females and the relative liver weights of all exposed groups of males and 200 and 400 mg/m^3^ females were significantly greater (up to 28%) than those of the chamber control groups (Table 11 and Table G-2); there were no corresponding histopathologic lesions in the liver. The absolute lung weights of 200 and 400 mg/m^3^ males and the relative lung weights of 100, 200, and 400 mg/m^3^ males were significantly increased (up to 44%). In females, the absolute and relative lung weights of the 100, 200, and 400 mg/m^3^ groups were significantly increased (up to 49%). The absolute and relative spleen weights of males exposed to 50 mg/m^3^ or greater and the relative spleen weight of 400 mg/m^3^ females were significantly increased (up to 31%). There were no corresponding histopathologic lesions in the spleen.

Table 11 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Inhalation Study of TRIM VX^a^

| Chamber Control | 25 mg/m^3^ | 50 mg/m^3^ | 100 mg/m^3^ | 200 mg/m^3^ | 400 mg/m^3^
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt. | 37.6 ± 0.8 | 35.8 ± 0.4 | 37.0 ± 0.7 | 36.1 ± 0.8 | 36.4 ± 0.6 | 34.7 ± 0.6*
Liver
Absolute | 1.54 ± 0.05 | 1.58 ± 0.03 | 1.71 ± 0.05 | 1.64 ± 0.04 | 1.81 ± 0.07** | 1.76 ± 0.05**
Relative | 40.795 ± 0.675 | 43.982 ± 0.513* | 46.136 ± 1.159** | 45.386 ± 0.861** | 49.719 ± 1.359** | 50.636 ± 0.900**
Lung
Absolute | 0.23 ± 0.02 | 0.21 ± 0.00 | 0.23 ± 0.01 | 0.25 ± 0.01 | 0.29 ± 0.01** | 0.30 ± 0.00**
Relative | 6.044 ± 0.420 | 5.862 ± 0.113 | 6.188 ± 0.189 | 6.886 ± 0.167* | 7.581 ± 0.162** | 8.684 ± 0.135**
Spleen
Absolute | 0.061 ± 0.002 | 0.065 ± 0.002 | 0.072 ± 0.003** | 0.070 ± 0.003* | 0.077 ± 0.004** | 0.068 ± 0.002**
Relative | 1.621 ± 0.046 | 1.815 ± 0.049 | 1.948 ± 0.070** | 1.949 ± 0.085** | 2.120 ± 0.106** | 1.961 ± 0.057**
Female
Necropsy body wt. | 29.8 ± 0.9 | 31.0 ± 0.9 | 30.7 ± 1.1 | 29.1 ± 0.8 | 30.1 ± 0.6 | 29.2 ± 0.5
Liver
Absolute | 1.35 ± 0.04 | 1.50 ± 0.06 | 1.51 ± 0.06 | 1.37 ± 0.04 | 1.57 ± 0.02** | 1.70 ± 0.04**
Relative | 45.360 ± 1.019 | 48.331 ± 0.916 | 49.196 ± 1.141 | 46.971 ± 1.036 | 52.298 ± 1.057** | 58.078 ± 1.027**
Lung
Absolute | 0.21 ± 0.00 | 0.22 ± 0.01 | 0.22 ± 0.01 | 0.25 ± 0.01** | 0.27 ± 0.01** | 0.30 ± 0.01**
Relative | 6.973 ± 0.262 | 7.103 ± 0.122 | 7.284 ± 0.255 | 8.519 ± 0.276** | 9.123 ± 0.256** | 10.382 ± 0.181**
Spleen
Absolute | 0.093 ± 0.003 | 0.096 ± 0.005 | 0.097 ± 0.004 | 0.089 ± 0.003 | 0.102 ± 0.003 | 0.106 ± 0.003
Relative | 3.129 ± 0.088 | 3.090 ± 0.102 | 3.167 ± 0.113 | 3.057 ± 0.077 | 3.391 ± 0.095 | 3.634 ± 0.098**

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** (P ≤ 0.01).

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

In the lung, the incidences of fibrosis and infiltration cellular histiocytic in males and females exposed to 100 mg/m^3^ or greater were significantly greater than those of the chamber control groups (Table 12). There were significantly increased incidences of chronic active inflammation in males exposed to 50 mg/m^3^ or greater and females exposed to 100 mg/m^3^ or greater. There were also significantly increased incidences of bronchiole hyperplasia in males and females exposed to 50 mg/m^3^ or greater. Fibrosis was characterized by increased deposition of collagen in the interstitial tissue at the junction of the terminal bronchioles and alveolar ducts and extending into alveolar ducts and occasionally adjacent alveoli. Masson’s trichrome staining of mouse lung confirmed the presence of increased interstitial collagen. The severity of inflammation chronic active was minimal to moderate in the lungs of all mice exposed to 100 mg/m^3^ or more and minimal in a few mice exposed to 50 mg/m^3^, and was characterized by increased numbers of alveolar macrophages and occasional neutrophils in alveolar spaces. There also were mononuclear cell infiltrates in alveolar septa and walls of alveolar ducts. Infiltration cellular histiocytic was characterized by the presence of large, vacuolated alveolar macrophages which were scattered throughout the alveolar spaces. Bronchiole hyperplasia, ranging from minimal to moderate in severity, was characterized by increased cellularity in the terminal bronchioles with apparent epithelial proliferation and piling up at the junctions of the terminal bronchioles and alveolar ducts.

Table 12 Incidences of Nonneoplastic Lesions of the Respiratory System in Mice in the Three-month Inhalation Study of TRIM VX

| Chamber Control | 25 mg/m^3^ | 50 mg/m^3^ | 100 mg/m^3^ | 200 mg/m^3^ | 400 mg/m^3^
Male
Lung^a^ | 10 | 10 | 10 | 10 | 10 | 10
Fibrosis^b^ | 0 | 0 | 1 (1.0)^c^ | 8** (1.0) | 10** (1.1) | 10** (3.0)
Infiltration Cellular, Histiocyte | 0 | 0 | 2 (1.0) | 9** (1.2) | 10** (1.2) | 10** (1.5)
Inflammation, Chronic Active | 0 | 0 | 4* (1.0) | 10** (1.2) | 10** (2.0) | 10** (3.0)
Bronchiole, Hyperplasia | 0 | 0 | 9** (1.0) | 10** (1.1) | 10** (2.1) | 10** (2.8)
Nose | 10 | 10 | 10 | 10 | 10 | 10
Inflammation, Suppurative | 0 | 7** (1.0) | 8** (1.0) | 8** (1.0) | 8** (1.0) | 10** (1.0)
Olfactory Epithelium, Accumulation, Hyaline Droplet | 0 | 10** (1.3) | 10** (1.6) | 10** (2.0) | 10** (2.0) | 10** (2.0)
Respiratory Epithelium, Accumulation, Hyaline Droplet | 0 | 10** (1.1) | 10** (1.0) | 10** (1.0) | 10** (1.4) | 10** (1.3)
Larynx | 10 | 10 | 10 | 10 | 10 | 10
Hyperplasia, Squamous | 0 | 0 | 2 (1.5) | 9** (1.7) | 8** (1.5) | 9** (1.9)
Inflammation, Chronic | 0 | 4* (1.0) | 0 | 3 (1.0) | 1 (1.0) | 0
Metaplasia, Squamous | 0 | 10** (2.2) | 10** (4.0) | 10** (4.0) | 10** (4.0) | 10** (4.0)
Female
Lung | 10 | 10 | 10 | 10 | 10 | 10
Fibrosis | 0 | 0 | 0 | 10** (1.0) | 10** (1.7) | 10** (2.9)
Infiltration Cellular, Histiocyte | 0 | 0 | 1 (1.0) | 5* (1.4) | 9** (1.1) | 10** (1.8)
Inflammation, Chronic Active | 1 (1.0) | 0 | 2 (1.0) | 10** (1.4) | 10** (2.2) | 10** (3.0)
Bronchiole, Hyperplasia | 0 | 0 | 4* (1.0) | 10** (1.4) | 10** (2.0) | 10** (2.9)
Nose | 10 | 10 | 10 | 10 | 10 | 10
Inflammation, Suppurative | 0 | 1 (1.0) | 6** (1.0) | 5* (1.0) | 10** (1.0) | 7** (1.0)
Olfactory Epithelium, Accumulation, Hyaline Droplet | 0 | 10** (1.5) | 10** (2.0) | 10** (2.0) | 10** (2.0) | 10** (2.0)
Respiratory Epithelium, Accumulation, Hyaline Droplet | 0 | 10** (1.3) | 10** (1.7) | 10** (2.1) | 10** (2.1) | 10** (2.1)
Larynx | 10 | 10 | 10 | 10 | 10 | 10
Hyperplasia, Squamous | 0 | 0 | 1 (2.0) | 7** (1.9) | 7** (2.0) | 8** (2.0)
Inflammation, Chronic | 0 | 4* (1.0) | 5* (1.0) | 8** (1.0) | 9** (1.0) | 5* (1.0)
Metaplasia, Squamous | 0 | 10** (2.2) | 10** (2.6) | 10** (3.4) | 10** (4.0) | 10** (4.0)

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

In the nose, there were significantly increased incidences of hyaline droplet accumulation of the olfactory and respiratory epithelium in all exposed groups of males and females (Table 12). There were also significantly increased incidences of suppurative inflammation in all exposed groups of males and in females exposed to 50 mg/m^3^ or greater. Hyaline droplet accumulation was minimal to mild in the olfactory epithelium of nasal Level III in all exposed mice. It was most prominent on the ventro-lateral regions of the ethmoturbinates. Accumulation of hyaline droplets in the respiratory epithelium was minimal to moderate in nearly all exposed mice, and involved the nasopharyngeal duct in Level III and the ventral nasal septum and/or lateral walls in Levels I and/or II. Suppurative inflammation consisted of small numbers of neutrophils scattered throughout the ethmoturbinate submucosa subjacent to the areas of hyaline droplet accumulation.

In the larynx, there were significantly increased incidences of squamous metaplasia in all exposed groups of males and females, squamous hyperplasia in males and females exposed to 100 mg/m^3^ or greater, and chronic inflammation in all exposed groups of females (Table 12). Squamous metaplasia involved the ventral epithelium at the base of the epiglottis, lateral walls of the anterior section (Level I), and dorsolateral walls and ventral diverticulum of the middle section (Level II). The normally pseudostratified ciliated columnar epithelium lining the base of the epiglottis and nonciliated cuboidal epithelium lining the ventral diverticulum were replaced by mature, sometimes keratinized, squamous epithelium. The metaplastic squamous epithelium was frequently thickened thus appearing hyperplastic as well. Squamous hyperplasia was characterized by thickening of the epithelium (more than three cell layers versus one to two cell layers in chamber controls) overlying the arytenoid cartilages in the middle section (Level II). Chronic inflammation in exposed mice consisted of submucosal infiltrates of small numbers of lymphocytes and plasma cells in anterior (Level I) and middle (Level II) laryngeal sections.

Exposure Concentration Selection Rationale: The exposure concentrations selected for the 2-year inhalation study in male and female B6C3F1/N mice were 10, 30, and 100 mg/m^3^. The highest exposure concentration was based on the incidence and severity of lung fibrosis in the current 3-month study. These concentrations were also used in the 2-year study of CIMSTAR 3800 in B6C3F1/N mice which will allow for comparisons between the two metalworking fluid studies.

### Two-year Study

#### Survival

Estimates of 2-year survival probabilities for male and female mice are shown in Table 13 and in the Kaplan-Meier survival curves (Figure 5). Survival of all exposed groups of male and female mice was similar to that of the chamber control groups.

Table 13 Survival of Mice in the Two-year Inhalation Study of TRIM VX

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Male
Animals initially in study | 50 | 50 | 50 | 50
Accidental death^a^ | 0 | 0 | 1 | 0
Moribund | 4 | 9 | 6 | 5
Natural deaths | 8 | 2 | 6 | 8
Animals surviving to study termination | 38 | 39 | 37^e^ | 37
Percent probability of survival at end of study^b^ | 76 | 78 | 76 | 74
Mean survival (days)^c^ | 692 | 701 | 688 | 701
Survival analysis^d^ | P = 0.877 | P = 0.937N | P = 1.000 | P = 1.000
Female
Animals initially in study | 50 | 50 | 50 | 50
Accidental death | 1 | 0 | 0 | 0
Moribund | 10 | 9 | 4 | 13
Natural deaths | 4 | 5 | 10 | 7
Animals surviving to study termination | 35^e^ | 36 | 36 | 30^e^
Percent probability of survival at end of study | 71 | 72 | 72 | 60
Mean survival (days) | 692 | 697 | 700 | 684
Survival analysis | P = 0.196 | P = 1.000 | P = 0.997N | P = 0.370

^a^ Censored in the survival analyses.

^b^ Kaplan-Meier determinations.

^c^ Mean of all deaths (uncensored, censored, and terminal kill).

^d^ The result of the life table trend test^82^ is in the chamber control column, and the results of the life table pairwise comparisons^81^ with the chamber controls are in the exposed group columns. A lower mortality in an exposure group is indicated by N.

^e^ Includes one animal that died during the last week of the study.

#### Body Weights and Clinical Findings

The mean body weights of all exposed groups of males and females were similar to those of the chamber control groups throughout the study (Tables 14 and 15; Figure 6). Clinical observations included abnormal breathing in a few exposed males and females but the occurrences did not appear to be dose related^114^.

Table 14 Mean Body Weights and Survival of Male Mice in the Two-year Inhalation Study of TRIM VX

Day | Chamber Control | | 10 mg/m^3^ | | | 30 mg/m^3^ | | | 100 mg/m^3^
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 23.0 | 50 | 22.9 | 100 | 50 | 22.8 | 99 | 50 | 22.9 | 100 | 50
10 | 25.4 | 50 | 25.4 | 100 | 50 | 25.2 | 99 | 50 | 25.2 | 100 | 50
17 | 26.4 | 50 | 26.6 | 101 | 50 | 26.2 | 99 | 50 | 26.3 | 100 | 50
24 | 27.5 | 50 | 27.4 | 100 | 50 | 27.2 | 99 | 50 | 27.4 | 100 | 50
31 | 28.5 | 50 | 28.3 | 99 | 50 | 28.1 | 99 | 50 | 28.5 | 100 | 50
38 | 29.7 | 50 | 29.0 | 98 | 50 | 28.9 | 98 | 50 | 29.2 | 99 | 50
45 | 30.6 | 50 | 30.3 | 99 | 50 | 30.2 | 99 | 50 | 29.9 | 98 | 50
52 | 31.5 | 50 | 31.2 | 99 | 50 | 30.8 | 98 | 50 | 30.6 | 97 | 50
59 | 32.1 | 50 | 32.0 | 100 | 50 | 31.6 | 99 | 50 | 31.0 | 97 | 50
66 | 32.9 | 50 | 32.1 | 97 | 50 | 32.1 | 98 | 50 | 31.8 | 97 | 50
73 | 33.8 | 50 | 32.7 | 97 | 50 | 32.8 | 97 | 49 | 32.6 | 97 | 50
80 | 34.8 | 50 | 33.7 | 97 | 50 | 33.8 | 97 | 49 | 33.6 | 97 | 50
87 | 35.4 | 50 | 34.3 | 97 | 50 | 34.3 | 97 | 49 | 34.5 | 97 | 50
115 | 38.9 | 50 | 37.9 | 97 | 50 | 38.2 | 98 | 49 | 37.5 | 96 | 50
142 | 40.5 | 50 | 39.7 | 98 | 50 | 39.8 | 98 | 49 | 39.1 | 97 | 50
171 | 42.6 | 50 | 41.8 | 98 | 50 | 42.2 | 99 | 49 | 41.5 | 97 | 50
199 | 44.1 | 50 | 43.0 | 97 | 50 | 43.6 | 99 | 49 | 42.5 | 96 | 50
227 | 45.8 | 50 | 44.7 | 98 | 50 | 45.0 | 98 | 49 | 44.9 | 98 | 50
255 | 46.8 | 50 | 46.2 | 99 | 50 | 46.5 | 99 | 49 | 46.3 | 99 | 50
283 | 47.7 | 50 | 47.4 | 99 | 50 | 47.5 | 100 | 49 | 46.9 | 98 | 50
311 | 48.3 | 50 | 47.9 | 99 | 50 | 47.9 | 99 | 49 | 47.8 | 99 | 50
339 | 48.9 | 50 | 48.6 | 100 | 50 | 48.9 | 100 | 49 | 48.6 | 99 | 50
367 | 49.0 | 50 | 48.4 | 99 | 50 | 49.1 | 100 | 48 | 49.1 | 100 | 50
395 | 50.6 | 49 | 50.2 | 99 | 50 | 50.2 | 99 | 48 | 50.7 | 100 | 50
423 | 51.3 | 48 | 51.0 | 99 | 50 | 51.2 | 100 | 48 | 51.4 | 100 | 50
451 | 51.1 | 48 | 50.6 | 99 | 50 | 50.9 | 100 | 48 | 51.2 | 100 | 49
479 | 51.5 | 48 | 50.9 | 99 | 50 | 51.5 | 100 | 48 | 51.7 | 100 | 49
507 | 52.4 | 47 | 52.2 | 100 | 48 | 52.1 | 99 | 48 | 52.9 | 101 | 49
535 | 50.9 | 47 | 51.4 | 101 | 48 | 51.3 | 101 | 47 | 51.7 | 102 | 49
563 | 51.1 | 45 | 51.7 | 101 | 47 | 51.3 | 100 | 46 | 52.2 | 102 | 47
591 | 51.2 | 45 | 51.8 | 101 | 46 | 51.9 | 101 | 45 | 52.3 | 102 | 45
619 | 51.2 | 42 | 51.1 | 100 | 46 | 51.7 | 101 | 44 | 52.0 | 102 | 44
647 | 51.0 | 41 | 51.6 | 101 | 42 | 51.7 | 101 | 42 | 52.0 | 102 | 43
675 | 51.0 | 39 | 52.3 | 103 | 39 | 51.4 | 101 | 41 | 51.7 | 101 | 40
703 | 50.0 | 39 | 50.8 | 102 | 39 | 51.1 | 102 | 38 | 50.7 | 102 | 40
Mean for Weeks
1–13 | 30.1 | | 29.7 | 99 | | 29.5 | 98 | | 29.5 | 98
14–52 | 44.8 | | 44.1 | 98 | | 44.4 | 99 | | 43.9 | 98
53–101 | 50.9 | | 51.1 | 100 | | 51.2 | 101 | | 51.5 | 101

Table 15 Mean Body Weights and Survival of Female Mice in the Two-year Inhalation Study of TRIM VX

Day | Chamber Control | | 10 mg/m^3^ | | | 30 mg/m^3^ | | | 100 mg/m^3^
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 19.3 | 50 | 18.9 | 98 | 50 | 19.1 | 99 | 50 | 18.9 | 98 | 50
10 | 21.0 | 50 | 21.2 | 101 | 50 | 21.1 | 100 | 50 | 21.0 | 100 | 50
17 | 22.2 | 50 | 22.5 | 102 | 50 | 22.1 | 100 | 50 | 22.4 | 101 | 50
24 | 23.1 | 50 | 23.4 | 101 | 50 | 23.7 | 102 | 50 | 23.4 | 101 | 50
31 | 24.2 | 50 | 24.4 | 101 | 50 | 24.5 | 101 | 50 | 24.5 | 101 | 50
38 | 24.6 | 50 | 25.2 | 102 | 50 | 25.1 | 102 | 50 | 25.1 | 102 | 50
45 | 25.5 | 50 | 26.3 | 103 | 50 | 26.0 | 102 | 50 | 26.4 | 104 | 50
52 | 26.2 | 50 | 27.5 | 105 | 50 | 26.2 | 100 | 50 | 27.0 | 103 | 50
59 | 26.9 | 50 | 27.8 | 103 | 50 | 27.5 | 102 | 50 | 27.3 | 101 | 50
66 | 27.3 | 50 | 28.3 | 104 | 50 | 27.7 | 101 | 50 | 28.1 | 103 | 50
73 | 27.6 | 50 | 28.8 | 104 | 50 | 28.4 | 103 | 50 | 28.7 | 104 | 50
80 | 28.4 | 50 | 29.3 | 103 | 50 | 29.3 | 103 | 50 | 29.3 | 103 | 50
87 | 28.8 | 50 | 30.0 | 104 | 50 | 29.7 | 103 | 50 | 29.8 | 104 | 50
115 | 31.5 | 50 | 33.2 | 106 | 50 | 33.1 | 105 | 50 | 32.8 | 104 | 50
142 | 33.3 | 50 | 35.3 | 106 | 50 | 35.1 | 106 | 50 | 34.8 | 105 | 50
171 | 35.3 | 50 | 37.7 | 107 | 50 | 37.5 | 106 | 50 | 37.6 | 107 | 49
199 | 37.9 | 50 | 40.0 | 106 | 50 | 39.6 | 105 | 49 | 39.8 | 105 | 49
227 | 39.5 | 50 | 41.7 | 105 | 50 | 41.4 | 105 | 49 | 41.7 | 106 | 49
255 | 41.2 | 50 | 43.4 | 105 | 50 | 42.4 | 103 | 49 | 43.3 | 105 | 49
283 | 43.2 | 50 | 45.4 | 105 | 50 | 44.7 | 103 | 49 | 45.3 | 105 | 49
311 | 44.5 | 50 | 46.1 | 104 | 50 | 45.6 | 103 | 49 | 46.1 | 104 | 49
339 | 45.4 | 50 | 47.7 | 105 | 50 | 46.1 | 102 | 49 | 47.5 | 105 | 48
367 | 47.2 | 49 | 48.6 | 103 | 49 | 48.1 | 102 | 49 | 48.8 | 103 | 48
395 | 50.7 | 49 | 51.9 | 102 | 49 | 51.1 | 101 | 49 | 51.8 | 102 | 48
423 | 52.5 | 49 | 53.6 | 102 | 49 | 53.0 | 101 | 49 | 53.2 | 101 | 48
451 | 53.2 | 49 | 54.0 | 102 | 49 | 54.1 | 102 | 49 | 54.2 | 102 | 48
479 | 55.4 | 49 | 56.3 | 102 | 48 | 55.3 | 100 | 49 | 56.0 | 101 | 48
507 | 56.7 | 48 | 57.9 | 102 | 48 | 57.2 | 101 | 47 | 58.3 | 103 | 48
535 | 57.2 | 47 | 58.1 | 101 | 48 | 57.5 | 100 | 47 | 57.8 | 101 | 47
563 | 56.6 | 46 | 57.4 | 101 | 48 | 57.1 | 101 | 47 | 57.3 | 101 | 46
591 | 57.8 | 45 | 57.8 | 100 | 45 | 58.1 | 101 | 47 | 57.1 | 99 | 45
619 | 57.6 | 43 | 58.7 | 102 | 42 | 57.9 | 101 | 46 | 57.3 | 100 | 44
647 | 57.9 | 39 | 59.3 | 102 | 40 | 57.8 | 100 | 45 | 56.7 | 98 | 41
675 | 56.6 | 38 | 57.9 | 102 | 40 | 57.1 | 101 | 42 | 56.0 | 99 | 37
703 | 55.9 | 36 | 56.8 | 102 | 38 | 55.0 | 98 | 42 | 52.4 | 94 | 33
Mean for Weeks
1–13 | 25.0 | | 25.7 | 103 | | 25.4 | 102 | | 25.5 | 102
14–52 | 39.1 | | 41.2 | 105 | | 40.6 | 104 | | 41.0 | 105
53–101 | 55.0 | | 56.0 | 102 | | 55.3 | 101 | | 55.1 | 100

Figure 5

Kaplan-Meier Survival Curves for Mice Exposed to TRIM VX by Inhalation for Two Years

Figure 6

Growth Curves for Mice Exposed to TRIM VX by Inhalation for 2 Years

#### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and nonneoplastic lesions of the lung, nose, larynx, bronchial lymph node, liver, and Harderian gland. Summaries of the incidences of neoplasms and nonneoplastic lesions, statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group, and historical incidences for the neoplasms mentioned in this section are presented in Appendix C for male mice and Appendix D for female mice.

Lung: In males exposed to 100 mg/m^3^, there were significantly increased incidences of alveolar/bronchiolar adenoma or carcinoma (combined) and multiple alveolar/bronchiolar carcinoma (Table 16, Table C-1 and Table C-2). There were also positive trends in the incidences of alveolar/bronchiolar adenoma or carcinoma (combined) and multiple alveolar/bronchiolar carcinoma. The incidences of alveolar/bronchiolar adenoma or carcinoma (combined) in the 100 mg/m^3^ group exceeded the historical control ranges for inhalation studies and for all routes of administration (Tables 16 and Table C-3). In females exposed to 100 mg/m^3^, there were significantly increased incidences of alveolar/bronchiolar carcinoma and alveolar/bronchiolar adenoma or carcinoma (combined) (Table 16 and Table D-2), and positive trends in the incidences of these neoplasms. There was an increased incidence of multiple aveolar/bronchiolar carcinoma in 100 mg/m^3^ females, but the incidence was not statistically significant. The incidences of alveolar/bronchiolar carcinoma and alveolar/bronchiolar adenoma or carcinoma (combined) in the 100 mg/m^3^ females exceeded the historical control ranges for inhalation studies and for all routes of administration (Table 16 and Table D-3). In addition, a bronchiole epithelium adenoma occurred in one 30 mg/m^3^ male; bronchiolar adenomas have not occurred in historical control male B6C3F1/N mice (Table 16 and Table C-3).

Table 16 Incidences of Neoplasms and Nonneoplastic Lesions of the Respiratory System in Mice in the Two-year Inhalation Study of TRIM VX

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Male
Lung^a^ | 50 | 50 | 49 | 50
Alveolar Epithelium, Hyperplasia^b^ | 3 (2.0)^c^ | 3 (1.0) | 7 (1.1) | 47** (1.7)
Alveolar/bronchiolar Epithelium, Hyperplasia | 3 (3.0) | 7 (1.4) | 15** (1.3) | 50** (2.3)
Fibrosis | 0 | 2 (1.0) | 5* (1.2) | 45** (1.3)
Infiltration Cellular, Histiocyte | 5 (2.0) | 9 (1.6) | 15* (1.5) | 49** (2.0)
Inflammation, Chronic | 5 (1.4) | 12 (1.0) | 16** (1.3) | 50** (2.4)
Bronchiole, Epithelium, Adenoma^d^ | 0 | 0 | 1 | 0
Alveolar/bronchiolar Adenoma, Multiple | 1 | 1 | 0 | 3
Alveolar/bronchiolar Adenoma (includes multiple) | 6 | 8 | 5 | 9
Alveolar/bronchiolar Carcinoma, Multiple | 2^▲▲^ | 0 | 2 | 8*
Alveolar/bronchiolar Carcinoma (includes multiple) | 10 | 8 | 9 | 17
Alveolar/bronchiolar Adenoma or Carcinoma^e^
Overall rate^f^ | 14/50 (28%) | 14/50 (28%) | 11/49 (22%) | 23/50 (46%)
Adjusted rate^g^ | 30.5% | 30.7% | 24.7% | 49.4%
Terminal rate^h^ | 9/38 (24%) | 13/39 (33%) | 9/37 (24%) | 18/37 (49%)
First incidence (days) | 549 | 656 | 533 | 571
Poly-3 test^i^ | P = 0.013 | P = 0.581 | P = 0.352N | P = 0.047
Nose | 49 | 50 | 49 | 50
Exudate | 2 (1.0) | 11** (1.2) | 35** (2.0) | 49** (2.5)
Inflammation, Chronic Active | 3 (1.0) | 33** (1.0) | 39** (1.3) | 50** (1.5)
Nasopharyngeal Duct, Perforation | 0 | 1 | 11** | 19**
Olfactory Epithelium, Accumulation, Hyaline Droplet | 2 (1.0) | 46** (1.5) | 48** (1.9) | 50** (2.0)
Respiratory Epithelium, Accumulation, Hyaline Droplet | 7 (1.0) | 49** (1.9) | 49** (1.9) | 50** (2.0)
Respiratory Epithelium, Atrophy | 0 | 1 (1.0) | 20** (1.0) | 40** (1.1)
Respiratory Epithelium, Necrosis | 2 (1.0) | 1 (1.0) | 2 (1.0) | 23** (1.1)
Turbinate, Atrophy | 0 | 2 (1.5) | 5* (1.0) | 14** (1.0)
Turbinate, Perforation | 0 | 0 | 1 | 13**
Larynx | 48 | 49 | 49 | 49
Epiglottis, Hyperplasia, Squamous | 1 (2.0) | 2 (1.0) | 14** (1.1) | 30** (1.2)
Epiglottis, Metaplasia, Squamous | 0 | 49** (2.0) | 49** (3.1) | 49** (3.9)
Lymph Node, Bronchial | 38 | 37 | 39 | 39
Hyperplasia, Lymphoid | 3 (1.7) | 3 (1.3) | 2 (1.0) | 14** (1.4)
Infiltration Cellular, Histiocyte | 0 | 1 (1.0) | 0 | 7** (1.6)
Female
Lung | 50 | 50 | 50 | 50
Alveolar Epithelium, Hyperplasia | 0 | 0 | 2 (1.5) | 43** (1.9)
Alveolar/bronchiolar Epithelium, Hyperplasia | 0 | 3 (1.0) | 8** (1.1) | 45** (2.6)
Fibrosis | 0 | 0 | 2 (1.0) | 42** (1.5)
Infiltration Cellular, Histiocyte | 1 (2.0) | 4 (2.3) | 15** (1.2) | 48** (2.3)
Inflammation, Chronic | 1 (1.0) | 6 (1.2) | 26** (1.1) | 47** (2.4)
Alveolar/bronchiolar Adenoma, Multiple | 0 | 0 | 0 | 2
Alveolar/bronchiolar Adenoma (includes multiple) | 4 | 5 | 3 | 8
Alveolar/bronchiolar Carcinoma, Multiple | 2 | 0 | 1 | 5
Alveolar/bronchiolar Carcinoma (includes multiple)^j^
Overall rate | 5/50 (10%) | 3/50 (6%) | 6/50 (12%) | 14/50 (28%)
Adjusted rate | 11.4% | 6.7% | 13.1% | 31.4%
Terminal rate | 5/35 (14%) | 2/36 (6%) | 6/36 (17%) | 8/30 (27%)
First incidence (days) | 731 (T) | 647 | 731 (T) | 513
Poly-3 test | P < 0.001 | P = 0.342N | P = 0.529 | P = 0.018
Alveolar/bronchiolar Adenoma or Carcinoma^k^
Overall rate | 9/50 (18%) | 8/50 (16%) | 8/50 (16%) | 20/50 (40%)
Adjusted rate | 20.2% | 17.8% | 17.5% | 44.5%
Terminal rate | 7/35 (20%) | 7/36 (19%) | 8/36 (22%) | 12/30 (40%)
First incidence (days) | 575 | 647 | 731 (T) | 513
Poly-3 test | P < 0.001 | P = 0.491N | P = 0.476N | P = 0.011
Nose | 50 | 50 | 50 | 50
Exudate | 8 (1.1) | 17* (1.0) | 48** (2.0) | 49** (2.9)
Inflammation, Chronic Active | 4 (1.3) | 25** (1.0) | 49** (1.2) | 49** (1.6)
Nasopharyngeal Duct, Perforation | 0 | 0 | 14** | 17**
Olfactory Epithelium, Accumulation, Hyaline Droplet | 14 (1.2) | 48** (1.6) | 50** (2.0) | 50** (2.0)
Respiratory Epithelium, Accumulation, Hyaline Droplet | 23 (1.2) | 50** (1.8) | 50** (2.0) | 50** (2.6)
Respiratory Epithelium, Atrophy | 1 (1.0) | 2 (1.0) | 28** (1.0) | 39** (1.1)
Respiratory Epithelium, Necrosis | 0 | 2 (1.0) | 13** (1.0) | 23** (1.0)
Turbinate, Atrophy | 0 | 0 | 10** (1.1) | 19** (1.0)
Turbinate, Perforation | 0 | 0 | 6* | 6*
Larynx | 50 | 50 | 50 | 50
Epiglottis, Hyperplasia, Squamous | 4 (1.0) | 3 (1.0) | 16** (1.5) | 42** (1.6)
Epiglottis, Metaplasia, Squamous | 0 | 50** (2.4) | 50** (3.5) | 50** (4.0)
Lymph Node, Bronchial | 44 | 44 | 44 | 43
Hyperplasia, Lymphoid | 6 (1.3) | 4 (1.0) | 9 (1.4) | 9 (2.0)
Infiltration Cellular, Histiocyte | 1 (1.0) | 0 | 2 (1.0) | 4 (2.0)

* Significantly different (P ≤ 0.05) from the chamber control group by the Poly-3 test.

** P ≤ 0.01.

^▲▲^Significant (P ≤ 0.01) Poly-3 trend test.

(T) Terminal kill.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical incidence for 2-year inhalation studies with chamber control groups (mean ± standard deviation): 0/250; all routes: 0/550.

^e^ Historical incidence for inhalation studies: 69/250 (27.6% ± 2.6%), range 26%–32%; all routes: 147/550 (26.7% ± 6.5%), range 16%–38%.

^f^ Number of animals with neoplasm per number of animals with lung examined microscopically.

^g^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^h^ Observed incidence at terminal kill.

^i^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in an exposure group is indicated by N.

^j^ Historical incidence for inhalation studies: 17/249 (6.8% ± 3.7%), range 2%–10%; all routes: 24/549 (4.4% ± 3.5%), range 0%–10%.

^k^ Historical incidence for inhalation studies: 28/249 (11.3% ± 5.5%), range 6%–18%; all routes: 50/549 (9.1% ± 5.2%), range 2%–18%.

Alveolar/bronchiolar adenomas were densely cellular expansile masses that replaced and sometimes partially compressed adjacent normal alveoli. Most of the masses were located within the alveolar parenchyma (Figure 35), whereas others involved the terminal bronchioles, alveolar ducts, and immediately adjacent alveoli. They were composed of relatively uniform columnar to polygonal cells with moderate amounts of eosinophilic cytoplasm and relatively uniform nuclei with homogeneous chromatin and formed glandlike, solid, or papillary structures (Figure 36). Mitoses were rare.

Alveolar/bronchiolar carcinomas were irregularly shaped, compressive masses that effaced the normal pulmonary parenchyma (Figure 37). Neoplastic cells had a heterogeneous growth pattern consisting of papillary and glandularlike structures and occasionally solid areas. The neoplastic cells were pleomorphic with scant to moderate amounts of eosinophilic cytoplasm and oval to round, hyperchromatic to vesicular nuclei. Nucleoli were occasionally prominent and occasional mitotic figures were seen (Figure 38).

The bronchiole epithelium adenoma was an expansile mass that occurred within a terminal bronchiole (Figure 39). It was a densely cellular mass composed of well-defined, irregular papillary structures lined by one to three layers of relatively uniform, plump, nonciliated cuboidal to low columnar epithelial cells (Figure 40). The toxicological significance of the single incidence of this neoplasm is not known.

There were significantly increased incidences of alveolar/bronchiolar epithelium hyperplasia, infiltration cellular histiocyte, and chronic inflammation in 30 and 100 mg/m^3^ males and females (Table 16, Table C-4, and Table D-4). There were significantly increased incidences of alveolar epithelium hyperplasia in 100 mg/m^3^ males and females. There were also significantly increased incidences of fibrosis in 30 and 100 mg/m^3^ males and 100 mg/m^3^ females. These lesions were qualitatively similar to the nonneoplastic lung lesions observed in rats but were not as severe. They were multifocal to locally extensive and were frequently intermingled and contiguous such that it was often difficult to establish clear demarcations between the various changes. In general, the incidences increased with increasing exposure concentration, and the severities were higher in the 100 mg/m^3^ groups than in the other groups.

Alveolar epithelium hyperplasia in mice was morphologically similar to the same lesion in the rat study. They were multifocal, discrete, irregularly shaped, minimal to marked proliferations of epithelial cells within the alveolar parenchyma in which the alveolar architecture was still discernable (Figure 41). Component epithelial cells were well-differentiated, plump, and typically flattened cuboidal cells (Figure 42).

Alveolar/bronchiolar epithelium hyperplasia in mice was also a discrete, multifocal lesion that was similar to the same lesion in the rat lungs and occurred in the periacinar region of the lung. However, in contrast to rats, the proliferating cells formed irregular papillary structures that sometimes projected from the epithelium and filled the lumens of the terminal bronchioles, alveolar ducts, and immediately adjacent septa (Figure 43). A single layer of mostly flat to cuboidal, typically nonciliated epithelial cells lined the papillary structures, but in some areas the cells were polygonal or low cuboidal (Figure 44). Also, in contrast to rats, the proliferations in the terminal bronchioles of mice occurred more proximally in mice.

Inflammation chronic was a multifocal to coalescing lesion of minimal to mild severity characterized by irregular areas in which the alveolar architecture was obscured by dense aggregates of mostly macrophages mixed with neutrophils, lymphocytes, and cellular debris. The lesions were often more prominent in perivascular areas and, in these areas, the lymphocytes component was the most prominent component. Variable epithelial cell hyperplasia and minimal to mild fibrosis of the alveolar septal interstitium was a consistent component of the areas of inflammation. It was often difficult to distinguish denser inflammatory cell accumulation from hyperplastic epithelium. Infiltration cellular histiocyte was composed of minimal to mild accumulations of large macrophages with foamy to amphophilic cytoplasm present in the surrounding alveoli.

Nose: In all exposed groups of males and females, there were significantly increased incidences of exudate, chronic active inflammation, and olfactory epithelium hyaline droplet accumulation (Table 16, Table C-4, and Table D-4). In the respiratory epithelium, there were significantly increased incidences of hyaline droplet accumulation in all exposed groups of males and females, atrophy in 30 and 100 mg/m^3^ males and females, and necrosis in 100 mg/m^3^ males and 30 and 100 mg/m^3^ females. The incidences of turbinate atrophy were significantly increased in 30 and 100 mg/m^3^ males and females, and the incidences of turbinate perforation were significantly increased in 100 mg/m^3^ males and 30 and 100 mg/m^3^ females. There were also significantly increased incidences of nasopharyngeal duct perforation in 30 and 100 mg/m^3^ males and females.

Exudate consisted of minimal to marked accumulations of dense proteinaceous fluid and/or concretions of amorphous, eosinophilic, hyaline material in the ventral nasal passages of the ethmoid region of the nose (Figure 45). The exudate contained variable numbers of neutrophils and cellular debris. Chronic active inflammation was characterized by the presence of mild to moderate infiltrates of macrophages, lymphocytes, and neutrophils within the submucosa adjacent to the areas of exudate. Nasopharyngeal duct perforation was characterized by rupture of the wall of the nasopharyngeal duct associated with the exudate in the nasal passages (Figure 45). Turbinate perforation, characterized by focal necrosis and discontinuity of the ventral ethmoid turbinates, was primarily associated with the exudate in the nasal passages. Both lesions most likely resulted from pressure necrosis caused by exudate. Turbinate atrophy was observed in the ethmoid turbinates and was also associated with the nasal exudate; affected turbinates were thin, short, and blunt (Figure 45).

Hyaline droplet accumulation in the respiratory and olfactory epithelia was morphologically similar to this lesion in rats. Respiratory epithelial atrophy was a focal minimal change associated with areas of exudate. In affected sites, the height of the epithelium decreased due to replacement of the normally present cuboidal to columnar sometimes ciliated epithelial cells by a single layer of flattened to low cuboidal epithelial cells. Necrosis of the respiratory epithelium in the ventral aspects of the ethmoid region was also associated with exudate and consisted of focal areas of denudation and loss of small focal areas of the epithelium (Figure 45).

Larynx: In the epiglottis, there were significantly increased incidences of squamous hyperplasia in 30 and 100 mg/m^3^ males and females and squamous metaplasia in all exposed groups of males and females (Table 16, Table C-4, and Table D-4). These lesions were morphologically similar to those observed in the larynx of male and female rats.

Bronchial Lymph Node: In 100 mg/m^3^ males, there were significantly increased incidences of lymphoid hyperplasia and infiltration cellular histiocyte (Table 16 and Table C-4). Lymphoid hyperplasia was characterized by enlargement of the affected lymph nodes due to increased numbers of well-differentiated small lymphocytes mixed with focal, multifocal to coalescing aggregates of plump macrophages with abundant, foamy, pale amphophilic cytoplasm. These lesions were morphologically similar to the changes that were observed in the bronchial and mediastinal lymph nodes of male and female rats and diagnosed as lymphohistiocytic hyperplasia. However, the changes were diagnosed separately because lymphoid hyperplasia sometimes occurred in the absence of histiocytic aggregates.

Liver: There was a positive trend in the incidences of hepatocellular adenoma in males and the incidence in the 100 mg/m^3^ group was significantly increased (chamber control, 23/50; 10 mg/m^3^, 29/50; 30 mg/m^3^, 26/50; 100 mg/m^3^, 36/50; Table C-2). However, the incidence in the 100 mg/m^3^ group was within the historical control ranges for inhalation studies [142/250 (56.8% ± 11.2%); range 46%–74%] and all routes [328/550 (59.6% ± 11.2%); range 46%–78%], and the significantly increased incidence was attributed to the uncommonly low incidence in the chamber control group. A few hepatoblastomas occurred in 30 and 100 mg/m^3^ males but the incidences were not statistically significant. In females, there was a positive trend in the incidences of hepatocellular carcinoma (7/50, 5/50, 7/50, 12/50; Table D-2) and the incidence in the 100 mg/m^3^ group exceeded the historical control ranges for inhalation studies [41/250 (16.4% ± 3.6%); range 12%–20%] and all routes [76/549 (13.9% ± 5.2%); range 4%–20%]. However, the incidence of hepatocellular carcinoma in the 100 mg/m^3^ group was not statistically significant relative to that of the concurrent chamber controls and was not considered to be related to treatment. The combined incidences of hepatocellular adenoma, hepatocellular carcinoma, and hepatoblastoma in both sexes were within the ranges observed in historical control animals. Tumors were morphologically similar to those that occur spontaneously.

Harderian Gland: In females, there was a positive trend in the incidence of adenoma or carcinoma (combined) (4/50, 3/50, 7/50, 9/50; Table D-2). The incidence in the 100 mg/m^3^ group exceeded the historical control range for inhalation studies [20/250 (8.0% ± 3.7%); range 4%–14%]. However, the incidence of adenoma or carcinoma (combined) was not statistically significant relative to that of the concurrent chamber controls and was not considered to be related to treatment.

## Genetic Toxicology

TRIM VX (dose range tested, 500 to 10,000 µg/plate) was not mutagenic in Salmonella typhimurium strains TA98 or TA100 or in Escherichia coli strain WP2 uvrA/pKM101 in the presence or absence of exogenous metabolic activation (S9) (Table E-1).

In vivo, no increases in the frequencies of micronucleated reticulocytes or erythrocytes were observed in peripheral blood samples from male or female Wistar Han rats or B6C3F1/N mice exposed to TRIM VX via inhalation (25 to 400 mg/m^3^) for 3 months (Table E-2 and Table E-3).

In addition to the micronucleus endpoint, the percentage of reticulocytes among circulating red blood cells was calculated as a measure of bone marrow toxicity or perturbations in erythropoiesis (Table E-2 and Table E-3). The very small increases in percent reticulocytes noted in male rats and female mice were within historical ranges for this endpoint and, in the absence of any observed hematological effects, were not considered biologically significant.

Figure 7

Alveolar/Bronchiolar Adenoma in the Lung of a Female Wistar Han Rat Exposed to 100 mg/m^3^ TRIM VX by Inhalation for Two Years (H&E)

The adenoma (arrows) appears as a densely cellular, nodular mass that is distinctly demarcated from the surrounding alveolar parenchyma.

Figure 8

Higher Magnification of Figure 7 (H&E)

The adenoma is composed of a generally uniform population of cuboidal epithelial cells forming relatively well-defined papillary (arrows) and glandular (asterisk) structures that are in some areas separated by thin bands of connective tissue.

Figure 9

Alveolar/Bronchiolar Carcinoma in the Lung of a Male Wistar Han Rat Exposed to 100 mg/m^3^ TRIM VX by Inhalation for Two Years (H&E)

The carcinoma is highly invasive (arrows) and has effaced the lung parenchyma.

Figure 10

Higher Magnification of Figure 9 (H&E)

There is moderate cellular pleomorphism. The neoplastic cells are mostly cuboidal to columnar and form poorly defined glandular structures (arrows) irregularly separated by thin connective tissue septae; in some areas, the cells are polygonal and densely aggregated. The cells have moderately abundant eosinophilic cytoplasm and variably sized round to elongate nuclei.

Figure 11

Cystic Keratinizing Epithelioma in the Lung of a Female Wistar Han Rat Exposed to 100 mg/m^3^ TRIM VX by Inhalation for Two Years (H&E)

This neoplasm is characterized by a central mass of keratin (asterisks) surrounded by a wall of squamous epithelium (arrows).

Figure 12

Higher Magnification of Figure 11 (H&E)

Note central keratin (asterisks) surrounded by well-differentiated squamous epithelium (arrows).

Figure 13

Discrete Area of Alveolar Epithelium Hyperplasia (Arrows) in the Lung of a Female Wistar Han Rat Exposed to 100 mg/m^3^ TRIM VX by Inhalation for Two Years (H&E)

The alveolar septae are hypercellular and the architecture of the alveolar parenchyma is generally maintained.

Figure 14

Higher Magnification of Figure 13 (H&E)

The alveolar septae are lined by flattened to low cuboidal epithelial (Type II) cells (arrows). Note macrophages within the alveolar spaces.

Figure 15

Multifocal Areas of Alveolar/Bronchiolar Epithelium Hyperplasia (arrows) in the Lung of a Female Wistar Han Rat Exposed to 100 mg/m^3^ TRIM VX by Inhalation for Two Years (H&E)

The lesions are centered on the terminal bronchioles, alveolar ducts, and immediately adjacent alveoli.

Figure 16

Higher Magnification of Figure 15 (H&E)

The hyperplastic cells lining the alveoli adjacent to the alveolar duct are mostly low cuboidal to columnar and ciliated and nonciliated epithelial cells (arrows).

Figure 17

Focal Area of Alveolar Epithelium Squamous Metaplasia (Long Arrows) Associated with Alveolar Epithelium Hyperplasia (Short Arrows) in the Lung of a Female Wistar Han Rat Exposed to 100 mg/m^3^ TRIM VX by Inhalation for Two Years (H&E)

Figure 18

Higher Magnification of Figure 17 (H&E)

Squamous metaplasia is characterized by irregular thickening of the alveolar septae by well-differentiated squamous epithelium (long arrows) and is adjacent to alveolar epithelium hyperplasia (short arrows) in which the alveolar septae are lined by ciliated columnar epithelium. Note numerous macrophages, cellular debris, and mucus within the alveolar spaces.

Figure 19

Infiltration Cellular, Histiocyte (Arrows) within an Area of Alveolar Epithelium Hyperplasia in the Lung of a Male Wistar Han Rat Exposed to 30 mg/m^3^ TRIM VX by Inhalation for Two Years (H&E)

Figure 20

Higher Magnification of Figure 19 (H&E)

The alveoli contain numerous swollen macrophages (histiocytes) (arrows) with foamy eosinophilic cytoplasm.

Figure 21

Alveolus Proteinosis in the Lung of a Female Wistar Han Rat Exposed to 100 mg/m^3^ TRIM VX by Inhalation for Two Years (H&E)

Alveoli within an area of alveolar epithelial hyperplasia contain pale or brightly eosinophilic protein material (arrows).

Figure 22

Alveolus Proteinosis in the Lung of a Female Wistar Han Rat Exposed to 100 mg/m^3^ TRIM VX by Inhalation for 2 Years (H&E)

Alveoli within an area of inflammation are filled by granular-appearing eosinophilic protein material (asterisks).

Figure 23

An Area of Marked Chronic Active Inflammation (Long Arrows) in the Lung of a Male Wistar Han Rat Exposed to 100 mg/m^3^ TRIM VX by Inhalation for Two Years (H&E)

The alveoli are filled mostly with macrophages mixed with lesser numbers of neutrophils, degenerate cellular debris, and a few multinucleated giant cells. Note clear, angular cleft-like spaces (cholesterol clefts) among the inflammatory cells and debris. The pleura is irregularly thickened by marked fibrosis (short arrows).

Figure 24

Higher Magnification of Figure 23 (H&E)

In addition to the inflammatory cell infiltrates, there is alveolar epithelium hyperplasia (long arrows) and irregular fibrosis of the alveolar septae (short arrows). Note multinucleated giant cells (arrowhead).

Figure 25

Section of the Lung of a Female Wistar Han Rat Exposed to 100 mg/m^3^ TRIM VX by Inhalation for Two Years (Oil-red-O)

Note oil droplets within macrophages (long arrows), within the hyperplastic alveolar epithelium (short arrows), and free within the alveolar spaces (curved arrows).

Figure 26

Lymphohistiocytic Hyperplasia in the Bronchus-Associated Lymphoid Tissue (BALT) in the Lung of a Female Wistar Han Rat Exposed to 100 mg/m^3^ TRIM VX by Inhalation for Two Years (H&E)

The BALT is markedly expanded by increased numbers of lymphocytes (long arrows) and macrophages (short arrows).

Figure 27

Higher Magnification of Figure 26 (H&E)

Note areas of well-differentiated lymphocytes (arrows) and macrophages swollen with abundant lightly eosinophilic foamy cytoplasm (asterisks) with scattered low numbers of plasma cells.

Figure 28

Suppurative Inflammation in a Nasal Maxilloturbinate in the Level II Section of the Nose of a Female Wistar Han Rat Exposed to 100 mg/m^3^ TRIM VX by Inhalation for 2 Years (H&E)

There are numerous neutrophils within the submucosal tissue of the turbinate (long arrows) adjacent to the nasal septum (short arrows).

Figure 29

Focal Area of Respiratory Epithelium Hyperplasia at the Tip of a Maxilloturbinate in the Nose of a Female Wistar Han Rat Exposed to 100 mg/m^3^ TRIM VX by Inhalation for Two Years (H&E)

In contrast to the normal pseudostratified, ciliated, tall columnar epithelium (short arrows) lining the remainder of the turbinate and the lateral wall, the affected segment of the epithelium appears hypercellular with disorganized piling up of the epithelial cells (long arrows).

Figure 30

Transitional Epithelium Hyperplasia in the Nose of a Female Wistar Han Rat Exposed to 100 mg/m^3^ TRIM VX by Inhalation for Two Years (H&E)

Note the disorganized piling up of the epithelial cells (arrows). Normal transitional epithelium lining the lateral wall is composed of a single row of ciliated, cuboidal to columnar epithelial cells.

Figure 31

Hyaline Droplet Accumulation in the Olfactory Epithelium in the Nose of a Male Wistar Han Rat Exposed to 100 mg/m^3^ TRIM VX by Inhalation for Two Years (H&E)

The olfactory epithelium is distorted due to distention of the epithelial cells by intracytoplasmic accumulation of brightly eosinophilic, homogenous, globular material (arrows) that partially or completely filled the cytoplasm.

Figure 32

Hyperplasia of the Submucosal Glands in the Olfactory Epithelium of the Ventral Ethmoid Turbinates in the Nose of a Male Wistar Han Rat Exposed to 100 mg/m^3^ TRIM VX by Inhalation for Two Years (H&E)

There are increases in the size of the glands and number of gland profiles (arrows). Note hyaline droplet accumulation within the olfactory epithelial cells.

Figure 33

Squamous Metaplasia in the Larynx of a Male Wistar Han Rat Exposed to 100 mg/m^3^ TRIM VX by Inhalation for 2 Years (H&E)

Squamous metaplasia is characterized by replacement of the cuboidal to low columnar, ciliated epithelium that normally lines the base and lateral aspects of the epiglottis by multiple layers of well-differentiated, variably keratinized squamous epithelium (arrows). Squamous hyperplasia was characterized by thickening of the squamous epithelium that normally lines the arytenoid cartilages (arrowheads).

Figure 34

Lymphohistiocytic Hyperplasia in the Bronchial Lymph Node of a Male Wistar Han Rat Exposed to 100 mg/m^3^ TRIM VX by Inhalation for Two Years (H&E)

The lymph node is markedly expanded by increased numbers of lymphocytes (arrows) and macrophages (asterisks).

Figure 35

Alveolar/Bronchiolar Adenoma in the Lung of a Female B6C3F1/N Mouse Exposed to 100 mg/m^3^ TRIM VX by Inhalation for Two Years (H&E)

The adenoma (arrows) is distinctly demarcated from the surrounding alveolar parenchyma.

Figure 36

Higher Magnification of Figure 35 (H&E)

Note that the neoplastic cells form poorly and well-defined papillary and glandular structures.

Figure 37

Alveolar/Bronchiolar Carcinoma in the Lung of a Male B6C3F1/N Mouse Exposed to 100 mg/m^3^ TRIM VX by Inhalation for 2 Years (H&E)

The carcinoma (arrows) is a densely cellular, well-demarcated mass that has effaced a large portion of the lung and compresses the immediately adjacent lung parenchyma.

Figure 38

Higher Magnification of Figure 37 (H&E)

The carcinoma is composed of neoplastic cells that form poorly defined papillary structures. Note that the neoplasm has invaded the epithelium lining the terminal bronchiole and has grown into the lumen (arrow).

Figure 39

Bronchiole Epithelium Adenoma in the Lung of a Male B6C3F1/N Mouse Exposed to 30 mg/m^3^ TRIM VX by Inhalation for Two Years (H&E)

The neoplasm is an exophytic mass (arrows) within the bronchial lumen and is composed of irregular papillary structures.

Figure 40

Higher Magnification of Figure 39 (H&E)

The neoplastic cells vary from cuboidal to columnar and form irregular papillary structures supported by a core of scant connective stroma.

Figure 41

Focal Alveolar Epithelium Hyperplasia in the Lung of a Male B6C3F1/N Mouse Exposed to 100 mg/m^3^ TRIM VX by Inhalation for Two Years (H&E)

In the area of hyperplasia (arrows), the alveolar septae appear hypercellular in contrast to the surrounding normal alveolar septae. The alveolar architecture is generally maintained.

Figure 42

Higher Magnification of Figure 41 (H&E)

Alveolar septae are hypercellular and lined by cuboidal to polygonal cells (long arrows). Note adjacent normal- appearing alveolar septae (short arrows).

Figure 43

Alveolar/Bronchiolar Epithelium Hyperplasia in the Lung of a Male B6C3F1/N Mouse Exposed to 100 mg/m^3^ TRIM VX by Inhalation for Two Years (H&E)

Focal areas of proliferating epithelial cells (arrows) are adjacent to a terminal bronchiole. Note numerous macrophages and proteinaceous material within the alveoli.

Figure 44

Higher Magnification of Figure 43 (H&E)

In the areas of hyperplasia, the alveolar septae are lined by cuboidal to polygonal cells (arrows).

Figure 45

Exudate in the Ventral Nasal Passages in the Ethmoid Region of the Nose of a Female B6C3F1/N Mouse Exposed to 100 mg/m^3^ TRIM VX by Inhalation for Two Years (H&E)

The exudate in the ventral nasal passages is deeply eosinophilic and amorphous (asterisks) and is associated with the ruptured walls (short arrows) of the nasopharyngeal duct (ND) and an atrophic ethmoid turbinate (long arrow).