# Materials and Methods

## Procurement and Characterization of TRIM^®^ VX

TRIM^®^ VX was obtained from Master Chemical Corporation (Perrysburg, OH) in two lots (101607N and 011509N). Lot 101607N was used during the 3-month studies, and lot 011509N was used during the 2-year studies. Characterization and stability analyses of the test material were conducted by the analytical chemistry laboratory at Chemir Analytical Services (Maryland Heights, MO) and by the study laboratory at Battelle Toxicology Northwest (Richland, WA) (Appendix H). Reports on analyses performed in support of the TRIM^®^ VX studies are on file at the National Institute of Environmental Health Sciences.

The test material was a dark brown liquid. Fourier transform infrared (FTIR) spectroscopy was used to estimate the relative presence of various functional groups and create a reference for future comparisons of the same lot.

Analyses for both lots included Karl Fischer titration for water content; the determination of pH, specific gravity, and refractive index; elemental analysis for carbon, hydrogen, nitrogen, and sulfur using a C, H, N, S analyzer; metal analysis using inductively coupled plasma/optical emission spectrometry; chlorine, chloride, nitrate, and nitrite analysis by ion chromatography with conductivity detection; and iodine and iodide by ion-selective electrode titration. The study laboratory initially analyzed for general organic components using gas chromatography (GC) with flame ionization detection (FID) and identified the major components using GC with mass spectrometry (MS) (lot 101607N). Alkanolamines were identified and quantified using liquid chromatography (LC)/MS. Major oil constituents of both lots were assessed using GC/FID (lots 101607N and 011509N). The total amount of n-hexane extractable material and the amounts of bacteria and fungi were also determined. Samples were collected from the top, middle, and bottom of a drum and analyzed in triplicate to determine specific gravity, pH, refractive index, bacteria and fungi, total n-hexane extractable material and organic constituents.

The pH of the neat test material was approximately 7.5. In general, the FTIR spectra of the two lots were similar and were consistent with the presence of organic amines.

The test material did not contain significant amounts of water soluble nitrates, nitrites, chlorides, or iodides. The analysis for organics identified 12 compounds (Table 1). The amount of hexane extractable materials was 80.2% (lot 101607N) and 85.0% (lot 011509N). The mass balance percentages, estimated based on elemental contributions, resulted in 95% (lot 101607N) and 93% (lot 011509N) coverage. The composition of both lots was similar based on these analyses. The amount of bacteria and fungi was less than 100 CFU/mL and 10 CFU/mL, respectively, in samples diluted to 10% for analysis.

Table 1 Measured Components of the Two Lots of TRIM VX Used in the Inhalation Studies of TRIM VX^a^

Component | Lot 101607N^b^ | Lot 011509N^c^
Water | 7.1 | 6.8
Hexane extractable material | 80.2 | 85.0
Identified organic compounds
Triethanolamine | 3.7 | 3.2
4-Chloro-3-methyl-phenol | 3.59 | 2.49
Diethylene glycol | 0.87 | 1.07
Diethylene glycol monobutyl ether | 1.02 | 1.11
Methyl palmitate | 1.18 | 1.20
Methyl oleate | 5.65 | 5.81
Methyl stearate | 0.89 | 0.93
Myristic acid | 0.49 | 0.23
Oleic acid | 3.18 | 1.23
Palmitic acid | 1.01 | 0.31
Propylene glycol | 0.20 | 0.20
α-Terpineol | 0.60 | 0.50

^a^ All values are percentages.

^b^ Used in the 3-month studies.

^c^ Used in the 2-year studies.

To ensure stability, the bulk test material was stored at room temperature, protected from light in metal drums. Periodic reanalyses of lot 011509N were performed by the analytical chemistry laboratory and the study laboratory at least every 6 months during the 2-year studies. FTIR spectra were obtained and compared to the reference spectrum of this lot obtained at the initial characterization; determinations were made for the pH, specific gravity, and refractive index; determination and quantitation of alkanolamines was performed using LC/MS; assessment of fatty acid methyl esters was performed using GC/FID; and the amounts of bacteria and fungi were determined. Based on these analyses, no degradation of the bulk test material was observed over the course of the study (Table H-3). Furthermore, the amounts of bacteria and fungi were below the limit of detection of the assay (Table H-3).

## Aerosol Generation and Exposure System

The generation and delivery system used in the 3-month and 2-year studies consisted of two generator assemblies configured together so that the output from each assembly containing multi-jet nebulizers was directed to a common distribution line. TRIM^®^ VX was continuously pumped to the liquid reservoir from the chemical cabinet reservoir by metering pumps during the aerosol generation process. Ports in the generator assembly introduced compressed air to drive the nebulizers and dilution air to transport aerosol to the distribution line.

High velocity compressed air created a vacuum in the liquid uptake tube that drew test material from the liquid reservoir into the multi-jet nebulizer streams where shear forces broke the resultant liquid filaments into droplets. Large droplets were impacted on the impaction plate of the nebulizer or the generator assembly walls and were returned to the liquid reservoir; smaller droplets were drawn into the dilution air and transported to the common distribution line. The common distribution line was divided into two branches to supply aerosol to exposure chambers located on both sides of the exposure room; each branch line terminated in a filter protecting the flowmeter controlling the line via the house vacuum supply. During exposures, at each chamber position, aerosol was removed from the distribution line and injected into a tee fitting where it was directed to the inlet of the exposure chamber where it was mixed with conditioned air to achieve the desired exposure concentrations.

## Aerosol Concentration Monitoring

Summaries of the chamber aerosol concentrations are given in Tables H3 and H4. The concentrations of methyl palmitate, methyl stearate, and methyl oleate in TRIM^®^ VX were monitored using GC/FID and compared to real-time aerosol monitor (RAM) measurements. The monitors were connected to the chambers by a sampling system designed by Battelle incorporating a valve that multiplexed each RAM to a 0 mg/m^3^ chamber or the room, a HEPA-filtered room air blank, and two additional exposure chambers. The output voltage of the RAM was recorded by a program designed by Battelle (Battelle Exposure Data Acquisition and Control) to select the correct sample stream and acquire a raw voltage signal from each RAM. Equations for the calibration curves resided within the program and were used to convert the measured RAM voltages to exposure chamber concentrations. Each RAM was calibrated by constructing a response curve using the measured RAM voltages (voltage readings were corrected by subtracting the RAM zero-offset voltage from measured RAM voltages) and concentrations of methyl palmitate, methyl stearate, and methyl oleate in TRIM^®^ VX that were determined by analyzing duplicate adsorbent gas sampling tubes collected daily from the exposure chambers.

For the 3-month and 2-year studies, methyl palmitate, methyl stearate, and methyl oleate in TRIM^®^ VX were extracted from the gas sampling tubes and analyzed using GC/FID. The GC/FID instrument was calibrated against serially diluted TRIM^®^ VX and the internal standard, methyl undecanoate.

## Chamber Atmosphere Characterization

Particle size distribution in each chamber was determined prior to the start of all studies and monthly during the studies. Impactor samples were taken from each exposure chamber using a Mercer-style seven-stage impactor and the stages were collected on glass coverslips lightly coated with silicone (stages 1-7) or filters (stage 8) and were analyzed by GC/FID for methyl oleate as a marker for TRIM^®^ VX. The relative mass collected on each stage was analyzed by the CASPACT impactor analysis program developed at Battelle based on probit analysis^76^. The resulting estimates of the mass median aerodynamic diameter (range 1.7 to 2.2 µm) and the geometric standard deviation (range 1.7 to 1.9 µm) of each set of samples are given in Tables H5 through H7.

Buildup and decay rates for chamber aerosol concentrations were determined with and without animals present in the chambers. At a chamber air flow rate of 15 cubic feet per minute, the theoretical value for the time to achieve 90% of the target concentration after the beginning of aerosol generation (T_90_) was approximately 9.2 minutes. T_90_ values of 10 minutes and 12 minutes were selected for the 3-month and 2-year studies, respectively.

The uniformity of aerosol concentration in the inhalation exposure chambers was measured once during the 3-month studies with animals present, once before the 2-year studies began without animals present, and approximately every three months during the 2-year studies with animals present. RAM measurements were taken from 12 different chamber positions. Chamber concentration uniformity was acceptable throughout the 3-month and 2-year studies (Appendix H).

The persistence of TRIM^®^ VX in the exposure chambers was monitored after aerosol delivery ended by monitoring the concentration in the 400 mg/m^3^ chambers in the 3-month studies with animals present and in the 100 mg/m^3^ chambers in the 2-year studies with and without animals present. In the 3-month studies, the concentration decreased to 1% of the starting concentration within approximately 18 minutes. In the 2-year study of male rats, the concentration decreased to 1% of the starting concentration within approximately 20 minutes with animals present and within 17 minutes without animals. In the 2-year studies of female rats and male and female mice, the concentration decreased to 1% of the starting concentration within 17 minutes with animals present and within 15 minutes without animals.

Stability studies of the test material in the generation and exposure system were performed before (2-year studies only) and during the studies by the study laboratory. Samples were collected, prepared, and assayed for oil constituents using GC/FID or LC/MS. The relative amounts of the major constituents in the samples generally reflected those of the bulk test material with the exceptions of propylene glycol, diethylene glycol, diethylene glycol monobutyl ether, and α-terpineol.

## Animal Source

Male and female Wistar Han [Crl:WI (Han)] rats, referred to as Wistar Han rats in this Technical Report, were obtained from Charles River Laboratories (Raleigh, NC). Male and female B6C3F1/N mice were obtained from the NTP colony maintained at Taconic Farms, Inc. (Germantown, NY).

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by the Association for the Assessment and Accreditation of Laboratory Animal Care International. Studies were approved by the Battelle Toxicology Northwest Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Three-month Studies

The 3-month studies were conducted to evaluate the cumulative toxic effects of repeated exposure to TRIM VX and to determine the appropriate exposure concentrations to be used in the 2-year studies.

On receipt, the rats were 4 weeks old and mice were 4 to 5 weeks old. Animals were quarantined for 12 days and were 6 weeks (rats) or 5 to 6 weeks (mice) old on the first day of the studies. Before the studies began, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. The health of the animals was monitored during the studies according to using the protocols of the NTP Sentinel Animal Program (Appendix J). All test results were negative.

Groups of 10 male and 10 female rats and mice were exposed by whole body inhalation to TRIM VX aerosol at concentrations of 0, 25, 50, 100, 200, or 400 mg/m^3^, 6 hours plus T_90_ (10 minutes) per day, 5 days per week for 14 weeks. Exposure concentrations for the 3-month studies were selected based on results from previously conducted 3-month toxicity studies in rats and mice. The highest achievable concentration in the 3-month studies was 400 mg/m^3^ and minimal toxicity was reported. Thus, 400 mg/m^3^ was selected as the highest exposure concentration for the 3-month studies in rats and mice. Feed was available ad libitum except during exposure periods; water was available ad libitum. Rats and mice were housed individually. Clinical findings were recorded after exposure on day 1, twice daily on days 2 through 5, 8 through 12, 15, and 19, weekly thereafter, and at study termination. The animals were weighed initially, on days 6, 13, and 19, weekly thereafter, and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 2.

Table 2 Experimental Design and Materials and Methods in the Inhalation Studies of TRIM VX

Three-month Studies | Two-year Studies
Study Laboratory
Battelle Toxicology Northwest (Richland, WA) | Battelle Toxicology Northwest (Richland, WA)
Strain and Species
Wistar Han [Crl:WI (Han)] rats B6C3F1/N mice | Wistar Han [Crl:WI (Han)] rats B6C3F1/N mice
Animal Source
Rats: Charles River Laboratories (Raleigh, NC) Mice: Taconic Farms, Inc. (Germantown, NY) | Rats: Charles River Laboratories (Raleigh, NC) Mice: Taconic Farms, Inc. (Germantown, NY)
Time Held Before Studies
12 days | 12 days
Average Age When Studies Began
Rats: 6 weeks Mice: 5 to 6 weeks | Rats: 6 weeks Mice: 5 to 6 weeks
Date of First Exposure
July 14, 2008 | Rats: July 20, 2009 Mice: August 3, 2009
Duration of Exposure
6 hours plus T90 (10 minutes) per day, 5 days per week, for 14 weeks | 6 hours plus T90 (12 minutes) per day, 5 days per week, for 105 weeks
Date of Last Exposure
Rats: October 13 (males) or 14 (females), 2008 Mice: October 15 (males) or 16 (females), 2008 | Rats: July 17-19 (males) or 19-21 (females), 2011 Mice: July 31-August 2 (males) or August 2-4 (females), 2011
Necropsy Dates
Rats: October 14 (males) or 15 (females), 2008 Mice: October 16 (males) or 17 (females), 2008 | Rats: July 18-20 (males) or 20-22 (females), 2011 Mice: August 1-3 (males) or 3-5 (females), 2011
Average Age at Necropsy
Rats: 19 weeks Mice: 19 to 20 weeks | Rats: 110 to 111 weeks Mice: 109 to 111 weeks
Size of Study Groups
10 males and 10 females | 50 males and 50 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as 3-month studies
Animals per Cage
1 | 1
Method of Animal Identification
Tail tattoo | Tail tattoo
Diet
Irradiated NTP-2000 wafers (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, except during exposure periods, changed weekly | Same as 3-month studies
Water
Tap water (Richland, WA, municipal supply) via automatic watering system (Edstrom Industries, Waterford, WI), available ad libitum | Same as 3-month studies
Cages
Stainless steel wire bottom (Lab Products, Inc., Seaford, DE), changed weekly, rotated daily on exposure days through day 15 then weekly within chambers | Same as 3-month studies, except rotated weekly within chambers
Cageboard
Techboard® Ultra untreated paper excreta pan liner (Shepherd Specialty Papers, Watertown, TN), changed daily | Same as 3-month studies
Chamber Air Supply Filters
Single HEPA (open stock) charcoal (RSE, Inc., New Baltimore, MI) Purafil (Environmental Systems, Lynnwood, WA), all new at study start | Same as 3-month studies, except HEPA changed annually
Chambers
Stainless steel, excreta pan at each of six levels (Lab Products, Inc., Seaford, DE), changed weekly, excreta pans changed daily | Same as 3-month studies
Chamber Environment
Temperature: 72° ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Chamber air changes: 15 ± 2/hour | Same as 3-month studies
Exposure Concentrations
0, 25, 50, 100, 200, and 400 mg/m^3^ | 0, 10, 30, and 100 mg/m^3^
Type and Frequency of Observation
Observed twice daily; animals were weighed initially, on days 6, 13, and 19, weekly thereafter, and at the end of the studies; clinical findings were recorded on day 1 postexposure, twice daily on days 2 through 5, 8 through 12, 15, and 19, weekly thereafter, and at the end of the studies. | Observed twice daily; animals were weighed initially, weekly for 13 weeks, monthly thereafter, and at the end of the studies; clinical findings were recorded at week 5, monthly thereafter, and at the end of the studies.
Method of Kill
Carbon dioxide asphyxiation | Same as 3-month studies
Necropsy
Necropsies were performed on all animals. Organs weighed were heart, right kidney, liver, lung, spleen, right testis, and thymus. | Necropsies were performed on all animals.
Clinical Pathology
Blood was collected from the retroorbital plexus of rats and the retroorbital sinus of mice at the end of the studies for hematology and clinical chemistry (rats only). Hematology: hematocrit; packed cell volume; hemoglobin; erythrocyte, reticulocyte, nucleated erythrocyte, and platelet counts; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte counts and differentials Clinical chemistry: urea nitrogen, creatinine, glucose, total protein, albumin, globulin, cholesterol, triglycerides, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, and total bile acids | None
Histopathology
Complete histopathology was performed on chamber control and 400 mg/m^3^ rats and mice. In addition to gross lesions and tissue masses, the following tissues were examined to a no-effect level: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder (mice), Harderian gland, heart and aorta, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, larynx, liver, lung (with bronchus), lymph nodes (bronchial, mandibular, mediastinal, mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, trachea, urinary bladder, and uterus. | Complete histopathology was performed on all rats and mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder (mice), Harderian gland, heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, larynx, liver, lung, lymph nodes (bronchial, mandibular, mediastinal, mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, trachea, urinary bladder, and uterus.

Blood was collected from the retroorbital plexus of rats and the retroorbital sinus of mice at the end of the studies for hematology and clinical chemistry (rats only) analyses. For the hematology samples, blood was collected in tubes containing potassium EDTA; for the clinical chemistry samples, the blood was collected in a tube devoid of anticoagulant but containing a separator gel for serum. An ADVIA 120 (Siemans Medical Solutions Diagnostics, Tarrytown, NY) was used to determine packed cell volume; hemoglobin concentration; erythrocyte, reticulocyte, platelet, and leukocyte counts; mean cell volume; mean cell hemoglobin; and mean cell hemoglobin concentration. Manual hematocrit values were determined using a microcentrifuge (Heraeus Haemofuge, Heraeus Holding GmbH; Hanau, Germany) and a Damon/IEC capillary reader (International Equipment Company, Needham Heights, MA) for comparison to ADVIA 120 values for packed cell volume. Blood smears were stained with a Romanosky-type aqueous stain in a Wescor 7120 slide stainer (Wescor, Inc., Logan, UT). Leukocyte differential counts were based on classifying a minimum of 100 white cells. Blood samples for clinical chemistry analyses were analyzed using a Roche Hitachi 912 System (Roche Diagnostic Corporation, Indianapolis, IN). The hematology and clinical chemistry parameters measured are listed in Table 2.

Necropsies were performed on all animals. The heart, right kidney, liver, lungs, spleen, right testis, and thymus were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes were first fixed in Davidson’s solution, and testes with vaginal tunics and epididymides were first fixed in a modified Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. Complete histopathologic examinations were performed by the study laboratory pathologist on chamber control and 400 mg/m^3^ groups of rats and mice. Table 2 lists the tissues and organs routinely examined.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to a NTP Pathology Working Group (PWG) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the NTP pathology peer review process. Final diagnoses for reviewed lesions represent a consensus of the PWG or a consensus between the study laboratory pathologist, NTP pathologist, QA pathologist(s), and the PWG coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^77^ and Boorman et al.^78^.

## Two-year Studies

### Study Design

Groups of 50 male and 50 female rats and mice were exposed by whole body inhalation to TRIM VX aerosol at concentrations of 0, 10, 30, or 100 mg/m^3^, 6 hours plus T_90_ (12 minutes) per day, 5 days per week for 105 weeks. Rats and mice were quarantined for 12 days before the beginning of the studies. Five male and five female rats and mice were randomly selected for parasite evaluation and gross observation of disease. Rats were approximately 6 weeks old and mice approximately 5 to 6 weeks old at the beginning of the studies. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix J). All test results were negative.

Rats and mice were housed individually. Feed was available ad libitum except during exposure periods; water was available ad libitum. Cages were rotated weekly. Further details of animal maintenance are given in Table 2. The feed was analyzed for contaminants and found acceptable. Information on feed composition and contaminants is provided in Appendix I.

### Clinical Examinations and Pathology

All animals were observed twice daily. Clinical findings were recorded at week 5, every 4 weeks thereafter, and at study termination. Body weights were recorded on day 1, weekly for 13 weeks, every 4 weeks thereafter, and at study termination.

Complete necropsies and microscopic examinations were performed on all rats and mice. At necropsy, all organs and tissues were examined for grossly visible lesions, and all major tissues were fixed and preserved in 10% neutral buffered formalin (except eyes were first fixed in Davidson’s solution, and testes with vaginal tunics and epididymides were first fixed in modified Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin for microscopic examination. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. Tissues examined microscopically are listed in Table 2.

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The report, slides, paraffin blocks, residual wet tissues, and pathology data were sent to the NTP Archives for inventory, slide/block match, wet tissue audit, and storage. The slides, individual animal data records, and pathology tables were evaluated by an independent QA laboratory. The individual animal records and tables were compared for accuracy, the slide and tissue counts were verified, and the histotechnique was evaluated. For the 2-year studies, a QA pathologist evaluated slides from all tumors and all potential target organs, which included the lung, larynx, and nose of rats and mice and the bronchial lymph node and liver of mice.

The QA report and the reviewed slides were submitted to the NTP PWG coordinator, who reviewed the selected tissues and addressed any inconsistencies in the diagnoses made by the laboratory and QA pathologists. Representative histopathology slides containing examples of lesions related to chemical administration, examples of disagreements in diagnoses between the laboratory and QA pathologists, or lesions of general interest were presented by the coordinator to the PWG for review. The PWG consisted of the QA pathologist and other pathologists experienced in rodent toxicologic pathology. This group examined the tissues without any knowledge of dose groups. When the PWG consensus differed from the opinion of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist(s), and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman^77^ and Boorman et al.^78^. For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of McConnell et al.^79^.

Formalin-fixed lung tissue from chamber control and 100 mg/m^3^ male and female rats from the 2-year study were retrieved from the NTP Archives, passed through a graded series of sucrose solutions (10%, 20%, and 30%, successively) to remove water from the tissues, and then frozen in Optimum Cutting Temperature medium. The frozen lung tissue was cryosectioned at 5 µm, and the cryosections were stained with Oil-Red-O histochemical stain, a fat-soluble diazo dye, to demonstrate oil, fat, or lipids in the tissues.

## Statistical Methods

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier^80^ and is presented in the form of graphs. Animals found dead of other than natural causes were censored; animals dying from natural causes were not censored. Statistical analyses for possible dose-related effects on survival used Cox’s^81^ method for testing two groups for equality and Tarone’s^82^ life table test to identify dose-related trends. All reported P values for the survival analyses are two sided.

### Calculation of Incidence

The incidences of neoplasms or nonneoplastic lesions are presented in Table A-1, Table A-4, Table B-1, Table B-4, Table C-1, Table C-4, Table D-1, and Table D-4 as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. For calculation of statistical significance, the incidences of most neoplasms (Table A-2, Table B-2, Table C-2, and Table D-2) and all nonneoplastic lesions are given as the numbers of animals affected at each site examined microscopically. However, when macroscopic examination was required to detect neoplasms in certain tissues (e.g., mesentery, pleura, peripheral nerve, skeletal muscle, tongue, tooth, and Zymbal’s gland) before microscopic evaluation, the denominators consist of the number of animals that had a gross abnormality. When neoplasms had multiple potential sites of occurrence (e.g., leukemia or lymphoma), the denominators consist of the number of animals on which a necropsy was performed. Table A-2, Table B-2, Table C-2, and Table D-2 also give the survival-adjusted neoplasm rate for each group and each site-specific neoplasm. This survival-adjusted rate (based on the Poly-3 method described below) accounts for differential mortality by assigning a reduced risk of neoplasm, proportional to the third power of the fraction of time on study, only to site-specific, lesion-free animals that do not reach terminal kill.

### Analysis of Neoplasm and Nonneoplastic Lesion Incidences

The Poly-k test^83-85^ was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to take survival differences into account. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight. This value is one if the animal had a lesion at that site or if it survived until terminal kill; if the animal died prior to terminal kill and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the kth power.

This method yields a lesion prevalence rate that depends only upon the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time^83^. Unless otherwise specified, a value of k = 3 was used in the analysis of site-specific lesions. This value was recommended by Bailer and Portier^83^ following an evaluation of neoplasm onset time distributions for a variety of site-specific neoplasms in control F344/N rats and B6C3F1/N mice^86^. Bailer and Portier^83^ showed that the Poly-3 test gave valid results if the true value of k was anywhere in the range from 1 to 5. A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams^87^.

Tests of significance included pairwise comparisons of each dosed group with controls and a test for an overall dose-related trend. Continuity-corrected Poly-3 tests were used in the analysis of lesion incidence, and reported P values are one sided. The significance of lower incidences or decreasing trends in lesions is represented as 1 – P with the letter N added (e.g., P = 0.99 is presented as P = 0.01N).

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^88^ and Williams.^89; 90^. Hematology and clinical chemistry data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^91^ (as modified by Williams^92^) and Dunn^93^. Jonckheere’s test^94^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^95^ were examined by NTP personnel, and implausible values were eliminated from the analysis.

### Historical Control Data

The concurrent control group represents the most valid comparison to the treated groups and is the only control group analyzed statistically in NTP bioassays. However, historical control data are often helpful in interpreting potential treatment-related effects, particularly for uncommon or rare neoplasm types. For meaningful comparisons, the conditions for studies in the historical control database must be generally similar. Significant factors affecting the background incidences of neoplasms at a variety of sites are diet, sex, strain/stock, and route of exposure. The NTP historical control database contains all 2-year studies for each species, sex, and strain/stock with histopathology findings in control animals completed within the most recent 5-year period^96-98^. In general, the historical control database for a given study includes studies using the same route of administration, and the overall incidences of neoplasms in controls for all routes of administration are included for comparison, including the current study.

## Quality Assurance Methods

The 3-month and 2-year studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations^99^. In addition, as records from the 3-month and 2-year studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent QA contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Technical Report.

## Genetic Toxicology

The genetic toxicity of TRIM VX was assessed by testing the ability of the chemical to induce mutations in various strains of Salmonella typhimurium and Escherichia coli and increases in the frequency of micronucleated erythrocytes in rat and mouse peripheral blood. Micronuclei (literally “small nuclei” or Howell-Jolly bodies) are biomarkers of induced structural or numerical chromosomal alterations and are formed when acentric fragments or whole chromosomes fail to incorporate into either of two daughter nuclei during cell division^100; 101^. The protocols for these studies and the results are given in Appendix E.

The genetic toxicity studies have evolved from an earlier effort by NTP to develop a comprehensive database permitting a critical anticipation of a chemical’s carcinogenicity in experimental animals based on numerous considerations, including the molecular structure of the chemical and its observed effects in short-term in vitro and in vivo genetic toxicity tests (structure-activity relationships). The short-term tests were originally developed to clarify proposed mechanisms of chemical-induced DNA damage based on the relationship between electrophilicity and mutagenicity^102^ and the somatic mutation theory of cancer^103; 104^. However, it should be noted that not all cancers arise through genotoxic mechanisms.

DNA reactivity combined with Salmonella mutagenicity is highly correlated with induction of carcinogenicity in multiple species/sexes of rodents and at multiple tissue sites^105^. A positive response in the Salmonella test was shown to be the most predictive in vitro indicator for rodent carcinogenicity (89% of the Salmonella mutagens are rodent carcinogens)^106; 107^. Additionally, no battery of tests that included the Salmonella test improved the predictivity of the Salmonella test alone. However, these other tests can provide useful information on the types of DNA and chromosomal damage induced by the chemical under investigation.

The predictivity for carcinogenicity of a positive response in acute in vivo bone marrow chromosome aberration or micronucleus tests appears to be less than that in the Salmonella test^108; 109^. However, clearly positive results in long-term peripheral blood micronucleus tests have high predictivity for rodent carcinogenicity; a weak response in one sex only or negative results in both sexes in this assay do not correlate well with either negative or positive results in rodent carcinogenicity studies^110^ . Because of the theoretical and observed associations between induced genetic damage and adverse effects in somatic and germ cells, the determination of in vivo genetic effects is important to the overall understanding of the risks associated with exposure to a particular chemical.