# Introduction

## Chemical and Physical Properties

TRIM VX, like many other metalworking fluids, is a highly complex mixture containing oils, detergents, surfactants, biocides, lubricants, anticorrosive agents, and other ingredients. Metalworking fluids are designed to enhance machining processes such as lubricating and cooling or for cleaning tools and parts during cutting, drilling, milling, and grinding. Therefore, chemical species present in these mixtures are dependent on requirements of the particular machining process. Metalworking fluids are classified into the general categories of straight oils, soluble oils, semisynthetic fluids, or synthetic fluids based upon the amount of highly refined oil they contain^3-5^. Straight oils contain 60% to 100% oil derived from highly refined napthenic or paraffinic oils. The soluble (emulsifiable) oils and semisynthetic fluids contain 5% to 85% oil, while the synthetic fluids contain no oil and are 70% to 95% water^6^. TRIM VX is classified as a soluble oil metalworking fluid because it is primarily oil but does contain approximately 7% water. Generally, the concentrated soluble metalworking fluids are diluted prior to use with water at ratios of one part concentrate to five to 40 parts water. These solutions form oil-water emulsions with the water acting as a cooling agent and the oil providing lubrication for enhanced heavy duty machining operations.

The specific chemical composition of TRIM VX and other metalworking fluids is considered proprietary information by the metalworking fluid industry. However, some typical components of soluble oil metalworking fluids include mineral oils, fatty acids, sulfur, chlorine, and phosphorus derivatives to provide enhanced lubrication^7; 8^. Other additives can include detergents to lower surface tension, polyol ester as an “oiliness agent,” petroleum sulfonate as an emulsifier, alkanolamines to provide reserve alkalinity and inhibit corrosion, chlorinated paraffins as “extreme pressure agents,” long chain fatty alcohols as defoamers, triazoles as metal passivators, antioxidants, dyes, and biocides^9^.

Metalworking fluids, including TRIM VX, are commonly recycled or reused because they are expensive and single use is not practical. Long-term physical and chemical effects can cause the components of metalworking fluids to deteriorate, and as a result, the composition of these “in-use” metalworking fluids is considerably different from unused metalworking fluids. For example, excessive temperatures can cause oxidation of metalworking fluid oils and constituents leading to the formation of acids, resins, varnishes, sludge, and carbonaceous deposits. Furthermore, depletion of performance additives with use requires routine product addition or supplementation. Finally, environmental contaminants including rust, weld spatter, metal chips and abrasives, as well as contaminants entering through broken seals, dirty oil filter pipes, and chemical residue on metal parts can accelerate metalworking fluid breakdown.

Contamination of in-use metalworking fluids with bacteria, bacterial endotoxins, and fungi is an added concern for individuals working with these chemicals. Contaminated metalworking fluids and aerosols increase the potential for respiratory effects when inhaled and skin infections following dermal contact. Antimicrobial agents are often added to metalworking fluids to control the growth of microbes and to extend the usable life of these fluids. However, the microbiocidal or microbiostatic activities of some antimicrobial agents occur through the release of formaldehyde, which is an airway irritant and a recognized cause of occupational asthma^10^. Studies suggest that exposure to certain antimicrobial agents can cause allergic or irritant contact dermatitis^8; 11^. TRIM VX reportedly contains the biocide 4-chloro-3-methylphenol (CMP), which was identified as a potent sensitizer in a combined local lymph node assay^12^, and is reported to be irritating to the eyes, skin, and respiratory tract following short-term exposure^13^.

Formulations of metalworking fluids are continuously changing to improve functionality and reduce potential health and environmental concerns. Examples of chemicals reduced or removed over time include rust inhibitors (nitrites), biocides, corrosion inhibitors [diethanolamines (DEA), 4-tert-butylbenzoic acid, dichromates], and lubricants such as polychlorinated biphenyls^6^. Efforts have been taken to remove components with suspected carcinogenicity such as polycyclic aromatic hydrocarbons (PAHs), nitrosating agents and short-chained chlorinated paraffin from metalworking fluids from 1950 to 1990 by the United States Environmental Protection Agency^14^. In addition, the concentrations of some suspected carcinogens, such as ethanolamine, have been reduced in some metalworking fluids as an attempt to reduce exposure-related health hazards. Efforts to reduce volatile organic compounds have resulted in the increased use of water as a major component of currently used metalworking fluids. Toxicity and carcinogenicity data on older metalworking fluids may not apply to metalworking fluids currently in use. Although many carcinogenic components have been removed, the newer metalworking fluids have not been tested so the current cancer risk is unclear.

## Production, Use, and Human Exposure

The production of metalworking fluids started in the early 1900s^15^. Today, specific data available on metalworking fluid (e.g., TRIM VX) production and use are not available as this information is considered proprietary by the metalworking fluid manufacturers. However, the Independent Lubricant Manufacturers Association^16^ reported that 95 to 103 million gallons of metalworking fluids were produced annually in the United States from 1994 to 1999. In 1999, five companies each reported producing more than 5 million gallons of these fluids. The largest use of metalworking fluids in terms of industry consumption is the metal removal fluids with more than 100 million gallons consumed annually^16^.

Metalworking fluids are primarily used to reduce friction, minimize heat generation, and extend tool life in metalworking operations. Most soluble oil metalworking fluids, such as TRIM VX, are recommended for use in heavy duty machining operations to prevent welding of the cutting tool to the work surface, reduce abrasive wear of the tool at high temperatures, and prevent distortion caused by residual heat. The manufacturer recommends diluting TRIM VX concentrate 5% to 20% in water before use^17^.

The National Occupational Exposure Survey^18^ estimated that over 1.2 million workers were potentially exposed to metalworking fluids from 1981 to 1983. Health hazard evaluations (HHEs) from the National Institute for Occupational Safety and Health^19^ indicate that exposures to metalworking fluid aerosols have decreased over time but it is unclear how many current workers are potentially exposed. HHEs conducted by NIOSH from approximately 1970 to 1990 indicate an overall exposure mean concentration of 0.96 mg/m^3^ across 38 individual plants using metalworking fluids^20^. Industry-sponsored exposure reports from three investigations indicated an arithmetic mean metalworking fluid airborne exposure concentration of less than 1.0 mg/m^3^.^21-23^

Exposure occurs primarily from inhalation of aerosols and dermal contact with aerosols or when handling equipment covered in metalworking fluids. Workers can receive significant exposure to metalworking fluids by inhalation of aerosols^24^. Aerosols form when a metalworking fluid is subjected to high shear forces or excess heat during use. The characteristics of these aerosols are dependent upon the particular metalworking fluid and the machining process for which it is being used; however, some aerosols can be stable and long lasting^25^. Dermal exposure to metalworking fluids can occur through contact with contaminated equipment, from splashes, or exposure to aerosols. The components and alkalinity of metalworking fluids are well-known causes of dermatitis in workers^26; 27^. There are no specific estimates of TRIM VX human exposure reported in the literature.

## Regulatory Status

NIOSH recommends an exposure limit (REL) for all metalworking fluid aerosols of 0.4 mg/m^3^ for thoracic particulate mass. The NIOSH REL for total particulate mass is 0.5 mg/m^3^ as a time-weighted average concentration up to 10 hours per day during a 40-hour workweek^28^. Metalworking fluid mists are regulated as a nuisance dust by the Occupational Safety and Health Administration (OSHA) and the permissible exposure limit is 15 mg/m^3^ for total particulate^29^. There are no specific regulations for TRIM VX use and exposure itself. The Material Safety Data Sheet provided by the manufacturer states that all TRIM VX ingredients are listed on the Toxic Substances Control Act Inventory of Chemical Substances.

## Absorption, Distribution, Metabolism, and Excretion

No studies evaluating the absorption, distribution, metabolism, or excretion (ADME) of metalworking fluids including TRIM VX in experimental animals or humans were found in the literature. For some of the components of TRIM VX, there are ADME data available in the literature; however, it is not the intent to discuss each individual component here.

## Toxicity

### Experimental Animals

Respiratory toxicity attributed to TRIM VX exposure was not found in the literature; however, several animal models have been used to evaluate different classes of metalworking fluids. Schaper and Detwiler^30^ used Swiss Webster mice to compare the effects of different classes of metalworking fluids on pulmonary function. Mice were exposed for 3 hours at concentrations ranging from 20 to 200 mg/m^3^. Results from this study demonstrated that all 10 proprietary metalworking fluids examined were sensory and pulmonary irritants. Increased breathing rate was most significant after inhalation of semisynthetic and synthetic fluids followed by soluble oils and finally straight oil aerosols. Furthermore, pulmonary irritation was similar in mice exposed to unused and used metalworking fluids. In a subsequent study^31^, the same mouse model was used to evaluate the sensory and pulmonary irritation properties of a single metalworking fluid from the 1991 study (classified as “neat, soluble oil”) and to identify the contribution of three major components. Results indicated that sensory irritation was caused mainly by tall oil fatty acids, whereas pulmonary irritation was caused primarily by sodium sulfonate (i.e., corrosion inhibitor). Paraffinic oils in the metalworking fluid decreased the irritant properties of both tall oil fatty acids and sodium sulfonate.

The subchronic respiratory toxicity of metalworking fluids has been investigated in several studies. Lim et al.^32^ exposed F344 rats to a water-soluble metalworking fluid at aerosol concentrations of 0, 20, 60, or 180 mg/m^3^ 6 hours/day, 5 days per week for 13 weeks. At 60 and 180 mg/m^3^, pulmonary inflammation consisting of increases in lung weights, bronchoalveolar lavage (BAL) fluid neutrophils, foamy macrophages, and thickening of the alveolar walls was observed in the absence of clinical observations. In a more recent subchronic study, male and female F344/NTac rats and B6C3F1/N mice were exposed to aerosol concentrations of 25 to 400 mg/m^3^ CIMSTAR 3800, a semisynthetic metalworking fluid, for 13 weeks^2^. Results of this study demonstrated toxicity to the respiratory tract of both rats and mice but no effect on survival. In the nasal cavity of rats, there were significantly increased incidences of goblet cell hyperplasia and hyaline droplet accumulation and suppurative inflammation of the olfactory and respiratory epithelia in all exposed groups of males and females. Mice had fewer lesions in the nose which included hyaline droplet accumulation of the olfactory and respiratory epithelia in all exposed groups. In the larynx of rat and mice, there were significantly increased incidences of squamous metaplasia, hyperplasia of the squamous epithelium, and chronic active inflammation in all exposed groups of rats and some exposed groups of mice. The incidences of epiglottis dysplasia were also significantly increased in the larynx of male and female mice exposed to 400 mg/m^3^ CIMSTAR 3800. In the lung, rats had fewer lesions than mice. In rats, there were significantly increased incidences of alveolus histiocytic cellular infiltration in male and females exposed to 200 or 400 mg/m^3^, while mice had significantly increased incidences of bronchiole hyperplasia in all exposed groups and perivascular chronic active inflammation and arteriole hypertrophy in some of the groups exposed to 100 mg/m^3^ or greater.

The acute and subacute effects of in-use metalworking fluids contaminated with endotoxins have also been investigated in experimental animals by several groups. Thorne and DeKoster^33^ reported that in-use metalworking fluids were consistently more toxic than neat metalworking fluids. In this report, acute inhalation exposure of mice to a high concentration of in-use metalworking fluid aerosol contaminated with endotoxin caused a significant elevation of neutrophils, TNF-α, and IL-6 in BAL fluid. DeLorme et al.^34^ demonstrated that acute exposure to water-soluble metalworking fluids containing endotoxin also caused an increase in BAL fluid neutrophils in Wistar rats. Sprague Dawley rats were exposed to water-soluble metalworking fluids with and without endotoxin for 2 weeks^35^. In this study, endotoxin-contaminated metalworking fluids caused a significantly elevated inflammatory response in the lung relative to uncontaminated metalworking fluid. Furthermore, the same investigators reported that exposure of F344 rats to endotoxin-contaminated metalworking fluids for 8 weeks increased lung inflammatory responses in the absence of altered pulmonary function^36^.

Dermal sensitization and irritancy potential of nine metalworking fluids, including TRIM VX, were investigated in a combined local lymph node assay using female BALB/c mice^12^. Significant irritation was observed after dermal exposure to seven of the nine metalworking fluids. TRIM VX was identified as an irritant at concentrations as low as 10%. In addition, six of the nine metalworking fluids tested induced a greater than threefold increase in lymphocyte proliferation; TRIM VX induced the most robust proliferative response. Several components of TRIM VX were identified by high performance liquid chromatography and were screened for sensitization potential using structure activity relationship (SAR) modeling and the local lymph node assay. SAR modeling predicted two TRIM VX components, triethanolamine (TEA) and 4-chloro-3-methylphenol (CMP), to be positive for sensitization. CMP and oleic acid stimulated lymphocyte proliferation but only at doses that resulted in significant irritancy.

Individual components of metalworking fluids and their potential to cause toxicity have been investigated in various experimental animal models. While it is not in the scope of this report to discuss the results, some of the data are summarized by NIOSH^20^.

### Humans

Occupational exposure to metalworking fluid aerosols is associated with a variety of nonmalignant respiratory and dermal conditions, however, there are no specific data linking TRIM VX exposure with toxicity in humans. Occupational exposure to metalworking fluid aerosols causes symptoms consistent with airway irritation, chronic bronchitis, and asthma. The epidemiologic evidence suggests that at least three classes of metalworking fluids (straight oil, soluble oil, and synthetic) are capable of inducing respiratory symptoms. Hypersensitivity pneumonitis, asthma, and allergic airways diseases are reported to be associated with metalworking fluid use and exposure in occupational settings^37^.

Hypersensitivity pneumonitis is characterized in its acute phase by alveolar inflammation and influenza-like symptoms. In its chronic phase (following repeated exposures), it is characterized by pulmonary fibrosis associated with respiratory insufficiency. Two cases of hypersensitivity pneumonitis associated with metalworking fluids were reported during a 3-year period in an occupational respiratory disease surveillance program operating in the United Kingdom^38^. Many more cases in North America have been recognized^39-42^. Some causative agents for hypersensitivity pneumonitis are small organic particles or volatile reactive chemicals^43^.

An elevated risk of asthma among workers exposed to metalworking fluid aerosols has been documented. Exposure to synthetic metalworking fluids has been associated with asthma^21; 44; 45^ and case reports have documented asthma caused by exposure to soluble oil metalworking fluids^46; 47^ or to common components of soluble oil metal-working fluids^48^. For example, 13 case reports of occupational asthma attributed to soluble oil metalworking fluids were documented in a surveillance program in Michigan during 1988 to 1994^45^. A variety of components, additives, and contaminants of metalworking fluids are sensitizers or irritants known to induce new-onset asthma, aggravate preexisting asthma, or irritate the airways of non-asthmatic workers. These sensitizers, irritants, or toxicants include ethanolamine and other amines, colophony, pine oil, tall oil, metals and metallic salts (e.g., chromium, nickel, cobalt, and tungsten carbide), castor oil, formaldehyde, chlorine, various acids, and fungal and other microbial contaminants (including gram-negative bacterial endotoxin)^46; 49; 50^.

There is no convincing evidence that identifies any particular component or components of metalworking fluid aerosol as the predominant cause of respiratory symptoms, although some irritant components of metalworking fluid are clearly suspect^51^. One large multiplant study in the United States with mean exposures for the major types of metalworking fluids ranging from 0.41 to 0.55 mg/m^3^ (thoracic fraction) found statistically significant quantitative exposure-response relationships between cumulative concentration of metalworking fluid aerosols and respiratory symptoms^21^. Likewise, another United States study found significant exposure-response relationships between aerosol exposure concentration and chest symptoms^51^. Other studies have shown the onset or worsening of many symptoms in workers over the course of a work shift^45; 51; 52^ and substantial symptomatic improvement in affected workers when away from work^21^. Controlling worker exposures may prevent chronic effects induced by metalworking fluid aerosol exposure and may reverse early metalworking fluid-induced airway effects.

In addition to respiratory conditions, occupational exposures to metalworking fluids are associated with irritant and allergic dermatitis in workers. The type and concentration of fluid and duration of use as well as the presence of preexisting skin disease may contribute to the development of dermatitis. The components and alkalinity of metalworking fluids are well-known causes of dermatitis in workers^26; 27^. The additives in metalworking fluids such as biocides, preservatives, corrosion inhibitors, amines and the impurities from metal (chrome, nickel), act as allergens and can cause an allergic reaction in some susceptible individuals.

## Reproductive and Developmental Toxicity

No studies on metalworking fluid reproductive or developmental toxicity in experimental animals or humans were found in the literature. For some of the components of TRIM VX, there are reproductive and developmental toxicity studies available in the literature; however, it is not the intent to discuss each individual component here.

## Carcinogenicity

### Experimental Animals

There have been no carcinogenicity studies of TRIM VX in experimental animals. However several studies have examined the carcinogenicity of neat and used metalworking fluids in experimental animals^2; 53-57^. Gilman and Vesselinovitch^53^ applied soluble cutting oils formulated from unrefined distillates to the skin three times weekly for 310 days in three mouse strains and found that 19% to 61% of mice developed skin tumors while no tumors occurred in the skin of unexposed controls. Jepsen et al.^55^ compared various forms of paraffin- and naphthalene-based straight oil and solvent-extracted metalworking fluids in mice following dermal application for 31 weeks. The incidences of skin papillomas (40% to 100%) were more pronounced in mice treated with undiluted (i.e., straight oil) metalworking fluids versus diluted versions. This study also demonstrated differences in skin lesions following application of unused versus used metalworking fluids. In mice treated with unused solvent-extracted paraffin oil, 45% of the animals had papillomas whereas there was a 0% occurrence with the used form of the oil. However, the papilloma incidence was 80% to 100% in mice treated with naphthalene-based straight oil regardless of whether it was used or unused. Another study found that both unused and used cutting oils were potent skin tumor initiators^54^. Among mice administered a single application of a cutting oil followed by a weekly application (three times a week) of the tumor promoting agent 12-O-tetradecanoylphorbol-13-acetate for 28 weeks, 90% and 60% of mice developed benign skin cancers after exposure to unused and used cutting oil, respectively. McKee et al.^56^ found no evidence of carcinogenicity from solvent-extracted cutting oils when they were administered to the skin of mice three times a week. The carcinogenic effects of metalworking fluid exposure following oral exposure were assessed by Wang et al.^57^. In the 2-year study in Wistar rats, pancreatic carcinoma occurred in nine of 40 rats dosed with undiluted rustproof cutting fluid consisting of sodium nitrite, TEA, and polyethylene glycol, while none of the control rats developed pancreatic cancer. All three of the components reported to be in this rustproof cutting fluid can be found in some metalworking fluids used in the United States. In a more recent study, groups of 50 male and 50 female Wistar Han rats and B6C3F1/N mice were exposed by whole body inhalation to aerosol concentrations of 0, 10, 30, or 100 mg/m^3^ CIMSTAR 3800, a semisynthetic metalworking fluid, for 2 years^2^. Survival and body weights of exposed groups of rats and mice were similar to those of the chamber control groups. Exposure to CIMSTAR 3800 resulted in increased incidences of nonneoplastic lesions of the nose, larynx, and lung in male and female rats and mice, lymph nodes in male and female rats, and thyroid gland in female mice. Increased incidences of prostate gland adenoma or carcinoma and of benign or malignant granular cell tumors of the brain occurred in exposed groups of male rats. Increased incidences of squamous cell papilloma or keratoacanthoma of the skin and of adenocarcinoma or mixed malignant Müllerian tumors of the uterus occurred in exposed groups of female rats. There was no evidence of carcinogenic activity of CIMSTAR 3800 in male mice; however, exposed groups of female mice had increased incidences of follicular cell carcinoma of the thyroid gland and of alveolar/ bronchiolar adenoma or carcinoma of the lung.

Specific components of metalworking fluids such as DEA, TEA, nitrosoamines, and formaldehyde have been evaluated for carcinogenic potential on an individual basis. Variable amounts of alkanolamines are present in many metalworking fluids. The carcinogenicity of TEA was investigated because of its potential conversion to the carcinogen N-nitrosodiethanolamine. Following dermal exposure for 2 years, there was equivocal evidence of carcinogenic activity of TEA in male F344/N rats based on marginally increased incidences of renal tubule adenoma and no evidence of carcinogenicity in female rats^58^. In a 2-year dermal study of TEA in B6C3F1 mice, there was equivocal evidence of carcinogenicity in males based on the occurrence of liver hemangiosarcoma and some evidence of carcinogenicity in females based on increased incidences of hepatocellular adenoma^59^. The carcinogenicity of DEA was also studied in F344/N rats and B6C3F1/N mice in 2-year dermal exposure studies^60^. There was no evidence of carcinogenic activity in rats; however, there was clear evidence of carcinogenic activity of DEA in mice based on increased incidences of liver neoplasms in males and females and increased incidences of renal tubule neoplasms in males.

### Humans

No epidemiologic studies have evaluated the carcinogenicity of TRIM VX in humans. In most studies, metalworking fluids have been treated as a single exposure agent, without regard to type, constituents, or concentration. Evidence exists for increased risk of squamous cell skin cancer^59; 61-63^ especially of the scrotum^64-66^ following exposure to metalworking fluids. The International Agency for Research on Cancer^67^ designated unused and mildly used mineral oil as carcinogenic to humans based on squamous cell carcinoma of the skin, sinonasal cancer, and bladder cancer. NIOSH^28^ concluded that substantial evidence exists for an increased risk of cancer at several tissue sites (larynx, rectum, pancreas, skin, scrotum, and urinary bladder) associated with at least some of the metalworking fluids used before the mid-1970s. The inconsistencies between studies with respect to the tissue sites that were affected, and the variation in the strength of association between the surrogates of exposure and specific sites are most likely related to the diverse nature of the metalworking fluid mixtures studied, the absence of detailed exposure information, and the limitations of the epidemiologic tools with which metalworking fluid exposures have been studied. The evidence is unclear for an association between metalworking fluid exposure and cancer at several other sites including the stomach, esophagus, lung, prostate gland, brain, colon, and hematopoietic system.

Given the small number of epidemiologic studies that have adequate exposure characterization, the specific metalworking fluid constituents or contaminants responsible for the various site-specific cancer risks remain to be determined. The study with the most statistical power and detailed exposure information included more than 46,000 autoworkers in Michigan^68^. Results of this study suggest that specific classes of metalworking fluids are associated with cancer at certain sites. However, within these metalworking fluid classes, the specific formulations responsible for the elevated cancer risks remain to be identified. Within the Tolbert et al.^68^ study, straight oil exposure was modestly associated with increased risks for laryngeal and rectal cancers, and there was limited evidence that synthetic metalworking fluid exposure was associated with an increased risk for pancreatic cancer. Subsequent case-control studies based on the original cohort have confirmed the association of laryngeal cancer with straight oil metalworking fluids^69^, and the association of pancreatic cancer with synthetic metalworking fluids^70^. The Tolbert et al.^68^ study found less evidence that soluble oil metalworking fluid exposure is associated with cancer at any specific site. The most recent extension of this study up to 2005 added a follow-up for incident cancer. The cohort was limited to white males hired after 1938. The results of this evaluation provided evidence that oil-based metalworking fluids, especially straight mineral oils, were associated with an increased incidence of malignant melanoma^71^. In another evaluation of the same incident cohort, long-term dermal exposure to oil-based metalworking fluids was reported to cause an increased risk of nonseminomatous testicular germ cell cancer^72; 73^. An assessment of cancer incidence risk in these autoworkers exposed to metalworking fluids was published by Friesen et al.^74^. The findings supported the previously published work on this cohort and demonstrated that water-based metalworking fluids increased colon cancer risk and decreased stomach cancer risk.

The studies that provide most of the data suggesting an association between metalworking fluid exposure and cancer involved workers employed as early as the 1930s and as late as the mid-1980s. Because there is a latency period of 10 to 20 years between initial exposure to a carcinogen and the initial appearance of a solid-organ cancer caused by that carcinogen, the excess cancer mortality observed in these cohort studies most likely reflects the cancer risk associated with exposure conditions in the mid-1970s and earlier. Over the last several decades, substantial changes have been made in the metalworking industry, including changes in metalworking fluid composition, reduction of impurities, and reduction of exposure concentrations. These changes have likely reduced the cancer risks. However, since the epidemiologic data do not usually identify the metalworking fluid composition and impurities associated with the cancer risks observed in earlier cohorts, there is insufficient data to conclude that these changes will have eliminated all carcinogenic risks. The risk of cancer from metalworking fluid exposures in the mid-1970s and later remains to be determined because a definitive study has not yet been conducted on workers entering metalworking fluid-exposed jobs during this period. Thus, there is an unclear potential for current metalworking fluids to pose a similar carcinogenic hazard.

## Genetic Toxicity

No studies were found in the literature on the genotoxicity of TRIM VX. Various components of TRIM VX were negative in bacterial mutagenicity tests conducted by NTP, including TEA, myristic acid, oleic acid, stearic acid, diethylene glycol, diethylene glycol monobutyl ether, propylene glycol, and 4-chloro-3-methylphenol. α-Terpineol, another component of TRIM VX, exhibited weak activity in Salmonella typhimurium strain TA102 with and without rat liver S9 mix; no activity was observed in any of several other bacterial strains^75^. Genotoxicity information could not be found for another component of this metalworking fluid, palmitic acid.

## Study Rationale

The class of metalworking fluids was nominated by NIOSH based on the large number of occupationally exposed workers, the associated epidemiologic data indicating increased incidences of laryngeal cancer in workers exposed to metalworking fluids, and the lack of carcinogenicity and chronic toxicology data for this class of complex mixtures. Three classes, including soluble oils, semisynthetic fluids, and synthetic fluids, encompass the majority of metalworking fluids in current use. The National Toxicology Program (NTP), in collaboration with NIOSH, selected metalworking fluids for inhalation toxicity testing by NTP based on a combination of considerations including commercial availability, chemical composition, and class. TRIM VX, a soluble oil metalworking fluid, was selected for 3-month inhalation studies along with three other metalworking fluids (CIMSTAR 3800, Syntilo 1023, and TRIM SC210). TRIM VX was selected for 2-year studies based on the incidence of fibrosis of the lung; TRIM VX was the only metalworking fluid with this lesion following a 3-month exposure.