# Appendix K Summary of Peer Review Panel Comments of Draft NTP Technical Report on TRIM VX (TR 591)

## K.1 Presentation

NTP study scientist Dr. K.R. Ryan briefed the panel on the draft NTP technical report on TRIM^®^ VX. TRIM^®^ VX is a water-soluble metalworking fluid (MWF) in the class known as soluble oils. Due to their high production volume, the large number of occupationally exposed workers, and the lack of carcinogenicity and toxicology data, the National Institute for Occupational Safety and Health nominated MWFs for NTP study. TRIM^®^ VX was one of four MWFs selected for study from the original slate of 30.

NTP conducted 3-month and 2-year whole body inhalation exposure studies in male and female Wistar Han rats and male and female B6C3F1/N mice.

The 3-month study showed that the major target of TRIM^®^ VX exposure was the respiratory tract, with similar toxicity in both sexes and species. Lung fibrosis was also seen, which was a distinct finding in NTP comparison studies with MWFs. No effects were seen on overall survival, clinical observations, or body weights in either sex or species.

Based on the 2-year studies, the draft NTP report’s conclusions on TRIM^®^ VX were:

Male Wistar Han rats

- Equivocal evidence of carcinogenic activity
  - Combined occurrences of alveolar/bronchiolar adenoma or carcinoma of the lung

Female Wistar Han rats

- Equivocal evidence of carcinogenic activity
  - Occurrences of alveolar/bronchiolar adenoma of the lung

Male B6C3F1/N mice

- Clear evidence of carcinogenic activity
  - Increased combined incidences of alveolar/bronchiolar adenoma or carcinoma of the lung

Female B6C3F1/N mice

- Clear evidence of carcinogenic activity
  - Increased combined incidences of alveolar/bronchiolar adenoma or carcinoma (primarily carcinoma) of the lung

Exposure to TRIM^®^ VX resulted in increased incidences of nonneoplastic lesions of the lung, nose, and larynx of male and female rats and mice; the bronchial lymph node in male and female rats and male mice, and the mediastinal lymph node in male and female rats.

## K.2 Questions for Clarification

Dr. Sabo-Attwood asked Dr. Ryan to comment on the bacterial fungal growth assays performed, and whether they also included an endotoxin assay. Dr. Ryan said they had not done an endotoxin assay. An assessment for bacterial and fungal growth was done, and no evidence of bacterial or fungal growth was detected throughout the studies.

Dr. Brock questioned the stability assessments performed on the test article. He asked for clarification on Dr. Ryan’s presentation to “data compared to frozen reference sample upon receipt of the material.” Dr. Ryan replied that when the test material was received, aliquots were taken out and frozen, so that current data could be compared to the reference samples at any point during the study to see if there was any degradation over time. Dr. Brock noted that method assumed that the frozen samples would not also degrade. Dr. Ryan said no evidence of degradation was seen. Dr. S. Waidyanatha, chemistry group leader in the Program Operations Branch of NTP, described the procedures that had been conducted to assess stability and clarified that the test article was stored at 5°C. Dr. Brock said he found the description in the report confusing.

## K.3 Public Comments

Dr. Mirsalis noted receipt and distribution to the panel of written comments from Ms. Holly Alfano of the Independent Lubricant Manufacturers Association (ILMA) and Dr. Steven Florio of Master Chemical Corporation (MCC). Dr. Mirsalis then recognized an oral public commenter, Dr. Franklin Mirer of the CUNY School of Public Health, who spoke on his own behalf by telephone.

Dr. Mirer described the history of the MWFs project, which began with a petition to NTP from the United Auto Workers. He noted that the respiratory effects of MWFs are as important to public health as carcinogenic effects. He noted the contrast between fresh fluids and in-use, contaminated fluids. He said that the respiratory effects of in-use MWFs of all types are generally accepted, with the dispute being whether they stem from microbial contamination or whether the fluids themselves have toxic potential. He cited several previous studies from the literature. He asked NTP to publish complete analyses of all nine test articles, especially the four articles subjected to 90-day testing. He noted that MCC has already discontinued TRIM^®^ VX. He pointed out that sulfonate had not appeared as a component of TRIM^®^ VX in NTP analysis. He stated that lung tumors in male rats should be “some evidence,” not “equivocal evidence.” He agreed with the “clear evidence” conclusion for lung tumors in mice of both genders.

Next, Dr. Mirsalis acknowledged a series of four public commenters. Dr. Walden Dalbey of DalbeyTox, LLC, and Dr. John Howell of GHS Resources, Inc., spoke on behalf of ILMA. Dr. Patricia Beattie of SciVera, LLC, and Dr. Steven Florio of Master Chemical Corporation spoke on behalf of MCC.

Dr. Dalbey asked NTP to clarify the rationale for the selection of TRIM^®^ VX. He questioned the handling of TRIM^®^ VX samples and asked why the material had not been diluted with water, as is common in the workplace. He asked for the rationale and validation of the methods used to determine particle size and monitor total aerosol concentration. He noted a discrepancy in NTP’s analysis of mineral oil content in TRIM^®^ VX compared with the Material Safety Data Sheet. He noted other issues with NTP’s analyses of TRIM^®^ VX, including the reported pH of the test article. He asked for a more explicit statement on the lack of systemic effects than what is currently in the draft report. He recommended NTP consider a different mode of action than what is stated in the report.

Dr. Beattie provided details about TRIM^®^ VX and the history of its toxicity testing. She noted that the tested TRIM^®^ VX concentrate would become alkaline when mixed with the moisture in the respiratory tract, likely causing the irritation, inflammation, and tumors formed at the site of contact. She said that the negative results in genotoxicity tests, the lack of systemic toxicity or tumors, and tumors only seen at the site of contact at the highest dose, all suggest a non-genotoxic mechanism. She noted that she made a request to NTP for more detailed chemical characterization and stability analytical information, and NIEHS denied the release of the additional analytical information.

Dr. Florio provided further background information about TRIM^®^ VX and listed several analytical concerns related to the NTP study, particularly the chemical degradation and analysis of the test article. He noted that the test article used in the study had aged outside of its recommended 1-year shelf life, affecting its stability. He concluded that the two lots of material tested were not chemically equivalent to the TRIM^®^ VX produced and marketed by MCC

Dr. Howell discussed the NTP selection process for MWFs, with which ILMA had cooperated. He asserted that NTP should find the TRIM^®^ VX study inadequate because of significant issues regarding the characterization of the test article, such as the potential for bacterial and fungal growth, variations in the characterization of the compound, and use of the product well beyond its stated shelf life. He noted that TRIM^®^ VX is a unique formulation and that according to Occupational Safety and Health Administration regulations, the study results cannot be extended to other MWFs.

## K.4 Peer Reviewer Comments

Dr. Elwell, the first reviewer, stated that overall the report was well written and the results supported the conclusions. Regarding the findings, he cited Table 9 in the report, and asked why some of the nonneoplastic results (nasal polyps) listed in the summary table in the appendix had not been discussed in the body of the report. He asked whether the cystic keratinizing epithelioma (CKE) seen in a high-dose female had been considered to be part of the equivocal evidence. He recommended adding discussion in the report about the occurrence of multiple adenomas in rats and mice. He asked for clarification of the sentence on page 62, “Alveolar/bronchiolar neoplasms were morphologically typical of those that occur spontaneously.” He agreed in principal with the conclusions; however, he suggested considering CKE as part of the equivocal evidence and asked for further information about nasal tumors in rats for possible inclusion in the report.

Dr. Ryan said that the nasal polyps appeared to be more inflammatory than neoplastic, and were deemed to not warrant inclusion in the report’s text. NTP study pathologist Dr. R.A. Herbert agreed with Dr. Ryan’s statement. Regarding the CKE, Dr. Ryan said that the corresponding text in the report could be clarified, and noted that since it was a single incidence, it was not considered part of the call. Regarding the multiple adenomas in the rats and mice, she said additional discussion would be added to report. Dr. Herbert explained that the bronchial adenoma had been listed as a single finding and was not included in the call. Dr. Ryan said further text changes to the report would be considered to provide clarification.

Dr. Brock, the second reviewer, said that the report was generally well-written. He noted that because TRIM^®^ VX is a mixture and the specific chemical composition has not been revealed, the results from the current TRIM^®^ VX studies make it difficult to determine the potential hazard associated with other soluble metal working fluids. He suggested that the authors insert an appendix or other reference for the chemical composition of other soluble MWFs to allow subsequent use of the toxicological data in the report for comparison to other mixtures. He noted the discrepancy between NTP’s stated chemical composition for TRIM^®^ VX and the manufacturer’s listing. He stated the high exposure concentration used in the 2-year studies was too high, and that an exposure concentration of 50 mg/m^3^ would have been sufficient. Thus, he asked for more description of exposure concentration selection in the discussion section of the report. He proceeded to provide specific recommendations for each section of the report. Notably, he asked for clarification on the methods used to test the stability of the test article and validate aerosol chamber concentrations. He asked for an explanation on what was unique about the occurrence of lung fibrosis.

Regarding Dr. Brock’s comment on the selection of TRIM^®^ VX, Dr. Ryan said that TRIM^®^ VX was selected as an example of a soluble oil and not to reflect all soluble oils. She said this would be clarified in the report. As to the exposure concentration selection rationale, she said the aim was to design a study to allow cross-species comparison; thus, the concentration needed to challenge both rats and mice. An exposure concentration of 50 mg/m^3^ would have been sufficient in rats; however, a higher concentration was needed to challenge the mice. Thus, 100 mg/m^3^ was chosen as an exposure concentration to not limit survival or have overt toxicity. There was also an aim to compare the TRIM^®^ VX study to the prior CIMSTAR study, which had similar exposure concentrations. Dr. Brock said that although he appreciated the complexity of 2-year bioassays, using the same exposure concentration in rats and mice because it is easier is not a good answer. He renewed his request for a more robust exposure concentration justification. Dr. Ryan responded to several of Dr. Brock’s specific suggestions. Regarding test article stability, she said that it was evaluated with a qualified method described in the appendix, and that there was no evidence of degradation in the bulk test article. She stated that the analysis of the chamber concentration was based on the quantitative assessment of three TRIM^®^ VX components as mentioned in the appendix. She said additional text could be added to the report to further describe the methods for test article stability and validating aerosol chamber concentrations. She noted that data regarding clinical signs of toxicity were available on a website, which would be added to the report. Regarding the lung fibrosis, it was not unique on its own; however, it was interesting that lung fibrosis was found in the TRIM^®^ VX studies in both species and this fibrosis was not seen in NTP studies of other MWFs.

Dr. Sabo-Attwood, the third reviewer, said the report represented a scientifically sound study and was well written. She asked for more clarity about the fibrotic lesions. Like Dr. Brock, she thought TRIM^®^ VX was representative of the larger class of water-soluble MWFs based on the text in the draft report. She recommended edits to the text to avoid that confusion. TRIM^®^ VX is a complex mixture, so it is unclear how the component chemicals are distributed in vivo. Based on the description provided, she anticipated that the constituents would be highly soluble and would not be the particulates in the aerosols that would be consistent with fibrotic lesions associated with particulate exposure. She noted the fibrotic lesions are described in the report as those commonly seen with irritation. She asked for clarification on what the irritation was and whether it was a distinguishing lesion for this particular material, especially compared to other MWFs that were tested. She noted tissues were stained with Oil-Red-O to indicate the presence of TRIM^®^ VX in immune cells, inflammatory lesions, and hyperplastic alveolar epithelium; however, the increase in staining could also represent phospholipid inclusions due to disruption of lung surfactant or result from cell death, perhaps of alveolar cells^145^. She suggested additions to the report because there are limited data available regarding metabolism and clearance of TRIM^®^ VX. She also asked for explanation for the use of Oil-Red-O stain in rats and not in mice. She asked about endotoxin testing, and whether the inflammatory responses that were seen were indicative of exposures to endotoxins or other pathogens.

Dr. Ryan would consider adding text to further describe the fibrotic lesions in the report; however, the studies were not designed to directly link particulates or components of TRIM^®^ VX with the fibrotic lesions. The fibrotic lesions were not indicative of the precancerous lesions. Dr. Herbert said that the fibrotic changes were not considered a part of the continuum from preneoplastic change to the tumors that were seen in the lung, which were mainly alveolar/bronchiolar carcinomas. He explained that Oil-Red-O staining had not been done in mice because the entire mouse lung tissue was embedded for preparation of histological slides; therefore, there was no residual wet lung tissue that could be used to perform Oil-Red-O staining. He said that the stain had been used because although TRIM^®^ VX is soluble, the lesions were morphologically similar to those observed with inhalation exposure to a particulate. Thus, there was an interest in seeing if there was an appreciable amount of oil left in the lung that was causing a foreign body reaction. Residue from oil was found in the tissues. Dr. Sabo-Attwood asked if one could distinguish it from material identified as TRIM^®^ VX and phospholipid damage, which would show up from staining. Dr. Herbert said he would add statements to the report to reflect Dr. Sabo-Attwood’s comments. Dr. Brock asked if the tissue had been formalin-fixed, which would remove all lipids. Dr. Herbert said the lipid was not removed by formalin fixation of the lungs and would only be removed if the tissue were subjected to histological processing. Thus, the wet tissue would still have oil present in the lungs. Dr. Ryan noted that endotoxin was not measured in the study; however, there was assessment of bacterial and fungal growth at several study time points. There was no evidence of bacterial or fungal growth.

Dr. Sabo-Attwood asked if there was anything indicative in the inflammatory response that was relevant to an endotoxin-type exposure. Dr. Herbert explained that with so many inflammatory changes, it was not possible to delineate whether they were due to an endotoxin or exposure and direct contact with the chemicals.

## K.5 Panel Discussion and Vote

Dr. Singal asked about necrotic lesions that were attributed to increased exudative pressure, and inquired about other characteristics aside from the necrotic changes that would suggest the potential for increased barotrauma. Dr. Herbert said there was an accumulation of exudate in the ventral portions of the nasal cavity, which was severe in some cases and most likely resulted in pressure degeneration, necrosis, and ultimately rupture and perforation of the nasal septa.

Dr. Pinkerton asked if the lung fibrosis was thought to lead to greater potential for carcinogenesis. Dr. Pinkerton asked if there was any evidence that greater fibrosis was associated with greater propensity to see tumors. Dr. Herbert replied that could not be stated with any certainty. There are some inhalation studies with particulates where fibrosis is observed without this type of scar tumor.

Dr. Mirsalis commented on the selection of TRIM^®^ VX. He suggested making the following points clear in the introduction: TRIM^®^ VX is an example of a MWF, relatively small volume of it was in use, and it has since been discontinued. He noted that wider conclusions about soluble MWFs should not and could not be drawn based on this study, which stands on its own. Dr. J.R. Bucher confirmed Dr. Mirsalis’ statement, adding that there should be an idea from the discussions about how difficult it was to sort through all of the different products on the market and determine their identifiable components versus trade secret components. It was difficult to select materials for 2-year study that would give some indication of whether some of the effects that were seen in the MWFs could be attributed to materials that were not contaminated with bacteria during the course of their use. Due to the complexity of the field, the materials chosen are not representative, but are individual materials.

Regarding the question of NTP’s chemical analysis of the materials, Dr. Mirsalis said that the information should be included in the final report, as it should be readily available. Regarding the earlier comment that the study should be considered inadequate because the material was not actually tested, he said that the study is an adequate study. One may argue the relevance of the study; however, it meets the requirements for an adequate study.

With no further discussion and no requests for edits to the conclusions, Dr. Mirsalis called for a motion on the conclusions. Dr. Elwell moved that the conclusions be accepted as written. Dr. Pinkerton seconded.

Dr. Brock asked for further clarification on the issue of the fibrosis and the carcinomas seen in the study. Dr. Herbert elaborated that in terms of the neoplasms seen in the study, fibrosis was not seen as a prerequisite.