# Appendix H Chemical Characterization and Generation of Chamber Concentrations

## H.1 Procurement and Characterization of TRIM^®^ VX

TRIM VX was obtained from Master Chemical Corporation (Perrysburg, OH) in two lots (101607N and 011509N). Lot 101607N was used during the 3-month studies, and lot 011509N was used during the 2-year studies. Characterization and stability analyses of the test article were conducted by the analytical chemistry laboratory at Chemir Analytical Services (Maryland Heights, MO) and by the study laboratory at Battelle Toxicology Northwest (Richland, WA). Reports on analyses performed in support of the TRIM VX studies are on file at the National Institute of Environmental Health Sciences.

The test article was a dark brown liquid. Fourier transform infrared (FTIR) spectroscopy was used to estimate the relative presence of various functional groups and create a reference for future comparisons of the same lot. A representative FTIR spectrum is presented in Figure H-1.

Analyses for both lots performed by the analytical chemistry laboratory included Karl Fischer titration for water content; elemental analysis for carbon, hydrogen, nitrogen, and sulfur using a C, H, N, S analyzer; metal analysis using inductively coupled plasma/optical emission spectrometry (ICP/OES); chlorine, chloride, nitrate, and nitrite analysis by ion chromatography (IC) with conductivity detection; and iodine and iodide by ion-selective electrode (ISE) titration. Analyses for both lots performed by the study laboratory included industry-standard determinations of specific gravity, pH, and refractive index; determination of total n-hexane extractable material; determination of bacteria and fungi; initial identification of general organic components using gas chromatography (GC) with flame ionization detection (FID) by system A (Table H-1), and the identification of the major components using GC with mass spectrometry (MS) detection by system B (lot 101607N only); determination of alkanolamines using liquid chromatography (LC)/MS as described below; and quantitation of major oil constituents using GC/FID by systems C and D (lot 011509N only). Samples were collected from the top, middle, and bottom of the drum and analyzed in triplicate to determine the specific gravity, pH, refractive index, bacteria and fungi, total n-hexane extractable material, and organic constituents.

The total amount of n-hexane extractable material was determined using United States Environmental Protection Agency Method #1664^144^, and the amounts of bacteria and fungi were determined using a Sani-Check^®^ test kit (Biosan Laboratories, Warren, MI); samples were diluted to 10% with sterile water and applied to paddles coated on one side with media for the determination of bacteria and on the other side for the determination of fungi, then incubated for 7 days at 25° to 30°C. The identification and quantitation of alkanolamines were determined using LC/MS: the system included an Agilent 6410 Triple Quad LC/MS instrument (Agilent Technologies, Inc., Santa Clara, CA), a Waters Nova-Pak^®^ C_18_ column (300 mm × 3.9 mm, 4 µm particle size) (Waters Corporation, Milford, MA), an isocratic mobile phase of 0.1% formic acid in water, and a flow rate of 0.7 mL/minute.

For lot 101607N, the water content was 7.1%, pH was 7.5, specific gravity was 1.003, and refractive index was 1.485. Elemental analysis indicated 67.5% carbon, 10.8% hydrogen, less than 0.5% nitrogen, and 1.6% sulfur; metal analysis by ICP/OES indicated all elements were below the level of detection; IC results indicated 8.6% chlorine, 187 ppm chloride, and nitrate and nitrite less than 18 ppm; and ISE titration indicated 12 ppm iodine and less than 5 ppm iodide. GC/FID analysis for general organic components indicated 12 separate peaks. Using standard addition and GC/MS, the peaks were identified as propylene glycol, diethylene glycol, diethylene glycol monobutyl ether, α-terpineol, 4-chloro-3-methyl-phenol, triethanolamine, myristic acid, methyl palmitate, palmitic acid, methyl oleate, methyl stearate, and oleic acid. Triethanolamine was determined to be present at 3.7% by LC/MS. Quantitation of 11 compounds in the oil fraction (Table H-2) was obtained using a second GC/FID system and indicated 1.18% methyl palmitate, 5.65% methyl oleate, and 0.89% methyl stearate for the fatty acid methyl esters. The total amount of n-hexane extractable material was determined to be approximately 80.2% by weight. The amount of bacteria was less than 100 colony forming units (CFU)/mL and the amount of fungi was less than 10 CFU/mL.

For lot 011509N, the water content was 6.8%, pH was 7.6, specific gravity was 1.008, and refractive index was 1.485. Elemental analysis indicated 65.4% carbon, 10.5% hydrogen, less than 0.5% nitrogen, and 1.8% sulfur; metal analysis by ICP/OES indicated all elements were below the level of detection; IC results indicated 8.8% chlorine, 249 ppm chloride, and nitrate and nitrite each less than 40 ppm; and ISE titration indicated less than 9 ppm iodine and less than 5 ppm iodide. GC/FID analysis for general organic components indicated nine separate peaks. Using the earlier standard addition and GC/MS analysis of lot 101607N, the peaks were identified as propylene glycol, diethylene glycol, diethylene glycol monobutyl ether, α-terpineol, 4-chloro-3-methyl-phenol, triethanolamine, methyl palmitate, methyl oleate, and methyl stearate. Triethanolamine was determined to be present at 3.2% by LC/MS. Quantitation of eight compounds in the oil fraction (Table H-2) was obtained using a second GC/FID system and indicated 1.20% methyl palmitate, 5.81% methyl oleate, and 0.93% methyl stearate for the fatty acid methyl esters. Using GC/FID and an alternate analytical column, myristic, oleic, and palmitic fatty acids were quantitated at 0.23%, 1.23%, and 0.31%, respectively. The total amount of n-hexane extractable material was determined to be approximately 85% by weight. The amount of bacteria was less than 100 CFU/mL and the amount of fungi was less than 10 CFU/mL.

The test article was determined to be composed of water, alkanolamines, and oil. The pH of the test article was approximately 7.5. In general, the FTIR spectra were consistent with the presence of organic amines. The test article did not contain significant amounts of water soluble nitrates, nitrites, chlorides, or iodides. The mass balance percentages based on elemental contributions resulted in 95% (lot 101607N) and 93% (lot 011509N) coverage. There were no differences between the two lots.

Periodic reanalyses of lot 011509N were performed by the analytical chemistry laboratory and the study laboratory at least every 6 months during the 2-year studies. FTIR spectra were obtained and compared to the reference spectrum of this lot; determinations were made for the pH, specific gravity, and refractive index; determination and quantitation of alkanolamines was performed using LC/MS as described above; assessment of fatty acid methyl esters was performed using GC/FID by system C (Table H-1); and the amounts of bacteria and fungi were determined using a Sani-Check^®^ BF test kit. To ensure stability, the bulk test article was stored at room temperature, protected from light in metal drums, and no degradation of the bulk test article was detected based on these analyses (Table H-3).

Following completion of the 2-year study, pH of bulk lot 011509N was measured as neat and 10% solutions using a VWR Symphony 14002-784 Posi-PHlo liquid-filled flushable-junction combination electrode with epoxy body (similar to the one used during the bioassay) and Thermo Scientific Orion 912600 low-maintenance sealed gel-filled electrode with epoxy body. The pH values of the neat and 10% solutions, respectively, were 7.56 and 8.68 when the liquid-filled electrode was used and 8.20 and 8.69 when the gel-filled electrode was used. The pH of the 10% solutions was similar (8.68 to 8.69) regardless of the type of probe used and was within the range (8.3 to 9.3) listed in the manufacturer’s data sheet for TRIM VX.

## H.2 Aerosol Generation and Exposure System

The generation and delivery system used in the 3-month and 2-year studies consisted of two generator assemblies configured together so that the output from each assembly was directed to a common distribution line (Figure H-2). For the 2-year studies, male and female rats were housed in separate chambers; female rat chambers also housed male and female mice from the concurrent study. Each assembly contained three multi-jet nebulizers, of which one was operational and two were backups. The bottom of the generator assembly contained the liquid reservoir. TRIM VX was continuously pumped to the liquid reservoir from the chemical cabinet reservoir by metering pumps during the aerosol generation process to ensure a fresh supply of test article and pumping rates that exceeded the rates at which aerosol was removed from the generator assemblies. Ports in the generator assembly introduced compressed air to drive the nebulizers and dilution air to transport aerosol to the distribution line.

Each nebulizer assembly consisted of a multi-jet thimble nebulizer, a liquid uptake tube, and a compressed air supply port. High velocity compressed air created a vacuum in the liquid uptake tube that drew test article from the liquid reservoir into the multi-jet nebulizer streams where shear forces broke the resultant liquid filaments into droplets. Large droplets were impacted on the impaction plate of the nebulizer or the generator assembly walls and were returned to the liquid reservoir. Smaller droplets were drawn into the dilution air and transported to the common distribution line made of bonded stainless steel, grounded to prevent electrostatic charge buildup. The common distribution line was divided into two branches to supply aerosol to exposure chambers located on both sides of the exposure room; each branch line terminated in a filter protecting the flowmeter controlling the line via the house vacuum supply. A second distribution line flow control system used during nonexposure periods consisted of a HEPA filter protecting the airvac pump that created a vacuum in the distribution lines that exceeded the pressures in the chambers, creating a minimal backflow from each chamber inlet tee ensuring that the test article did not migrate into the chambers during off exposure periods.

During exposures, at each chamber position, aerosol was removed from the distribution line and injected into a tee fitting where it was directed either to the inlet of the exposure chamber where it was mixed with conditioned air or to siphon flow exhaust. Conditioned air was defined as the mix of air derived from each exposure chamber’s wet and dry air duct supplies. The temperature of the resultant mixture of air was adjusted by passage over a temperature-controlled radiator after sequential treatment with Purafil, charcoal, and HEPA filters. Target dewpoint temperatures of the wet and dry ducts were 60°F and 40°F, respectively. Air for the ducts was obtained from the building air supply and was either passed over chillers to lower the dewpoint (dry duct) or injected with steam to raise it (wet duct). The amount of aerosol removed from the distribution line was controlled by a control orifice and siphon flow rotameter. Minor adjustments to chamber concentrations were performed by changing the amount of aerosol drawn off through a HEPA-filter protected siphon flow rotameter.

## H.3 Aerosol Concentration Monitoring

Summaries of the chamber aerosol concentrations are given in Table H-3 and Table H-4. The concentrations of methyl palmitate, methyl stearate, and methyl oleate in TRIM VX were monitored using GC/FID and compared to real-time aerosol monitor (RAM) measurements (MicroDust pro, Casella CEL LTD; Kempson, Bedford, England). The monitors were connected to the chambers by a sampling system designed by Battelle incorporating a valve that multiplexed each RAM to a 0 mg/m^3^ chamber or the room, a HEPA-filtered room air blank, and two additional exposure chambers. The output voltage of the RAM was recorded by a program designed by Battelle (Battelle Exposure Data Acquisition and Control) to select the correct sample stream and acquire a raw voltage signal from each RAM. Equations for the calibration curves resided within the program and were used to convert the measured RAM voltages to exposure chamber concentrations. Concentration control limits within the program were compared to each measured concentration and, if limits were exceeded, an audible alarm was triggered or, in extreme cases, exposure was terminated.

Each RAM was calibrated by constructing a response curve using the measured RAM voltages (voltage readings were corrected by subtracting the RAM zero-offset voltage from measured RAM voltages) and concentrations of methyl palmitate, methyl stearate, and methyl oleate in TRIM VX that were determined by analyzing duplicate adsorbent gas sampling tubes (ORBO-52™; silica gel; Supelco, Bellafonte, PA) collected daily from the exposure chambers.

For the 3-month and 2-year studies, methyl palmitate, methyl stearate, and methyl oleate in TRIM VX were extracted from the gas sampling tubes with 2-propanol and analyzed using GC/FID by system C (Table H-1) or a system similar to system C; methyl undecanoate was used as the internal standard.

The GC/FID instrument was calibrated against serially diluted standards of TRIM VX and the internal standard, methyl undecanoate. Quality control standards and a reagent blank were analyzed after calibration, after approximately every tenth sample, and at the end of the analysis to determine accuracy and calibration drift during analysis.

## H.4 Chamber Atmosphere Characterization

Particle size distribution in each chamber was determined prior to the start of all studies and monthly during the studies. Cascade impactor samples of TRIM VX were taken from each exposure chamber using a Mercer-style seven-stage impactor (In-Tox Products, Moriarty, NM) and the stages [22 mm glass coverslips lightly coated with silicone to prevent particle bounce for stages 1 to 7, or 25 mm Pallflex TX40HI20WW Emfab Teflon^®^-coated glass-fiber filters (Pell Corporation, Port Washington, NY) for stage 8] were analyzed by GD/FID using system C (Table H-1) or a similar system for methyl oleate as a marker for TRIM VX. The relative mass collected on each stage was analyzed by the CASPACT impactor analysis program developed at Battelle based on probit analysis^76^. The resulting estimates of the mass median aerodynamic diameter and the geometric standard deviation of each set of samples are given in Table H-5, Table H-6, and Table H-7. All samples were within the 1 to 3 µm range required by protocol.

Buildup and decay rates for chamber aerosol concentrations were determined with (all studies) and without (2-year studies) animals present in the chambers. At a chamber air flow rate of 15 cubic feet per minute, the theoretical value for the time to achieve 90% of the target concentration after the beginning of aerosol generation (T_90_) and the time for the chamber concentration to decay to 10% of the target concentration after aerosol generation was terminated (T_10_) was approximately 9.2 minutes. For rats and mice in the 3-month studies with animals present, T_90_ values ranged from 8 to 9 minutes; T_10_ values ranged from 9 to 10 minutes. For rats and mice in the 2-year studies, T_90_ values ranged from 8 to 10 minutes without animals present and from 7 to 10 minutes with animals; T_10_ values ranged from 7 to 9 minutes without animals present and from 8 to 10 minutes with animals. T_90_ values of 10 minutes and 12 minutes were selected for the 3-month and 2-year studies, respectively.

The uniformity of aerosol concentration in the inhalation exposure chambers was measured once during the 3-month studies with animals present, once before the 2-year studies began without animals present, and approximately every 3 months during the 2-year studies with animals present. RAM measurements were taken from 12 different chamber positions. Chamber concentration uniformity was acceptable throughout the 3-month and 2-year studies.

The persistence of TRIM VX in the exposure chambers was monitored after aerosol delivery ended by monitoring the concentration in the 400 mg/m^3^ chambers in the 3-month studies with animals present and in the 100 mg/m^3^ chambers in the 2-year studies with and without animals present. In the 3-month studies, the concentration decreased to 1% of the starting concentration within approximately 18 minutes. In the 2-year study of male rats, the concentration decreased to 1% of the starting concentration within approximately 20 minutes with animals present and within 17 minutes without animals. In the 2-year studies of female rats and male and female mice, the concentration decreased to 1% of the starting concentration within 17 minutes with animals present and within 15 minutes without animals.

Stability studies of the test article in the generation and exposure system were performed before (2-year studies only) and during the studies by the study laboratory. Samples of the test atmosphere were taken during the first, middle, and last 2 hours of the generation day from the distribution line, 25 and 400 mg/m^3^ chambers (3-month studies), and 10 and 100 mg/m^3^ chambers (2-year studies); bulk samples of the test article were taken from the generator reservoir at the end of the generation day. Samples of the test atmosphere were collected using adsorbent gas sampling tubes (ORBO-52™, Supelco). Test atmosphere and generator reservoir samples were assayed for oil constituents using GC/FID by systems C (all studies) and D (2-year studies) (Table H-1). Additional samples collected using bubblers filled with 2-propanol containing triethanolamine-d15 were analyzed for alkanolamines using LC/MS method A as described above. The amount of each constituent in the exposure atmosphere was calculated as a percentage of the expected amount based on concentration as determined by the on-line monitor (MicroDust pro, Casella CEL LTD) (3-month studies) or the amount of methyl oleate (2-year studies). Reservoir results were calculated relative to the bulk test article.

For all studies, the relative amounts of the major constituents in the exposure atmospheres and generator reservoir samples generally reflected those of the bulk test article with the exceptions of propylene glycol (in all atmosphere samples for the 3-month studies with animals present and the 2-year studies with and without animals present), diethylene glycol (in the 10 mg/m^3^ atmospheres in the 2-year studies without animals present), and diethylene glycol monobutyl ether and α-terpineol (in the 10 mg/m^3^ atmospheres in the 2-year studies with animals present).

Table H-1 Gas Chromatography Systems Used in the Inhalation Studies of TRIM VXa

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Flame ionization | RTX^®^-5 Amine, 30 m × 0.32 mm, 1.0 µm film (Restek, Bellefonte, PA) | Helium at 10 psi | 45°C for 1 minute, then 6°C/minute to 300°C, held for 5 minutes
System B
Mass spectrometry | RTX^®^-5 Amine, 30 m × 0.25 mm, 1.0 µm film (Restek) | Helium at 10 psi | 40°C for 2 minutes, then 10°C/minute to 170°C, held for 7 minutes, then 25°C/minute to 300°C, held for 10 minutes
System C
Flame ionization | RTX^®^-5 Amine, 30 m × 0.32 mm, 1.0 µm film (Restek) | Helium at 10 psi | 40°C for 2 minutes, then 10°C/minute to 170°C, held for 7 minutes, then 25°C/minute to 300°C, held for 10 minutes
System D
Flame ionization | DB™-WAXETR, 30 m × 0.25 mm, 0.25 µm film (Agilent Technologies, Inc., Santa Clara, CA) | Helium at 15 psi | 50°C for 2 minutes, then 25°C/minute to 280°C, held for 10 minutes

^a^ The gas chromatographs and mass spectrometer were manufactured by Agilent Technologies, Inc. (Santa Clara, CA).

Table H-2 Measured Components of the Two Lots of TRIM VX Used in the Inhalation Studies of TRIM VX^a^

Component | Lot 101607Nb | Lot 011509Nc
Water | 7.1 | 6.8
Hexane extractable material | 80.2 | 85.0
Identified organic compounds
Triethanolamine | 3.7 | 3.2
4-Chloro-3-methyl-phenol | 3.59 | 2.49
Diethylene glycol | 0.87 | 1.07
Diethylene glycol monobutyl ether | 1.02 | 1.11
Methyl palmitate | 1.18 | 1.20
Methyl oleate | 5.65 | 5.81
Methyl stearate | 0.89 | 0.93
Myristic acid | 0.49 | 0.23
Oleic acid | 3.18 | 1.23
Palmitic acid | 1.01 | 0.31
Propylene glycol | 0.20 | 0.20
α-Terpineol | 0.60 | 0.50

^a^ All values are percentages.

^b^ Used in the 3-month studies.

^c^ Used in the 2-year studies.

Table H-3 Summary of Test Material Analysis Before, During, and After the Two-year Inhalation Studies of TRIM VX^a^

Sample Date | Sample Description^b^ | pH | Specific Gravity (g/mL) | Refract-ive Index | Bacteria (cfu/mL)^c^ | Fungi (cfu/mL)^c^ | Fourier Transform Infrared Spectroscopy^b^ | Selected Constituents (% w/w)
Sample Date | Sample Description^b^ | pH | Specific Gravity (g/mL) | Refract-ive Index | Bacteria (cfu/mL)^c^ | Fungi (cfu/mL)^c^ | Fourier Transform Infrared Spectroscopy^b^ | n-Hexane Extract-ables | Triethan-olamine | Propylene Glycol | Diethylene Glycol | DGMBE | α-Terpineol | 4-Chloro-3-Methylphenol | Methyl Palmitate | Methyl Oleate | Methyl Stearate | Myristic Acid^d^ | Palmitic Acid^d^ | Oleic Acid^d^
Initial Analysis
03/13/09 | Drum 1 (top) | 7.5 | 1.008 | 1.486 | ND | ND | N/A | 85 | 3.2 | 0.2 | 1.0 | 1.1 | 0.5 | 2.5 | 1.2 | 5.8 | 0.9 | 0.2 | 0.3 | 1.3
| Drum 1 (middle) | 7.6 | 1.008 | 1.484 | ND | ND | | 85 | 3.2 | 0.2 | 1.1 | 1.1 | 0.5 | 2.5 | 1.2 | 5.9 | 0.9 | 0.2 | 0.3 | 1.2
| Drum 1 (bottom) | 7.6 | 1.008 | 1.484 | ND | ND | | 85 | 3.2 | 0.2 | 1.1 | 1.1 | 0.5 | 2.4 | 1.2 | 5.7 | 0.9 | 0.2 | 0.3 | 1.2
Analysis Prior to Study Start
06/23/09 through | Drum 1 | 7.6 | 1.007 | 1.484 | ND | ND | Consistent with initial analysis | 84 | 3.3 | 0.2 | 0.9 | 1.0 | 0.6 | 2.9 | 1.1 | 5.6 | 0.9 | 0.7 | 0.7 | 4.2
06/25/09 | Drum 2 | 7.6 | 1.006 | 1.484 | ND | ND | | 85 | 3.2 | 0.2 | 0.8 | 0.9 | 0.6 | 2.8 | 1.1 | 5.5 | 0.9 | 0.7 | 0.7 | 4.1
| Drum 3 | 7.6 | 1.005 | 1.483 | ND | ND | | 85 | 3.1 | 0.2 | 0.8 | 0.9 | 0.6 | 2.8 | 1.2 | 5.7 | 0.9 | 0.7 | 0.7 | 3.9
| Reference^e^ | 7.6 | 1.007 | 1.483 | ND | ND | | 85 | 3.2 | 0.2 | 0.8 | 1.0 | 0.6 | 2.9 | 1.1 | 5.5 | 0.9 | 0.8 | 0.8 | 4.2
Analysis During Study
12/01/2009 through | Drum 2 | 7.6 | 1.006 | 1.487 | ND | ND | Consistent with initial analysis | 86 | 3.5 | 0.2 | 0.9 | 1.0 | 0.6 | 3.0 | 1.2 | 5.6 | 0.9 | 0.4 | 0.4 | 3.6
12/03/2009 | Drum 3 | 7.6 | 1.005 | 1.479 | ND | ND | | 85 | 3.0 | 0.2 | 0.8 | 0.9 | 0.6 | 2.9 | 1.2 | 5.6 | 0.9 | 0.4 | 0.4 | 3.4
| Drum 4 | 7.6 | 1.004 | 1.472 | ND | ND | | 84 | 2.9 | 0.2 | 0.8 | 0.9 | 0.5 | 2.8 | 1.2 | 5.7 | 0.9 | 0.4 | 0.4 | 3.3
| Reference^e^ | 7.6 | 1.006 | 1.487 | ND | ND | | 86 | 3.4 | 0.2 | 0.9 | 1.0 | 0.6 | 3.0 | 1.2 | 5.7 | 0.9 | 0.4 | 0.4 | 3.7
05/10/2010 through | Drum 2 | 7.6 | 1.005 | 1.485 | ND | ND | Consistent with initial analysis | 84^e^ | 3.4 | 0.2 | 0.9 | 0.9 | 0.6 | 2.9 | 1.1 | 5.3 | 0.9 | 0.3 | 0.3 | 1.7
05/12/2010 | Drum 3 | 7.6 | 1.005 | 1.484 | ND | ND | | 83 | 3.2 | 0.2 | 0.8 | 0.9 | 0.5 | 2.8 | 1.1 | 5.4 | 0.9 | 0.3 | 0.3 | 1.6
| Drum 4 | 7.6 | 1.004 | 1.484 | ND | ND | | 85 | 3.0 | 0.2 | 0.8 | 0.9 | 0.5 | 2.8 | 1.1 | 5.5 | 0.9 | 0.3 | 0.3 | 1.5
| Reference^e^ | 7.7 | 1.003 | 1.484 | ND | ND | | 85 | 3.2 | 0.2 | 0.9 | 0.9 | 0.5 | 2.8 | 1.1 | 5.4 | 0.9 | 0.3 | 0.3 | 1.7
11/01/2010 through | Drum 3 | 7.5 | 1.007 | 1.484 | ND | ND | Consistent with initial analysis | 84 | 3.5 | 0.2 | 0.9 | 1.0 | 0.5 | 2.9 | 1.1 | 5.4 | 0.9 | 0.5 | 0.7 | 3.4
11/03/2010 | Drum 4 | 7.5 | 1.005 | 1.484 | ND | ND | | 87 | 3.1 | 0.2 | 0.8 | 0.9 | 0.5 | 2.8 | 1.1 | 5.6 | 0.9 | 0.5 | 0.7 | 2.9
| Drum 5 | 7.5 | 1.005 | 1.484 | ND | ND | | 85 | 3.0 | 0.2 | 0.8 | 0.9 | 0.5 | 2.8 | 1.2 | 5.6 | 0.9 | 0.5 | 0.6 | 2.9
| Reference^e^ | 7.5 | 1.005 | 1.483 | ND | ND | | 84 | 3.3 | 0.2 | 0.9 | 1.0 | 0.5 | 2.9 | 1.1 | 5.5 | 0.9 | 0.5 | 0.7 | 3.4
04/15/2011 | Drum 4 | 7.5 | 1.008 | 1.484 | ND | ND | Consistent with initial analysis | 81 | 3.4 | 0.2 | 0.9 | 1.0 | 0.5 | 2.9 | 1.1 | 5.2 | 0.9 | 0.7 | 0.9 | 3.9
| Drum 5 | 7.5 | 1.005 | 1.486 | ND | ND | | 85 | 2.9 | 0.2 | 0.8 | 0.9 | 0.5 | 2.8 | 1.1 | 5.5 | 0.9 | 0.7 | 0.9 | 3.5
| Reference^e^ | 7.5 | 1.004 | 1.485 | ND | ND | | 85 | 2.9 | 0.2 | 0.8 | 0.9 | 0.5 | 2.9 | 1.1 | 5.4 | 0.9 | 0.7 | 0.9 | 4.1
Analysis Post Study
08/10/2011 | Drum 5 | 7.6 | 1.008 | 1.485 | ND | ND | Consistent with initial analysis | 83 | 3.4 | 0.2 | 0.9 | 0.9 | 0.5 | 2.8 | 1.0 | 4.9 | 0.8 | 0.5 | 0.8 | 3.2
| Reference^e^ | 7.6 | 1.006 | 1.485 | ND | ND | | 84 | 3.1 | 0.2 | 0.9 | 1.0 | 0.5 | 2.9 | 1.1 | 5.1 | 0.8 | 0.5 | 0.8 | 3.4

cfu=colony forming units; ND=not detected; N/A=not applicable; DGMBE=diethylene glycol monobutyl ether.

^a^ Except as noted, all values reported as mean, n = 3.

^b^ All drums tested prior to use. For initial purity analyses, three samples were taken from top, middle, and bottom of Drum 1. For subsequent analysis, three samples were taken from one location of the drum.

^c^ Samples diluted 1:10 for analysis, n = 1 or 2.

^d^ Variability in free fatty acid weight percentages between analyses (e.g., time points) was attributed to variability of the analysis method rather than a change in test material composition.

^e^ Reference = a sample taken at the initial handling of the bulk test material (Drum 1) and stored at 5°C.

Table H-4 Summary of Chamber Concentrations in the Three-month Inhalation Studies of TRIM VX

| Target Concentration (mg/m^3^) | Total Number of Readings | Average Concentration^a^ (mg/m^3^)
Rat Chambers
| 25 | 684 | 24.9 ± 1.2
| 50 | 681 | 50.1 ± 3.1
| 100 | 684 | 98.7 ± 4.3
| 200 | 681 | 201 ± 8.3
| 400 | 684 | 380 ± 16
Mouse Chambers
| 25 | 704 | 25.0 ± 1.2
| 50 | 701 | 50.2 ± 3.1
| 100 | 704 | 98.8 ± 4.3
| 200 | 701 | 201 ± 8.2
| 400 | 704 | 381 ± 16

^a^ Mean ± standard deviation.

Table H-5 Summary of Chamber Concentrations in the Two-year Inhalation Studies of TRIM VX

| Target Concentration (mg/m^3^) | Total Number of Readings | Average Concentrationa (mg/m^3^)
Male Rat Chambers
| 10 | 5,120 | 9.9 ± 0.4
| 30 | 5,120 | 29.9 ± 1.1
| 100 | 5,163 | 99.2 ± 2.6
Female Rat Chambers
| 10 | 5,184 | 10.0 ± 0.4
| 30 | 5,186 | 30.0 ± 0.9
| 100 | 5,140 | 99.3 ± 2.7
Mouse Chambers
| 10 | 5,175 | 10.0 ± 0.4
| 30 | 5,177 | 30.0 ± 0.9
| 100 | 5,133 | 99.3 ± 2.7

^a^ Mean ± standard deviation.

Table H-6 Summary of Aerosol Size Measurements for the Rat and Mouse Exposure Chambers in the Three-month Inhalation Studies of TRIM VX

Date of Test | Target Concentration (mg/m^3^) | Mass Median Aerodynamic Diameter (µm) | Geometric Standard Deviation
July 2008 | 25 | 2.0 | 1.8
| 50 | 1.9 | 1.9
| 100 | 2.0 | 1.9
| 200 | 2.0 | 1.9
| 400 | 2.1 | 1.9
August 2008 | 25 | 2.1 | 1.8
| 50 | 1.9 | 1.9
| 100 | 1.9 | 1.8
| 200 | 1.9 | 1.8
| 400 | 1.9 | 1.8
September 2008 | 25 | 1.8 | 1.9
| 50 | 1.9 | 1.9
| 100 | 1.9 | 1.9
| 200 | 1.8 | 1.9
| 400 | 1.8 | 1.9
October 2008 | 25 | 1.8 | 1.8
| 50 | 1.9 | 1.8
| 100 | 2.0 | 1.9
| 200 | 1.9 | 1.9
| 400 | 2.0 | 1.9

Table H-7 Summary of Aerosol Size Measurements for the Male Rat Exposure Chambers in the Two-year Inhalation Study of TRIM VX

Date of Test | Target Concentration (mg/m^3^) | Mass Median Aerodynamic Diameter (µm) | Geometric Standard Deviation
August 2009 | 10 | 2.0 | 1.7
| 30 | 2.2 | 1.8
| 100 | 2.0 | 1.8
September 2009 | 10 | 2.1 | 1.8
| 30 | 2.1 | 1.8
| 100 | 2.1 | 1.8
October 2009 | 10 | 1.9 | 1.7
| 30 | 1.9 | 1.7
| 100 | 2.0 | 1.8
November 2009 | 10 | 2.0 | 1.8
| 30 | 2.0 | 1.8
| 100 | 1.9 | 1.8
December 2009 | 10 | 2.0 | 1.7
| 30 | 1.9 | 1.8
| 100 | 2.1 | 1.8
January 2010 | 10 | 2.0 | 1.8
| 30 | 1.8 | 1.8
| 100 | 2.0 | 1.8
February 2010 | 10 | 2.0 | 1.8
| 30 | 2.0 | 1.8
| 100 | 2.0 | 1.8
March 2010 | 10 | 1.9 | 1.8
| 30 | 1.9 | 1.8
| 100 | 1.9 | 1.8
April 2010 | 10 | 2.1 | 1.8
| 30 | 2.0 | 1.8
| 100 | 2.0 | 1.8
May 2010 | 10 | 1.9 | 1.7
| 30 | 1.9 | 1.7
| 100 | 2.0 | 1.8
June 2010 | 10 | 2.0 | 1.8
| 30 | 2.0 | 1.8
| 100 | 2.0 | 1.8
July 2010 | 10 | 2.0 | 1.8
| 30 | 1.9 | 1.8
| 100 | 2.0 | 1.8
August 2010 | 10 | 2.0 | 1.8
| 30 | 2.0 | 1.8
| 100 | 2.0 | 1.8
September 2010 | 10 | 1.9 | 1.7
| 30 | 1.9 | 1.8
| 100 | 1.9 | 1.8
October 2010 | 10 | 1.9 | 1.8
| 30 | 2.0 | 1.8
| 100 | 1.9 | 1.8
November 2010 | 10 | 2.0 | 1.8
| 30 | 2.0 | 1.8
| 100 | 2.0 | 1.8
December 2010 | 10 | 2.0 | 1.8
| 30 | 2.0 | 1.8
| 100 | 2.0 | 1.8
January 2011 | 10 | 2.0 | 1.8
| 30 | 2.0 | 1.8
| 100 | 2.0 | 1.8
February 2011 | 10 | 2.0 | 1.8
| 30 | 1.9 | 1.8
| 100 | 2.0 | 1.8
March 2011 | 10 | 2.0 | 1.8
| 30 | 1.9 | 1.8
| 100 | 1.9 | 1.7
April 2011 | 10 | 2.0 | 1.8
| 30 | 2.0 | 1.7
| 100 | 2.0 | 1.8
May 2011 | 10 | 2.0 | 1.7
| 30 | 2.1 | 1.8
| 100 | 2.1 | 1.7
June 2011 | 10 | 2.0 | 1.8
| 30 | 2.0 | 1.8
| 100 | 1.9 | 1.8
July 2011 | 10 | 1.9 | 1.8
| 30 | 1.8 | 1.8
| 100 | 2.0 | 1.8
Range | 10 | 1.9–2.1 | 1.7–1.8
| 30 | 1.8–2.2 | 1.7–1.8
| 100 | 1.9–2.1 | 1.7–1.8

Table H-8 Summary of Aerosol Size Measurements for the Female Rat and Male and Female Mouse Exposure Chambers in the Two-year Inhalation Studies of TRIM VX

Date of Test | Target Concentration (mg/m^3^) | Mass Median Aerodynamic Diameter (µm) | Geometric Standard Deviation
August 2009 | 10 | 2.0 | 1.8
| 30 | 2.1 | 1.8
| 100 | 2.1 | 1.8
September 2009 | 10 | 2.1 | 1.8
| 30 | 2.1 | 1.8
| 100 | 2.0 | 1.8
October 2009 | 10 | 1.8 | 1.7
| 30 | 1.9 | 1.8
| 100 | 2.0 | 1.7
November 2009 | 10 | 1.8 | 1.7
| 30 | 1.9 | 1.8
| 100 | 1.9 | 1.8
December 2009 | 10 | 1.7 | 1.7
| 30 | 1.9 | 1.8
| 100 | 2.0 | 1.8
January 2010 | 10 | 2.0 | 1.8
| 30 | 1.9 | 1.8
| 100 | 1.9 | 1.8
February 2010 | 10 | 1.9 | 1.7
| 30 | 1.9 | 1.8
| 100 | 2.0 | 1.8
March 2010 | 10 | 2.0 | 1.8
| 30 | 1.9 | 1.8
| 100 | 1.9 | 1.8
April 2010 | 10 | 2.0 | 1.8
| 30 | 2.0 | 1.8
| 100 | 2.0 | 1.8
May 2010 | 10 | 2.0 | 1.8
| 30 | 1.9 | 1.8
| 100 | 2.0 | 1.8
June 2010 | 10 | 2.0 | 1.8
| 30 | 1.9 | 1.8
| 100 | 1.9 | 1.8
July 2010 | 10 | 1.9 | 1.8
| 30 | 1.9 | 1.8
| 100 | 1.9 | 1.8
August 2010 | 10 | 2.0 | 1.8
| 30 | 1.9 | 1.7
| 100 | 1.9 | 1.7
September 2010 | 10 | 1.9 | 1.8
| 30 | 1.9 | 1.8
| 100 | 1.9 | 1.8
October 2010 | 10 | 2.0 | 1.8
| 30 | 1.9 | 1.8
| 100 | 1.8 | 1.8
November 2010 | 10 | 1.9 | 1.8
| 30 | 2.0 | 1.8
| 100 | 2.0 | 1.8
December 2010 | 10 | 2.1 | 1.8
| 30 | 1.9 | 1.8
| 100 | 2.1 | 1.8
January 2011 | 10 | 2.0 | 1.8
| 30 | 1.9 | 1.8
| 100 | 1.9 | 1.8
February 2011 | 10 | 1.9 | 1.7
| 30 | 1.9 | 1.8
| 100 | 1.9 | 1.7
March 2011 | 10 | 1.8 | 1.8
| 30 | 1.9 | 1.7
| 100 | 1.8 | 1.8
April 2011 | 10 | 2.0 | 1.8
| 30 | 1.9 | 1.7
| 100 | 2.0 | 1.7
May 2011 | 10 | 2.0 | 1.7
| 30 | 1.9 | 1.7
| 100 | 2.0 | 1.7
June 2011 | 10 | 1.9 | 1.8
| 30 | 1.8 | 1.8
| 100 | 1.9 | 1.8
July 2011 | 10 | 1.9 | 1.8
| 30 | 1.9 | 1.8
| 100 | 1.9 | 1.8
Range | 10 | 1.7–2.1 | 1.7–1.8
| 30 | 1.8–2.1 | 1.7–1.8
| 100 | 1.8–2.1 | 1.7–1.8

Figure H-1

Fourier Transform Infrared Absorption Spectrum of TRIM VX

Figure H-2

Schematic of the Aerosol Generation and Delivery System in the Inhalation Studies of TRIM VX

The exposure chamber configuration shown is for the 2-year studies.