# Appendix G Organ Weights and Organ-Weight-to-Body-Weight Ratios

Table G-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Three-month Inhalation Study of TRIM VX^a^

| Chamber Control | 25 mg/m^3^ | 50 mg/m^3^ | 100 mg/m^3^ | 200 mg/m^3^ | 400 mg/m^3^
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 425 ± 8 | 387 ± 8* | 416 ± 9 | 404 ± 8 | 413 ± 12 | 380 ± 14*
Heart
Absolute | 1.12 ± 0.03 | 1.03 ± 0.03 | 1.16 ± 0.04 | 1.10 ± 0.03 | 1.13 ± 0.03 | 1.08 ± 0.04
Relative | 2.644 ± 0.058 | 2.661 ± 0.047 | 2.782 ± 0.030 | 2.730 ± 0.043 | 2.755 ± 0.062 | 2.857 ± 0.084*
R. Kidney
Absolute | 1.29 ± 0.02 | 1.19 ± 0.02 | 1.33 ± 0.04 | 1.32 ± 0.04 | 1.34 ± 0.05 | 1.27 ± 0.05
Relative | 3.027 ± 0.043 | 3.085 ± 0.058 | 3.193 ± 0.052 | 3.267 ± 0.067* | 3.242 ± 0.084* | 3.342 ± 0.069**
Liver
Absolute | 12.30 ± 0.35 | 11.75 ± 0.25 | 12.52 ± 0.30 | 12.18 ± 0.47 | 12.87 ± 0.39 | 12.59 ± 0.73
Relative | 28.903 ± 0.499 | 30.416 ± 0.370 | 30.125 ± 0.452 | 30.101 ± 0.785 | 31.244 ± 0.645* | 33.002 ± 0.935**
Lung
Absolute | 2.50 ± 0.13 | 2.17 ± 0.11 | 2.44 ± 0.16 | 2.44 ± 0.14 | 2.52 ± 0.08 | 2.54 ± 0.12
Relative | 5.893 ± 0.311 | 5.622 ± 0.294 | 5.890 ± 0.430 | 6.048 ± 0.312 | 6.154 ± 0.250 | 6.715 ± 0.334
Spleen
Absolute | 0.665 ± 0.025 | 0.607 ± 0.035 | 0.705 ± 0.021 | 0.665 ± 0.021 | 0.689 ± 0.023 | 0.651 ± 0.022
Relative | 1.564 ± 0.054 | 1.575 ± 0.094 | 1.702 ± 0.060 | 1.649 ± 0.046 | 1.674 ± 0.047 | 1.725 ± 0.066
R. Testis
Absolute | 1.847 ± 0.064 | 1.833 ± 0.059 | 1.841 ± 0.036 | 1.838 ± 0.051 | 1.909 ± 0.043 | 1.720 ± 0.049
Relative | 4.361 ± 0.180 | 4.749 ± 0.145 | 4.434 ± 0.078 | 4.562 ± 0.131 | 4.661 ± 0.170 | 4.558 ± 0.149
Thymus
Absolute | 0.519 ± 0.024 | 0.517 ± 0.038 | 0.524 ± 0.028 | 0.507 ± 0.025 | 0.526 ± 0.036 | 0.513 ± 0.023
Relative | 1.222 ± 0.058 | 1.333 ± 0.084 | 1.262 ± 0.069 | 1.254 ± 0.054 | 1.265 ± 0.066 | 1.369 ± 0.089
Female
Necropsy body wt | 237 ± 6 | 222 ± 5 | 230 ± 5 | 232 ± 6 | 236 ± 6 | 227 ± 6
Heart
Absolute | 0.76 ± 0.02 | 0.73 ± 0.02 | 0.75 ± 0.01 | 0.78 ± 0.02 | 0.79 ± 0.01 | 0.76 ± 0.02
Relative | 3.222 ± 0.059 | 3.311 ± 0.035 | 3.283 ± 0.053 | 3.353 ± 0.069 | 3.349 ± 0.061 | 3.372 ± 0.049
R. Kidney
Absolute | 0.83 ± 0.02 | 0.81 ± 0.03 | 0.82 ± 0.03 | 0.81 ± 0.02 | 0.87 ± 0.03 | 0.84 ± 0.02
Relative | 3.509 ± 0.094 | 3.644 ± 0.049 | 3.550 ± 0.085 | 3.515 ± 0.091 | 3.708 ± 0.116 | 3.721 ± 0.071
Liver
Absolute | 7.39 ± 0.21 | 6.95 ± 0.25 | 7.14 ± 0.25 | 7.56 ± 0.15 | 8.25 ± 0.36* | 8.37 ± 0.25**
Relative | 31.311 ± 0.855 | 31.326 ± 0.758 | 31.045 ± 0.450 | 32.658 ± 0.620 | 34.940 ± 0.888** | 36.843 ± 0.390**
Lung
Absolute | 1.60 ± 0.08 | 1.40 ± 0.06 | 1.56 ± 0.07 | 1.85 ± 0.11* | 1.86 ± 0.08* | 1.85 ± 0.06*
Relative | 6.779 ± 0.279 | 6.301 ± 0.182 | 6.778 ± 0.199 | 7.930 ± 0.368** | 7.953 ± 0.378** | 8.157 ± 0.246**
Spleen
Absolute | 0.459 ± 0.029 | 0.406 ± 0.023 | 0.415 ± 0.015 | 0.441 ± 0.014 | 0.464 ± 0.019 | 0.480 ± 0.020
Relative | 1.943 ± 0.120 | 1.823 ± 0.072 | 1.821 ± 0.090 | 1.914 ± 0.081 | 1.990 ± 0.110 | 2.123 ± 0.096
Thymus
Absolute | 0.434 ± 0.021 | 0.431 ± 0.015 | 0.452 ± 0.021 | 0.463 ± 0.016 | 0.454 ± 0.032 | 0.455 ± 0.024
Relative | 1.834 ± 0.083 | 1.948 ± 0.059 | 1.980 ± 0.104 | 1.998 ± 0.052 | 1.922 ± 0.106 | 2.016 ± 0.116

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** Significantly different (P ≤ 0.01) from the chamber control group by Williams’ test.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table G-2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Inhalation Study of TRIM VX^a^

| Chamber Control | 25 mg/m^3^ | 50 mg/m^3^ | 100 mg/m^3^ | 200 mg/m^3^ | 400 mg/m^3^
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 37.6 ± 0.8 | 35.8 ± 0.4 | 37.0 ± 0.7 | 36.1 ± 0.8 | 36.4 ± 0.6 | 34.7 ± 0.6*
Heart
Absolute | 0.16 ± 0.01 | 0.16 ± 0.01 | 0.17 ± 0.01 | 0.16 ± 0.01 | 0.17 ± 0.01 | 0.16 ± 0.00
Relative | 4.311 ± 0.131 | 4.493 ± 0.127 | 4.461 ± 0.127 | 4.498 ± 0.112 | 4.714 ± 0.166 | 4.468 ± 0.106
R. Kidney
Absolute | 0.31 ± 0.01 | 0.31 ± 0.01 | 0.31 ± 0.01 | 0.31 ± 0.01 | 0.31 ± 0.01 | 0.29 ± 0.00
Relative | 8.315 ± 0.137 | 8.737 ± 0.165 | 8.367 ± 0.142 | 8.659 ± 0.104 | 8.523 ± 0.114 | 8.455 ± 0.148
Liver
Absolute | 1.54 ± 0.05 | 1.58 ± 0.03 | 1.71 ± 0.05 | 1.64 ± 0.04 | 1.81 ± 0.07** | 1.76 ± 0.05**
Relative | 40.795 ± 0.675 | 43.982 ± 0.513* | 46.136 ± 1.159** | 45.386 ± 0.861** | 49.719 ± 1.359** | 50.636 ± 0.900**
Lung
Absolute | 0.23 ± 0.02 | 0.21 ± 0.00 | 0.23 ± 0.01 | 0.25 ± 0.01 | 0.29 ± 0.01** | 0.30 ± 0.00**
Relative | 6.044 ± 0.420 | 5.862 ± 0.113 | 6.188 ± 0.189 | 6.886 ± 0.167* | 7.851 ± 0.162** | 8.684 ± 0.135**
Spleen
Absolute | 0.061 ± 0.002 | 0.065 ± 0.002 | 0.072 ± 0.003** | 0.070 ± 0.003* | 0.077 ± 0.004** | 0.068 ± 0.002**
Relative | 1.621 ± 0.046 | 1.815 ± 0.049 | 1.948 ± 0.070** | 1.949 ± 0.085** | 2.120 ± 0.106** | 1.961 ± 0.057**
R. Testis
Absolute | 0.111 ± 0.004 | 0.112 ± 0.002 | 0.115 ± 0.001 | 0.111 ± 0.002 | 0.110 ± 0.002 | 0.114 ± 0.001
Relative | 2.955 ± 0.094 | 3.126 ± 0.062 | 3.121 ± 0.057 | 3.096 ± 0.056 | 3.012 ± 0.052 | 3.294 ± 0.075**
Thymus
Absolute | 0.049 ± 0.003 | 0.047 ± 0.002 | 0.047 ± 0.002 | 0.042 ± 0.002 | 0.043 ± 0.001 | 0.049 ± 0.002
Relative | 1.298 ± 0.071 | 1.310 ± 0.060 | 1.264 ± 0.042 | 1.161 ± 0.050 | 1.182 ± 0.037 | 1.412 ± 0.068
Female
Necropsy body wt | 29.8 ± 0.9 | 31.0 ± 0.9 | 30.7 ± 1.1 | 29.1 ± 0.8 | 30.1 ± 0.6 | 29.2 ± 0.5
Heart
Absolute | 0.14 ± 0.00 | 0.14 ± 0.00 | 0.14 ± 0.00 | 0.14 ± 0.00 | 0.14 ± 0.00 | 0.14 ± 0.00
Relative | 4.659 ± 0.136 | 4.566 ± 0.128 | 4.679 ± 0.152 | 4.731 ± 0.110 | 4.697 ± 0.107 | 4.765 ± 0.097
R. Kidney
Absolute | 0.21 ± 0.01 | 0.21 ± 0.00 | 0.21 ± 0.01 | 0.21 ± 0.01 | 0.22 ± 0.01 | 0.21 ± 0.00
Relative | 7.012 ± 0.158 | 6.765 ± 0.151 | 6.940 ± 0.183 | 7.157 ± 0.228 | 7.187 ± 0.178 | 7.134 ± 0.189
Liver
Absolute | 1.35 ± 0.04 | 1.50 ± 0.06 | 1.51 ± 0.06 | 1.37 ± 0.04 | 1.57 ± 0.02** | 1.70 ± 0.04**
Relative | 45.360 ± 1.019 | 48.331 ± 0.916 | 49.196 ± 1.141 | 46.971 ± 1.036 | 52.298 ± 1.057** | 58.078 ± 1.027**
Lung
Absolute | 0.21 ± 0.00 | 0.22 ± 0.01 | 0.22 ± 0.01 | 0.25 ± 0.01** | 0.27 ± 0.01** | 0.30 ± 0.01**
Relative | 6.973 ± 0.262 | 7.103 ± 0.122 | 7.284 ± 0.255 | 8.519 ± 0.276** | 9.123 ± 0.256** | 10.382 ± 0.181**
Spleen
Absolute | 0.093 ± 0.003 | 0.096 ± 0.005 | 0.097 ± 0.004 | 0.089 ± 0.003 | 0.102 ± 0.003 | 0.106 ± 0.003
Relative | 3.129 ± 0.088 | 3.090 ± 0.102 | 3.167 ± 0.113 | 3.057 ± 0.077 | 3.391 ± 0.095 | 3.634 ± 0.098**
Thymus
Absolute | 0.053 ± 0.004 | 0.059 ± 0.003 | 0.060 ± 0.004 | 0.059 ± 0.002 | 0.054 ± 0.003 | 0.051 ± 0.003
Relative | 1.772 ± 0.149 | 1.914 ± 0.087 | 1.940 ± 0.120 | 2.013 ± 0.049 | 1.778 ± 0.077 | 1.737 ± 0.096

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).