# Appendix F Clinical Pathology Results

Table F-1 Hematology and Clinical Chemistry Data for Rats in the Three-month Inhalation Study of TRIM VX^a^

| Chamber Control | 25 mg/m^3^ | 50 mg/m^3^ | 100 mg/m^3^ | 200 mg/m^3^ | 400 mg/m^3^
Male
Hematology
n | 10 | 10 | 10 | 9 | 10 | 10
Hematocrit (%) | 50.7 ± 0.5 | 49.9 ± 0.7 | 50.3 ± 0.6 | 49.4 ± 0.6^b^ | 50.8 ± 0.4 | 49.3 ± 0.4
Packed cell volume (%) | 51.5 ± 0.5 | 51.3 ± 0.7 | 51.0 ± 0.7 | 50.2 ± 0.6 | 52.1 ± 0.7 | 50.7 ± 0.6
Hemoglobin (g/dL) | 16.4 ± 0.1 | 16.3 ± 0.2 | 16.3 ± 0.2 | 16.1 ± 0.2 | 16.5 ± 0.2 | 16.1 ± 0.2
Erythrocytes (10^6^/μL) | 9.22 ± 0.09 | 9.30 ± 0.17 | 9.19 ± 0.19 | 9.12 ± 0.11 | 9.31 ± 0.11 | 9.12 ± 0.11
Reticulocytes (10^3^/μL) | 213.7 ± 12.3 | 198.2 ± 7.2 | 209.0 ± 9.0 | 214.0 ± 6.5 | 212.8 ± 8.4 | 219.5 ± 10.0
Nucleated erythrocytes/ 100 leukocytes | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0
Mean cell volume (fL) | 55.9 ± 0.5 | 55.2 ± 0.6 | 55.6 ± 0.8 | 55.1 ± 0.5 | 56.0 ± 0.5 | 55.6 ± 0.7
Mean cell hemoglobin (pg) | 17.8 ± 0.2 | 17.6 ± 0.2 | 17.8 ± 0.3 | 17.7 ± 0.2 | 17.7 ± 0.2 | 17.6 ± 0.2
Mean cell hemoglobin concentration (g/dL) | 31.9 ± 0.3 | 31.8 ± 0.2 | 32.0 ± 0.3 | 32.1 ± 0.3 | 31.6 ± 0.3 | 31.7 ± 0.2
Platelets (10^3^/μL) | 740 ± 23 | 756 ± 56 | 780 ± 25 | 800 ± 52 | 836 ± 42 | 800 ± 34
Leukocytes (10^3^/μL) | 8.65 ± 0.61 | 8.42 ± 0.34 | 9.09 ± 0.54 | 8.52 ± 0.23 | 8.76 ± 0.38 | 8.67 ± 0.55
Segmented neutrophils (10^3^/μL) | 1.23 ± 0.11 | 1.14 ± 0.10 | 1.21 ± 0.11 | 1.09 ± 0.08 | 1.20 ± 0.08 | 1.26 ± 0.10
Bands (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL) | 7.17 ± 0.59 | 7.02 ± 0.27 | 7.57 ± 0.44 | 7.19 ± 0.16 | 7.25 ± 0.36 | 7.11 ± 0.54
Monocytes (10^3^/μL) | 0.15 ± 0.02 | 0.15 ± 0.01 | 0.19 ± 0.02 | 0.15 ± 0.01 | 0.17 ± 0.01 | 0.17 ± 0.01
Basophils (10^3^/μL) | 0.02 ± 0.01 | 0.03 ± 0.00 | 0.02 ± 0.00 | 0.03 ± 0.00 | 0.03 ± 0.00 | 0.03 ± 0.00
Eosinophils (10^3^/μL) | 0.08 ± 0.00 | 0.09 ± 0.02 | 0.09 ± 0.02 | 0.08 ± 0.01 | 0.12 ± 0.01 | 0.12 ± 0.01
Clinical Chemistry
n | 10 | 10 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL) | 15.3 ± 0.7 | 17.8 ± 0.4 | 17.5 ± 0.7 | 17.1 ± 1.0 | 16.1 ± 0.6 | 18.1 ± 0.6*
Creatinine (mg/dL) | 0.41 ± 0.01 | 0.44 ± 0.02 | 0.41 ± 0.02 | 0.47 ± 0.02* | 0.46 ± 0.02* | 0.47 ± 0.02*
Glucose (mg/dL) | 132 ± 10 | 127 ± 4 | 125 ± 3 | 140 ± 8 | 139 ± 13 | 132 ± 5
Total protein (g/dL) | 7.1 ± 0.1 | 7.0 ± 0.1 | 7.1 ± 0.0 | 7.0 ± 0.1 | 7.1 ± 0.1 | 7.0 ± 0.1
Albumin (g/dL) | 4.6 ± 0.1 | 4.6 ± 0.1 | 4.6 ± 0.0 | 4.6 ± 0.1 | 4.6 ± 0.1 | 4.6 ± 0.1
Globulin (g/dL) | 2.5 ± 0.1 | 2.5 ± 0.1 | 2.5 ± 0.1 | 2.5 ± 0.1 | 2.5 ± 0.1 | 2.4 ± 0.1
Albumin/globulin ratio | 1.9 ± 0.1 | 1.9 ± 0.1 | 1.9 ± 0.1 | 1.9 ± 0.1 | 1.9 ± 0.0 | 1.9 ± 0.1
Cholesterol (mg/dL) | 83 ± 4 | 82 ± 5 | 82 ± 3 | 78 ± 3 | 82 ± 5 | 81 ± 5
Triglycerides (mg/dL) | 97 ± 13 | 97 ± 8 | 112 ± 11 | 86 ± 12 | 95 ± 11 | 87 ± 10
Alanine aminotransferase (IU/L) | 34 ± 1 | 34 ± 2 | 34 ± 1 | 38 ± 5 | 33 ± 2 | 40 ± 6
Alkaline phosphatase (IU/L) | 107 ± 6 | 123 ± 8 | 129 ± 11 | 114 ± 11 | 120 ± 7 | 119 ± 9
Creatine kinase (IU/L) | 151 ± 18 | 167 ± 22 | 156 ± 15 | 332 ± 118 | 152 ± 21 | 487 ± 200*
Sorbitol dehydrogenase (IU/L) | 12 ± 1 | 11 ± 1 | 12 ± 1 | 9 ± 1 | 11 ± 1 | 11 ± 1
Bile acids (µmol/L) | 5.9 ± 1.3 | 10.8 ± 3.2 | 10.6 ± 3.9 | 17.3 ± 4.6 | 9.4 ± 2.8 | 6.5 ± 2.8
Female
n | 10 | 10 | 10 | 10 | 10 | 10
Hematology
Hematocrit (%) | 48.2 ± 0.7 | 47.1 ± 0.5 | 47.9 ± 0.4 | 47.3 ± 0.5 | 47.1 ± 0.4 | 46.5 ± 0.7
Packed cell volume (%) | 49.4 ± 0.9 | 48.2 ± 0.6 | 49.1 ± 0.4 | 48.2 ± 0.5 | 47.8 ± 0.4 | 47.6 ± 0.6
Hemoglobin (g/dL) | 16.1 ± 0.2 | 15.6 ± 0.2 | 15.9 ± 0.2 | 15.5 ± 0.2 | 15.6 ± 0.1 | 15.5 ± 0.1
Erythrocytes (10^6^/μL) | 8.55 ± 0.13 | 8.29 ± 0.11 | 8.51 ± 0.10 | 8.24 ± 0.07 | 8.34 ± 0.10 | 8.24 ± 0.11
Reticulocytes (10^3^/μL) | 229.4 ± 14.1 | 246.8 ± 6.2 | 245.7 ± 13.1 | 240.8 ± 8.4 | 247.4 ± 9.8 | 248.0 ± 10.0
Nucleated erythrocytes/ 100 leukocytes | 0.1 ± 0.1 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0
Mean cell volume (fL) | 57.8 ± 0.6 | 58.2 ± 0.3 | 57.7 ± 0.5 | 58.6 ± 0.4 | 57.4 ± 0.5 | 57.7 ± 0.4
Mean cell Hemoglobin (pg) | 18.8 ± 0.1 | 18.9 ± 0.1 | 18.7 ± 0.2 | 18.9 ± 0.2 | 18.7 ± 0.2 | 18.8 ± 0.2
Mean cell hemoglobin concentration (g/dL) | 32.5 ± 0.2 | 32.4 ± 0.1 | 32.4 ± 0.3 | 32.2 ± 0.1 | 32.6 ± 0.2 | 32.6 ± 0.2
Platelets (10^3^/μL) | 720 ± 32 | 690 ± 33 | 691 ± 19 | 773 ± 28 | 788 ± 34 | 751 ± 41
Leukocytes (10^3^/μL) | 6.25 ± 0.55 | 6.52 ± 0.29 | 6.38 ± 0.40 | 5.85 ± 0.67 | 6.58 ± 0.47 | 5.92 ± 0.48
Segmented neutrophils (10^3^/μL) | 1.06 ± 0.12 | 1.07 ± 0.11 | 1.11 ± 0.10 | 0.86 ± 0.09 | 1.08 ± 0.12 | 0.90 ± 0.07
Bands (10^3^/μL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL) | 4.97 ± 0.44 | 5.22 ± 0.23 | 5.04 ± 0.38 | 4.79 ± 0.58 | 5.23 ± 0.44 | 4.76 ± 0.45
Monocytes (10^3^/μL) | 0.14 ± 0.01 | 0.13 ± 0.01 | 0.12 ± 0.01 | 0.12 ± 0.01 | 0.16 ± 0.02 | 0.12 ± 0.02
Basophils (10^3^/μL) | 0.02 ± 0.00 | 0.02 ± 0.00 | 0.03 ± 0.00 | 0.02 ± 0.00 | 0.03 ± 0.00** | 0.03 ± 0.00*
Eosinophils (10^3^/μL) | 0.06 ± 0.01 | 0.08 ± 0.01 | 0.08 ± 0.01 | 0.07 ± 0.01 | 0.08 ± 0.01 | 0.11 ± 0.01*
Clinical Chemistry
Urea nitrogen (mg/dL) | 18.3 ± 0.5 | 20.1 ± 1.0 | 21.1 ± 1.7 | 22.8 ± 2.6 | 25.5 ± 4.0 | 19.0 ± 1.0
Creatinine (mg/dL) | 0.46 ± 0.03 | 0.42 ± 0.01 | 0.40 ± 0.01 | 0.43 ± 0.02 | 0.43 ± 0.02 | 0.45 ± 0.02
Glucose (mg/dL) | 145 ± 5 | 123 ± 4* | 132 ± 4 | 135 ± 4 | 136 ± 6 | 145 ± 9
Total protein (g/dL) | 7.4 ± 0.1 | 7.6 ± 0.1 | 7.5 ± 0.1 | 7.5 ± 0.1 | 7.5 ± 0.1 | 7.4 ± 0.1
Albumin (g/dL) | 5.4 ± 0.1 | 5.5 ± 0.1 | 5.4 ± 0.1 | 5.3 ± 0.1 | 5.2 ± 0.1 | 5.3 ± 0.1
Globulin (g/dL) | 2.0 ± 0.1 | 2.1 ± 0.0 | 2.1 ± 0.1 | 2.2 ± 0.1 | 2.2 ± 0.1* | 2.2 ± 0.1
Albumin/globulin ratio | 2.7 ± 0.1 | 2.6 ± 0.1 | 2.6 ± 0.1 | 2.4 ± 0.1* | 2.3 ± 0.1** | 2.5 ± 0.1*
Cholesterol (mg/dL) | 62 ± 3 | 62 ± 3 | 57 ± 3 | 62 ± 3 | 63 ± 4 | 61 ± 2
Triglycerides (mg/dL) | 54 ± 5 | 73 ± 8 | 56 ± 4 | 64 ± 4 | 76 ± 7* | 62 ± 6
Alanine aminotransferase (IU/L) | 30 ± 1 | 34 ± 4 | 31 ± 2 | 30 ± 1 | 30 ± 2 | 31 ± 2
Alkaline phosphatase (IU/L) | 75 ± 7 | 82 ± 11 | 73 ± 6 | 77 ± 6 | 83 ± 8 | 54 ± 3
Creatine kinase (IU/L) | 208 ± 34 | 197 ± 22 | 189 ± 22 | 233 ± 48 | 177 ± 24 | 289 ± 65
Sorbitol dehydrogenase (IU/L) | 12 ± 1 | 12 ± 1 | 12 ± 1 | 11 ± 1 | 11 ± 1 | 8 ± 1*
Bile acids (µmol/L) | 11.8 ± 3.6 | 8.4 ± 2.6 | 7.9 ± 1.5 | 10.6 ± 3.1 | 7.4 ± 2.1 | 13.7 ± 3.7

* Significantly different (P ≤ 0.05) from the chamber control group by Dunn’s or Shirley’s test.

** Significantly different (P ≤ 0.01) from the chamber control group by Shirley’s test.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 8.

Table F-2 Hematology Data for Mice in the Three-month Inhalation Study of TRIM VXa

| Chamber Control | 25 mg/m^3^ | 50 mg/m^3^ | 100 mg/m^3^ | 200 mg/m^3^ | 400 mg/m^3^
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Hematocrit (%) | 51.8 ± 0.6 | 51.8 ± 0.3 | 51.8 ± 0.7 | 51.7 ± 0.3 | 49.0 ± 1.1* | 51.0 ± 0.5
Packed cell volume (%) | 53.5 ± 0.7 | 52.8 ± 0.3 | 52.3 ± 0.5 | 53.1 ± 0.4 | 50.3 ± 1.1** | 51.7 ± 0.4**
Hemoglobin (g/dL) | 17.1 ± 0.2 | 16.8 ± 0.1 | 16.7 ± 0.1 | 17.0 ± 0.1 | 16.1 ± 0.3** | 16.6 ± 0.1
Erythrocytes (10^6^/µL) | 11.09 ± 0.13 | 10.93 ± 0.06 | 10.80 ± 0.08 | 10.96 ± 0.07 | 10.44 ± 0.24** | 10.64 ± 0.09**
Reticulocytes (10^3^/µL) | 306.5 ± 5.0 | 306.3 ± 5.9 | 287.5 ± 15.7 | 297.8 ± 7.2 | 270.9 ± 13.2** | 270.9 ± 7.9**
Nucleated erythrocytes/ 100 leukocytes | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Howell-Jolly bodies (%erythrocytes) | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0
Mean cell volume (fL) | 48.2 ± 0.2 | 48.3 ± 0.2 | 48.5 ± 0.4 | 48.4 ± 0.2 | 48.2 ± 0.3 | 48.6 ± 0.2
Mean cell hemoglobin (pg) | 15.4 ± 0.0 | 15.4 ± 0.1 | 15.5 ± 0.1 | 15.5 ± 0.0 | 15.5 ± 0.1 | 15.6 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 31.9 ± 0.2 | 31.8 ± 0.1 | 32.0 ± 0.1 | 32.0 ± 0.1 | 32.1 ± 0.2 | 32.1 ± 0.1
Platelets (10^3^/µL) | 1,232 ± 53 | 1,384 ± 23 | 1,323 ± 25 | 1,275 ± 49 | 1,426 ± 89 | 1,395 ± 43
Leukocytes (10^3^/µL) | 3.25 ± 0.34 | 3.06 ± 0.45 | 3.09 ± 0.25 | 3.33 ± 0.35 | 3.00 ± 0.55 | 2.77 ± 0.26
Segmented neutrophils (10^3^/µL) | 0.40 ± 0.06 | 0.37 ± 0.06 | 0.42 ± 0.06 | 0.46 ± 0.08 | 0.48 ± 0.14 | 0.31 ± 0.04
Bands (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/µL) | 2.70 ± 0.28 | 2.55 ± 0.38 | 2.53 ± 0.19 | 2.76 ± 0.27 | 2.38 ± 0.42 | 2.34 ± 0.21
Monocytes (10^3^/µL) | 0.04 ± 0.01 | 0.04 ± 0.01 | 0.03 ± 0.00 | 0.02 ± 0.01 | 0.05 ± 0.02 | 0.02 ± 0.01
Basophils (10^3^/µL) | 0.02 ± 0.00 | 0.02 ± 0.00 | 0.02 ± 0.00 | 0.01 ± 0.00 | 0.02 ± 0.00 | 0.01 ± 0.00
Eosinophils (10^3^/µL) | 0.10 ± 0.02 | 0.10 ± 0.02 | 0.10 ± 0.01 | 0.09 ± 0.03 | 0.08 ± 0.02 | 0.09 ± 0.02
Female
Hematocrit (%) | 50.8 ± 0.4 | 50.9 ± 0.3 | 51.1 ± 0.5 | 50.5 ± 0.4 | 49.7 ± 0.4 | 50.1 ± 0.3
Packed cell volume (%) | 51.4 ± 0.4 | 51.2 ± 0.4 | 51.9 ± 0.5 | 50.7 ± 0.4 | 50.4 ± 0.5 | 50.5 ± 0.4
Hemoglobin (g/dL) | 16.9 ± 0.1 | 16.8 ± 0.1 | 16.9 ± 0.2 | 16.7 ± 0.1 | 16.7 ± 0.1 | 16.6 ± 0.1
Erythrocytes (10^6^/µL) | 10.66 ± 0.08 | 10.57 ± 0.08 | 10.78 ± 0.10 | 10.60 ± 0.09 | 10.50 ± 0.09 | 10.48 ± 0.06
Reticulocytes (10^3^/µL) | 305.1 ± 12.8 | 315.7 ± 15.8 | 287.3 ± 9.0 | 269.0 ± 7.9 | 293.1 ± 19.0 | 322.4 ± 16.9
Nucleated erythrocytes/ 100 leukocytes | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Howell-Jolly bodies (% erythrocytes) | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0
Mean cell volume (fL) | 48.3 ± 0.2 | 48.5 ± 0.2 | 48.1 ± 0.2 | 47.9 ± 0.1 | 48.0 ± 0.1 | 48.1 ± 0.1
Mean cell hemoglobin (pg) | 15.9 ± 0.1 | 15.9 ± 0.1 | 15.7 ± 0.1 | 15.8 ± 0.1 | 15.9 ± 0.1 | 15.9 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 32.8 ± 0.1 | 32.7 ± 0.2 | 32.6 ± 0.2 | 32.9 ± 0.1 | 33.0 ± 0.2 | 33.0 ± 0.1
Platelets (10^3^/µL) | 1,178 ± 39 | 1,153 ± 36 | 1,092 ± 29 | 1,222 ± 20 | 1,174 ± 35 | 1,216 ± 35
Leukocytes (10^3^/µL) | 2.74 ± 0.22 | 2.70 ± 0.27 | 2.90 ± 0.21 | 3.26 ± 0.21 | 3.28 ± 0.35 | 3.08 ± 0.17
Segmented neutrophils (10^3^/µL) | 0.36 ± 0.03 | 0.30 ± 0.05 | 0.30 ± 0.04 | 0.41 ± 0.05 | 0.34 ± 0.06 | 0.34 ± 0.06
Bands (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/µL) | 2.26 ± 0.18 | 2.26 ± 0.21 | 2.47 ± 0.19 | 2.70 ± 0.17 | 2.84 ± 0.29 | 2.63 ± 0.16
Monocytes (10^3^/µL) | 0.03 ± 0.01 | 0.03 ± 0.01 | 0.03 ± 0.00 | 0.04 ± 0.01 | 0.04 ± 0.01 | 0.03 ± 0.00
Basophils (10^3^/µL) | 0.01 ± 0.00 | 0.01 ± 0.00 | 0.01 ± 0.00 | 0.01 ± 0.00 | 0.00 ± 0.00** | 0.01 ± 0.00*
Eosinophils (10^3^/µL) | 0.08 ± 0.01 | 0.09 ± 0.02 | 0.08 ± 0.01 | 0.10 ± 0.02 | 0.07 ± 0.02 | 0.07 ± 0.02

* Significantly different (P ≤ 0.05) from the chamber control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.