# Appendix D Summary of Lesions in Female Mice in the Two-year Inhalation Study of TRIM VX

Table D-1 Summary of the Incidence of Neoplasms in Female Mice in the Two-year Inhalation Study of TRIM VX^a^

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental death | 1 | – | – | –
Moribund | 10 | 9 | 4 | 13
Natural deaths | 4 | 5 | 10 | 7
Survivors
Died last week of study | 1 | – | – | 1
Terminal kill | 34 | 36 | 36 | 29
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (49)
Gallbladder | (46) | (46) | (44) | (44)
Intestine large, cecum | (50) | (49) | (46) | (45)
Intestine large, colon | (50) | (50) | (47) | (50)
Intestine large, rectum | (48) | (48) | (46) | (45)
Intestine small, duodenum | (48) | (46) | (43) | (45)
Intestine small, ileum | (48) | (47) | (44) | (46)
Intestine small, jejunum | (48) | (45) | (45) | (46)
Liver | (50) | (50) | (50) | (50)
Carcinoma, metastatic, islets, pancreatic | – | – | – | 1 (2%)
Hepatoblastoma | 1 (2%) | – | – | –
Hepatocellular adenoma | 7 (14%) | 11 (22%) | 7 (14%) | 9 (18%)
Hepatocellular adenoma, multiple | 2 (4%) | 4 (8%) | 3 (6%) | 6 (12%)
Hepatocellular carcinoma | 7 (14%) | 2 (4%) | 5 (10%) | 9 (18%)
Hepatocellular carcinoma, multiple | – | 3 (6%) | 2 (4%) | 3 (6%)
Ito cell tumor benign | – | 1 (2%) | – | –
Mesentery | (10) | (10) | (5) | (11)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (9%)
Hemangioma | – | – | – | 1 (9%)
Schwannoma malignant, metastatic, heart | – | – | – | 1 (9%)
Pancreas | (50) | 50) | (49) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Sarcoma, metastatic, skin | –– | – | – | 1 (2%)
Salivary glands | (50) | (50) | (50) | (50)
Mast cell tumor benign | – | | 1 (2%) | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Squamous cell papilloma | 1 (2%) | – | – | –
Stomach, glandular | (49) | (50) | (49) | (50)
Tooth | (0) | (1) | (0) | (0)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Aorta, alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Aorta, hemangiosarcoma | 1 (2%) | – | – | –
Heart | (50) | (50) | (49) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 2 (4%)
Endocardium, schwannoma malignant | – | – | – | 1 (2%)
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Subcapsular, adenoma | – | – | – | 1 (2%)
Adrenal medulla | (50) | (50) | (50) | (50)
Pheochromocytoma benign | 2 (4%) | 1 (2%) | 1 (2%) | –
Pheochromocytoma malignant | – | 1 (2%) | – | –
Islets, pancreatic | (50) | (49) | (49) | (50)
Adenoma | – | – | 1 (2%) | –
Carcinoma | – | – | – | 1 (2%)
Parathyroid gland | (35) | (30) | (36) | (28)
Adenoma | 1 (3%) | – | – | –
Pituitary gland | (48) | (49) | (49) | (49)
Pars distalis, adenoma | 8 (17%) | 6 (12%) | 7 (14%) | 6 (12%)
Pars distalis, carcinoma | 3 (6%) | – | – | 2 (4%)
Thyroid gland | (50) | (50) | (50) | (49)
C-cell, carcinoma | 1 (2%) | – | – | –
Follicular cell, adenoma | – | – | 1 (2%) | –
Follicular cell, carcinoma, multiple | – | – | – | 1 (2%)
General Body System
Tissue NOS | (1) | (0) | (0) | (0)
Genital System
Clitoral gland | (46) | (48) | (45) | (46)
Ovary | (50) | (49) | (49) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Cystadenoma | 1 (2%) | 4 (8%) | 2 (4%) | 3 (6%)
Granulosa cell tumor benign | 1 (2%) | – | – | 1 (2%)
Periovarian tissue, alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Periovarian tissue, sarcoma, metastatic, skin | – | – | – | 1 (2%)
Uterus | (50) | (50) | (50) | (50)
Carcinoma | – | – | – | 1 (2%)
Hemangioma | – | 1 (2%) | – | 1 (2%)
Hemangiosarcoma | 1 (2%) | 2 (4%) | – | –
Polyp stromal | 1 (2%) | 3 (6%) | 5 (10%) | 1 (2%)
Endometrium, adenoma | – | – | 1 (2%) | –
Hematopoietic System
Bone marrow | (49) | (50) | (50) | (50)
Hemangiosarcoma, metastatic, spleen | – | – | 1 (2%) | –
Lymph node | (11) | (11) | (11) | (10)
Axillary, alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (10%)
Axillary, schwannoma malignant, metastatic, skin | – | 1 (9%) | – | –
Lumbar, hemangiosarcoma | 1 (9%) | – | – | –
Pancreatic, hemangiosarcoma | – | – | – | 1 (10%)
Renal, alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (10%)
Lymph node, bronchial | (44) | (44) | (44) | (43)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 4 (9%)
Carcinoma, metastatic, Harderian gland | – | – | – | 1 (2%)
Carcinoma, metastatic, mammary gland | – | 1 (2%) | – | –
Lymph node, mandibular | (35) | (42) | (37) | (39)
Lymph node, mediastinal | (40) | (44) | (45) | (45)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 3 (7%)
Schwannoma malignant, metastatic, skin | – | 1 (2%) | – | –
Lymph node, mesenteric | (49) | (49) | (47) | (48)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Hemangioma | 1 (2%) | – | – | –
Sarcoma, metastatic, skin | – | – | – | 1 (2%)
Spleen | (50) | (49) | (48) | (49)
Hemangiosarcoma | – | 1 (2%) | (4%) | –
Thymus | (48) | (48) | (47) | (49)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 2 (4%)
Sarcoma, metastatic, skin | – | – | – | 1 (2%)
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Adenoma | – | 1 (2%) | 1 (2%) | –
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Carcinoma | – | 1 (2%) | 1 (2%) | –
Skin | (50) | (50) | (50) | (50)
Schwannoma benign | – | – | – | 1 (2%)
Schwannoma malignant | – | – | 1 (2%) | –
Subcutaneous tissue, fibrous histiocytoma | – | 1 (2%) | – | 1 (2%)
Subcutaneous tissue, hemangiosarcoma | – | – | 1 (2%) | –
Subcutaneous tissue, sarcoma | – | – | – | 1 (2%)
Subcutaneous tissue, schwannoma malignant | – | 3 (6%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Hemangiosarcoma, metastatic, spleen | – | – | 1 (2%) | –
Mandible, fibrosarcoma | – | – | – | 1 (2%)
Skeletal muscle | (3) | (4) | (2) | (4)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (25%)
Sarcoma | – | – | – | 1 (25%)
Nervous System
Brain | (50) | (50) | (50) | (50)
Carcinoma, metastatic, mammary gland | – | 1 (2%) | – | –
Peripheral nerve | (3) | (3) | (1) | (2)
Spinal cord | (2) | (3) | (1) | (2)
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | 4 (8%) | 5 (10%) | 3 (6%) | 6 (12%)
Alveolar/bronchiolar adenoma, multiple | – | – | – | 2 (4%)
Alveolar/bronchiolar carcinoma | 3 (6%) | 3 (6%) | 5 (10%) | 9 (18%)
Alveolar/bronchiolar carcinoma, multiple | 2 (4%) | – | 1 (2%) | 5 (10%)
Carcinoma, metastatic, Harderian gland | – | – | – | 1 (2%)
Carcinoma, metastatic, mammary gland | – | 1 (2%) | – | –
Carcinoma, metastatic, thyroid gland | 1 (2%) | – | – | –
Hepatocellular carcinoma, metastatic, liver | – | 2 (4%) | 2 (4%) | 3 (6%)
Pheochromocytoma malignant, metastatic, adrenal medulla | – | 1 (2%) | – | –
Sarcoma, metastatic, skin | – | – | – | 1 (2%)
Nose | (50) | (50) | (50) | (50)
Carcinoma, metastatic, Harderian gland | – | – | – | 1 (2%)
Trachea | (49) | (50) | (50) | (49)
Special Senses System
Ear | (0) | (0) | (0) | (1)
Eye | (49) | (50) | (50) | (50)
Harderian gland | (50) | (49) | (49) | (49)
Adenoma | 1 (2%) | 1 (2%) | 5 (10%) | 4 (8%)
Carcinoma | 3 (6%) | 2 (4%) | 2 (4%) | 5 (10%)
Urinary System
Kidney | (49) | (50) | (49) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 2 (4%)
Carcinoma, metastatic, mammary gland | – | 1 (2%) | – | –
Pheochromocytoma malignant, metastatic, adrenal medulla | – | 1 (2%) | – | –
Sarcoma, metastatic, skin | – | – | – | 1 (2%)
Schwannoma malignant, metastatic, heart | – | – | – | (2%)
Urethra | (0) | (1) | (0) | (0)
Urinary bladder | (50) | (50) | (50) | (50)
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | 4 (8%) | 5 (10%) | 3 (6%) | 3 (6%)
Lymphoma malignant | 10 (20%) | 8 (16%) | 14 (28%) | 12 (24%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 38 | 41 | 42 | 46
Total primary neoplasms | 67 | 70 | 75 | 99
Total animals with benign neoplasms | 23 | 22 | 28 | 30
Total benign neoplasms | 30 | 38 | 38 | 42
Total animals with malignant neoplasms | 27 | 29 | 2 | 37
Total malignant neoplasms | 37 | 32 | 37 | 57
Total animals with metastatic neoplasms | 7 | 8 | 5 | 11
Total metastatic neoplasms | 9 | 15 | 7 | 42

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table D-2 Statistical Analysis of Primary Neoplasms in Female Mice in the Two-year Inhalation Study of TRIM VX

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Harderian Gland: Adenoma
Overall rate^a^ | 1/50 (2%) | 1/50 (2%) | 5/50 (10%) | 4/50 (8%)
Adjusted rate^b^ | 2.3% | 2.2% | 10.9% | 9.2%
Terminal rate^c^ | 0/35 (0%) | 1/36 (3%) | 4/36 (11%) | 2/30 (7%)
First incidence (days) | 683 | 731 (T) | 716 | 645
Poly-3 test^d^ | P = 0.122 | P = 0.758N | P = 0.110 | P = 0.175
Harderian Gland: Carcinoma
Overall rate | 3/50 (6%) | 2/50 (4%) | 2/50 (4%) | 5/50 (10%)
Adjusted rate | 6.8% | 4.5% | 4.4% | 11.5%
Terminal rate | 3/35 (9%) | 2/36 (6%) | 2/36 (6%) | 3/30 (10%)
First incidence (days) | 731 (T) | 731 (T) | 731 (T) | 661
Poly-3 test | P = 0.163 | P = 0.492N | P = 0.481N | P = 0.352
Harderian Gland: Adenoma or Carcinoma
Overall rate | 4/50 (8%) | 3/50 (6%) | 7/50 (14%) | 9/50 (18%)
Adjusted rate | 9.1% | 6.7% | 15.3% | 20.5%
Terminal rate | 3/35 (9%) | 3/36 (8%) | 6/36 (17%) | 5/30 (17%)
First incidence (days) | 683 | 731 (T) | 716 | 645
Poly-3 test | P = 0.039 | P = 0.492N | P = 0.283 | P = 0.112
Liver: Hepatocellular Adenoma
Overall rate | 9/50 (18%) | 15/50 (30%) | 10/50 (20%) | 15/50 (30%)
Adjusted rate | 20.5% | 33.5% | 21.6% | 33.8%
Terminal rate | 8/35 (23%) | 14/36 (39%) | 8/36 (22%) | 10/30 (33%)
First incidence (days) | 721 | 721 | 649 | 572
Poly-3 test | P = 0.197 | P = 0.124 | P = 0.551 | P = 0.120
Liver: Hepatocellular Carcinoma
Overall rate | 7/50 (14%)^e^ | 5/50 (10%) | 7/50 (14%) | 12/50 (24%)
Adjusted rate | 15.8% | 11.1% | 15.2% | 26.7%
Terminal rate | 5/35 (14%) | 3/36 (8%) | 4/36 (11%) | 4/30 (13%)
First incidence (days) | 645 | 607 | 649 | 557
Poly-3 test | P = 0.042 | P = 0.364N | P = 0.581N | P = 0.158
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 15/50 (30%)^e^ | 19/50 (38%) | 15/50 (30%) | 24/50 (48%)
Adjusted rate | 33.9% | 42.1% | 32.3% | 52.3%
Terminal rate | 13/35 (37%) | 16/36 (44%) | 11/36 (31%) | 13/30 (43%)
First incidence (days) | 645 | 607 | 649 | 557
Poly-3 test | P = 0.049 | P = 0.281 | P = 0.525N | P = 0.056
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 4/50 (8%) | 5/50 (10%) | 3/50 (6%) | 8/50 (16%)
Adjusted rate | 9.0% | 11.2% | 6.6% | 18.3%
Terminal rate | 2/35 (6%) | 5/36 (14%) | 3/36 (8%) | 5/30 (17%)
First incidence (days) | 575 | 731 (T) | 731 (T) | 668
Poly-3 test | P = 0.100 | P = 0.502 | P = 0.486N | P = 0.166
Lung: Alveolar/bronchiolar Carcinoma
Overall rate | 5/50 (10%) | 3/50 (6%) | 6/50 (12%) | 14/50 (28%)
Adjusted rate | 11.4% | 6.7% | 13.1% | 31.4%
Terminal rate | 5/35 (14%) | 2/36 (6%) | 6/36 (17%) | 8/30 (27%)
First incidence (days) | 731 (T) | 647 | 731 (T) | 513
Poly-3 test | P < 0.001 | P = 0.342N | P = 0.529 | P = 0.018
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 9/50 (18%) | 8/50 (16%) | 8/50 (16%) | 20/50 (40%)
Adjusted rate | 20.2% | 17.8% | 17.5% | 44.5%
Terminal rate | 7/35 (20%) | 7/36 (19%) | 8/36 (22%) | 12/30 (40%)
First incidence (days) | 575 | 647 | 731 (T) | 513
Poly-3 test | P < 0.001 | P = 0.491N | P = 0.476N | P = 0.011
Ovary: Cystadenoma
Overall rate | 1/50 (2%) | 4/49 (8%) | 2/49 (4%) | 3/50 (6%)
Adjusted rate | 2.3% | 9.2% | 4.5% | 6.9%
Terminal rate | 1/35 (3%) | 4/35 (11%) | 1/36 (3%) | 3/30 (10%)
First incidence (days) | 731 (T) | 731 (T) | 725 | 731 (T)
Poly-3 test | P = 0.446 | P = 0.177 | P = 0.507 | P = 0.300
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 8/48 (17%) | 6/49 (12%) | 7/49 (14%) | 6/49 (12%)
Adjusted rate | 18.7% | 13.4% | 15.6% | 14.0%
Terminal rate | 6/35 (17%) | 5/36 (14%) | 6/36 (17%) | 5/29 (17%)
First incidence (days) | 647 | 647 | 722 | 557
Poly-3 test | P = 0.437N | P = 0.351N | P = 0.463N | P = 0.387N
Pituitary Gland (Pars Distalis): Carcinoma
Overall rate | 3/48 (6%) | 0/49 (0%) | 0/49 (0%) | 2/49 (4%)
Adjusted rate | 7.0% | 0.0% | 0.0% | 4.7%
Terminal rate | 2/35 (6%) | 0/36 (0%) | 0/36 (0%) | 2/29 (7%)
First incidence (days) | 522 | –^f^ | – | 731 (T)
Poly-3 test | P = 0.536 | P = 0.113N | P = 0.112N | P = 0.510N
Pituitary Gland (Pars Distalis): Adenoma or Carcinoma
Overall rate | 11/48 (23%) | 6/49 (12%) | 7/49 (14%) | 8/49 (16%)
Adjusted rate | 25.3% | 13.4% | 15.6% | 18.7%
Terminal rate | 8/35 (23%) | 5/36 (14%) | 6/36 (17%) | 7/29 (24%)
First incidence (days) | 522 | 647 | 722 | 557
Poly-3 test | P = 0.499N | P = 0.124N | P = 0.194N | P = 0.316N
Skin: Malignant Schwannoma
Overall rate | 0/50 (%) | 3/50 (6%) | 1/50 (2%) | 0/50 (0%)
Adjusted rate | 0.0% | 6.5% | 2.2% | 0.0%
Terminal rate | 0/35 (0%) | 1/36 (3%) | 0/36 (0%) | 0/30 (0%)
First incidence (days) | – | 479 | 655 | –
Poly-3 test | P = 0.278N | P = 0.127 | P = 0.509 | –^g^
Skin: Benign or Malignant Schwannoma
Overall rate | 0/50 (%) | 3/50 (6%) | 1/50 (2%) | 1/50 (2%)
Adjusted rate | 0.0% | 6.5% | 2.2% | 2.3%
Terminal rate | 0/35 (0%) | 1/36 (3%) | 0/36 (0%) | 1/30 (3%)
First incidence (days) | – | 479 | 655 | 731 (T)
Poly-3 test | P = 0.592N | P = 0.127 | P = 0.509 | P = 0.497
Uterus: Stromal Polyp
Overall rate | 1/50 (2%) | 3/50 (6%) | 5/50 (10%) | 1/50 (2%)
Adjusted rate | 2.3% | 6.7% | 10.9% | 2.3%
Terminal rate | 1/35 (3%) | 2/36 (6%) | 4/36 (11%) | 1/30 (3%)
First incidence (days) | 731 (T) | 721 | 715 | 731 (T)
Poly-3 test | P = 0.401N | P = 0.312 | P = 0.111 | P = 0.758
All Organs: Hemangiosarcoma
Overall rate | 2/50 (4%) | 3/50 (6%) | 3/50 (6%) | 1/50 (2%)
Adjusted rate | 4.5% | 6.7% | 6.5% | 2.3%
Terminal rate | 1/35 (3%) | 2/36 (6%) | 1/36 (3%) | 1/30 (3%)
First incidence (days) | 647 | 640 | 637 | 731 (T)
Poly-3 test | P = 0.314N | P = 0.508 | P = 0.519 | P = 0.508N
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 3/50 (6%) | 4/50 (8%) | 3/50 (6%) | 3/50 (6%)
Adjusted rate | 6.8% | 8.9% | 6.5% | 6.9%
Terminal rate | 1/35 (3%) | 3/36 (8%) | 1/36 (3%) | 2/30 (7%)
First incidence (days) | 647 | 640 | 637 | 673
Poly-3 test | P = 0.544N | P = 0.507 | P = 0.645N | P = 0.653
All Organs: Histiocytic Sarcoma
Overall rate | 4/50 (8%) | 5/50 (10%) | 3/50 (6%) | 3/50 (6%)
Adjusted rate | 8.9% | 11.1% | 6.6% | 6.9%
Terminal rate | 1/35 (3%) | 3/36 (8%) | 3/36 (8%) | 0/30 (0%)
First incidence (days) | 550 | 688 | 731 (T) | 645
Poly-3 test | P = 0.381N | P = 0.499 | P = 0.492N | P = 0.516N
All Organs: Malignant Lymphoma
Overall rate | 10/50 (20%) | 8/50 (16%) | 14/50 (28%) | 12/50 (24%)
Adjusted rate | 22.2% | 17.6% | 30.1% | 27.1%
Terminal rate | 7/35 (20%) | 7/36 (19%) | 10/36 (28%) | 8/30 (27%)
First incidence (days) | 575 | 365 | 619 | 572
Poly-3 test | P = 0.261 | P = 0.386N | P = 0.266 | P = 0.387
All Organs: Benign Neoplasms
Overall rate | 23/50 (46%) | 22/50 (44%) | 28/50 (56%) | 30/50 (60%)
Adjusted rate | 50.8% | 48.5% | 60.2% | 65.5%
Terminal rate | 17/35 (49%) | 19/36 (53%) | 22/36 (61%) | 20/30 (67%)
First incidence (days) | 575 | 640 | 649 | 557
Poly-3 test | P = 0.056 | P = 0.497N | P = 0.238 | P = 0.107
All Organs: Malignant Neoplasms
Overall rate | 27/50 (54%) | 29/50 (58%) | 32/50 (64%) | 37/50 (74%)
Adjusted rate | 57.2% | 59.6% | 67.3% | 76.8%
Terminal rate | 18/35 (51%) | 19/36 (53%) | 22/36 (61%) | 21/30 (70%)
First incidence (days) | 522 | 365 | 619 | 319
Poly-3 test | P = 0.019 | P = 0.488 | P = 0.209 | P = 0.030
All Organs: Benign or Malignant Neoplasms
Overall rate | 38/50 (76%) | 41/50 (82%) | 42/50 (84%) | 46/50 (92%)
Adjusted rate | 80.0% | 84.2% | 88.2% | 94.7%
Terminal rate | 27/35 (77%) | 30/36 (83%) | 31/36 (86%) | 28/30 (93%)
First incidence (days) | 522 | 365 | 619 | 319
Poly-3 test | P = 0.022 | P = 0.389 | P = 0.198 | P = 0.024

(T) Terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for liver, lung, ovary, and pituitary gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ A single incidence of hepatoblastoma occurred in an animal that also had a hepatocellular carcinoma.

^f^ Not applicable; no neoplasms in animal group.

^g^ Value of statistic cannot be computed.

Table D-3 Historical Incidence of Alveolar/bronchiolar Neoplasms in Control Female B6C3F1/N Mice^a^

Study (Study Start) | Adenoma | Carcinoma | Adenoma or Carcinoma
Historical Incidence: Inhalation Studies
Antimony trioxide (October 2008) | 1/50 | 2/50 | 3/50
Cobalt metal (May 2006) | 3/49 | 5/49 | 8/49
CIMSTAR 3800 (May 2008) | 1/50 | 4/50 | 4/50
TRIM VX (August 2009) | 4/50 | 5/50 | 9/50
Vinylidene chloride (June 2005) | 3/50 | 1/50 | 4/50
Total (%) | 12/249 (4.8%) | 17/249 (6.8%) | 28/249 (11.2%)
Mean ± standard deviation | 0.8% ± 2.7% | 6.8% ± 3.7% | 11.3% ± 5.5%
Range | 2%–8% | 2%–10% | 6%–18%
Overall Historical Incidence: All Routes
Total (%) | 27/549 (4.9%) | 24/549 (4.4%) | 50/549 (9.1%)
Mean ± standard deviation | 4.9% ± 3.5% | 4.4% ± 3.5% | 9.1% ± 5.2%
Range | 0%–10% | 0%–10% | 2%–18%

^a^ Data as of July 2015.

Table D-4 Summary of the Incidence of Nonneoplastic Lesions in Female Mice in the Two-year Inhalation Study of TRIM VX^a^

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental death | 1 | – | – | –
Moribund | 10 | 9 | 4 | 13
Natural deaths | 4 | 5 | 10 | 7
Survivors
Died last week of study | 1 | – | – | 1
Terminal kill | 34 | 36 | 36 | 29
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (49)
Periesophageal tissue, inflammation, chronic active | 1 (2%) | – | – | 1 (2%)
Gallbladder | (46) | (46) | (44) | (44)
Inflammation, chronic active | 1 (2%) | – | – | –
Vacuolization cytoplasmic | – | – | 1 (2%) | –
Intestine large, cecum | (50) | (49) | (46) | (45)
Hyperplasia, lymphoid | – | 1 (2%) | – | –
Inflammation | 2 (4%) | – | 1 (2%) | 1 (2%)
Intestine large, colon | (50) | (50) | (47) | (50)
Hyperplasia, lymphoid | – | – | – | 1 (2%)
Inflammation | 1 (2%) | – | – | –
Intestine large, rectum | (48) | (48) | (46) | (45)
Edema | 1 (2%) | – | – | –
Inflammation | – | 1 (2%) | – | –
Intestine small, duodenum | (48) | (46) | (43) | (45)
Hyperplasia, lymphoid | – | 1 (2%) | – | –
Infiltration cellular, lymphoid | – | 1 (2%) | – | –
Inflammation | 1 (2%) | 3 (7%) | 1 (2%) | –
Necrosis | – | – | 1 (2%) | –
Intestine small, ileum | (48) | (47) | (44) | (46)
Hyperplasia, lymphoid | 4 (8%) | 8 (17%) | 4 (9%) | 2 (4%)
Hyperplasia, plasma cell | – | – | – | 1 (2%)
Inflammation | 1 (2%) | 4 (9%) | – | –
Perforation | – | 1 (2%) | – | –
Serosa, fibrosis | – | 1 (2%) | – | –
Intestine small, jejunum | (48) | (45) | (45) | (46)
Hyperplasia, lymphoid | 2 (4%) | 2 (4%) | 1 (2%) | 1 (2%)
Inflammation | 1 (2%) | 1 (2%) | 1 (2%) | –
Perforation | 1 (2%) | – | – | –
Ulcer | – | – | 1 (2%) | –
Liver | (50) | (50) | (50) | (50)
Angiectasis | 1 (2%) | 2 (4%) | 1 (2%) | –
Basophilic focus | 6 (12%) | 2 (4%) | 2 (4%) | 4 (8%)
Clear cell focus | – | 5 (10%) | 3 (6%) | 3 (6%)
Cyst | – | 1 (2%) | – | –
Eosinophilic focus | 3 (6%) | 8 (16%) | 7 (14%) | 8 (16%)
Fatty change | 1 (2%) | 2 (4%) | 1 (2%) | –
Hematopoietic cell proliferation | – | 1 (2%) | 1 (2%) | –
Hepatodiaphragmatic nodule | – | 1 (2%) | – | –
Hyperplasia, granulocytic | 1 (2%) | – | – | –
Infarct | – | 1 (2%) | – | –
Inflammation, chronic active | 5 (10%) | 1 (2%) | 1 (2%) | 2 (4%)
Mixed cell focus | 1 (2%) | 1 (2%) | – | 1 (2%)
Necrosis | 1 (2%) | 1 (2%) | – | –
Tension lipidosis | 1 (2%) | 4 (8%) | – | –
Hepatocyte, degeneration | – | – | – | 2 (4%)
Hepatocyte, hypertrophy | – | 2 (4%) | 1 (2%) | 1 (2%)
Hepatocyte, necrosis | 3 (6%) | 1 (2%) | 2 (4%) | 5 (10%)
Mesentery | (10) | (10) | (5) | (11)
Inflammation, chronic active | 2 (20%) | 1 (10%) | – | –
Pigmentation | 1 (10%) | – | – | –
Fat, necrosis | 6 (60%) | 9 (90%) | 5 (100%) | 6 (55%)
Pancreas | (50) | (50) | (49) | (50)
Atrophy | 2 (4%) | 1 (2%) | 1 (2%) | 1 (2%)
Hypertrophy | – | – | – | 3 (6%)
Infiltration cellular, lymphoid | 1 (2%) | 1 (2%) | – | 1 (2%)
Inflammation, chronic active | 3 (6%) | – | 3 (6%) | –
Necrosis | 1 (2%) | – | – | –
Duct, cyst | 1 (2%) | – | 1 (2%) | –
Salivary glands | (50) | (50) | (50) | (50)
Inflammation, suppurative | – | 1 (2%) | – | –
Necrosis, acute | – | 1 (2%) | – | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Cyst, squamous | – | 1 (2%) | – | –
Hyperkeratosis | 2 (4%) | 4 (8%) | 1 (2%) | 2 (4%)
Hyperplasia | 3 (6%) | 6 (12%) | 1 (2%) | 2 (4%)
Inflammation | – | – | 1 (2%) | 1 (2%)
Inflammation, chronic active | 5 (10%) | 1 (2%) | 1 (2%) | 1 (2%)
Ulcer | – | 1 (2%) | 1 (2%) | 1 (2%)
Stomach, glandular | (49) | (50) | (49) | (50)
Cyst | – | 1 (2%) | 1 (2%) | –
Hyperplasia, lymphoid | – | 1 (2%) | – | –
Inflammation, chronic active | 4 (8%) | 3 (6%) | 2 (4%) | 1 (2%)
Mineralization | 1 (2%) | 2 (4%) | – | –
Tooth | (0) | (1) | (0) | (0)
Dysplasia | – | 1 (100%) | – | –
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Heart | (50) | (50) | (49) | (50)
Cardiomyopathy | 12 (24%) | 18 (36%) | 12 (24%) | 15 (30%)
Infiltration cellular, lymphoid | 1 (2%) | – | – | –
Inflammation, suppurative | – | – | 1 (2%) | –
Inflammation, chronic active | 1 (2%) | 5 (10%) | 3 (6%) | 6 (12%)
Mineralization | 1 (2%) | – | 1 (2%) | –
Necrosis | – | – | 2 (4%) | 1 (2%)
Thrombosis | – | – | – | 1 (2%)
Coronary artery, fibrosis | 1 (2%) | – | – | –
Coronary artery, thrombosis | – | – | – | 1 (2%)
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Accessory adrenal cortical nodule | 2 (4%) | 2 (4%) | 3 (6%) | 1 (2%)
Angiectasis | – | 3 (6%) | 2 (4%) | 2 (4%)
Degeneration, cystic | – | – | – | 1 (2%)
Hematopoietic cell proliferation | 1 (2%) | – | 1 (2%) | –
Hyperplasia | 6 (12%) | 6 (12%) | 2 (4%) | 7 (14%)
Hypertrophy | 14 (28%) | 8 (16%) | 13 (26%) | 10 (20%)
Inflammation, chronic active | 1 (2%) | – | – | –
Adrenal medulla | (50) | (50) | (50) | (50)
Hyperplasia | 11 (22%) | 7 (14%) | 5 (10%) | 5 (10%)
Hypertrophy | 1 (2%) | – | 1 (2%) | –
Pigmentation | – | – | – | 1 (2%)
Islets, pancreatic | (50) | (49) | (49) | (50)
Parathyroid gland | (35) | (30) | (36) | (28)
Ectopic tissue | 1 (3%) | – | – | –
Pituitary gland | (48) | (49) | (49) | (49)
Pars distalis, angiectasis | 5 (10%) | 2 (4%) | 2 (4%) | 5 (10%)
Pars distalis, cyst | – | – | – | 1 (2%)
Pars distalis, hyperplasia | 11 (23%) | 17 (35%) | 15 (31%) | 10 (20%)
Pars distalis, hypertrophy | 1 (2%) | – | – | 1 (2%)
Pars intermedia, hyperplasia | 1 (2%) | – | – | –
Thyroid gland | (50) | (50) | (50) | (49)
Cyst | 1 (2%) | 1 (2%) | 1 (2%) | –
Inflammation, suppurative | – | – | 1 (2%) | –
Inflammation, chronic active | – | 2 (4%) | – | 1 (2%)
Follicular cell, hyperplasia | 3 (6%) | – | 2 (4%) | 2 (4%)
Follicular cell, hypertrophy | – | – | – | 1 (2%)
General Body System
Tissue NOS | (1) | (0) | (0) | (0)
Hemorrhage | 1 (100%) | – | – | –
Genital System
Clitoral gland | (46) | (48) | (45) | (46)
Ovary | (50) | (49) | (49) | (50)
Angiectasis | 1 (2%) | 1 (2%) | – | 3 (6%)
Congestion | – | – | 1 (2%) | –
Cyst | 13 (26%) | 8 (16%) | 9 (18%) | 7 (14%)
Cyst, multiple | 1 (2%) | – | – | 1 (2%)
Hemorrhage | 1 (2%) | – | – | –
Inflammation, chronic active | 2 (4%) | 1 (2%) | 2 (4%) | –
Periovarian tissue, inflammation, chronic active | 1 (2%) | – | – | –
Uterus | (50) | (50) | (50) | (50)
Adenomyosis | 1 (2%) | – | – | –
Angiectasis | 1 (2%) | 4 (8%) | 3 (6%) | 2 (4%)
Hemorrhage | – | – | 1 (2%) | –
Inflammation, chronic active | 3 (6%) | 4 (8%) | 3 (6%) | 5 (10%)
Necrosis | – | – | – | 1 (2%)
Endometrium, hyperplasia, cystic | 45 (90%) | 35 (70%) | 43 (86%) | 43 (86%)
Hematopoietic System
Bone marrow | (49) | (50) | (50) | (50)
Atrophy | – | 1 (2%) | – | –
Hyperplasia, granulocytic | 1 (2%) | – | – | –
Myelofibrosis | 1 (2%) | – | – | –
Necrosis | – | – | – | 2 (4%)
Myeloid cell, hyperplasia | 1 (2%) | – | 4 (8%) | 1 (2%)
Lymph node | (11) | (11) | (11) | (10)
Pigmentation | – | – | 1 (9%) | 1 (10%)
Artery, lumbar, inflammation, chronic active | – | – | – | 1 (10%)
Artery, renal, inflammation, chronic active | – | – | – | 1 (10%)
Iliac, angiectasis | – | – | 1 (9%) | 1 (10%)
Iliac, infiltration cellular, mixed cell | 1 (9%) | – | – | –
Lumbar, angiectasis | 1 (9%) | 3 (27%) | 1 (9%) | 1 (10%)
Lumbar, hematopoietic cell proliferation | – | – | 1 (9%) | –
Lumbar, infiltration cellular, plasma cell | – | – | – | 1 (10%)
Lumbar, inflammation, suppurative | 1 (9%) | – | – | –
Lumbar, necrosis | 1 (9%) | – | – | –
Pancreatic, hyperplasia, lymphoid | – | 1 (9%) | 1 (9%) | –
Renal, angiectasis | – | – | 1 (9%) | 1 (10%)
Renal, hyperplasia, lymphoid | – | – | 1 (9%) | –
Renal, infiltration cellular plasma cell | – | – | – | 1 (10%)
Renal, necrosis | – | – | – | 1 (10%)
Lymph node, bronchial | (44) | (44) | (44) | (43)
Hematopoietic cell proliferation | – | – | 1 (2%) | –
Hyperplasia, lymphoid | 6 (14%) | 4 (9%) | 9 (20%) | 9 (21%)
Infiltration cellular, histiocyte | 1 (2%) | – | 2 (5%) | 4 (9%)
Inflammation, suppurative | – | – | 1 (2%) | –
Plasma cell, hyperplasia | – | – | – | 1 (2%)
Lymph node, mandibular | (35) | (42) | (37) | (39)
Hematopoietic cell proliferation | – | – | 1 (3%) | –
Hyperplasia, lymphoid | 4 (11%) | 1 (2%) | 3 (8%) | 1 (3%)
Infiltration cellular, histiocyte | – | – | 1 (3%) | 1 (3%)
Infiltration cellular, plasma cell | 1 (3%) | – | – | –
Lymph node, mediastinal | (40) | (44) | (45) | (45)
Hyperplasia, lymphoid | 2 (5%) | 4 (9%) | 7 (16%) | 5 (11%)
Hyperplasia, plasma cell | 1 (3%) | 1 (2%) | – | –
Infiltration cellular, histiocyte | 1 (3%) | – | 1 (2%) | 1 (2%)
Pigmentation | – | – | – | 1 (2%)
Lymph node, mesenteric | (49) | (49) | (47) | (48)
Angiectasis | – | 3 (6%) | 2 (4%) | 1 (2%)
Hematopoietic cell proliferation | | | 1 (2%) | 1 (2%)
Hyperplasia, lymphoid | 11 (22%) | 7 (14%) | 12 (26%) | 4 (8%)
Inflammation, chronic active | 1 (2%) | – | – | –
Necrosis | 1 (2%) | 1 (2%) | – | –
Artery, inflammation | – | 1 (2%) | – | –
Spleen | (50) | (49) | (48) | (49)
Angiectasis | 2 (4%) | 1 (2%) | 2 (4%) | 1 (2%)
Hematopoietic cell proliferation | 11 (22%) | 7 (14%) | 11 (23%) | 11 (22%)
Hyperplasia, granulocytic | 1 (2%) | – | 1 (2%) | –
Hyperplasia, lymphoid | 20 (40%) | 26 (53%) | 17 (35%) | 13 (27%)
Inflammation, suppurative | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Necrosis, lymphoid | – | 1 (2%) | – | 1 (2%)
Thymus | (48) | (48) | (47) | (49)
Angiectasis | – | 2 (4%) | – | 3 (6%)
Atrophy | 6 (13%) | 1 (2%) | 7 (15%) | 4 (8%)
Cyst | 1 (2%) | 1 (2%) | 1 (2%) | 5 (10%)
Ectopic parathyroid gland | 2 (4%) | 3 (6%) | 5 (11%) | 5 (10%)
Hyperplasia, lymphoid | 11 (23%) | 15 (31%) | 13 (28%) | 11 (22%)
Necrosis, lymphoid | – | – | – | 1 (2%)
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Dilatation | – | 1 (2%) | – | –
Hyperplasia | 1 (2%) | – | 1 (2%) | 1 (2%)
Inflammation | 1 (2%) | – | – | –
Skin | (50) | (50) | (50) | (50)
Edema | 1 (2%) | – | 1 (2%) | –
Hemorrhage, acute | 1 (2%) | – | – | –
Hyperplasia | – | – | – | 1 (2%)
Inflammation, chronic active | 2 (4%) | 3 (6%) | 2 (4%) | 5 (10%)
Necrosis | – | – | – | 1 (2%)
Ulcer | – | 2 (4%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Fibro-osseous lesion | 6 (12%) | 10 (20%) | 12 (24%) | 9 (18%)
Skeletal muscle | (3) | (4) | (2) | (4)
Degeneration | 1 (33%) | – | – | –
Infiltration cellular, lymphoid | 1 (33%) | – | – | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Compression | 5 (10%) | 1 (2%) | 1 (2%) | 3 (6%)
Demyelination | – | – | 1 (2%) | –
Hemorrhage | 2 (4%) | – | – | –
Hydrocephalus | 1 (2%) | – | – | –
Infiltration cellular | – | 1 (2%) | 3 (6%) | –
Infiltration cellular, lymphocyte | – | 1 (2%) | – | –
Inflammation, chronic active | 3 (6%) | – | – | –
Necrosis, focal | – | 1 (2%) | – | –
Meninges, infiltration cellular | – | – | 1 (2%) | –
Peripheral nerve | (3) | (3) | (1) | (2)
Degeneration | 1 (33%) | – | – | 1 (50%)
Spinal cord | (2) | (3) | (1) | (2)
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Inflammation, chronic active | 44 (88%) | 50 (100%) | 48 (96%) | 47 (94%)
Necrosis | 2 (4%) | – | – | 3 (6%)
Epiglottis, hyperplasia, squamous | 4 (8%) | 3 (6%) | 16 (32%) | 42 (84%)
Epiglottis, metaplasia, squamous | – | 50 (100%) | 50 (100%) | 50 (100%)
Lung | (50) | (50) | (50) | (50)
Fibrosis | – | – | 2 (4%) | 42 (84%)
Hemorrhage | – | 1 (2%) | 2 (4%) | –
Hyperplasia, lymphoid | – | – | – | 1 (2%)
Infiltration cellular, histiocyte | 1 (2%) | 4 (8%) | 15 (30%) | 48 (96%)
Inflammation, chronic | 1 (2%) | 6 (12%) | 26 (52%) | 47 (94%)
Metaplasia, osseous | – | – | – | 1 (2%)
Metaplasia, squamous | – | – | – | 1 (2%)
Mineralization | – | – | 1 (2%) | –
Pigmentation | – | – | – | 1 (2%)
Proteinosis | – | – | 1 (2%) | –
Thrombosis | 1 (2%) | – | – | –
Alveolar/bronchiolar epithelium, hyperplasia | – | 3 (6%) | 8 (16%) | 45 (90%)
Alveolar epithelium, hyperplasia | – | – | 2 (4%) | 43 (86%)
Alveolar epithelium, metaplasia, squamous | – | – | – | 1 (2%)
Interstitium, inflammation, suppurative | 1 (2%) | – | – | –
Mediastinum, necrosis | – | – | 1 (2%) | –
Nose | (50) | (50) | (50) | (50)
Cyst, squamous | – | 1 (2%) | – | –
Exudate | 8 (16%) | 17 (34%) | 48 (96%) | 49 (98%)
Foreign body | – | 1 (2%) | – | –
Inflammation, chronic active | 4 (8%) | 25 (50%) | 49 (98%) | 49 (98%)
Glands, hyperplasia | – | 1 (2%) | – | –
Goblet cell, hyperplasia | – | – | – | 2 (4%)
Lateral wall, inflammation, chronic active | – | 2 (4%) | – | –
Nasolacrimal duct, inflammation, chronic active | 2 (4%) | – | 2 (4%) | –
Nasopharyngeal duct, perforation | – | – | 14 (28%) | 17 (34%)
Olfactory epithelium, accumulation, hyaline droplet | 14 (28%) | 48 (96%) | 50 (100%) | 50 (100%)
Olfactory epithelium, atrophy | 1 (2%) | 2 (4%) | 1 (2%) | 5 (10%)
Olfactory epithelium, metaplasia, respiratory | 2 (4%) | 2 (4%) | 1 (2%) | 4 (8%)
Respiratory epithelium, accumulation, hyaline droplet | 23 (46%) | 50 (100%) | 50 (100%) | 50 (100%)
Respiratory epithelium, atrophy | 1 (2%) | 2 (4%) | 28 (56%) | 39 (78%)
Respiratory epithelium, hyperplasia | 49 (98%) | 44 (88%) | 48 (96%) | 49 (98%)
Respiratory epithelium, metaplasia, squamous | 1 (2%) | 2 (4%) | 2 (4%) | 2 (4%)
Respiratory epithelium, necrosis | – | 2 (4%) | 13 (26%) | 23 (46%)
Turbinate, atrophy | – | – | 10 (20%) | 19 (38%)
Turbinate, perforation | – | – | 6 (12%) | 6 (12%)
Trachea | (49) | (50) | (50) | (49)
Pigmentation | – | – | – | 1 (2%)
Cartilage, metaplasia, osseous | – | – | 2 (4%) | 4 (8%)
Epithelium, degeneration | – | – | – | 2 (4%)
Epithelium, hyperplasia | – | – | 1 (2%) | 5 (10%)
Epithelium, necrosis | – | – | – | 1 (2%)
Special Senses System
Ear | (0) | (0) | (0) | (1)
Eye | (49) | (50) | (50) | (50)
Inflammation, chronic active | – | – | 1 (2%) | 1 (2%)
Cornea, hyperplasia | – | – | 1 (2%) | 1 (2%)
Harderian gland | (50) | (49) | (49) | (49)
Cyst | – | – | 1 (2%) | –
Hyperplasia | 3 (6%) | 2 (4%) | 2 (4%) | 1 (2%)
Hypertrophy | – | 1 (2%) | – | –
Urinary System
Kidney | (49) | (50) | (49) | (50)
Amyloid deposition | – | – | 1 (2%) | –
Angiectasis | – | – | – | 1 (2%)
Cyst | 1 (2%) | – | – | 2 (4%)
Hyperplasia, lymphoid | 2 (4%) | 4 (8%) | – | –
Infarct, chronic | 4 (8%) | 5 (10%) | 5 (10%) | –
Infiltration cellular, lymphoid | 1 (2%) | – | – | –
Inflammation, chronic active | 1 (2%) | 2 (4%) | 1 (2%) | –
Metaplasia, osseous | – | 2 (4%) | 2 (4%) | –
Mineralization | 1 (2%) | – | – | –
Necrosis | 1 (2%) | – | – | –
Nephropathy | 38 (78%) | 28 (56%) | 26 (53%) | 29 (58%)
Pigmentation | – | – | – | 1 (2%)
Glomerulus, inflammation, acute | – | 1 (2%) | – | –
Renal tubule, hyperplasia | 1 (2%) | – | – | –
Urethra | (0) | (1) | (0) | (0)
Inflammation, chronic active | – | 1 (100%) | – | –
Urinary bladder | (50) | (50) | (50) | (50)
Angiectasis | – | – | 1 (2%) | –
Hyperplasia, lymphoid | 2 (4%) | 3 (6%) | – | 3 (6%)
Inflammation, chronic active | 2 (4%) | – | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.