# Appendix C Summary of Lesions in Male Mice in the Two-year Inhalation Study of TRIM VX

Table C-1 Summary of the Incidence of Neoplasms in Male Mice in the Two-year Inhalation Study of TRIM VX^a^

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths | – | – | – | –
Accidental death | – | – | 1 | –
Mo ribund | 4 | 9 | 6 | 5
Natural deaths | 8 | 2 | 6 | 8
Survivors | – | – | – | –
Died last week of study | – | – | 1 | –
Terminal kill | 38 | 39 | 36 | 37
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Gallbladder | (43) | (46) | (39) | (42)
Intestine large, cecum | (45) | (49) | (47) | (46)
Intestine large, colon | (48) | (50) | (48) | (48)
Intestine large, rectum | (46) | (48) | (46) | (45)
Intestine small, duodenum | (44) | (48) | (45) | (44)
Adenoma | 2 (5%) | – | – | –
Intestine small, ileum | (45) | (49) | (46) | (43)
Intestine small, jejunum | (45) | (48) | (45) | (44)
Liver | (50) | (50) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | 1 (2%) | – | – | –
Fibrous histiocytoma | – | – | – | 1 (2%)
Hemangiosarcoma, multiple | – | – | 1 (2%) | –
Hepatoblastoma | – | – | 4 (8%) | 2 (4%)
Hepatocellular adenoma | 13 (26%) | 11 (22%) | 12 (24%) | 12 (24%)
Hepatocellular adenoma, multiple | 10 (20%) | 18 (36%) | 14 (28%) | 24 (48%)
Hepatocellular carcinoma | 10 (20%) | 13 (26%) | 11 (22%) | 8 (16%)
Hepatocellular carcinoma, multiple | 11 (22%) | 5 (10%) | 3 (6%) | 13 (26%)
Hepatocholangiocarcinoma | – | – | 1 (2%) | –
Sarcoma, metastatic, mesentery | – | – | 1 (2%) | –
Mesentery | (5) | (7) | (4) | (2)
Hemangiosarcoma | – | 1 (14%) | 1 (25%) | –
Hepatocellular carcinoma, metastatic, liver | – | 2 (29%) | – | –
Sarcoma | – | – | 1 (25%) | –
Pancreas | (50) | (50) | (49) | (50)
Fibrous histiocytoma | – | – | – | 1 (2%)
Hepatocellular carcinoma, metastatic, liver | – | 1 (2%) | – | –
Salivary glands | (50) | (50) | (49) | (50)
Stomach, forestomach | (50) | (50) | (49) | (50)
Mast cell tumor malignant, metastatic, bone marrow | 1 (2%) | – | – | –
Squamous cell papilloma | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Stomach, glandular | (48) | (50) | (49) | (50)
Sarcoma, metastatic, mesentery | – | – | 1 (2%) | –
Tooth | (5) | (10) | (8) | (5)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Heart | (50) | (50) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | 3 (6%) | –
Endocardium, Schwannoma benign | – | 1 (2%) | – | –
Endocrine System
Adrenal cortex | (50) | (50) | (49) | (49)
Adenoma | 2 (4%) | 1 (2%) | 1 (2%) | 1 (2%)
Adenoma, multiple | 1 (2%) | – | – | –
Mast cell tumor malignant, metastatic, bone marrow | 1 (2%) | – | – | –
Subcapsular, adenoma | – | 3 (6%) | 1 (2%) | 6 (12%)
Adrenal medulla | (50) | (50) | (48) | (49)
Islets, pancreatic | (50) | (50) | (48) | (50)
Parathyroid gland | (28) | (28) | (36) | (34)
Carcinoma | – | – | – | 1 (3%)
Pituitary gland | (50) | (49) | (48) | (48)
Pars distalis, adenoma | 1 (2%) | – | – | –
Thyroid gland | (50) | (49) | (47) | (49)
General Body System
None
Genital System
Epididymis | (50) | (50) | (49) | (50)
Preputial gland | (49) | (50) | (48) | (49)
Prostate | (50) | (49) | (50) | (50)
Seminal vesicle | (50) | (50) | (50) | (50)
Testes | (50) | (50) | (49) | (50)
Interstitial cell, adenoma | – | 1 (2%) | – | –
Hematopoietic System
Bone marrow | (50) | (50) | (49) | (50)
Mast cell tumor malignant | 1 (2%) | – | – | –
Schwannoma malignant, metastatic, peripheral nerve | – | – | 1 (2%) | –
Lymph node | (3) | (0) | (3) | (1)
Pancreatic, sarcoma, metastatic, mesentery | – | – | 1 (33%) | –
Renal, fibrous histiocytoma | – | – | – | 1 (100%)
Renal, sarcoma, metastatic, mesentery | – | – | 1 (33%) | –
Lymph node, bronchial | (38) | (37) | (39) | (39)
Alveolar/bronchiolar carcinoma, metastatic, lung | 1 (3%) | – | 2 (5%) | –
Hepatoblastoma, metastatic, liver | – | – | – | 1 (3%)
Hepatocellular carcinoma, metastatic, liver | 1 (3%) | – | – | 1 (3%)
Lymph node, mandibular | (20) | (27) | (25) | (27)
Lymph node, mediastinal | (35) | (35) | (41) | (40)
Alveolar/bronchiolar carcinoma, metastatic, lung | 1 (3%) | – | 1 (2%) | –
Hepatoblastoma, metastatic, liver | – | – | – | 1 (3%)
Mast cell tumor malignant, metastatic, bone marrow | 1 (3%) | – | – | –
Lymph node, mesenteric | (48) | (49) | (47) | (48)
Fibrous histiocytoma | – | – | – | 1 (2%)
Hemangioma | – | – | 1 (2%) | 1 (2%)
Hemangiosarcoma | – | – | – | 2 (4%)
Hepatoblastoma, metastatic, liver | – | – | – | 1 (2%)
Sarcoma, metastatic, mesentery | – | – | 1 (2%) | –
Spleen | (49) | (50) | (49) | (50)
Thymus | (44) | (44) | (47) | (46)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | 2 (4%) | 1 (2%)
Hepatocellular carcinoma, metastatic, liver | 1 (2%) | – | – | –
Mast cell tumor malignant, metastatic, bone marrow | 1 (2%) | – | – | –
Integumentary System
Mammary gland | (3) | (3) | (0) | (0)
Skin | (50) | (50) | (50) | (50)
Fibrosarcoma | 1 (2%) | – | – | –
Fibrous histiocytoma | – | – | – | 1 (2%)
Subcutaneous tissue, hemangiosarcoma | – | – | 1 (2%) | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Osteoma | – | 1 (2%) | – | –
Skeletal muscle | (0) | (1) | (2) | (1)
Sarcoma, metastatic, mesentery | – | – | 1 (50%) | –
Schwannoma malignant, metastatic, peripheral nerve | – | – | 1 (50%) | –
Nervous System
Brain | (50) | (50) | (49) | (50)
Peripheral nerve | (0) | (1) | (1) | (2)
Schwannoma malignant | – | – | 1 (100%) | –
Spinal cord | (0) | (1) | (1) | (2)
Respiratory System
Larynx | (48) | (49) | (49) | (49)
Lung | (50) | (50) | (49) | (50)
Alveolar/bronchiolar adenoma | 5 (10%) | 7 (14%) | 5 (10%) | 6 (12%)
Alveolar/bronchiolar adenoma, multiple | 1 (2%) | 1 (2%) | – | 3 (6%)
Alveolar/bronchiolar carcinoma | 8 (16%) | 8 (16%) | 7 (14%) | 9 (18%)
Alveolar/bronchiolar carcinoma, multiple | 2 (4%) | – | 2 (4%) | 8 (16%)
Carcinoma, metastatic, Harderian gland | – | – | – | 1 (2%)
Hepatoblastoma, metastatic, liver | – | – | 1 (2%) | 1 (2%)
Hepatocellular carcinoma, metastatic, liver | 8 (16%) | 5 (10%) | 4 (8%) | 6 (12%)
Hepatocholangiocarcinoma, metastatic, liver | – | – | 1 (2%) | –
Schwannoma malignant, metastatic, peripheral nerve | – | – | 1 (2%) | –
Bronchiole, epithelium, adenoma | – | – | 1 (2%) | –
Mediastinum, hepatocellular carcinoma, metastatic, liver | – | 1 (2%) | – | –
Nose | (49) | (50) | (49) | (50)
Carcinoma, metastatic, Harderian gland | – | – | – | 1 (2%)
Pleura | (0) | (1) | (0) | (1)
Trachea | (46) | (50) | (47) | (48)
Special Senses System
Eye | (50) | (50) | (49) | (49)
Carcinoma, metastatic, Harderian gland | – | – | – | 1 (2%)
Harderian gland | (50) | (50) | (49) | (50)
Adenoma | 4 (8%) | 5 (10%) | 3 (6%) | 6 (12%)
Adenoma, multiple | – | – | – | 1 (2%)
Carcinoma | 2 (4%) | 3 (6%) | 2 (4%) | 1 (2%)
Urinary System
Kidney | (50) | (50) | (49) | (50)
Hepatoblastoma, metastatic, liver | | | | 1 (2%)
Mast cell tumor malignant, metastatic, bone marrow | 1 (2%) | – | – | –
Urethra | (0) | (0) | (1) | (0)
Urinary bladder | (50) | (50) | (49) | (50)
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | – | 1 (2%) | 1 (2%) | 1 (2%)
Lymphoma malignant | 6 (12%) | 2 (4%) | 3 (6%) | 2 (4%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 42 | 42 | 42 | 48
Total primary neoplasms | 81 | 83 | 78 | 113
Total animals with benign neoplasms | 32 | 34 | 31 | 41
Total benign neoplasms | 40 | 50 | 39 | 61
Total animals with malignant neoplasms | 32 | 32 | 30 | 36
Total malignant neoplasms | 41 | 33 | 39 | 52
Total animals with metastatic neoplasms | 10 | 7 | 11 | 9
Total metastatic neoplasms | 18 | 9 | 25 | 16

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table C-2 Statistical Analysis of Primary Neoplasms in Male Mice in the Two-year Inhalation Study of TRIM VX

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Adrenal Cortex: Adenoma
Overall rate^a^ | 3/50 (6%) | 4/50 (8%) | 2/49 (4%) | 7/49 (14%)
Adjusted rate^b^ | 6.8% | 8.8% | 4.6% | 15.7%
Terminal rate^c^ | 3/38 (8%) | 4/39 (10%) | 2/37 (5%) | 7/37 (19%)
First incidence (days) | 729 (T) | 729 (T) | 729 (T) | 729 (T)
Poly-3 test^d^ | P = 0.084 | P = 0.511 | P = 0.506N | P = 0.158
Harderian Gland: Adenoma
Overall rate | 4/50 (8%) | 5/50 (10%) | 3/50 (6%) | 7/50 (14%)
Adjusted rate | 8.8% | 11.0% | 6.7% | 15.4%
Terminal rate | 3/38 (8%) | 4/39 (10%) | 2/37 (5%) | 7/37 (19%)
First incidence (days) | 414 | 656 | 647 | 729 (T)
Poly-3 test | P = 0.195 | P = 0.505 | P = 0.503N | P = 0.263
Harderian Gland: Carcinoma
Overall rate | 2/50 (4%) | 3/50 (6%) | 2/50 (4%) | 1/50 (2%)
Adjusted rate | 4.5% | 6.6% | 4.5% | 2.2%
Terminal rate | 2/38 (5%) | 3/39 (8%) | 2/37 (5%) | 1/37 (3%)
First incidence (days) | 729 (T) | 729 (T) | 729 (T) | 729 (T)
Poly-3 test | P = 0.298N | P = 0.509 | P = 0.692N | P = 0.492N
Harderian Gland: Adenoma or Carcinoma
Overall rate | 6/50 (12%) | 8/50 (16%) | 5/50 (10%) | 8/50 (16%)
Adjusted rate | 13.3% | 17.5% | 11.1% | 17.6%
Terminal rate | 5/38 (13%) | 7/39 (18%) | 4/37 (11%) | 8/37 (22%)
First incidence (days) | 414 | 656 | 647 | 729 (T)
Poly-3 test | P = 0.398 | P = 0.392 | P = 0.504N | P = 0.389
Liver: Hepatocellular Adenoma
Overall rate | 23/50 (46%) | 29/50 (58%) | 26/50 (52%) | 36/50 (72%)
Adjusted rate | 50.7% | 62.7% | 56.2% | 74.8%
Terminal rate | 20/38 (53%) | 26/39 (67%) | 22/37 (60%) | 26/37 (70%)
First incidence (days) | 618 | 628 | 344 | 537
Poly-3 test | P = 0.014 | P = 0.166 | P = 0.373 | P = 0.011
Liver: Hepatocellular Carcinoma
Overall rate | 21/50 (42%) | 18/50 (36%) | 14/50 (28%) | 21/50 (42%)
Adjusted rate | 43.3% | 38.2% | 30.5% | 42.9%
Terminal rate | 12/38 (32%) | 13/39 (33%) | 9/37 (24%) | 11/37 (30%)
First incidence (days) | 414 | 550 | 583 | 424
Poly-3 test | P = 0.436 | P = 0.382N | P = 0.139N | P = 0.563N
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 34/50 (68%) | 35/50 (70%) | 33/50 (66%) | 41/50 (82%)
Adjusted rate | 69.6% | 73.8% | 70.3% | 82.0%
Terminal rate | 24/38 (63%) | 29/39 (74%) | 26/37 (70%) | 28/37 (76%)
First incidence (days) | 414 | 550 | 344 | 424
Poly-3 test | P = 0.092 | P = 0.407 | P = 0.561 | P = 0.113
Liver: Hepatoblastoma
Overall rate | 0/50 (0%) | 0/50 (0%) | 4/50 (8%) | 2/50 (4%)
Adjusted rate | 0.0% | 0.0% | 8.8% | 4.4%
Terminal rate | 0/38 (0%) | 0/39 (0%) | 3/37 (8%) | 1/37 (3%)
First incidence (days) | –^e^ | – | 549 | 571
Poly-3 test | P = 0.216 | –^f^ | P = 0.063 | P = 0.245
Liver: Hepatocellular Carcinoma or Hepatoblastoma
Overall rate | 21/50 (42%) | 18/50 (36%) | 18/50 (36%) | 23/50 (46%)
Adjusted rate | 43.3% | 38.2% | 38.7% | 46.5%
Terminal rate | 12/38 (32%) | 13/39 (33%) | 12/37 (32%) | 12/37 (32%)
First incidence (days) | 414 | 550 | 549 | 424
Poly-3 test | P = 0.302 | P = 0.382N | P = 0.402N | P = 0.457
Liver: Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma
Overall rate | 34/50 (68%) | 35/50 (70%) | 35/50 (70%) | 41/50 (82%)
Adjusted rate | 69.6% | 73.8% | 73.6% | 82.0%
Terminal rate | 24/38 (63%) | 29/39 (74%) | 27/37 (73%) | 28/37 (76%)
First incidence (days) | 414 | 550 | 344 | 424
Poly-3 test | P = 0.097 | P = 0.407 | P = 0.415 | P = 0.113
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 6/50 (12%) | 8/50 (16%) | 5/49 (10%) | 9/50 (18%)
Adjusted rate | 13.1% | 17.5% | 11.3% | 19.6%
Terminal rate | 2/38 (5%) | 7/39 (18%) | 4/37 (11%) | 8/37 (22%)
First incidence (days) | 549 | 656 | 533 | 571
Poly-3 test | P = 0.279 | P = 0.382 | P = 0.522N | P = 0.287
Lung: Alveolar/bronchiolar Carcinoma
Overall rate | 10/50 (20%) | 8/50 (16%) | 9/49 (18%) | 17/50 (34%)
Adjusted rate | 22.1% | 17.7% | 20.2% | 36.5%
Terminal rate | 7/38 (18%) | 8/39 (21%) | 7/37 (19%) | 12/37 (32%)
First incidence (days) | 549 | 729 (T) | 533 | 571
Poly-3 test | P = 0.021 | P = 0.394N | P = 0.516N | P = 0.097
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 14/50 (28%) | 14/50 (28%) | 11/49 (22%) | 23/50 (46%)
Adjusted rate | 30.5% | 30.7% | 24.7% | 49.4%
Terminal rate | 9/38 (24%) | 13/39 (33%) | 9/37 (24%) | 18/37 (49%)
First incidence (days) | 549 | 656 | 533 | 571
Poly-3 test | P = 0.013 | P = 0.581 | P = 0.352N | P = 0.047
All Organs: Hemangiosarcoma
Overall rate | 0/50 (0%) | 1/50 (2%) | 3/50 (6%) | 2/50 (4%)
Adjusted rate | 0.0% | 2.2% | 6.7% | 4.4%
Terminal rate | 0/38 (0%) | 0/39 (0%) | 3/37 (8%) | 2/37 (5%)
First incidence (days) | – | 644 | 729 (T) | 729 (T)
Poly-3 test | P = 0.282 | P = 0.505 | P = 0.120 | P = 0.242
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 0/50 (0%) | 1/50 (2%) | 4/50 (8%) | 3/50 (6%)
Adjusted rate | 0.0% | 2.2% | 9.0% | 6.6%
Terminal rate | 0/38 (0%) | 0/39 (0%) | 4/37 (11%) | 3/37 (8%)
First incidence (days) | – | 644 | 729 (T) | 729 (T)
Poly-3 test | P = 0.144 | P = 0.505 | P = 0.061 | P = 0.123
All Organs: Malignant Lymphoma
Overall rate | 6/50 (12%) | 2/50 (4%) | 3/50 (6%) | 2/50 (4%)
Adjusted rate | 13.4% | 4.3% | 6.6% | 4.4%
Terminal rate | 5/38 (13%) | 1/39 (3%) | 2/37 (5%) | 2/37 (5%)
First incidence (days) | 619 | 481 | 549 | 729 (T)
Poly-3 test | P = 0.211N | P = 0.124N | P = 0.237N | P = 0.128N
All Organs: Benign Neoplasms
Overall rate | 32/50 (64%) | 34/50 (68%) | 31/50 (62%) | 41/50 (82%)
Adjusted rate | 68.0% | 72.5% | 65.7% | 85.2%
Terminal rate | 26/38 (68%) | 29/39 (74%) | 25/37 (68%) | 31/37 (84%)
First incidence (days) | 414 | 621 | 344 | 537
Poly-3 test | P = 0.025 | P = 0.399 | P = 0.494N | P = 0.034
All Organs: Malignant Neoplasms
Overall rate | 32/50 (64%) | 32/50 (64%) | 30/50 (60%) | 36/50 (72%)
Adjusted rate | 65.5% | 66.1% | 62.7% | 72.5%
Terminal rate | 22/38 (58%) | 24/39 (62%) | 21/37 (57%) | 24/37 (65%)
First incidence (days) | 414 | 481 | 533 | 424
Poly-3 test | P = 0.233 | P = 0.560 | P = 0.470N | P = 0.300
All Organs: Benign or Malignant Neoplasms
Overall rate | 42/50 (84%) | 42/50 (84%) | 42/50 (84%) | 48/50 (96%)
Adjusted rate | 86.0% | 86.1% | 85.9% | 96.0%
Terminal rate | 32/38 (84%) | 33/39 (85%) | 31/37 (84%) | 35/37 (95%)
First incidence (days) | 414 | 481 | 344 | 424
Poly-3 test | P = 0.047 | P = 0.610 | P = 0.612N | P = 0.077

(T)Terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal cortex, liver, and lung; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table C-3 Historical Incidence of Lung Neoplasms in Control Male B6C3F1/N Mice^a^

Study (Study Start) | Alveolar/bronchiolar Adenoma | Alveolar/bronchiolar Carcinoma | Alveolar/bronchiolar Adenoma or Carcinoma | Bronchiole Epithelium Adenoma
Historical Incidence: Inhalation Studies
Antimony trioxide (October 2008) | 10/50 | 4/50 | 13/50 | 0/50
Cobalt metal (May 2006) | 7/50 | 11/50 | 16/50 | 0/50
CIMSTAR 3800 (May 2008) | 5/50 | 8/50 | 13/50 | 0/50
TRIM VX (August 2009) | 6/50 | 10/50 | 14/50 | 0/50
Vinylidene chloride (June 2005) | 7/50 | 9/50 | 13/50 | 0/50
Total (%) | 35/250 (14.0%) | 42/250 (16.8%) | 69/250 (27.6%) | 0/250
Mean ± standard deviation | 14.0% ± 3.7% | 16.8% ± 5.4% | 27.6% ± 2.6% | –
Range | 10%–20% | 8%–22% | 26%–32% | –
Overall Historical Incidence: All Routes
Total (%) | 83/550 (15.1%) | 75/550 (13.6%) | 147/550 (26.7%) | 0/550
Mean ± standard deviation | 15.1% ± 5.9% | 13.6% ± 6.4% | 26.7% ± 6.5% | –
Range | 8%–26% | 4%–22% | 16%–38% | –

^a^ Data as of July 2015.

Table C-4 Summary of the Incidence of Nonneoplastic Lesions in Male Mice in the Two-year Inhalation Study of TRIM VX^a^

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths | – | – | – | –
Accidental death | – | – | 1 | –
Moribund | 4 | 9 | 6 | 5
Natural deaths | 8 | 2 | 6 | 8
Survivors | – | – | – | –
Died last week of study | – | – | 1 | –
Terminal kill | 38 | 39 | 36 | 37
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Gallbladder | (43) | (46) | (39) | (42)
Infiltration cellular, lymphoid | – | – | 1 (3%) | –
Inflammation, chronic active | 1 (2%) | 1 (2%) | 1 (3%) | 1 (2%)
Vacuolization cytoplasmic | – | 1 (2%) | – | 2 (5%)
Epithelium, hyperplasia | – | – | – | 1 (2%)
Intestine large, cecum | (45) | (49) | (47) | (46)
Hemorrhage | 1 (2%) | – | – | –
Hyperplasia | 1 (2%) | – | – | –
Hyperplasia, lymphoid | 2 (4%) | – | – | 3 (7%)
Infiltration cellular, lymphoid | – | – | 1 (2%) | –
Inflammation | 2 (4%) | 2 (4%) | 3 (6%) | 1 (2%)
Necrosis | 1 (2%) | – | 1 (2%) | –
Intestine large, colon | (48) | (50) | (48) | (48)
Hyperplasia, lymphoid | – | – | 1 (2%) | –
Intestine large, rectum | (46) | (48) | (46) | (45)
Inflammation | – | 1 (2%) | – | –
Intestine small, duodenum | (44) | (48) | (45) | (44)
Inflammation | – | – | – | 1 (2%)
Intestine small, ileum | (45) | (49) | (46) | (43)
Cyst | – | 1 (2%) | – | –
Hyperplasia, lymphoid | 8 (18%) | 9 (18%) | 11 (24%) | 11 (26%)
Inflammation | – | 1 (2%) | 1 (2%) | –
Intestine small, jejunum | (45) | (48) | (45) | (44)
Hyperplasia, lymphoid | 1 (2%) | 1 (2%) | 3 (7%) | 2 (5%)
Inflammation | – | – | 1 (2%) | –
Necrosis | – | – | 1 (2%) | –
Perforation | – | – | 1 (2%) | –
Liver | (50) | (50) | (50) | (50)
Angiectasis | 1 (2%) | – | – | –
Basophilic focus | 11 (22%) | 9 (18%) | 3 (6%) | 4 (8%)
Clear cell focus | 14 (28%) | 11 (22%) | 9 (18%) | 13 (26%)
Congestion | 1 (2%) | – | – | –
Eosinophilic focus | 8 (16%) | 12 (24%) | 17 (34%) | 7 (14%)
Fatty change | – | – | – | 1 (2%)
Fibrosis | – | – | 1 (2%) | –
Hemorrhage | 1 (2%) | – | – | –
Inflammation, chronic active | – | – | 2 (4%) | 1 (2%)
Mixed cell focus | 3 (6%) | 3 (6%) | 6 (12%) | 5 (10%)
Necrosis | – | – | – | 1 (2%)
Tension lipidosis | 1 (2%) | 3 (6%) | 3 (6%) | –
Thrombosis | – | – | – | 1 (2%)
Bile duct, vacuolization cytoplasmic | – | – | – | 1 (2%)
Centrilobular, hepatocyte, fatty change | – | 2 (4%) | – | –
Centrilobular, hepatocyte, necrosis | 2 (4%) | – | – | –
Hepatocyte, hypertrophy | 1 (2%) | 1 (2%) | – | 1 (2%)
Hepatocyte, necrosis | 3 (6%) | 7 (14%) | 5 (10%) | 5 (10%)
Hepatocyte, vacuolization cytoplasmic | 1 (2%) | – | – | –
Periportal, fatty change | – | – | 1 (2%) | –
Serosa, fibrosis | – | – | 1 (2%) | –
Mesentery | (5) | (7) | (4) | (2)
Fat, necrosis | 4 (80%) | 4 (57%) | 1 (25%) | 2 (100%)
Pancreas | (50) | (50) | (49) | (50)
Atrophy | – | – | 1 (2%) | –
Cyst | – | – | – | 1 (2%)
Hemorrhage, acute | – | 1 (2%) | – | –
Hypertrophy | 2 (4%) | – | – | –
Inflammation, chronic active | – | 3 (6%) | – | –
Acinus, atrophy | – | – | – | 1 (2%)
Duct, hyperplasia | – | 1 (2%) | – | –
Salivary glands | (50) | (50) | (49) | (50)
Stomach, forestomach | (50) | (50) | (49) | (50)
Abscess | – | – | – | 1 (2%)
Cyst, squamous | – | – | – | 1 (2%)
Hyperplasia | – | 1 (2%) | 5 (10%) | 1 (2%)
Infiltration cellular, lymphoid | – | 1 (2%) | – | –
Inflammation, chronic active | 1 (2%) | 3 (6%) | 3 (6%) | 5 (10%)
Necrosis | – | 1 (2%) | 1 (2%) | –
Stomach, glandular | (48) | (50) | (49) | (50)
Cyst, squamous | 1 (2%) | – | – | –
Infiltration cellular, lymphoid | – | – | 1 (2%) | –
Inflammation, chronic active | 1 (2%) | 4 (8%) | 2 (4%) | 4 (8%)
Mineralization | 1 (2%) | 1 (2%) | 2 (4%) | –
Tooth | (5) | (10) | (8) | (5)
Dysplasia | 4 (80%) | 9 (90%) | 7 (88%) | 3 (60%)
Inflammation, suppurative, chronic active | – | 2 (20%) | – | –
Inflammation, suppurative | – | – | 1 (13%) | 2 (40%)
Malformation | 1 (20%) | – | – | –
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 19 (38%) | 17 (34%) | 18 (36%) | 19 (38%)
Inflammation, chronic active | 1 (2%) | 3 (6%) | – | 1 (2%)
Mineralization | 1 (2%) | – | – | –
Atrium, thrombosis | 2 (4%) | – | – | –
Endocrine System
Adrenal cortex | (50) | (50) | (49) | (49)
Accessory adrenal cortical nodule | – | 1 (2%) | 1 (2%) | 1 (2%)
Angiectasis | – | – | 1 (2%) | 2 (4%)
Hyperplasia | 3 (6%) | 2 (4%) | 1 (2%) | 1 (2%)
Hypertrophy | 21 (42%) | 30 (60%) | 26 (53%) | 18 (37%)
Subcapsular, hyperplasia | – | 1 (2%) | – | –
Subcapsular, hypertrophy | – | 1 (2%) | – | –
Adrenal medulla | (50) | (50) | (48) | (49)
Angiectasis | 1 (2%) | 2 (4%) | – | 1 (2%)
Hyperplasia | 6 (12%) | 5 (10%) | 5 (10%) | 5 (10%)
Hypertrophy | 1 (2%) | – | – | 1 (2%)
Islets, pancreatic | (50) | (50) | (48) | (50)
Hyperplasia | – | 2 (4%) | – | –
Hypertrophy | – | – | 1 (2%) | –
Parathyroid gland | (28) | (28) | (36) | (34)
Cyst | – | 1 (4%) | – | 1 (3%)
Pituitary gland | (50) | (49) | (48) | (48)
Pars distalis, angiectasis | – | – | 1 (2%) | 1 (2%)
Pars distalis, cyst | 4 (8%) | 1 (2%) | 3 (6%) | 6 (13%)
Pars distalis, hyperplasia | 3 (6%) | 3 (6%) | 2 (4%) | 3 (6%)
Pars intermedia, cyst | 1 (2%) | – | – | –
Thyroid gland | (50) | (49) | (47) | (49)
General Body System
None
Genital System
Epididymis | (50) | (50) | (49) | (50)
Exfoliated germ cell | 39 (78%) | 40 (80%) | 44 (90%) | 40 (80%)
Infiltration cellular, lymphoid | – | – | – | 1 (2%)
Inflammation, chronic active | 1 (2%) | 3 (6%) | 1 (2%) | 1 (2%)
Preputial gland | (49) | (50) | (48) | (49)
Ectasia | 4 (8%) | 3 (6%) | 3 (6%) | 4 (8%)
Inflammation, chronic active | 9 (18%) | 14 (28%) | 12 (25%) | 12 (24%)
Necrosis | – | – | 1 (2%) | –
Duct, ectasia | – | 2 (4%) | – | –
Prostate | (50) | (49) | (50) | (50)
Hyperplasia | – | – | 3 (6%) | –
Infiltration cellular, lymphoid | 1 (2%) | 1 (2%) | 1 (2%) | 2 (4%)
Inflammation | 2 (4%) | 1 (2%) | 1 (2%) | –
Arteriole, inflammation, chronic active | 1 (2%) | – | – | –
Seminal vesicle | (50) | (50) | (50) | (50)
Dilatation | – | – | – | 1 (2%)
Infiltration cellular, lymphoid | 1 (2%) | 1 (2%) | 1 (2%) | –
Inflammation | 1 (2%) | 2 (4%) | 1 (2%) | –
Testes | (50) | (50) | (49) | (50)
Degeneration | 9 (18%) | 17 (34%) | 15 (31%) | 9 (18%)
Necrosis | – | 1 (2%) | – | –
Hematopoietic System
Bone marrow | (50) | (50) | (49) | (50)
Necrosis | – | 2 (4%) | – | –
Myeloid cell, hyperplasia | 16 (32%) | 29 (58%) | 18 (37%) | 29 (58%)
Lymph node | (3) | (0) | (3) | (1)
Lumbar, hyperplasia, lymphoid | – | – | 1 (33%) | –
Pancreatic, hyperplasia, lymphoid | 1 (33%) | – | – | –
Lymph node, bronchial | (38) | (37) | (39) | (39)
Hematopoietic cell proliferation | – | 1 (3%) | – | –
Hyperplasia, lymphoid | 3 (8%) | 3 (8%) | 2 (5%) | 14 (36%)
Infiltration cellular, histiocyte | – | 1 (3%) | – | 7 (18%)
Infiltration cellular, plasma cell | – | – | – | 1 (3%)
Plasma cell, hyperplasia | – | – | 1 (3%) | –
Lymph node, mandibular | (20) | (27) | (25) | (27)
Hematopoietic cell proliferation | 1 (5%) | – | – | –
Hyperplasia, lymphoid | 3 (15%) | 3 (11%) | 2 (8%) | 1 (4%)
Infiltration cellular, histiocyte | 1 (5%) | 1 (4%) | 1 (4%) | 1 (4%)
Lymph node, mediastinal | (35) | (35) | (41) | (40)
Hematopoietic cell proliferation | – | – | 1 (2%) | –
Hyperplasia, lymphoid | 3 (9%) | 2 (6%) | 1 (2%) | 5 (13%)
Lymph node, mesenteric | (48) | (49) | (47) | (48)
Angiectasis | 1 (2%) | – | 3 (6%) | –
Congestion | 1 (2%) | – | – | –
Hematopoietic cell proliferation | – | 3 (6%) | 4 (9%) | 1 (2%)
Hyperplasia, lymphoid | 15 (31%) | 11 (22%) | 9 (19%) | 6 (13%)
Hyperplasia, plasma cell | 1 (2%) | – | 1 (2%) | –
Infiltration cellular | – | 1 (2%) | – | –
Inflammation, chronic active | – | 1 (2%) | 1 (2%) | 1 (2%)
Spleen | (49) | (50) | (49) | (50)
Angiectasis | – | 1 (2%) | – | –
Hematopoietic cell proliferation | 11 (22%) | 8 (16%) | 11 (22%) | 10 (20%)
Hyperplasia, lymphoid | 13 (27%) | 15 (30%) | 9 (18%) | 8 (16%)
Necrosis, lymphoid | – | 1 (2%) | – | –
Thymus | (44) | (44) | (47) | (46)
Atrophy | 5 (11%) | 5 (11%) | 8 (17%) | 9 (20%)
Cyst | 1 (2%) | 3 (7%) | 5 (11%) | 5 (11%)
Ectopic parathyroid gland | 1 (2%) | 2 (5%) | 3 (6%) | –
Ectopic thyroid | – | – | – | 1 (2%)
Hyperplasia, lymphoid | 1 (2%) | 5 (11%) | – | 4 (9%)
Epithelial cell, hyperplasia | 1 (2%) | – | – | –
Integumentary System
Mammary gland | (3) | (3) | (0) | (0)
Skin | (50) | (50) | (50) | (50)
Cyst epithelial inclusion | – | 1 (2%) | – | 4 (8%)
Fibrosis | – | – | 1 (2%) | –
Hyperkeratosis | – | – | – | 1 (2%)
Hyperplasia | 3 (6%) | 2 (4%) | – | 3 (6%)
Inflammation, chronic active | 10 (20%) | 6 (12%) | 8 (16%) | 11 (22%)
Metaplasia, osseous | – | – | 1 (2%) | –
Necrosis | 1 (2%) | 3 (6%) | 1 (2%) | –
Ulcer | 3 (6%) | 2 (4%) | 3 (6%) | 3 (6%)
Hair follicle, atrophy | – | – | 1 (2%) | –
Subcutaneous tissue, inflammation, chronic active | – | 1 (2%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Fibro-osseous lesion | 1 (2%) | 3 (6%) | 1 (2%) | –
Hyperostosis | 1 (2%) | 1 (2%) | – | –
Skeletal muscle | (0) | (1) | (2) | (1)
Degeneration | – | 1 (100%) | – | 1 (100%)
Nervous System
Brain | (50) | (50) | (49) | (50)
Compression | – | – | 1 (2%) | –
Gliosis | – | – | – | 1 (2%)
Infiltration cellular | 1 (2%) | 2 (4%) | 1 (2%) | –
Inflammation, chronic active | 2 (4%) | 1 (2%) | 1 (2%) | 1 (2%)
Peripheral nerve | (0) | (1) | (1) | (2)
Degeneration | – | 1 (100%) | – | 1 (50%)
Spinal cord | (0) | (1) | (1) | (2)
Respiratory System
Larynx | (48) | (49) | (49) | (49)
Foreign body | – | 1 (2%) | – | –
Inflammation, chronic active | 45 (94%) | 47 (96%) | 46 (94%) | 48 (98%)
Mineralization | – | – | 1 (2%) | –
Necrosis | – | 1 (2%) | 1 (2%) | –
Epiglottis, hyperplasia, squamous | 1 (2%) | 2 (4%) | 14 (29%) | 30 (61%)
Epiglottis, metaplasia, squamous | – | 49 (100%) | 49 (100%) | 49 (100%)
Squamous epithelium, hyperplasia | 1 (2%) | – | – | –
Lung | (50) | (50) | (49) | (50)
Fibrosis | – | 2 (4%) | 5 (10%) | 45 (90%)
Hemorrhage | – | 1 (2%) | 1 (2%) | –
Infiltration cellular, histiocyte | 5 (10%) | 9 (18%) | 15 (31%) | 49 (98%)
Inflammation, chronic | 5 (10%) | 12 (24%) | 16 (33%) | 50 (100%)
Metaplasia, osseous | – | – | – | 1 (2%)
Pigmentation | 2 (4%) | 2 (4%) | 2 (4%) | 8 (16%)
Proteinosis | – | – | 1 (2%) | –
Thrombosis | – | 1 (2%) | 2 (4%) | –
Alveolar/bronchiolar epithelium, hyperplasia | 3 (6%) | 7 (14%) | 15 (31%) | 50 (100%)
Alveolar epithelium, hyperplasia | 3 (6%) | 3 (6%) | 7 (14%) | 47 (94%)
Bronchiole, metaplasia, squamous | – | – | – | 1 (2%)
Nose | (49) | (50) | (49) | (50)
Exudate | 2 (4%) | 11 (22%) | 35 (71%) | 49 (98%)
Inflammation, suppurative | 1 (2%) | – | – | –
Inflammation, chronic | – | – | 1 (2%) | –
Inflammation, chronic active | 3 (6%) | 33 (66%) | 39 (80%) | 50 (100%)
Polyp, inflammatory | – | – | 1 (2%) | –
Glands, olfactory epithelium, hyperplasia | – | – | – | 1 (2%)
Lateral wall, inflammation, chronic active | 2 (4%) | 7 (14%) | 4 (8%) | 5 (10%)
Lateral wall, necrosis | – | 1 (2%) | – | –
Nasolacrimal duct, abscess | 1 (2%) | – | – | –
Nasolacrimal duct, inflammation, chronic active | 3 (6%) | 2 (4%) | 2 (4%) | 2 (4%)
Nasopharyngeal duct, hyperplasia | – | 1 (2%) | – | –
Nasopharyngeal duct, inflammation, chronic active | – | 1 (2%) | – | –
Nasopharyngeal duct, perforation | – | 1 (2%) | 11 (22%) | 19 (38%)
Olfactory epithelium, accumulation, hyaline droplet | 2 (4%) | 46 (92%) | 48 (98%) | 50 (100%)
Olfactory epithelium, atrophy | – | 1 (2%) | – | 4 (8%)
Olfactory epithelium, metaplasia, respiratory | 3 (6%) | 2 (4%) | 3 (6%) | 5 (10%)
Respiratory epithelium, accumulation, hyaline droplet | 7 (14%) | 49 (98%) | 49 (100%) | 50 (100%)
Respiratory epithelium, atrophy | – | 1 (2%) | 20 (41%) | 40 (80%)
Respiratory epithelium, hyperplasia | 41 (84%) | 49 (98%) | 47 (96%) | 48 (96%)
Respiratory epithelium, metaplasia, squamous | 1 (2%) | 2 (4%) | 1 (2%) | 1 (2%)
Respiratory epithelium, necrosis | 2 (4%) | 1 (2%) | 2 (4%) | 23 (46%)
Turbinate, atrophy | – | 2 (4%) | 5 (10%) | 14 (28%)
Turbinate, perforation | – | – | 1 (2%) | 13 (26%)
Pleura | (0) | (1) | (0) | (1)
Trachea | (46) | (50) | (47) | (48)
Cartilage, metaplasia, osseous | 1 (2%) | – | 1 (2%) | 1 (2%)
Epithelium, hyperplasia | – | – | – | 3 (6%)
Special Senses System
Eye | (50) | (50) | (49) | (49)
Cataract | – | – | – | 1 (2%)
Inflammation, chronic active | 1 (2%) | 4 (8%) | 3 (6%) | 3 (6%)
Necrosis | – | – | 1 (2%) | –
Harderian gland | (50) | (50) | (49) | (50)
Hyperplasia | 1 (2%) | 1 (2%) | 3 (6%) | 1 (2%)
Inflammation | – | 1 (2%) | – | –
Urinary System
Kidney | (50) | (50) | (49) | (50)
Angiectasis | – | – | 1 (2%) | –
Cyst | – | – | 1 (2%) | 1 (2%)
Hydronephrosis | – | – | – | 1 (2%)
Hyperplasia, lymphoid | 1 (2%) | 2 (4%) | – | –
Infarct, chronic | 1 (2%) | 2 (4%) | 1 (2%) | 2 (4%)
Inflammation, chronic active | 1 (2%) | 1 (2%) | 2 (4%) | 2 (4%)
Metaplasia, osseous | – | 2 (4%) | 1 (2%) | 1 (2%)
Mineralization | 1 (2%) | 1 (2%) | – | –
Nephropathy | 47 (94%) | 46 (92%) | 45 (92%) | 49 (98%)
Artery, inflammation, chronic active | – | – | 1 (2%) | –
Urethra | (0) | (0) | (1) | (0)
Urinary bladder | (50) | (50) | (49) | (50)
Angiectasis | – | 1 (2%) | – | –
Calculus microscopic observation only | 1 (2%) | – | – | –
Inflammation, suppurative | – | 1 (2%) | – | –
Inflammation, chronic active | – | – | 1 (2%) | –
Ulcer | – | 1 (2%) | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.