# Appendix B Summary of Lesions in Female Rats in the Two-year Inhalation Study of TRIM VX

Table B-1 Summary of the Incidence of Neoplasms in Female Rats in the Two-year Inhalation Study of TRIM VX^a^

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 19 | 15 | 15 | 16
Natural deaths | 1 | 2 | 2 | 4
Survivors
Died last week of study | 1 | 1 | – | –
Terminal kill | 29 | 32 | 33 | 30
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (50) | (50) | (50) | (50)
Neoplasm NOS | – | 1 (2%) | – | –
Intestine large, colon | (50) | (50) | (50) | (50)
Neoplasm NOS | – | 1 (2%) | – | –
Schwannoma malignant, metastatic, uterus | – | – | 1 (2%) | –
Intestine large, rectum | (50) | (50) | (50) | (50)
Intestine small, duodenum | (50) | (50) | (50) | (50)
Intestine small, ileum | (50) | (50) | (50) | (50)
Intestine small, jejunum | (50) | (50) | (50) | (50)
Liver | (50) | (50) | (50) | (50)
Cholangioma | – | 1 (2%) | – | –
Hepatocellular adenoma | – | – | – | 1 (2%)
Mesentery | (4) | (5) | (9) | (4)
Adenocarcinoma, metastatic, uterus | – | – | 1 (11%) | –
Neoplasm NOS | – | 1 (20%) | – | –
Schwannoma malignant, metastatic, uterus | – | – | 1 (11%) | –
Pancreas | (50) | (50) | (50) | (50)
Adenocarcinoma, metastatic, uterus | – | – | 1 (2%) | –
Neoplasm NOS | – | 1 (2%) | – | –
Salivary glands | (50) | (50) | (50) | (50)
Stomach, forestomach | (50) | (50) | (50) | (50)
Neoplasm NOS | – | 1 (2%) | – | –
Stomach, glandular | (50) | (50) | (50) | (50)
Neoplasm NOS | – | 1 (2%) | – | –
Tongue | (0) | (0) | (0) | (1)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Heart | (50) | (50) | (50) | (50)
Schwannoma malignant | – | – | – | 1 (2%)
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Adenoma | – | – | – | 2 (4%)
Adrenal medulla | (50) | (50) | (50) | (49)
Pheochromocytoma malignant | – | – | 1 (2%) | 1 (2%)
Islets, pancreatic | (50) | (50) | (50) | (50)
Adenoma | – | – | – | 1 (2%)
Parathyroid gland | (42) | (43) | (47) | (47)
Adenoma | 1 (2%) | – | – | –
Pituitary gland | (50) | (50) | (50) | (50)
Pars distalis, adenoma | 34 (68%) | 31 (62%) | 26 (52%) | 22 (44%)
Pars distalis, adenoma, multiple | – | 2 (4%) | 6 (12%) | 2 (4%)
Pars intermedia, adenoma | 1 (2%) | – | 1 (2%) | –
Thyroid gland | (49) | (50) | (50) | (50)
Bilateral, c-cell, adenoma | 1 (2%) | 1 (2%) | – | –
C-cell, adenoma | 6 (12%) | 3 (6%) | 4 (8%) | 6 (12%)
Follicle, adenoma | – | 1 (2%) | 2 (4%) | 1 (2%)
Follicle, carcinoma | 1 (2%) | 2 (4%) | – | –
General Body System
None
Genital System
Clitoral gland | (50) | (48) | (49) | (50)
Squamous cell papilloma | – | 1 (2%) | – | –
Ovary | (50) | (50) | (50) | (50)
Granulosa cell tumor benign | – | 2 (4%) | – | 2 (4%)
Granulosa cell tumor malignant | 1 (2%) | 1 (2%) | – | –
Tubulostromal adenoma | – | – | – | 1 (2%)
Tubulostromal carcinoma | – | – | – | 1 (2%)
Bilateral, tubulostromal adenoma | – | – | – | 1 (2%)
Uterus | (50) | (50) | (50) | (50)
Adenocarcinoma | 1 (2%) | 1 (2%) | 4 (8%) | 1 (2%)
Adenoma | 1 (2%) | 1 (2%) | 2 (4%) | 1 (2%)
Granular cell tumor benign | 1 (2%) | – | – | –
Polyp stromal | 4 (8%) | – | 7 (14%) | 1 (2%)
Polyp stromal, multiple | 2 (4%) | – | 1 (2%) | –
Sarcoma stromal | 1 (2%) | – | 1 (2%) | –
Schwannoma malignant | 2 (4%) | – | 4 (8%) | 1 (2%)
Vagina | (1) | (0) | (0) | (0)
Fibrosarcoma | 1 (100%) | – | – | –
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Neoplasm NOS | – | 1 (2%) | – | –
Lymph node | (4) | (1) | (2) | (1)
Lumbar, hemangiosarcoma | – | 1 (100%) | – | –
Pancreatic, adenocarcinoma, metastatic, uterus | – | – | 1 (50%) | –
Renal, schwannoma malignant, metastatic, uterus | – | – | 1 (50%) | –
Lymph node, bronchial | (37) | (37) | (44) | (36)
Lymph node, mandibular | (40) | (46) | (47) | (50)
Lymph node, mediastinal | (46) | (49) | (46) | (45)
Neoplasm NOS | – | 1 (2%) | – | –
Schwannoma malignant, metastatic, lung | – | – | – | 1 (2%)
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Hemangiosarcoma | – | – | – | 1 (2%)
Neoplasm NOS | – | 1 (2%) | – | –
Spleen | (50) | (50) | (50) | (50)
Thymus | (48) | (49) | (49) | (49)
Schwannoma malignant, metastatic, lung | – | – | – | 1 (2%)
Thymoma benign | 8 (17%) | 4 (8%) | 7 (14%) | 10 (20%)
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Adenoma | 3 (6%) | 1 (2%) | 2 (4%) | 1 (2%)
Adenoma, multiple | 1(2%) | – | – | –
Carcinoma | 3 (6%) | 2 (4%) | 2 (4%) | 4 (8%)
Carcinoma, multiple | 1 (2%) | 2 (4%) | 3 (6%) | 2 (4%)
Fibroadenoma | 2 (4%) | 7 (14%) | 7 (14%) | 4 (8%)
Fibroadenoma, multiple | – | 2 (4%) | – | 1 (2%)
Skin | (50) | (50) | (50) | (50)
Epidermis, squamous cell papilloma | – | – | 1 (2%) | 2 (4%)
Subcutaneous tissue, lipoma | – | 1 (2%) | – | –
Subcutaneous tissue, neoplasm NOS | – | 1 (2%) | – | –
Subcutaneous tissue, schwannoma malignant | – | – | – | 2 (4%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Skeletal muscle | (4) | (3) | (3) | (4)
Adenocarcinoma, metastatic, uterus | – | – | 1 (33%) | –
Schwannoma malignant, metastatic, skin | – | – | – | 1 (25%)
Nervous System
Brain | (50) | (50) | (50) | (50)
Granular cell tumor benign | – | – | 1 (2%) | –
Oligodendroglioma benign | – | – | 1 (2%) | –
Peripheral nerve | (4) | (3) | (2) | (3)
Spinal cord | (4) | (3) | (2) | (3)
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | – | – | 1 (2%) | 1 (2%)
Alveolar/bronchiolar adenoma, multiple | – | – | – | 2 (4%)
Carcinoma, metastatic, kidney | – | 1 (2%) | – | –
Carcinoma, metastatic, uterus | – | – | 1 (2%) | –
Cystic keratinizing epithelioma | – | – | – | 1 (2%)
Neoplasm NOS | – | 1 (2%) | – | –
Schwannoma malignant, metastatic, uterus | – | – | 1 (2%) | –
Mediastinum, schwannoma malignant | – | – | – | 1 (2%)
Nose | (50) | (50) | (49) | (50)
Polyp | – | – | – | 1 (2%)
Schwannoma benign | – | – | – | 1 (2%)
Schwannoma malignant, metastatic, skin | – | – | – | 1 (2%)
Trachea | (49) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (50)
Harderian gland | (50) | (50) | (50) | (50)
Zymbal’s gland | (0) | (2) | (1) | (1)
Carcinoma | – | 1 (50%) | 1 (100%) | 1 (100%)
Squamous cell papilloma | – | 1 (50%) | – | –
Urinary System
Kidney | (50) | (50) | (50) | (50)
Neoplasm NOS | – | 1 (2%) | – | –
Transitional epithelium, carcinoma | – | 1 (2%) | – | –
Ureter | (0) | (0) | (0) | (1)
Urinary bladder | (50) | (50) | (50) | (50)
Adenocarcinoma, metastatic, uterus | – | – | – | 1 (2%)
Neoplasm NOS | – | 1 (2%) | – | –
Schwannoma malignant, metastatic, uterus | – | – | 1 (2%) | –
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | 2 (4%) | – | – | 1 (2%)
Lymphoma malignant | 1 (2%) | 1 (2%) | – | –
Neoplasm Summary
Total animals with primary neoplasms^c^ | 47 | 43 | 44 | 41
Total primary neoplasms | 79 | 84 | 85 | 82
Total animals with benign neoplasms | 42 | 39 | 40 | 35
Total benign neoplasms | 65 | 59 | 69 | 65
Total animals with malignant neoplasms | 13 | 11 | 15 | 16
Total malignant neoplasms | 14 | 12 | 16 | 17
Total animals with metastatic neoplasms | – | 1 | 2 | 4
Total metastatic neoplasms | – | 1 | 10 | 5
Total animals with uncertain Neoplasms-benign or malignant | – | 1 | – | –
Total uncertain neoplasms | – | 13 | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table B-2 Statistical Analysis of Primary Neoplasms in Female Rats in the Two-year Inhalation Study of TRIM VX

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Lung: Alveolar/bronchiolar Adenoma
Overall rate^a^ | 0/50 (0%) | 0/50 (0%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate^b^ | 0.0% | 0.0% | 2.3% | 6.8%
Terminal rate^c^ | 0/30 (0%) | 0/33 (0%) | 1/33 (3%) | 3/30 (10%)
First incidence (days) | –^e^ | – | 731 (T) | 731 (T)
Poly-3 test^d^ | P = 0.024 | –^f^ | P = 0.511 | P = 0.127
Mammary Gland: Fibroadenoma
Overall rate | 2/50 (4%) | 9/50 (18%) | 7/50 (14%) | 5/50 (10%)
Adjusted rate | 4.8% | 20.6% | 15.6% | 11.2%
Terminal rate | 2/30 (7%) | 6/33 (18%) | 5/33 (15%) | 2/30 (7%)
First incidence (days) | 731 (T) | 354 | 604 | 572
Poly-3 test | P = 0.515N | P = 0.029 | P = 0.095 | P = 0.243
Mammary Gland: Adenoma
Overall rate | 4/50 (8%) | 1/50 (2%) | 2/50 (4%) | 1/50 (2%)
Adjusted rate | 9.3% | 2.4% | 4.5% | 2.3%
Terminal rate | 1/30 (3%) | 1/33 (3%) | 1/33 (3%) | 0/30 (0%)
First incidence (days) | 535 | 731 (T) | 626 | 593
Poly-3 test | P = 0.231N | P = 0.185N | P = 0.322N | P = 0.170N
Mammary Gland: Fibroadenoma or Adenoma
Overall rate | 6/50 (12%) | 10/50 (20%) | 9/50 (18%) | 6/50 (12%)
Adjusted rate | 13.9% | 22.9% | 19.9% | 13.3%
Terminal rate | 3/30 (10%) | 7/33 (21%) | 6/33 (18%) | 2/30 (7%)
First incidence (days) | 535 | 354 | 604 | 572
Poly-3 test | P = 0.303N | P = 0.210 | P = 0.321 | P = 0.587N
Mammary Gland: Carcinoma
Overall rate | 4/50 (8%) | 4/50 (8%) | 5/50 (10%) | 6/50 (12%)
Adjusted rate | 9.5% | 9.5% | 11.2% | 13.4%
Terminal rate | 3/30 (10%) | 3/33 (9%) | 3/33 (9%) | 2/30 (7%)
First incidence (days) | 702 | 725 | 626 | 593
Poly-3 test | P = 0.326 | P = 0.641N | P = 0.539 | P = 0.408
Mammary Gland: Adenoma or Carcinoma
Overall rate | 8/50 (16%) | 4/50 (8%) | 6/50 (12%) | 6/50 (12%)
Adjusted rate | 18.5% | 9.5% | 13.4% | 13.4%
Terminal rate | 4/30 (13%) | 3/33 (9%) | 4/33 (12%) | 2/30 (7%)
First incidence (days) | 535 | 725 | 626 | 593
Poly-3 test | P = 0.499N | P = 0.186N | P = 0.360N | P = 0.361N
Mammary Gland: Fibroadenoma, Adenoma, or Carcinoma
Overall rate | 9/50 (18%) | 13/50 (26%) | 12/50 (24%) | 11/50 (22%)
Adjusted rate | 20.8% | 29.8% | 26.4% | 24.1%
Terminal rate | 5/30 (17%) | 9/33 (27%) | 8/33 (24%) | 4/30 (13%)
First incidence (days) | 535 | 354 | 604 | 572
Poly-3 test | P = 0.528N | P = 0.236 | P = 0.356 | P = 0.451
Ovary: Benign or Malignant Granulosa Cell Tumor
Overall rate | 1/50 (2%) | 3/50 (6%) | 0/50 (0%) | 2/50 (4%)
Adjusted rate | 2.4% | 7.1% | 0.0% | 4.6%
Terminal rate | 1/30 (3%) | 3/33 (9%) | 0/33 (0%) | 2/30 (7%)
First incidence (days) | 731 (T) | 731 (T) | – | 731 (T)
Poly-3 test | P = 0.581 | P = 0.307 | P = 0.489N | P = 0.516
Ovary: Tubulostromal Adenoma or Carcinoma
Overall rate | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 6.8%
Terminal rate | 0/30 (0%) | 0/33 (0%) | 0/33 (0%) | 3/30 (10%)
First incidence (days) | – | – | – | 731 (T)
Poly-3 test | P = 0.008 | – | – | P=0.127
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 34/50 (68%) | 33/50 (66%) | 32/50 (64%) | 24/50 (48%)
Adjusted rate | 72.1% | 69.7% | 67.1% | 49.8%
Terminal rate | 20/30 (67%) | 20/33 (61%) | 21/33 (64%) | 11/30 (37%)
First incidence (days) | 534 | 346 | 516 | 436
Poly-3 test | P = 0.007N | P = 0.489N | P = 0.377N | P = 0.018N
Thymus: Benign Thymoma
Overall rate | 8/48 (17%) | 4/49 (8%) | 7/49 (14%) | 10/49 (20%)
Adjusted rate | 19.6% | 9.5% | 16.1% | 22.7%
Terminal rate | 6/28 (21%) | 4/33 (12%) | 6/32 (19%) | 6/29 (21%)
First incidence (days) | 613 | 731 (T) | 614 | 436
Poly-3 test | P = 0.180 | P = 0.157N | P = 0.442N | P = 0.468
Thyroid Gland (C-Cell): Adenoma
Overall rate | 7/49 (14%) | 4/50 (8%) | 4/50 (8%) | 6/50 (12%)
Adjusted rate | 16.8% | 9.5% | 9.1% | 13.5%
Terminal rate | 5/29 (17%) | 4/33 (12%) | 4/33 (12%) | 5/30 (17%)
First incidence (days) | 615 | 731 (T) | 731 (T) | 577
Poly-3 test | P = 0.565 | P = 0.252N | P = 0.227N | P = 0.451N
Thyroid Gland (Follicular Cell): Adenoma or Carcinoma
Overall rate | 1/49 (2%) | 3/50 (6%) | 2/50 (4%) | 1/50 (2%)
Adjusted rate | 2.4% | 7.1% | 4.5% | 2.3%
Terminal rate | 0/29 (0%) | 3/33 (9%) | 1/33 (3%) | 1/30 (3%)
First incidence (days) | 697 | 731 (T) | 677 | 731 (T)
Poly-3 test | P = 0.398N | P = 0.315 | P = 0.527 | P = 0.746N
Uterus: Stromal Polyp
Overall rate | 6/50 (12%) | 0/50 (0%) | 8/50 (16%) | 1/50 (2%)
Adjusted rate | 14.2% | 0.0% | 18.1% | 2.3
Terminal rate | 5/30 (17%) | 0/33 (0%) | 7/33 (21%) | 1/30 (3%)
First incidence (days) | 618 | – | 708 | 731 (T)
Poly-3 test | P = 0.130N | P = 0.015N | P = 0.421 | P = 0.049N
Uterus: Stromal Polyp or Stromal Sarcoma
Overall rate | 7/50 (14%) | 0/50 (0%) | 9/50 (18%) | 1/50 (2%)
Adjusted rate | 16.5% | 0.0% | 20.3% | 2.3%
Terminal rate | 5/30 (17%) | 0/33 (0%) | 7/33 (21%) | 1/30 (3%)
First incidence (days) | 618 | – | 689 | 731 (T)
Poly-3 test | P = 0.089N | P = 0.007N | P = 0.431 | P = 0.026N
Uterus: Malignant Schwannoma
Overall rate | 2/50 (4%) | 0/50 (0%) | 4/50 (8%) | 1/50 (2%)
Adjusted rate | 4.7% | 0.0% | 8.8% | 2.3%
Terminal rate | 0/30 (0%) | 0/33 (0%) | 1/33 (3%) | 1/30 (3%)
First incidence (days) | 536 | – | 590 | 731 (T)
Poly-3 test | P = 0.526N | P = 0.240N | P = 0.366 | P = 0.491N
Uterus: Carcinoma
Overall rate | 1/50 (2%) | 1/50 (2%) | 4/50 (8%) | 1/50 (2%)
Adjusted rate | 2.4% | 2.4% | 9.0% | 2.3%
Terminal rate | 1/30 (3%) | 0/33 (0%) | 3/33 (9%) | 0/30 (0%)
First incidence (days) | 731 (T) | 649 | 689 | 705
Poly-3 test | P = 0.558N | P = 0.758N | P = 0.196 | P = 0.750N
Uterus: Adenoma or Carcinoma
Overall rate | 2/50 (4%) | 2/50 (4%) | 6/50 (12%) | 2/50 (4%)
Adjusted rate | 4.8% | 4.7% | 13.5% | 4.5%
Terminal rate | 2/30 (7%) | 1/33 (3%) | 4/33 (12%) | 1/30 (3%)
First incidence (days) | 731 (T) | 649 | 677 | 705
Poly-3 test | P = 0.519N | P = 0.689N | P = 0.152 | P = 0.676N
All Organs: Benign Neoplasms
Overall rate | 42/50 (84%) | 39/50 (78%) | 40/50 (80%) | 35/50 (70%)
Adjusted rate | 88.3% | 80.9% | 82.5% | 71.6%
Terminal rate | 27/30 (90%) | 25/33 (76%) | 27/33 (82%) | 20/30 (67%)
First incidence (days) | 534 | 346 | 516 | 436
Poly-3 test | P = 0.031N | P = 0.229N | P = 0.296N | P = 0.031N
All Organs: Malignant Neoplasms
Overall rate | 13/50 (26%) | 11/50 (22%) | 15/50 (30%) | 16/50 (32%)
Adjusted rate | 28.7% | 25.0% | 31.8% | 34.9%
Terminal rate | 4/30 (13%) | 7/33 (21%) | 7/33 (21%) | 6/30 (20%)
First incidence (days) | 352 | 104 | 516 | 593
Poly-3 test | P = 0.225 | P = 0.438N | P = 0.461 | P = 0.340
All Organs: Benign or Malignant Neoplasms
Overall rate | 47/50 (94%) | 43/50 (86%) | 44/50 (88%) | 41/50 (82%)
Adjusted rate | 94.0% | 86.0% | 88.0% | 82.9%
Terminal rate | 27/30 (90%) | 26/33 (79%) | 27/33 (82%) | 23/30 (77%)
First incidence (days) | 352 | 104 | 516 | 436
Poly-3 test | P = 0.123N | P = 0.159N | P = 0.243N | P = 0.074N

(T) Terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for lung, ovary, pituitary gland, thymus, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table B-3 Historical Incidence of Lung Neoplasms in Control Female Wistar Han Rats^a^

Study (Study Start) | Alveolar/bronchiolar Adenoma | Alveolar/bronchiolar Carcinoma | Alveolar/bronchiolar Adenoma or Carcinoma | Cystic Keratinizing Epithelioma
Historical Incidence: Inhalation Studies
Antimony trioxide (September 2008) | 0/50 | 0/50 | 0/50 | 0/50
CIMSTAR 3800 (April 2008) | 0/50 | 0/50 | 0/50 | 0/50
TRIM VX (July 2009) | 0/50 | 0/50 | 0/50 | 0/50
Total | 0/150 | 0/150 | 0/150 | 0/150
Overall Historical Incidence: All Routes
Total | 0/300 | 0/300 | 0/300 | 0/300

^a^ Data as of November 2014.

Table B-4 Summary of the Incidence of Nonneoplastic Lesions in Female Rats in the Two-year Inhalation Study of TRIM VX^a^

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 19 | 15 | 15 | 16
Natural deaths | 1 | 2 | 2 | 4
Survivors
Died last week of study | 1 | 1 | – | –
Terminal kill | 29 | 32 | 33 | 30
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (50) | (50) | (50) | (50)
Intestine large, colon | (50) | (50) | (50) | (50)
Intestine large, rectum | (50) | (50) | (50) | (50)
Intestine small, duodenum | (50) | (50) | (50) | (50)
Intestine small, ileum | (50) | (50) | (50) | (50)
Intestine small, jejunum | (50) | (50) | (50) | (50)
Liver | (50) | (50) | (50) | (50)
Angiectasis | – | 4 (8%) | 1 (2%) | –
Basophilic focus | 21 (42%) | 30 (60%) | 24 (48%) | 25 (50%)
Clear cell focus | 6 (12%) | 16 (32%) | 4 (8%) | 8 (16%)
Eosinophilic focus | 2 (4%) | 3 (6%) | – | 2 (4%)
Fatty change | 2 (4%) | – | 3 (6%) | –
Fibrosis | – | 1 (2%) | – | –
Hematopoietic cell proliferation | 1 (2%) | – | – | –
Hepatodiaphragmatic nodule | – | – | 1 (2%) | 1 (2%)
Inflammation, granulomatous | 1 (2%) | 3 (6%) | – | 2 (4%)
Mixed cell focus | 3 (6%) | 5 (10%) | – | –
Necrosis | – | – | 1 (2%) | –
Bile duct, cyst | – | – | 2 (4%) | 1 (2%)
Bile duct, dilatation | – | 1 (2%) | 1 (2%) | –
Bile duct, hyperplasia | 2 (4%) | 8 (16%) | 6 (12%) | 4 (8%)
Centrilobular, degeneration | 1 (2%) | – | – | –
Serosa, fibrosis | – | – | – | 1 (2%)
Sinusoid, dilatation | 1 (2%) | – | – | –
Mesentery | (4) | (5) | (9) | (4)
Fat, necrosis | 4 (100%) | 4 (80%) | 7 (78%) | 4 (100%)
Pancreas | (50) | (50) | (50) | (50)
Hyperplasia | 1 (2%) | – | – | –
Acinus, atrophy | 4 (8%) | 2 (4%) | 2 (4%) | 1 (2%)
Salivary glands | (50) | (50) | (50) | (50)
Sublingual gland, inflammation | – | 1 (2%) | – | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Inflammation | 2 (4%) | – | – | –
Epithelium, hyperplasia | 2 (4%) | – | – | –
Stomach, glandular | (50) | (50) | (50) | (50)
Tongue | (0) | (0) | (0) | (1)
Hyperkeratosis | – | – | – | 1 (100%)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 7 (14%) | 7 (14%) | 8 (16%) | 1 (2%)
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Angiectasis | 28 (56%) | 25 (50%) | 28 (56%) | 27 (54%)
Hematopoietic cell proliferation | 3 (6%) | – | – | –
Hyperplasia | – | 1 (2%) | – | 1 (2%)
Hypertrophy | 10 (20%) | 5 (10%) | 15 (30%) | 10 (20%)
Necrosis | – | – | 2 (4%) | 1 (2%)
Vacuolization cytoplasmic | 9 (18%) | 8 (16%) | 14 (28%) | 11 (22%)
Zona fasciculata, atrophy | – | 1 (2%) | – | –
Adrenal medulla | (50) | (50) | (50) | (49)
Hyperplasia | 3 (6%) | 1 (2%) | – | 1 (2%)
Islets, pancreatic | (50) | (50) | (50) | (50)
Hyperplasia | 1 (2%) | – | – | –
Parathyroid gland | (42) | (43) | (47) | (47)
Fibrosis | – | 2 (5%) | 1 (2%) | –
Hyperplasia | 1 (2%) | – | – | –
Pituitary gland | (50) | (50) | (50) | (50)
Angiectasis | – | – | – | 1 (2%)
Cyst | – | 1 (2%) | – | –
Pars distalis, hyperplasia | 4 (8%) | 13 (26%) | 12 (24%) | 16 (32%)
Pars intermedia, hyperplasia | – | 1 (2%) | – | –
Thyroid gland | (49) | (50) | (50) | (50)
C-cell, hyperplasia | 40 (82%) | 44 (88%) | 45 (90%) | 42 (84%)
Follicle, hyperplasia | 2 (4%) | 4 (8%) | 7 (14%) | 3 (6%)
General Body System
None
Genital System
Clitoral gland | (50) | (48) | (49) | (50)
Cyst | – | – | – | 2 (4%)
Fibrosis | 1 (2%) | – | – | –
Inflammation | 11 (22%) | 12 (25%) | 13 (27%) | 12 (24%)
Ovary | (50) | (50) | (50) | (50)
Cyst | 9 (18%) | 10 (20%) | 12 (24%) | 10 (20%)
Uterus | (50) | (50) | (50) | (50)
Inflammation, suppurative | 1 (2%) | – | – | –
Thrombosis | – | – | – | 1 (2%)
Cervix, hyperplasia | – | 1 (2%) | – | –
Endometrium, hyperplasia, cystic | 12 (24%) | 11 (22%) | 12 (24%) | 10 (20%)
Epithelium, metaplasia, squamous | – | – | – | 1 (2%)
Vagina | (1) | (0) | (0) | (0)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (4) | (1) | (2) | (1)
Lumbar, hyperplasia, plasma cell | 3 (75%) | – | – | –
Popliteal, hyperplasia, plasma cell | 1 (25%) | – | – | –
Renal, hyperplasia, plasma cell | 1 (25%) | – | – | –
Lymph node, bronchial | (37) | (37) | (44) | (36)
Hematopoietic cell proliferation | 1 (3%) | – | – | –
Hyperplasia, lymphohistiocytic | 1 (3%) | 18 (49%) | 37 (84%) | 31 (86%)
Hyperplasia, plasma cell | 1 (3%) | – | – | –
Lymph node, mandibular | (40) | (46) | (47) | (50)
Hematopoietic cell proliferation | 1 (3%) | – | – | –
Hyperplasia, plasma cell | – | – | – | 1 (2%)
Lymph node, mediastinal | (46) | (49) | (46) | (45)
Hematopoietic cell proliferation | 1 (2%) | – | – | –
Hyperplasia, lymphohistiocytic | – | 11 (22%) | 14 (30%) | 28 (62%)
Hyperplasia, plasma cell | 5 (11%) | – | 1 (2%) | 1 (2%)
Pigmentation, hemosiderin | – | – | – | 1 (2%)
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Hyperplasia, plasma cell | – | – | – | 1 (2%)
Spleen | (50) | (50) | (50) | (50)
Cyst | – | – | – | 1 (2%)
Hematopoietic cell proliferation | 13 (26%) | 7 (14%) | 11 (22%) | 9 (18%)
Lymphoid follicle, atrophy | 2 (4%) | 2 (4%) | 6 (12%) | 7 (14%)
Thymus | (48) | (49) | (49) | (49)
Atrophy | 14 (29%) | 12 (24%) | 21 (43%) | 15 (31%)
Cyst | – | 1 (2%) | 2 (4%) | –
Ectopic thyroid | 1 (2%) | – | – | –
Hyperplasia, lymphohistiocytic | – | – | 1 (2%) | –
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Hyperplasia | 3 (6%) | – | 4 (8%) | 3 (6%)
Duct, cyst | 4 (8%) | 7 (14%) | 6 (12%) | 2 (4%)
Skin | (50) | (50) | (50) | (50)
Cyst epithelial inclusion | 1 (2%) | – | 1 (2%) | –
Inflammation | – | 1 (2%) | 1 (2%) | 1 (2%)
Ulcer | 6 (12%) | – | 3 (6%) | 2 (4%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Osteopetrosis | 1 (2%) | – | – | –
Joint, inflammation | 1 (2%) | – | – | –
Skeletal muscle | (4) | (3) | (3) | (4)
Nervous System
Brain | (50) | (50) | (50) | (50)
Compression | 17 (34%) | 16 (32%) | 21 (42%) | 17 (34%)
Degeneration | 1 (2%) | – | – | –
Hydrocephalus | 6 (12%) | 9 (18%) | 4 (8%) | 8 (16%)
Peripheral nerve | (4) | (3) | (2) | (3)
Spinal cord | (4) | (3) | (2) | (3)
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Infiltration cellular, mixed cell | – | 9 (18%) | 18 (36%) | 22 (44%)
Inflammation, chronic active | – | 2 (4%) | – | 1 (2%)
Epiglottis, hyperplasia, squamous | 1 (2%) | 24 (48%) | 41 (82%) | 50 (100%)
Epiglottis, metaplasia, squamous | – | 49 (98%) | 50 (100%) | 50 (100%)
Lung | (50) | (50) | (50) | (50)
Fibrosis | 5 (10%) | 35 (70%) | 49 (98%) | 50 (100%)
Hyperplasia, lymphohistiocytic | – | – | – | 1 (2%)
Infiltration cellular, histiocyte | 16 (32%) | 48 (96%) | 50 (100%) | 50 (100%)
Inflammation, chronic | 1 (2%) | – | – | –
Inflammation, chronic active | 5 (10%) | 46 (92%) | 50 (100%) | 50 (100%)
Alveolar/bronchiolar epithelium, hyperplasia | 2 (4%) | 9 (18%) | 31 (62%) | 50 (100%)
Alveolar epithelium, hyperplasia | 8 (16%) | 43 (86%) | 49 (98%) | 50 (100%)
Alveolar epithelium, metaplasia, squamous | – | 3 (6%) | 9 (18%) | 21 (42%)
Alveolus, proteinosis | 1 (2%) | 15 (30%) | 41 (82%) | 48 (96%)
Bronchus-associated lymphoid tissue, hyperplasia, lymphohistiocytic | – | 2 (4%) | 7 (14%) | 10 (20%)
Nose | (50) | (50) | (49) | (50)
Inflammation, suppurative | 1 (2%) | 46 (92%) | 47 (96%) | 48 (96%)
Glands, olfactory epithelium, hyperplasia | – | 32 (64%) | 43 (88%) | 46 (92%)
Glands, olfactory epithelium, hyperplasia, squamous | – | – | 1 (2%) | –
Goblet cell, hyperplasia | 3 (6%) | 36 (72%) | 40 (82%) | 47 (94%)
Olfactory epithelium, accumulation, hyaline droplet | 14 (28%) | 50 (100%) | 49 (100%) | 50 (100%)
Olfactory epithelium, metaplasia, respiratory | 1 (2%) | – | – | –
Olfactory epithelium, metaplasia, squamous | – | – | – | 2 (4%)
Respiratory epithelium, accumulation, hyaline droplet | 5 (10%) | 50 (100%) | 48 (98%) | 50 (100%)
Respiratory epithelium, hyperplasia | – | 7 (14%) | 8 (16%) | 25 (50%)
Transitional epithelium, hyperplasia | 5 (10%) | 11 (22%) | 4 (8%) | 21 (42%)
Transitional epithelium, metaplasia, squamous | 1 (2%) | 5 (10%) | 1 (2%) | 2 (4%)
Trachea | (49) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (50)
Cataract | | | 1 (2%) | 1 (2%)
Retina, atrophy | 3 (6%) | 2 (4%) | 1 (2%) | 2 (4%)
Harderian gland | (50) | (50) | (50) | (50)
Atrophy | 1 (2%) | – | – | –
Inflammation | 1 (2%) | 3 (6%) | 3 (6%) | 2 (4%)
Zymbal’s gland | (0) | (2) | (1) | (1)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Hydronephrosis | – | 2 (4%) | – | 1 (2%)
Infarct | 1 (2%) | 2 (4%) | – | –
Metaplasia, lipocyte | – | 1 (2%) | – | –
Nephropathy | 4 (8%) | 5 (10%) | 5 (10%) | 7 (14%)
Pelvis, inflammation | 28 (56%) | 32 (64%) | 41 (82%) | 30 (60%)
Renal tubule, cyst | – | 1 (2%) | 1 (2%) | 3 (6%)
Renal tubule, hyperplasia | – | 1 (2%) | – | –
Ureter | (0) | (0) | (0) | (1)
Cyst | – | – | – | 1 (100%)
Urinary bladder | (50) | (50) | (50) | (50)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.