# Appendix A Summary of Lesions in Male Rats in the Two-year Inhalation Study of TRIM VX

Table A-1 Summary of the Incidence of Neoplasms in Male Rats in the Two-year Inhalation Study of TRIM VX^a^

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 12 | 10 | 14 | 15
Natural deaths | 2 | 1 | 3 | 1
Survivors
Terminal kill | 36 | 39 | 33 | 34
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (50) | (50) | (50) | (50)
Intestine large, colon | (50) | (50) | (50) | (50)
Adenoma | – | – | – | 1 (2%)
Intestine large, rectum | (50) | (50) | (50) | (50)
Intestine small, duodenum | (50) | (50) | (50) | (50)
Intestine small, ileum | (50) | (50) | (50) | (50)
Intestine small, jejunum | (50) | (50) | (50) | (50)
Liver | (50) | (50) | (50) | (50)
Hepatocellular adenoma | 1 (2%) | 1 (2%) | – | 1 (2%)
Mesentery | (2) | (2) | (3) | (5)
Pancreas | (50) | (50) | (50) | (50)
Acinus, adenoma | 1 (2%) | – | – | –
Salivary glands | (50) | (50) | (50) | (50)
Schwannoma malignant | – | – | – | 1 (2%)
Stomach, forestomach | (50) | (50) | (50) | (50)
Squamous cell papilloma | – | – | – | 1 (2%)
Stomach, glandular | (50) | (50) | (50) | (50)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Heart | (50) | (50) | (50) | (50)
Schwannoma malignant, metastatic, skeletal muscle | – | – | 1 (2%) | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Adenoma | 1 (2%) | – | – | –
Carcinoma | – | – | – | 2 (4%)
Adrenal medulla | (50) | (50) | (49) | (49)
Pheochromocytoma benign | – | 2 (4%) | 1 (2%) | –
Pheochromocytoma malignant | – | – | – | 1 (2%)
Schwannoma malignant, metastatic, skeletal muscle | – | – | 1 (2%) | –
Islets, pancreatic | (50) | (50) | (50) | (50)
Adenoma | 5 (10%) | 1 (2%) | – | 1 (2%)
Carcinoma | – | – | – | 1 (2%)
Parathyroid gland | (39) | (44) | (46) | (49)
Pituitary gland | (50) | (50) | (50) | (50)
Pars distalis, adenoma | 13 (26%) | 12 (24%) | 14 (28%) | 15 (30%)
Pars distalis, adenoma, multiple | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Pars intermedia, adenoma | 1 (2%) | 1 (2%) | 2 (4%) | –
Pars nervosa, granular cell tumor benign | – | – | 1 (2%) | –
Thyroid gland | (50) | (50) | (50) | (50)
Bilateral, c-cell, adenoma | – | – | – | 1 (2%)
C-cell, adenoma | 3 (6%) | 5 (10%) | 2 (4%) | 6 (12%)
Follicle, adenoma | – | 1 (2%) | 3 (6%) | 1 (2%)
Follicle, carcinoma | – | 1 (2%) | 1 (2%) | –
General Body System
None
Genital System
Epididymis | (50) | (50) | (50) | (50)
Preputial gland | (49) | (50) | (50) | (50)
Prostate | (50) | (50) | (50) | (50)
Seminal vesicle | (50) | (50) | (50) | (50)
Testes | (50) | (50) | (50) | (50)
Hemangiosarcoma | – | – | – | 1 (2%)
Interstitial cell, adenoma | – | 1 (2%) | 2 (4%) | 1 (2%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (11) | (7) | (7) | (8)
Lumbar, hemangioma | 1 (9%) | – | – | –
Lymph node, bronchial | (39) | (43) | (42) | (42)
Lymph node, mandibular | (46) | (46) | (46) | (48)
Lymph node, mediastinal | (43) | (48) | (44) | (43)
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Hemangiosarcoma | – | 1 (2%) | 1 (2%) | –
Spleen | (50) | (50) | (50) | (50)
Thymus | (48) | (49) | (50) | (50)
Schwannoma malignant, metastatic, skeletal muscle | – | – | 1 (2%) | –
Thymoma benign | 3 (6%) | 3 (6%) | 4 (8%) | 1 (2%)
Integumentary System
Mammary gland | (4) | (5) | (1) | (2)
Skin | (50) | (50) | (50) | (50)
Epidermis, keratoacanthoma | 1 (2%) | 1 (2%) | – | 1 (2%)
Epidermis, squamous cell papilloma | – | 2 (4%) | – | –
Sebaceous gland, adenoma | 1 (2%) | – | – | –
Subcutaneous tissue, fibroma | 1 (2%) | 1 (2%) | 1 (2%) | –
Subcutaneous tissue, hemangiosarcoma | – | 1 (2%) | – | –
Subcutaneous tissue, schwannoma malignant | – | 1 (2%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Skeletal muscle | (4) | (4) | (8) | (3)
Hemangiosarcoma | – | – | – | 2 (67%)
Rhabdomyosarcoma | – | 1 (25%) | – | –
Schwannoma malignant | – | – | 1 (13%) | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Carcinoma, metastatic, Zymbal’s gland | 1 (2%) | – | – | –
Granular cell tumor benign | – | 1 (2%) | – | –
Oligodendroglioma benign | – | – | 1 (2%) | –
Peripheral nerve | (4) | (2) | (8) | (2)
Schwannoma malignant | – | – | 1 (13%) | –
Spinal cord | (4) | (2) | (7) | (2)
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | – | – | – | 1 (2%)
Alveolar/bronchiolar carcinoma | – | – | – | 2 (4%)
Carcinoma, metastatic, Zymbal’s gland | 1 (2%) | – | – | –
Schwannoma malignant, metastatic, skeletal muscle | – | – | 1 (2%) | –
Nose | (50) | (50) | (50) | (50)
Polyp, multiple | – | – | – | 1 (2%)
Squamous cell papilloma | – | – | – | 1 (2%)
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (50)
Harderian gland | (50) | (50) | (50) | (50)
Lacrimal gland | (1) | (0) | (0) | (1)
Zymbal’s gland | (1) | (0) | (0) | (0)
Carcinoma | 1 (100%) | – | – | –
Urinary System
Kidney | (50) | (50) | (50) | (50)
Renal tubule, carcinoma | 1 (2%) | – | – | –
Urinary bladder | (50) | (50) | (50) | (50)
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | – | – | – | 1 (2%)
Lymphoma malignant | 1 (2%) | 1 (2%) | – | 1 (2%)
Mesothelioma malignant | 1 (2%) | 1 (2%) | – | –
Mesothelioma NOS | 1 (2%) | – | 1 (2%) | 1 (2%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 26 | 27 | 24 | 31
Total primary neoplasms | 38 | 40 | 37 | 47
Total animals with benign neoplasms | 24 | 25 | 23 | 27
Total benign neoplasms | 33 | 33 | 32 | 34
Total animals with malignant neoplasms | 4 | 6 | 3 | 10
Total malignant neoplasms | 4 | 7 | 4 | 12
Total animals with metastatic neoplasms | 1 | – | 1 | –
Total metastatic neoplasms | 2 | – | 4 | –
Total animals with uncertain neoplasms benign or malignant | 1 | – | 1 | 1
Total uncertain neoplasms | 2 | – | 1 | 2

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table A-2 Statistical Analysis of Primary Neoplasms in Male Rats in the Two-year Inhalation Study of TRIM VX

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate^a^ | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate^b^ | 0.0% | 0.0% | 0.0% | 7.2%
Terminal rate^c^ | 0/36 (0%) | 0/39 (0%) | 0/33 (0%) | 3/34 (9%)
First incidence (days) | –^e^ | – | – | 729 (T)
Poly-3 test^d^ | P = 0.007 | –^f^ | – | P = 0.106
Pancreatic Islets: Adenoma
Overall rate | 5/50 (10%) | 1/50 (2%) | 0/50 (0%) | 1/50 (2%)
Adjusted rate | 11.1% | 2.1% | 0.0% | 2.4%
Terminal rate | 3/36 (8%) | 0/39 (0%) | 0/33 (0%) | 0/34 (0%)
First incidence (days) | 662 | 715 | – | 540
Poly-3 test | P = 0.172N | P = 0.092N | P = 0.037N | P = 0.117N
Pancreatic Islets: Adenoma or Carcinoma
Overall rate | 5/50 (10%) | 1/50 (2%) | 0/50 (0%) | 2/50 (4%)
Adjusted rate | 11.1% | 2.1% | 0.0% | 4.7%
Terminal rate | 3/36 (8%) | 0/39 (0%) | 0/33 (0%) | 1/34 (3%)
First incidence (days) | 662 | 715 | – | 540
Poly-3 test | P = 0.394N | P = 0.092N | P = 0.037N | P = 0.244N
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 14/50 (28%) | 13/50 (26%) | 15/50 (30%) | 16/50 (32%)
Adjusted rate | 29.6% | 27.3% | 33.0% | 34.0%
Terminal rate | 7/36 (19%) | 9/39 (23%) | 6/33 (18%) | 7/34 (21%)
First incidence (days) | 421 | 684 | 452 | 367
Poly-3 test | P = 0.310 | P = 0.492N | P = 0.447 | P = 0.403
Skin: Squamous Cell Papilloma or Keratoacanthoma
Overall rate | 1/50 (2%) | 3/50 (6%) | 0/50 (0%) | 1/50 (2%)
Adjusted rate | 2.2% | 6.3% | 0.0% | 2.4%
Terminal rate | 1/36 (3%) | 2/39 (5%) | 0/33 (0%) | 1/34 (3%)
First incidence (days) | 729 (T) | 323 | – | 729 (T)
Poly-3 test | P = 0.462N | P = 0.331 | P = 0.513N | P = 0.744
Thymus: Benign Thymoma
Overall rate | 3/48 (6%) | 3/49 (6%) | 4/50 (8%) | 1/50 (2%)
Adjusted rate | 6.9% | 6.3% | 9.5% | 2.4%
Terminal rate | 2/34 (6%) | 2/39 (5%) | 3/33 (9%) | 1/34 (3%)
First incidence (days) | 535 | 589 | 666 | 729 (T)
Poly-3 test | P = 0.252N | P = 0.619N | P = 0.485 | P = 0.320N
Thyroid Gland (C-Cell): Adenoma
Overall rate | 3/50 (6%) | 5/50 (10%) | 2/50 (4%) | 7/50 (14%)
Adjusted rate | 6.7% | 10.6% | 4.8% | 16.3%
Terminal rate | 3/36 (8%) | 5/39 (13%) | 2/33 (6%) | 4/34 (12%)
First incidence (days) | 729 (T) | 729 (T) | 729 (T) | 409
Poly-3 test | P = 0.105 | P = 0.385 | P = 0.529N | P = 0.140
Thyroid Gland (Follicular Cell): Adenoma
Overall rate | 0/50 (0%) | 1/50 (2%) | 3/50 (6%) | 1/50 (2%)
Adjusted rate | 0.0% | 2.1% | 7.2% | 2.4%
Terminal rate | 0/36 (0%) | 1/39 (3%) | 3/33 (9%) | 1/34 (3%)
First incidence (days) | – | 729 (T) | 729 (T) | 729 (T)
Poly-3 test | P = 0.489 | P = 0.510 | P = 0.107 | P = 0.486
Thyroid Gland (Follicular Cell): Adenoma or Carcinoma
Overall rate | 0/50 (0%) | 2/50 (4%) | 4/50 (8%) | 1/50 (2%)
Adjusted rate | 0.0% | 4.3% | 9.4% | 2.4%
Terminal rate | 0/36 (0%) | 2/39 (5%) | 3/33 (9%) | 1/34 (3%)
First incidence (days) | – | 729 (T) | 551 | 729 (T)
Poly-3 test | P = 0.595 | P = 0.249 | P = 0.054 | P = 0.486
All Organs: Hemangiosarcoma
Overall rate | 0/50 (0%) | 2/50 (4%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 0.0% | 4.3% | 2.4% | 7.0%
Terminal rate | 0/36 (0%) | 2/39 (5%) | 1/33 (3%) | 1/34 (3%)
First incidence (days) | – | 729 (T) | 729 (T) | 459
Poly-3 test | P = 0.122 | P = 0.249 | P = 0.487 | P = 0.111
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 1/50 (2%) | 2/50 (4%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 2.2% | 4.3% | 2.4% | 7.0%
Terminal rate | 0/36 (0%) | 2/39 (5%) | 1/33 (3%) | 1/34 (3%)
First incidence (days) | 626 | 729 (T) | 729 (T) | 459
Poly-3 test | P = 0.227 | P = 0.515 | P = 0.744 | P = 0.288
All Organs: Benign Neoplasms
Overall rate | 24/50 (48%) | 25/50 (50%) | 23/50 (46%) | 27/50 (54%)
Adjusted rate | 49.7% | 50.7% | 49.6% | 57.3%
Terminal rate | 15/36 (42%) | 17/39 (44%) | 13/33 (39%) | 17/34 (50%)
First incidence (days) | 421 | 323 | 270 | 367
Poly-3 test | P = 0.243 | P = 0.540 | P = 0.578N | P = 0.293
All Organs: Malignant Neoplasms
Overall rate | 4/50 (8%) | 6/50 (12%) | 3/50 (6%) | 10/50 (20%)
Adjusted rate | 8.8% | 12.4% | 7.0% | 22.9%
Terminal rate | 2/36 (6%) | 4/39 (10%) | 1/33 (3%) | 7/34 (21%)
First incidence (days) | 421 | 323 | 551 | 459
Poly-3 test | P = 0.029 | P = 0.408 | P = 0.538N | P = 0.059
All Organs: Benign or Malignant Neoplasms
Overall rate | 26/50 (52%) | 27/50 (54%) | 24/50 (48%) | 31/50 (62%)
Adjusted rate | 53.8% | 54.2% | 51.1% | 63.7%
Terminal rate | 17/36 (47%) | 18/39 (46%) | 13/33 (39%) | 19/34 (56%)
First incidence (days) | 421 | 323 | 270 | 367
Poly-3 test | P = 0.149 | P = 0.566 | P = 0.476N | P = 0.214

(T) Terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for lung, pancreatic islets, pituitary gland, thymus, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table A-3 Historical Incidence of Lung Neoplasms in Control Male Wistar Han Rats^a^

Study (Study Start) | Alveolar/bronchiolar Adenoma | Alveolar/bronchiolar Carcinoma | Alveolar/bronchiolar Adenoma or Carcinoma
Historical Incidence: Inhalation Studies
Antimony trioxide (September 2008) | 3/50 | 0/50 | 3/50
CIMSTAR 3800 (April 2008) | 1/50 | 0/50 | 1/50
TRIM VX (July 2009) | 0/50 | 0/50 | 0/50
Total (%) | 4/150 (2.7%) | 0/150 | 4/150 (2.7%)
Mean ± standard deviation | 2.7% ± 3.1% | – | 2.7% ± 3.1%
Range | 0%–6% | – | 0%–6%
Overall Historical Incidence: All Routes
Total (%) | 4/299 (1.3%) | 0/299 | 4/299 (1.3%)
Mean ± standard deviation | 1.3% ± 2.4% | – | 1.3% ± 2.4%
Range | 0%–6% | – | 0%–6%

^a^ Data as of November 2014.

Table A-4 Summary of the Incidence of Nonneoplastic Lesions in Male Rats in the Two-year Inhalation Study of TRIM VX^a^

| Chamber Control | 10 mg/m^3^ | 30 mg/m^3^ | 100 mg/m^3^
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 12 | 10 | 14 | 15
Natural deaths | 2 | 1 | 3 | 1
Survivors
Terminal kill | 36 | 39 | 33 | 34
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (50) | (50) | (50) | (50)
Inflammation | 1 (2%) | – | – | 1 (2%)
Artery, inflammation | 1 (2%) | – | – | –
Lymphoid tissue, hyperplasia | – | – | – | 1 (2%)
Intestine large, colon | (50) | (50) | (50) | (50)
Lymphoid tissue, hyperplasia | – | – | 1 (2%) | –
Intestine large, rectum | (50) | (50) | (50) | (50)
Intestine small, duodenum | (50) | (50) | (50) | (50)
Artery, inflammation | 1 (2%) | – | – | –
Intestine small, ileum | (50) | (50) | (50) | (50)
Intestine small, jejunum | (50) | (50) | (50) | (50)
Liver | (50) | (50) | (50) | (50)
Angiectasis | 5 (10%) | 2 (4%) | – | 4 (8%)
Basophilic focus | 5 (10%) | 10 (20%) | 15 (30%) | 9 (18%)
Clear cell focus | 14 (28%) | 23 (46%) | 17 (34%) | 23 (46%)
Eosinophilic focus | 2 (4%) | – | – | 2 (4%)
Fatty change | – | – | 1 (2%) | 1 (2%)
Hepatodiaphragmatic nodule | 1 (2%) | 2 (4%) | – | 1 (2%)
Infiltration cellular, lymphocyte | – | 1 (2%) | – | –
Inflammation, granulomatous | – | 1 (2%) | – | 2 (4%)
Mixed cell focus | – | 1 (2%) | 2 (4%) | 1 (2%)
Bile duct, cyst | – | – | 2 (4%) | 1 (2%)
Bile duct, dilatation | 1 (2%) | – | – | 2 (4%)
Bile duct, hyperplasia | 2 (4%) | 2 (4%) | 1 (2%) | 1 (2%)
Serosa, fibrosis | – | – | 1 (2%) | –
Mesentery | (2) | (2) | (3) | (5)
Fat, hemorrhage | – | – | 1 (33%) | –
Fat, necrosis | 2 (100%) | 2 (100%) | 2 (67%) | 4 (80%)
Pancreas | (50) | (50) | (50) | (50)
Inflammation | 1 (2%) | 1 (2%) | – | –
Acinus, atrophy | 7 (14%) | 2 (4%) | 9 (18%) | 2 (4%)
Acinus, hyperplasia | – | – | 1 (2%) | –
Acinus, inflammation | 1 (2%) | – | – | –
Salivary glands | (50) | (50) | (50) | (50)
Stomach, forestomach | (50) | (50) | (50) | (50)
Cyst | 1 (2%) | – | – | –
Inflammation | 1 (2%) | – | – | –
Stomach, glandular | (50) | (50) | (50) | (50)
Mineralization | – | – | – | 1 (2%)
Artery, inflammation | 1 (2%) | – | – | –
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 21 (42%) | 17 (34%) | 22 (44%) | 18 (36%)
Endocardium, hyperplasia | – | – | 2 (4%) | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Angiectasis | 4 (8%) | 1 (2%) | 1 (2%) | 3 (6%)
Hypertrophy | 13 (26%) | 18 (36%) | 13 (26%) | 15 (30%)
Necrosis | 2 (4%) | – | – | –
Thrombosis | – | – | 1 (2%) | –
Vacuolization cytoplasmic | 19 (38%) | 23 (46%) | 21 (42%) | 21 (42%)
Adrenal medulla | (50) | (50) | (49) | (49)
Hyperplasia | 1 (2%) | 1 (2%) | – | 1 (2%)
Islets, pancreatic | (50) | (50) | (50) | (50)
Parathyroid gland | (39) | (44) | (46) | (49)
Fibrosis | 1 (3%) | – | – | –
Hyperplasia | – | 1 (2%) | 1 (2%) | –
Pituitary gland | (50) | (50) | (50) | (50)
Angiectasis | 1 (2%) | – | – | –
Cyst | 2 (4%) | 2 (4%) | 4 (8%) | 1 (2%)
Pars distalis, hyperplasia | 12 (24%) | 15 (30%) | 8 (16%) | 11 (22%)
Pars intermedia, hyperplasia | – | – | 3 (6%) | –
Thyroid gland | (50) | (50) | (50) | (50)
C-cell, hyperplasia | 36 (72%) | 39 (78%) | 34 (68%) | 40 (80%)
Follicle, hyperplasia | 4 (8%) | 7 (14%) | 4 (8%) | 1 (2%)
General Body System
None
Genital System
Epididymis | (50) | (50) | (50) | (50)
Granuloma sperm | – | 1 (2%) | – | –
Preputial gland | (49) | (50) | (50) | (50)
Cyst | 1 (2%) | – | – | –
Fibrosis | – | – | – | 1 (2%)
Inflammation | 17 (35%) | 13 (26%) | 11 (22%) | 16 (32%)
Prostate | (50) | (50) | (50) | (50)
Atrophy | – | 1 (2%) | – | –
Fibrosis | – | 1 (2%) | – | –
Inflammation | 17 (34%) | 12 (24%) | 10 (20%) | 10 (20%)
Seminal vesicle | (50) | (50) | (50) | (50)
Atrophy | – | – | – | 1 (2%)
Fibrosis | 1 (2%) | – | – | –
Inflammation | 4 (8%) | – | 1 (2%) | –
Testes | (50) | (50) | (50) | (50)
Cyst | – | – | – | 1 (2%)
Edema | 3 (6%) | 2 (4%) | 1 (2%) | 2 (4%)
Artery, inflammation, chronic | 3 (6%) | – | – | 1 (2%)
Germinal epithelium, atrophy | 3 (6%) | 8 (16%) | – | 6 (12%)
Germinal epithelium, hypoplasia | – | – | 1 (2%) | –
Interstitial cell, hyperplasia | 2 (4%) | – | – | 1 (2%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (11) | (7) | (7) | (8)
Axillary, hyperplasia, plasma cell | – | 1 (14%) | – | –
Iliac, hyperplasia, plasma cell | 1 (9%) | 2 (29%) | 4 (57%) | 1 (13%)
Lumbar, hyperplasia, lymphoid | – | – | – | 1 (13%)
Lumbar, hyperplasia, plasma cell | 7 (64%) | 5 (71%) | 3 (43%) | 4 (50%)
Renal, hyperplasia, plasma cell | 2 (18%) | – | – | 2 (25%)
Lymph node, bronchial | (39) | (43) | (42) | (42)
Hyperplasia, lymphohistiocytic | – | 17 (40%) | 29 (69%) | 35 (83%)
Lymph node, mandibular | (46) | (46) | (46) | (48)
Hyperplasia, plasma cell | 1 (2%) | 1 (2%) | – | –
Lymph node, mediastinal | (43) | (48) | (44) | (43)
Congestion | – | – | – | 1 (2%)
Hyperplasia, lymphohistiocytic | – | 20 (42%) | 22 (50%) | 32 (74%)
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Hemorrhage | – | – | 1 (2%) | –
Hyperplasia, lymphohistiocytic | – | – | – | 1 (2%)
Spleen | (50) | (50) | (50) | (50)
Congestion | – | – | 1 (2%) | –
Cyst | – | 1 (2%) | – | –
Hematopoietic cell proliferation | 7 (14%) | 9 (18%) | 8 (16%) | 8 (16%)
Hemorrhage | – | 1 (2%) | – | –
Lymphoid follicle, atrophy | 3 (6%) | – | 2 (4%) | –
Thymus | (48) | (49) | (50) | (50)
Atrophy | 35 (73%) | 36 (73%) | 26 (52%) | 26 (52%)
Cyst | – | – | 1 (2%) | –
Integumentary System
Mammary gland | (4) | (5) | (1) | (2)
Galactocele | 1 (25%) | – | – | –
Hyperplasia | 1 (25%) | – | – | –
Skin | (50) | (50) | (50) | (50)
Cyst epithelial inclusion | 2 (4%) | 2 (4%) | 1 (2%) | 1 (2%)
Hyperkeratosis | 1 (2%) | – | – | –
Inflammation | 2 (4%) | 1 (2%) | – | 4 (8%)
Ulcer | 16 (32%) | 14 (28%) | 13 (26%) | 13 (26%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Hyperostosis | – | – | – | 1 (2%)
Skeletal muscle | (4) | (4) | (8) | (3)
Nervous System
Brain | (50) | (50) | (50) | (50)
Compression | 8 (16%) | 6 (12%) | 8 (16%) | 7 (14%)
Degeneration | 1 (2%) | – | – | –
Gliosis | 1 (2%) | – | – | –
Hemorrhage | 1 (2%) | – | – | –
Hydrocephalus | 5 (10%) | 3 (6%) | 8 (16%) | 4 (8%)
Necrosis | – | – | 1 (2%) | –
Meninges, inflammation | 1 (2%) | – | – | –
Peripheral nerve | (4) | (2) | (8) | (2)
Axon, degeneration | – | – | 2 (25%) | –
Spinal cord | (4) | (2) | (7) | (2)
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Foreign body | 1 (2%) | – | 1 (2%) | –
Infiltration cellular, mixed cell | 1 (2%) | 9 (18%) | 27 (54%) | 31 (62%)
Inflammation, chronic active | 1 (2%) | 1 (2%) | – | –
Epiglottis, hyperplasia, squamous | – | 26 (52%) | 48 (96%) | 50 (100%)
Epiglottis, metaplasia, squamous | 3 (6%) | 50 (100%) | 50 (100%) | 50 (100%)
Lung | (50) | (50) | (50) | (50)
Fibrosis | 4 (8%) | 43 (86%) | 45 (90%) | 49 (98%)
Foreign body | – | – | 1 (2%) | –
Hyperplasia, lymphohistiocytic | – | 1 (2%) | 1 (2%) | –
Infiltration cellular, histiocyte | 14 (28%) | 50 (100%) | 50 (100%) | 50 (100%)
Inflammation, chronic active | 7 (14%) | 46 (92%) | 46 (92%) | 48 (96%)
Alveolar/bronchiolar epithelium, hyperplasia | 4 (8%) | 22 (44%) | 39 (78%) | 46 (92%)
Alveolar epithelium, hyperplasia | 11 (22%) | 43 (86%) | 45 (90%) | 49 (98%)
Alveolar epithelium, metaplasia, squamous | – | – | – | 5 (10%)
Alveolus, proteinosis | – | 1 (2%) | 31 (62%) | 45 (90%)
Bronchus-associated lymphoid tissue, hyperplasia, lymphohistiocytic | – | 1 (2%) | 4 (8%) | 6 (12%)
Mediastinum, inflammation, chronic | – | 1 (2%) | – | –
Nose | (50) | (50) | (50) | (50)
Foreign body | 1 (2%) | – | 1 (2%) | 1 (2%)
Inflammation, suppurative | 7 (14%) | 46 (92%) | 47 (94%) | 46 (92%)
Glands, olfactory epithelium, hyperplasia | – | 43 (86%) | 41 (82%) | 49 (98%)
Goblet cell, hyperplasia | 5 (10%) | 36 (72%) | 37 (74%) | 42 (84%)
Goblet cell, nasolacrimal duct, metaplasia | – | 1 (2%) | – | –
Goblet cell, olfactory epithelium, hyperplasia | – | – | 1 (2%) | –
Nasolacrimal duct, inflammation, chronic | – | 1 (2%) | – | –
Nasolacrimal duct, metaplasia, squamous | – | 1 (2%) | – | –
Olfactory epithelium, accumulation, hyaline droplet | 20 (40%) | 50 (100%) | 50 (100%) | 50 (100%)
Olfactory epithelium, atrophy | – | 1 (2%) | 1 (2%) | –
Olfactory epithelium, metaplasia, squamous | – | 1 (2%) | – | 1 (2%)
Respiratory epithelium, accumulation, hyaline droplet | 10 (20%) | 50 (100%) | 48 (96%) | 50 (100%)
Respiratory epithelium, hyperplasia | 2 (4%) | 7 (14%) | 7 (14%) | 19 (38%)
Transitional epithelium, hyperplasia | 7 (14%) | 7 (14%) | 8 (16%) | 13 (26%)
Transitional epithelium, metaplasia, squamous | 2 (4%) | 2 (4%) | 3 (6%) | 6 (12%)
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (50) | (50) | (50)
Cataract | – | – | 1 (2%) | 1 (2%)
Inflammation | – | – | 1 (2%) | –
Retina, atrophy | 5 (10%) | 5 (10%) | 1 (2%) | 3 (6%)
Harderian gland | (50) | (50) | (50) | (50)
Cyst | – | 1 (2%) | – | –
Hyperplasia | 1 (2%) | 1 (2%) | – | 1 (2%)
Inflammation | 1 (2%) | 1 (2%) | 1 (2%) | 2 (4%)
Lacrimal gland | (1) | (0) | (0) | (1)
Atrophy | 1 (100%) | – | – | 1 (100%)
Zymbal’s gland | (1) | (0) | (0) | (0)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Cyst | – | – | 1 (2%) | –
Hydronephrosis | 1 (2%) | – | 1 (2%) | 3 (6%)
Infarct | – | 1 (2%) | 2 (4%) | –
Inflammation, granulomatous | – | – | – | 1 (2%)
Metaplasia, lipocyte | – | – | 1 (2%) | 1 (2%)
Necrosis | – | 1 (2%) | – | –
Nephropathy | 27 (54%) | 31 (62%) | 27 (54%) | 28 (56%)
Pelvis, inflammation | 19 (38%) | 17 (34%) | 5 (10%) | 9 (18%)
Renal tubule, cyst | – | 1 (2%) | 1 (2%) | –
Renal tubule, hyperplasia | – | – | 1 (2%) | –
Urinary bladder | (50) | (50) | (50) | (50)
Hemorrhage | – | – | 1 (2%) | –
Inflammation | – | 1 (2%) | 1 (2%) | –
Transitional epithelium, hyperplasia | – | – | 1 (2%) | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.