# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8925

DOI: https://doi.org/10.22427/NTP-TR-590

Report Series: NTP Technical Report Series

Report Series Number: 590

Official citation: National Toxicology Program (NTP). 2017. NTP technical report on the toxicology and carcinogenesis studies of antimony trioxide (CASRN 1309-64-4) in Wistar Han [Crl:WI(Han)] rats and B6C3F1/N mice (inhalation studies). Research Triangle Park, NC: National Toxicology Program. Technical Report 590.