# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  M.D. Stout, Ph.D., Co-Study Scientist
  B.C. Sayers, Ph.D., Co-Study Scientist
  G.P. Flake, M.D., Study Pathologist
  C.R. Blystone, Ph.D.
  P.M. Foster, Ph.D.
  R.A. Herbert, D.V.M., Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  A.R. Pandiri, B.V.Sc. & A.H., Ph.D.
  S.L. Smith-Roe, Ph.D.
  G.S. Travlos, D.V.M.
  M.K. Vallant, M.S., MT
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- Battelle Toxicology Northwest, Richland, Washington, USA
  Conducted studies and evaluated pathology findings
  J.A. Dill, Ph.D., Principal Investigator
  G.L. Baker, Ph.D., Study Director
  S.L. Grumbein, D.V.M., Ph.D.
  B.K. Hayden
  K.M. Patton, D.V.M., Ph.D.
  L.M. Staska, D.V.M., Ph.D.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Conducted pathology review
  R.A. Miller, D.V.M., Ph.D.
  A.R. Pandiri, B.V.Sc. & A.H., Ph.D.
- Pathology Associates International, A Charles River Company, Research Triangle Park, North Carolina, USA
  Coordinated NTP Pathology Working Groups
  J.S. Hoane, D.V.M., Coordinated 2-year rats (October 17, 2013, and November 14, 2013)
  K.A. Szabo, D.V.M., M.S., Coordinated 2-year mice (December 10, 2013)