# References

1 National Research Council (NRC). Toxicological Risk of Selected Flame-Retardant Chemicals. Washington (DC): National Academy Press; 2000.
2 Kuroda K, Endo G, Okamoto A, Yoo YS, Horiguchi S. Genotoxicity of beryllium, gallium and antimony in short-term assays. Mutat Res. 1991;264(4):163–170. 10.1016/0165-7992(91)90072-C 1723493
3 Agency for Toxic Substances and Disease Registry (ATSDR). Toxicological profile for antimony and compounds. Atlanta, GA: U.S. Public Health Service; 1992. https://www.atsdr.cdc.gov/toxprofiles/tp23.pdf
4 Antimony compounds. Environmental Defense: GoodGuide; 2005.
5 Anderson CG. The metallurgy of antimony. Chem Erde. 2012;72:3–8. 10.1016/j.chemer.2012.04.001
6 Hazardous Substances Data Bank (HSDB). Antimony trioxide database search. 2013. [accessed July 2, 2015] https://pubchem.ncbi.nlm.nih.gov/.
7 High Density Packaging User Group International (HDPUGI). Environmental assessment of halogen-free printed circuit boards. Austin (TX): High Density Packaging User Group International Inc; 2005.
8 KEMI. Information on substances — Antimony trioxide. Sweden; 2015. https://web.archive.org/web/20140119053654/http://apps.kemi.se/flodessok/floden/kemamne_eng/antimon_eng.htm [Accessed May 21, 2015]
9 Murray HW, Berman JD, Davies CR, Saravia NG. Advances in leishmaniasis. Lancet. 2005;366(9496):1561–1577. 10.1016/S0140-6736(05)67629-5 16257344
10 Iyengar GV, Tanner JT, Wolf WR, Zeisler R. Preparation of a mixed human diet material for the determination of nutrient elements, selected toxic elements and organic nutrients: a preliminary report. Sci Total Environ. 1987;61:235–252. 10.1016/0048-9697(87)90371-8 3576179
11 Centers for Disease Control and Prevention (CDC). Third national report on human exposure to environmental chemicals. Atlanta, GA: Department of Health and Human Services, Centers for Disease Control and Prevention, National Center for Environmental Health; 2005. NCEH Publication No. 05 0570.
12 American Conference of Governmental Industrial Hygienist (ACGIH). 2015 TLVs® and BEIs® threshold limit values for chemical substances and physical agents and biological exposure indices. Cincinnati, OH: ACGIH; 2015.
13 National Institute for Occupational Safety and Health (NIOSH). NIOSH Pocket Guide to Chemical Hazards. Cincinnati (OH): U.S. Department of Health and Human Services, Public Health Service, Centers for Disease Control and Prevention; 2007.
14 United States Environmental Protection Agency (USEPA). Integrated Risk Information System (IRIS). United States Environmental Protection Agency (USEPA); 2014. https://www.epa.gov/iris/subst/0676.htm [Accessed June 29, 2015]
15 Leffler P, Gerhardsson L, Brune D, Nordberg GF. Lung retention of antimony and arsenic in hamsters after the intratracheal instillation of industrial dust. Scand J Work Environ Health. 1984;10(4):245–251. 10.5271/sjweh.2330 6541805
16 Newton PE, Bolte HF, Daly IW, Pillsbury BD, Terrill JB, Drew RT, Ben-Dyke R, Sheldon AW, Rubin LF. Subchronic and chronic inhalation toxicity of antimony trioxide in the rat. Fundam Appl Toxicol. 1994;22(4):561–576. 10.1006/faat.1994.1063 8056203
17 Felicetti SW, Thomas RG, McClellan RO. Retention of inhaled antimony-124 in the beagle dog as a function of temperature of aerosol formation. Health Phys. 1974;26(6):515–531. 10.1097/00004032-197406000-00006 4209292
18 Thomas RG, Felicetti SW, Lucchino RV, McClellan RO. Retention patterns of antimony in mice following inhalation of particles formed at different temperatures. Proc Soc Exp Biol Med. 1973;144(2):544–550. 10.3181/00379727-144-37632 4746928
19 Felicetti SA, Thomas RG, McClellan RO. Metabolism of two valence states of inhaled antimony in hamsters. Am Ind Hyg Assoc J. 1974;35(5):292–300. 10.1080/0002889748507037 4208632
20 Bailly R, Lauwerys R, Buchet JP, Mahieu P, Konings J. Experimental and human studies on antimony metabolism: their relevance for the biological monitoring of workers exposed to inorganic antimony. Br J Ind Med. 1991;48(2):93–97. 10.1136/oem.48.2.93 1998614
21 Cooper DA, Pendergrass EP, Vorwald AJ, Mayock RL, Brieger H. Pneumoconiosis among workers in an antimony industry. Am J Roentgenol Radium Ther Nucl Med. 1968;103(3):496–508. 10.2214/ajr.103.3.495 5659960
22 Ludersdorf R, Fuchs A, Mayer P, Skulsuksai G, Schacke G. Biological assessment of exposure to antimony and lead in the glass-producing industry. Int Arch Occup Environ Health. 1987;59(5):469–474. 10.1007/BF00377841 3653992
23 McCallum RI. The work of an occupational hygiene service in environmental control. Ann Occup Hyg. 1963;6:55–64. 13932030
24 Gerhardsson L, Brune D, Nordberg GF, Wester PO. Antimony in lung, liver and kidney tissue from deceased smelter workers. Scand J Work Environ Health. 1982;8(3):201–208. 10.5271/sjweh.2475 7156939
25 Vanoeteren C, Cornelis R, Dams R. Evaluation of trace elements in human lung tissue. II. Recovery and analysis of inhaled particulates. Sci Total Environ. 1986;54:231–236. 10.1016/0048-9697(86)90268-8 3810129
26 Vanoeteren C, Cornelis R, Verbeeck P. Evaluation of trace elements in human lung tissue. III. Correspondence analysis. Sci Total Environ. 1986;54:237–245. 10.1016/0048-9697(86)90269-X 3810130
27 Vanoeteren C, Cornelis R, Versieck J. Evaluation of trace elements in human lung tissue. I. Concentration and distribution. Sci Total Environ. 1986;54:217–230. 10.1016/0048-9697(86)90267-6 3810128
28 Hext PM, Pinto PJ, Rimmel BA. Subchronic feeding study of antimony trioxide in rats. J Appl Toxicol. 1999;19(3):205–209. 10.1002/(SICI)1099-1263(199905/06)19:3<205::AID-JAT567>3.0.CO;2-X 10362272
29 McCallum RI. Detection of antimony in process workers’ lungs by x-radiation. Trans Soc Occup Med. 1967;17(4):134–138. 10.1093/occmed/17.4.134 6079333
30 Potkonjak V, Pavlovich M. Antimoniosis: A particular form of pneumoconiosis. I. Etiology, clinical and X-ray findings. Int Arch Occup Environ Health. 1983;51(3):199–207. 10.1007/BF00377752 6222000
31 McCallum RI, Day MJ, Underhill J, Aird EG. Measurement of antimony oxide dust in human lungs in vivo by X-ray spectrophotometry. Inhaled Part. 1970;2:611–619. 5527730
32 Lauwers LF, Roelants A, Rosseel PM, Heyndrickx B, Baute L. Oral antimony intoxications in man. Crit Care Med. 1990;18(3):324–326. 10.1097/00003246-199003000-00017 2302961
33 Belyaeva AP. [The effect of antimony on reproduction (in Russian)]. Gig Tr Prof Zabol. 1967;11:32–37.
34 Omura M, Tanaka A, Hirata M, Inoue N. Testicular toxicity evaluation of two antimony compounds, antimony trioxide and antimony potassium tartrate, in rats and mice. Environ Health Prev Med. 2002;7:15–18. 10.1007/BF02898061 21432285
35 Groth DH, Stettler LE, Burg JR, Busey WM, Grant GC, Wong L. Carcinogenic effects of antimony trioxide and antimony ore concentrate in rats. J Toxicol Environ Health. 1986;18(4):607–626. 10.1080/15287398609530898 3735460
36 Elliott BM, Mackay JM, Clay P, Ashby J. An assessment of the genetic toxicology of antimony trioxide. Mutat Res. 1998;415(1-2):109–117. 10.1016/S1383-5718(98)00065-5 9711267
37 Kanematsu N, Hara M, Kada T. Rec assay and mutagenicity studies on metal compounds. Mutat Res. 1980;77(2):109–116. 10.1016/0165-1218(80)90127-5 6769036
38 Gebel T, Christensen S, Dunkelberg H. Comparative and environmental genotoxicity of antimony and arsenic. Anticancer Res. 1997;17 4a:2603–2607. 9252688
39 Kirkland D, Whitwell J, Deyo J, Serex T. Failure of antimony trioxide to induce micronuclei or chromosomal aberrations in rat bone-marrow after sub-chronic oral dosing. Mutat Res. 2007;627(2):119–128. 10.1016/j.mrgentox.2006.10.012 17174592
40 Cavallo D, Iavicoli I, Setini A, Marinaccio A, Perniconi B, Carelli G, Iavicoli S. Genotoxic risk and oxidative DNA damage in workers exposed to antimony trioxide. Environ Mol Mutagen. 2002;40(3):184–189. 10.1002/em.10102 12355552
41 Griffis LC, Wolff RK, Beethe RL, Hobbs CH, McClellan RO. Evaluation of a multitiered inhalation exposure chamber. Fundam Appl Toxicol. 1981;1(1):8–12. 10.1093/toxsci/1.1.8 7184776
42 Hill MA, Watson CR, Moss OR. NEWCAS - An interactive computer program for particle size analysis. Richland, WA: Pacific Northwest Laboratory; 1977. PNL-2405, UC-32.
43 Lewis TR, Morrow PE, McClellan RO, Raabe OG, Kennedy GL, Schwetz BA, Goehl TJ, Roycroft JH, Chhabra RS. Establishing aerosol exposure concentrations for inhalation toxicity studies. Toxicol Appl Pharmacol. 1989;99(3):377–383. 10.1016/0041-008X(89)90147-6 2749728
44 King-Herbert A, Thayer K. NTP Workshop: Animal models for the NTP rodent cancer bioassay: Stocks and strains—Should we switch? Toxicol Pathol. 2006;34(6):802–805. 10.1080/01926230600935938 17162538
45 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982;10(2):71–78. 10.1177/019262338201000210 28094716
46 Boorman GA, Montgomery CA Jr, Eustis SL, Wolfe MJ, McConnell EE, Hardisty JF. Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA, Weisburger EK, editors. Handbook of Carcinogen Testing. Park Ridge (NJ): Noyes Publications; 1985. p. 345–357.
47 McConnell EE, Solleveld HA, Swenberg JA, Boorman GA. Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. J Natl Cancer Inst. 1986;76(2):283–289. 3456066
48 Kaplan EL, Meier P. Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958;53(282):457–481. 10.1080/01621459.1958.10501452
49 Cox DR. Regression models and life-tables. J R Stat Soc [Ser A]. 1972;B34(2):187–220.
50 Tarone RE. Tests for trend in life table analysis. Biometrika. 1975;62(3):679–690. 10.1093/biomet/62.3.679
51 Bailer AJ, Portier CJ. Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988;44(2):417–431. 10.2307/2531856 3390507
52 Piegorsch WW, Bailer AJ. Statistics for Environmental Biology and Toxicology, Section 6.3.2. London, UK: Chapman and Hall; 1997.
53 Portier CJ, Bailer AJ. Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam Appl Toxicol. 1989;12(4):731–737. 10.1016/0272-0590(89)90004-3 2744275
54 Portier CJ, Hedges JC, Hoel DG. Age-specific models of mortality and tumor onset for historical control animals in the National Toxicology Program’s carcinogenicity experiments. Cancer Res. 1986;46(9):4372–4378. 3731095
55 Bieler GS, Williams RL. Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993;49(3):793–801. 10.2307/2532200 8241374
56 Gart JJ, Chu KC, Tarone RE. Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979;62(4):957–974. 285297
57 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955;50(272):1096–1121. 10.1080/01621459.1955.10501294
58 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971;27(1):103–117. 10.2307/2528930 5547548
59 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972;28(2):519–531. 10.2307/2556164 5037867
60 Dixon WJ, Massey FJ Jr. Introduction to statistical analysis. 2nd ed. New York (NY): McGraw Hill Book Company Inc; 1957. 10.2307/2332898
61 Haseman JK. Value of historical controls in the interpretation of rodent tumor data. Drug Inf J. 1992;26(2):191–200. 10.1177/009286159202600210
62 Haseman JK. Data analysis: statistical analysis and use of historical control data. Regul Toxicol Pharmacol. 1995;21(1):52–59, discussion 81–86. 10.1006/rtph.1995.1009 7784636
63 Haseman JK, Rao GN. Effects of corn oil, time-related changes, and inter-laboratory variability on tumor occurrence in control Fischer 344 (F344/N) rats. Toxicol Pathol. 1992;20(1):52–60. 10.1177/019262339202000107 1411131
64 Code of Federal Regulations (CFR). 21:Part 58.
65 Heddle JA, Hite M, Kirkhart B, Mavournin K, MacGregor JT, Newell GW, Salamone MF. The induction of micronuclei as a measure of genotoxicity. A report of the U.S. Environmental Protection Agency Gene-Tox Program. Mutat Res. 1983;123(1):61–118. 10.1016/0165-1110(83)90047-7 6888413
66 Schmid W. The micronucleus test. Mutat Res. 1975;31(1):9–15. 10.1016/0165-1161(75)90058-8 48190
67 Miller JA, Miller EC. Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt HH, Watson JD, Winsten JA, editors. Origins of Human Cancer. Cold Spring Harbor (NY): Cold Spring Harbor Laboratory; 1977. p. 605–627.
68 Crawford BD. Perspectives on the somatic mutation model of carcinogenesis. In: Mehlman MA, Flamm WG, Lorentzen RJ, editors. Advances in Modern Environmental Toxicology Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton (NJ): Princton Scientific Publishing Co. Inc.; 1985. p. 13–59.
69 Straus DS. Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981;67(2):233–241. 7021938
70 Witt KL, Knapton A, Wehr CM, Hook GJ, Mirsalis J, Shelby MD, MacGregor JT. Micronucleated erythrocyte frequency in peripheral blood of B6C3F1 mice from short-term, prechronic, and chronic studies of the NTP carcinogenesis bioassay program. Environ Mol Mutagen. 2000;36(3):163–194. 10.1002/1098-2280(2000)36:3<163::AID-EM1>3.0.CO;2-P 11044899
71 Sasaki YF, Sekihashi K, Izumiyama F, Nishidate E, Saga A, Ishida K, Tsuda S. The comet assay with multiple mouse organs: comparison of comet assay results and carcinogenicity with 208 chemicals selected from the IARC monographs and U.S. NTP Carcinogenicity Database. Crit Rev Toxicol. 2000;30(6):629–799. 10.1080/10408440008951123 11145306
72 Greaves P. Histopathology of Preclinical Toxicity Studies. 4th ed. London, UK: Academic Press; 2012.
73 Whalen JE, Foureman GL, Vandenberg JJ. Inhalation Risk Assessment at the Environmental Protection Agency. In: Salem H, Katz SA, editors. Inhalation Toxicology. 2nd ed. Boca Raton (FL): CRC Press Taylor and Francis Group; 2006. p. 3–38.
74 Morrow PE. Possible mechanisms to explain dust overloading of the lungs. Fundam Appl Toxicol. 1988;10(3):369–384. 10.1016/0272-0590(88)90284-9 3286345
75 Morrow PE. Dust overloading of the lungs: update and appraisal. Toxicol Appl Pharmacol. 1992;113(1):1–12. 10.1016/0041-008X(92)90002-A 1553742
76 Tran CL, Buchanan D, Cullen RT, Searl A, Jones AD, Donaldson K. Inhalation of poorly soluble particles. II. Influence Of particle surface area on inflammation and clearance. Inhal Toxicol. 2000;12(12):1113–1126. 10.1080/08958370050166796 11114784
77 Howroyd P, Allison N, Foley JF, Hardisty J. Apparent alveolar bronchiolar tumors arising in the mediastinum of F344 rats. Toxicol Pathol. 2009;37(3):351–358. 10.1177/0192623309332988 19380845
78 Boorman GA, Brockmann M, Carlton WW, Davis JM, Dungworth DL, Hahn FF, Mohr U, Reichhelm HB, Turusov VS, Wagner BM. Classification of cystic keratinizing squamous lesions of the rat lung: report of a workshop. Toxicol Pathol. 1996;24(5):564–572. 10.1177/019262339602400505 8923677
79 National Toxicology Program (NTP). Toxicology and Carcinogenesis Studies of Talc (CAS No. 14807-96-6) in F344/N Rats and B6C3F1 Mice (Inhalation Studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1993. Technical Report Series No. 421. NIH Publication No. 93-3152.
80 National Toxicology Program (NTP). Toxicology and Carcinogenesis Studies of Nickel Subsulfide (CAS No. 12035-72-2) in F344/N Rats and B6C3F1 Mice (Inhalation Studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1996. Technical Report Series No. 453. NIH Publication No. 96-3369.
81 National Toxicology Program (NTP). Toxicology and Carcinogenesis Studies of Nickel Sulfate Hexahydrate (CAS No. 10101-97-0) in F344/N Rats and B6C3F1 Mice (Inhalation Studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1996. Technical Report Series No. 454. NIH Publication No. 96-3370.
82 National Toxicology Program (NTP). Toxicology and Carcinogenesis Studies of Molybdenum Trioxide (CAS No. 1313-27-5) in F344/N Rats and B6C3F1 Mice (Inhalation Studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1997. Technical Report Series No. 462. NIH Publication No. 97-3378.
83 National Toxicology Program (NTP). Toxicology and Carcinogenesis Studies of Cobalt Sulfate Heptahydrate (CAS No. 10026-24-1) in F344/N Rats and B6C3F1 Mice (Inhalation Studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1998. Technical Report Series No. 471. NIH Publication No. 98-3961.
84 National Toxicology Program (NTP). Toxicology and Carcinogenesis Studies of Gallium Arsenide (CAS No. 1303-00-0) in F344/N Rats and B6C3F1 Mice (Inhalation Studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2000. Technical Report Series No. 492. NIH Publication No. 00-3951.
85 National Toxicology Program (NTP). Toxicology and Carcinogenesis Studies of Indium Phosphide (CAS No. 22398-80-7) in F344/N Rats and B6C3F1 Mice (Inhalation Studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2001. Technical Report Series No. 499. NIH Publication No. 01-4433.
86 National Toxicology Program (NTP). Toxicology Studies of Cobalt Metal (CAS No. 7440-48-4) in F344/N Rats and B6C3F1/N Mice and Toxicology and Carcinogenesis Studies of Cobalt Metal in F344/NTac Rats and B6C3F1/N Mice (Inhalation Studies). Research Triangle Park, NC: National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services; 2014. Technical Report Series No. 581.
87 Ozaki K, Haseman JK, Hailey JR, Maronpot RR, Nyska A. Association of adrenal pheochromocytoma and lung pathology in inhalation studies with particulate compounds in the male F344 rat—the National Toxicology Program experience. Toxicol Pathol. 2002;30(2):263–270. 10.1080/019262302753559605 11950170
88 Teixeira L, Dubielzig RR. Chapter 53, Eye. In: Haschek WM, Rousseaux CG, Wallig MA, editors. Haschek and Rosseaux’s Handbook of Toxicologic Pathology. Vol. 3. 3rd ed. Boston (MA): Elsevier; 2013. p. 2095–2185. 10.1016/B978-0-12-415759-0.00053-4
89 Moyer CF, Kodavanti UP, Haseman JK, Costa DL, Nyska A. Systemic vascular disease in male B6C3F1 mice exposed to particulate matter by inhalation: Studies conducted by the National Toxicology Program. Toxicol Pathol. 2002;30(4):427–434. 10.1080/01926230290105631 12187935
90 Frazier KS, Seely JC, Hard GC, Betton G, Burnett R, Nakatsuji S, Nishikawa A, Durchfeld-Meyer B, Bube A. Proliferative and nonproliferative lesions of the rat and mouse urinary system. Toxicol Pathol. 2012;40(4) Suppl:14S–86S. 10.1177/0192623312438736 22637735
91 Cooper RG, Harrison AP. The exposure to and health effects of antimony. Indian J Occup Environ Med. 2009;13(1):3–10. 10.4103/0019-5278.50716 20165605
92 Sundar S, Chakravarty J. Antimony toxicity. Int J Environ Res Public Health. 2010;7(12):4267–4277. 10.3390/ijerph7124267 21318007
93 ILSI Risk Science Institute. The relevance of the rat lung response to particle overload for human risk assessment: A workshop consensus report. Inhal Toxicol. 2000;12(1-2):1–17. 10.1080/08958370050029725 10715616
94 Torous DK, Hall NE, Illi-Love AH, Diehl MS, Cederbrant K, Sandelin K, Ponten I, Bolcsfoldi G, Ferguson LR, Pearson A, et al. Interlaboratory validation of a CD71-based flow cytometric method (Microflow) for the scoring of micronucleated reticulocytes in mouse peripheral blood. Environ Mol Mutagen. 2005;45(1):44–55. 10.1002/em.20081 15605355
95 Witt KL, Livanos E, Kissling GE, Torous DK, Caspary W, Tice RR, Recio L. Comparison of flow cytometry- and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res. 2008;649(1-2):101–113. 10.1016/j.mrgentox.2007.08.004 17869571
96 Dertinger SD, Camphausen K, Macgregor JT, Bishop ME, Torous DK, Avlasevich S, Cairns S, Tometsko CR, Menard C, Muanza T, et al. Three-color labeling method for flow cytometric measurement of cytogenetic damage in rodent and human blood. Environ Mol Mutagen. 2004;44(5):427–435. 10.1002/em.20075 15517570
97 MacGregor JT, Bishop ME, McNamee JP, Hayashi M, Asano N, Wakata A, Nakajima M, Saito J, Aidoo A, Moore MM, et al. Flow cytometric analysis of micronuclei in peripheral blood reticulocytes: II. An efficient method of monitoring chromosomal damage in the rat. Toxicol Sci. 2006;94(1):92–107. 10.1093/toxsci/kfl076 16888079
98 Kissling GE, Dertinger SD, Hayashi M, MacGregor JT. Sensitivity of the erythrocyte micronucleus assay: dependence on number of cells scored and inter-animal variability. Mutat Res. 2007;634(1-2):235–240. 10.1016/j.mrgentox.2007.07.010 17851117
99 Recio L, Hobbs C, Caspary W, Witt KL. Dose-response assessment of four genotoxic chemicals in a combined mouse and rat micronucleus (MN) and Comet assay protocol. J Toxicol Sci. 2010;35(2):149–162. 10.2131/jts.35.149 20371966
100 Burlinson B, Tice RR, Speit G, Agurell E, Brendler-Schwaab SY, Collins AR, Escobar P, Honma M, Kumaravel TS, Nakajima M, et al. Fourth International Workgroup on Genotoxicity testing: results of the in vivo Comet assay workgroup. Mutat Res. 2007;627(1):31–35. 10.1016/j.mrgentox.2006.08.011 17118697
101 Ghanayem BI, Witt KL, Kissling GE, Tice RR, Recio L. Absence of acrylamide-induced genotoxicity in CYP2E1-null mice: evidence consistent with a glycidamide-mediated effect. Mutat Res. 2005;578(1-2):284–297. 10.1016/j.mrfmmm.2005.05.004 15982677
102 Tice RR, Agurell E, Anderson D, Burlinson B, Hartmann A, Kobayashi H, Miyamae Y, Rojas E, Ryu J-C, Sasaki YF. Single cell gel/comet assay: guidelines for in vitro and in vivo genetic toxicology testing. Environ Mol Mutagen. 2000;35(3):206–221. 10.1002/(SICI)1098-2280(2000)35:3<206::AID-EM8>3.0.CO;2-J 10737956
103 Mann HB, Whitney DR. On a test of whether one of two random variables is stochastically larger than the other. Ann Math Stat. 1947;18(1):50–60. 10.1214/aoms/1177730491
104 Kendall MG. A new measure of rank correlation. Biometrika. 1938;30(1/2):81–93. 10.2307/2332226
105 Bolton RE, Vincent JH, Jones AD, Addison J, Beckett ST. An overload hypothesis for pulmonary clearance of UICC amosite fibres inhaled by rats. Br J Ind Med. 1983;40(3):264–272. 10.1136/oem.40.3.264 6307338
106 Mauderly JL. Lung overload: The dilemma and opportunities for resolution. In: Mauderly JL, McCuinney RJ, editors. Particle Overload in the Rat Lung and Lung Cancer: Implications for Human Risk Assessmen. Washington (DC): Taylor and Francis; 1995. p. 1–28.
107 Lehnert BE, Morrow PE. Characteristics of alveolar macrophages following the deposition of a low burden or iron oxide in the lung. J Toxicol Environ Health. 1985;16(6):855–868. 10.1080/15287398509530793 4093998
108 Lehnert BE, Morrow PE. Association of 59iron oxide with alveolar macrophages during alveolar clearance. Exp Lung Res. 1985;9(1-2):1–16. 10.3109/01902148509061524 4065055
109 Masse R, Fritsch P, Nolike D, LaFuma J, Chretien J. Cytokinetic study of alveolar macrophage renewal in rats. In: Sanders CL, Snieder RP, Doyle GE, Ragan HA, editors. Pulmonary Macrophage and Epithelial Cells. Washington (DC): Energy Research and Development Administration, Technical Information Center; 1977. p. 106–114.
110 Crapo JD, Barry BE, Foscue HA, Shelburne J. Structural and biochemical changes in rat lungs occurring during exposures to lethal and adaptive doses of oxygen. Am Rev Respir Dis. 1980;122(1):123–143. 7406333
111 Boch C, Kollmeier J, Roth A, Stephan-Falkenau S, Misch D, Gruning W, Bauer TT, Mairinger T. The frequency of EGFR and KRAS mutations in non-small cell lung cancer (NSCLC): routine screening data for central Europe from a cohort study. BMJ Open. 2013;3(4):e002560. 10.1136/bmjopen-2013-002560 23558737
112 Ellis CA, Clark G. The importance of being K-Ras. Cell Signal. 2000;12(7):425–434. 10.1016/S0898-6568(00)00084-X 10989276
113 Roberts PJ, Der CJ. Targeting the Raf-MEK-ERK mitogen-activated protein kinase cascade for the treatment of cancer. Oncogene. 2007;26(22):3291–3310. 10.1038/sj.onc.1210422 17496923
114 Johnson BE, Janne PA. Epidermal growth factor receptor mutations in patients with non-small cell lung cancer. Cancer Res. 2005;65(17):7525–7529. 10.1158/0008-5472.CAN-05-1257 16140912
115 Baan RA. Carcinogenic hazards from inhaled carbon black, titanium dioxide, and talc not containing asbestos or asbestiform fibers: recent evaluations by an IARC Monographs Working Group. Inhal Toxicol. 2007;19 Suppl 1:213–228. 10.1080/08958370701497903 17886070
116 Hong H-HL, Ton T-VT, Kim Y, Wakamatsu N, Clayton NP, Chan P-C, Sills RC, Lahousse SA. Genetic alterations in K-ras and p53 cancer genes in lung neoplasms from B6C3F1 mice exposed to cumene. Toxicol Pathol. 2008;36(5):720–726. 10.1177/0192623308320280 18648094
117 Eberhard DA, Johnson BE, Amler LC, Goddard AD, Heldens SL, Herbst RS, Ince WL, Janne PA, Januario T, Johnson DH, et al. Mutations in the epidermal growth factor receptor and in KRAS are predictive and prognostic indicators in patients with non-small-cell lung cancer treated with chemotherapy alone and in combination with erlotinib. J Clin Oncol. 2005;23(25):5900–5909. 10.1200/JCO.2005.02.857 16043828
118 Shigematsu H, Lin L, Takahashi T, Nomura M, Suzuki M, Wistuba II, Fong KM, Lee H, Toyooka S, Shimizu N, et al. Clinical and biological features associated with epidermal growth factor receptor gene mutations in lung cancers. J Natl Cancer Inst. 2005;97(5):339–346. 10.1093/jnci/dji055 15741570
119 Blons H, Cote JF, Le Corre D, Riquet M, Fabre-Guilevin E, Laurent-Puig P, Danel C. Epidermal growth factor receptor mutation in lung cancer are linked to bronchioloalveolar differentiation. Am J Surg Pathol. 2006;30(10):1309–1315. 10.1097/01.pas.0000213285.65907.31 17001163