# Conclusions

Under the conditions of these 2-year inhalation studies, there was some evidence of carcinogenic activity^1^ of antimony trioxide in male Wistar Han rats based on increased combined incidences of alveolar/bronchiolar adenoma or carcinoma in the lung and on increased incidences of benign pheochromocytoma of the adrenal medulla. There was some evidence of carcinogenic activity of antimony trioxide in female Wistar Han rats based on increased incidences of alveolar/bronchiolar adenoma in the lung and on increased combined incidences of benign or malignant pheochromocytoma of the adrenal medulla. The combined occurrence of cystic keratinizing epithelioma or squamous cell carcinoma in the lung may have been related to exposure. There was clear evidence of carcinogenic activity of antimony trioxide in male B6C3F1/N mice based on increased incidences of alveolar/bronchiolar carcinoma of the lung. Increases in the incidences of fibrous histiocytoma in the skin, as well as the combined incidences of fibrous histiocytoma or fibrosarcoma in the skin of male mice were also considered to be related to exposure. There was clear evidence of carcinogenic activity in female B6C3F1/N mice based on increases in the incidences of alveolar/bronchiolar adenoma and alveolar/bronchiolar carcinoma of the lung and on increased incidences of malignant lymphoma. The occurrence of squamous cell carcinoma of the skin may have been related to exposure.

1 See Explanation of Levels of Evidence of Carcinogenic Activity. See summary of the peer review panel comments and the public discussion on this Technical Report in Appendix L.

Exposure to antimony trioxide resulted in increased incidences of nonneoplastic findings of the lung, nose, larynx, trachea, bronchial and mediastinal lymph nodes, and bone marrow of male and female rats and mice; the adrenal medulla, arteries of multiple tissues (mesentery, pancreas, mediastinum, kidney, and lung), kidney, and eye of male and female rats; the thymus and heart of male and female mice; the forestomach of male mice; and the spleen of female mice.