# Discussion

Antimony trioxide was nominated for National Toxicology Program testing by the Consumer Product Safety Commission and the National Institute of Environmental Health Sciences due to the potential for substantial human exposure in occupational settings and the lack of adequate 2-year exposure carcinogenicity studies. Three 1-year inhalation exposure studies in rats are reported in the literature^14; 16; 35^; however, the methodologies and lung carcinogenicity results were inconsistent among the three studies. In response, NTP conducted 2-week and 2-year inhalation studies to assess whether antimony trioxide poses a carcinogenic hazard in rats, to generate data in a second species, and to characterize the exposure-concentration responses in rats and mice. A 12-month interim evaluation was added as a means of comparison to previous inhalation studies. Inhalation exposure was selected because this is the most common route of occupational exposure to antimony trioxide in humans.

Due to the lack of overt toxicity in the current 2-week studies in rats and mice, the similar incidences and severities of chronic active lung inflammation in the 30 and 60 mg/m^3^ groups in rats, and the effects observed in the previous 1-year studies in rats^14; 16; 35^, 30 mg/m^3^ was selected as the highest exposure concentration for the 2-year studies in rats and mice. Lower concentrations were spaced in half-log intervals, such that the lowest exposure concentration (3 mg/m^3^) selected for the 2-year studies, was lower than the exposure concentration that resulted in modest increases in nonneoplastic lesions and no increases in neoplastic lesions following exposure of rats for 1 year^16^. There were several design differences between the current and previous chronic studies, notably, the exposure duration of 2 years, the inclusion of mice in the studies, and the antimony trioxide particle size in the exposure atmospheres. The mass median aerodynamic particle diameter and geometric standard deviation in the current studies were consistent with NTP specifications and were utilized to maximize deposition in the lower respiratory tract, particularly with the inclusion of mice in the studies^43^. The difference in particle size, increased alveolar deposition, and 2-year exposure duration likely explain, in part, the more apparent lung toxicity and carcinogenicity in the current studies in comparison to those reported in the literature.

In the 2-year studies, there were decreases in survival and body weight (greater than 10%) at the higher concentrations; these decreases were observed relatively late (approximately 18 months or later) in the studies. Decreases in survival were attributed primarily to nonneoplastic and/or neoplastic lung lesions (rats and mice) or malignant lymphoma (female mice). Consistent with the observed pulmonary toxicity and retention of particles, exposure-related clinical observations included abnormal breathing and thinness in male and female rats and mice and cyanosis in both sexes of rats. These observations were most prominent in the 10 and 30 mg/m^3^ groups. These effects were not generally observed until the second year of exposure; there was no pattern observed when comparing day of onset with exposure concentration.

The lung was the major target of toxicity and carcinogenicity in rats and mice exposed to antimony trioxide for 2 years. Exposure-related increases in the incidences of lung neoplasms and in nonneoplastic lesions were observed in rats and mice of both sexes; increases in nonneoplastic lung lesions were observed at all exposure concentrations. Notably, the incidences of alveolar epithelium hyperplasia and bronchiole epithelium hyperplasia were increased in all exposed groups of rats and mice in the 2-year studies; these lesions are considered to be preneoplastic. A 12-month interim evaluation was included in the current 2-year studies to compare to the previous 1-year exposure studies reported in the literature^14; 16; 35^. Overall, in comparison to studies reported in the literature, the toxicity of antimony trioxide to the lung was more pronounced and occurred at a lower concentration under a similar exposure paradigm.

In 2-year male rats, although not statistically significant, the incidences of alveolar/bronchiolar adenoma in the 10 and 30 mg/m^3^ groups were higher than that of concurrent chamber controls and exceeded the historical control incidences for inhalation studies (4/150) and for all routes of administration (4/299). The concurrent chamber control incidence of alveolar/bronchiolar adenoma (3/50) was the highest observed incidence in the historical control database (consisting of six 2-year studies in Wistar Han rats). Multiple alveolar/bronchiolar adenomas were observed in 3 and 30 mg/m^3^ male rats, and alveolar/bronchiolar carcinomas were observed in two 10 mg/m^3^ male rats. In two of the male rats, alveolar/bronchiolar tumors were noted in the mediastinum as well as in the lung; although it is unusual for these tumors to be found in the mediastinum, this has been previously reported^77^. Alveolar/bronchiolar carcinomas have not been observed in the historical controls (inhalation studies: 0/150; all routes: 0/299). Finally, exposure-related increases in lung neoplasms occurred in female rats as well as male and female mice. Collectively, the higher combined incidences of adenoma or carcinoma were considered to be some evidence of carcinogenic activity in male rats.

In female rats at 2 years, incidences of alveolar/bronchiolar adenoma were higher than that in the concurrent chamber controls at all exposure concentrations, and these increases were statistically significant at 10 and 30 mg/m^3^. Alveolar/bronchiolar adenomas were not observed in the historical control female rats (inhalation studies: 0/150; all routes: 0/300). Additionally, an alveolar/bronchiolar adenoma was observed in a 30 mg/m^3^ female rat at the 12-month interim evaluation. These neoplasms are known to progress to carcinomas. However, the alveolar/bronchiolar adenoma response observed in this study was not marked and no alveolar/bronchiolar carcinomas were observed; alveolar/bronchiolar carcinomas were not observed in historical control female rats (inhalation studies: 0/150; all routes: 0/300). Collectively, these data were considered to be some evidence of carcinogenic activity in female rats.

Incidences of alveolar/bronchiolar carcinoma were significantly increased in all exposed groups of male and female mice compared to the chamber controls at 2 years. Additionally, the incidences of alveolar/bronchiolar adenoma were significantly increased in all exposed groups of female mice. These incidences exceeded the historical control ranges for inhalation studies and for all routes of administration in all exposed groups of males and females. The incidences of multiple alveolar/bronchiolar carcinomas were significantly increased in all groups of exposed males and females compared to the chamber controls. In addition, the incidence of metastases was elevated in all exposed groups of male and female mice; this response was exposure-concentration related in males. Finally, alveolar/bronchiolar neoplasms were observed at the 12-month interim evaluation in 10 and 30 mg/m^3^ males and 30 mg/m^3^ females. Collectively, these data were considered to be clear evidence of carcinogenic activity in male and female mice.

In addition to the alveolar/bronchiolar lung neoplasms, two occurrences of cystic keratinizing epithelioma and one occurrence of squamous cell carcinoma occurred in 30 mg/m^3^ female rats; neither of these neoplasms has been observed in the historical controls. Squamous metaplasia of alveolar septa also occurred only in treated female rats. Cystic keratinizing epitheliomas are considered part of a spectrum of lesions that form a morphologic continuum considered to progress from squamous metaplasia to keratin cysts to cystic keratinizing epithelioma to squamous cell carcinoma^78^. The occurrence of these lesions in female rats may have been related to treatment.

The overall pattern of nonneoplastic lung lesion incidences was similar between the sexes and between the 12-month and 2-year exposure durations within each species. In general, severities were similar or slightly higher in the 2-year studies, as compared to the 12-month interim evaluations. The incidences of a number of nonneoplastic lung lesions were increased in all exposed groups in most to all exposed animals. These included foreign body (presumed test article), chronic active inflammation, and alveolar fibrosis in addition to the hyperplasia discussed above. However, there were some notable differences between the species, including the presence of proteinosis exclusively in the lungs of rats, the presence of marked peribronchial and perivascular lymphoid hyperplasia in the lungs of mice, and the more prominent pleural inflammation and fibrosis in mice. Because pulmonary alveolar proteinosis in humans is usually associated with accumulation of surfactant, immunohistochemical stains for surfactants A and C were performed, resulting in strong, diffuse staining of the proteinosis for surfactant A. To our knowledge, this is the first demonstration of surfactant accumulation as a cause of proteinosis in rats.

In the upper respiratory tract, including the larynx, trachea, and nose of rats and mice, foreign body (presumed test article) was observed at both the 12-month interim evaluations and in the 2-year studies. Additional upper respiratory tract lesions occurred in both rats and mice, consisting primarily of respiratory epithelium hyperplasia and squamous metaplasia and occurred in the nose of rats and the larynx of mice.

The adrenal medulla was also a target tissue in the 2-year rat study. Exposure-related increases in the incidences of benign pheochromocytoma and of hyperplasia were observed in male and female rats and the incidences were significant at 30 mg/m^3^ compared to the chamber controls. The incidences of benign pheochromocytoma in 30 mg/m^3^ male and female rats exceeded the historical control ranges for inhalation studies and for all routes of administration. Malignant pheochromocytoma was observed in a single 30 mg/m^3^ female rat. These increases were considered to be related to exposure in male and female rats. The results of several NTP inhalation studies with particulate compounds suggest that there may be an association between benign and malignant alveolar/bronchiolar neoplasms and variably extensive chronic pulmonary nonneoplastic lesions and significantly increased incidences of hyperplasias and benign and malignant pheochromocytomas of the adrenal medulla in rats^79-86^. With varying degrees of statistical significance, in some but not all studies, this relationship appeared to be associated with the severities of lung fibrosis and inflammation^87^. The mechanism(s) of this association between lung lesions and adrenal medulla pheochromocytoma in rats is not understood. However, reduced gas exchange induced by extensive space-occupying neoplasms and nonneoplastic lung lesions such as fibrosis, chronic inflammation, and alveolar proteinosis may lead to systemic hypoxemia that chronically stimulates catecholamine secretion from the adrenal medulla. This chronic hypersecretory activity may lead to medullary hyperplasia and subsequent neoplasia^87^. Clinically, the extensive lung disease was manifested by abnormal breathing (rats and mice) and cyanosis (rats only) during the second year of exposure in the current 2-year studies and considered to be related to exposure.

In 2-year female mice, the incidences of malignant lymphoma were increased in an exposure-concentration dependent manner, with significant increases in all exposed groups compared to the chamber controls; the incidences in the 10 and 30 mg/m^3^ groups exceeded the historical control ranges for inhalation studies and for all routes of administration. The malignant lymphomas typically involved spleen, lung, bronchial and mediastinal lymph nodes, and sometimes the liver. Since almost all exposed mice exhibited prominent perivascular and peribronchial lymphoid hyperplasia, which was similar to the distribution of the lymphomatous infiltrates in the lung, the possibility of malignant transformation from the lymphoid hyperplasia in the lung to lymphoma was considered. However, almost all of the malignant lymphomas also involved the spleen, so the alternative possibility of splenic origin with secondary pulmonary involvement cannot be excluded. At the 12-month interim evaluation, three incidences of malignant lymphoma occurred in 30 mg/m^3^ female mice and other 12-month interim evaluation female mice exhibited atypical lymphoid proliferations in the lung and spleen that were suggestive of preneoplastic proliferations or evolving lymphomas. Immunohistochemical stains for B and T cell markers in selected lymphomas from the 2-year study revealed a predominance of B cells with a significant admixture of T cells. The increased incidences of malignant lymphomas in female mice were considered to be clear evidence of carcinogenic activity.

The incidence of fibrous histiocytoma in the skin was significantly increased in 30 mg/m^3^ male mice compared to the chamber controls at 2 years. In addition, fibrosarcoma was observed in two 10 mg/m^3^ male mice. The increases in the combined incidences of fibrous histiocytoma and fibrosarcoma were considered to be related to exposure because the increases were exposure-related, a potential target after whole body exposure, and exceeded the historical control range. In 2-year female mice, squamous cell carcinoma of the skin occurred with a positive trend. This lesion has not been observed in historical control females in inhalation studies or all routes of administration. This occurrence in the 30 mg/m^3^ females may have been related to exposure.

There were increased incidences of nonneoplastic lesions in the hematopoietic system. In the lung associated (bronchial and mediastinal) lymph nodes, foreign body (presumed test article) was present in most exposed rats and mice, while lymphoid hyperplasia was observed in exposed rats. Observed increases in bone marrow hyperplasia in rats and mice and hematopoietic cell proliferation of the spleen in female mice were probably secondary responses to hypoxia and pulmonary inflammation. The increased incidence and severity of cellular depletion of the thymus in both male and female mice in the 2-year study were probably related to stress. The decreased incidence of lymphoid hyperplasia in the spleen of exposed female mice at 2 years appeared to coincide with the concomitant transformation to malignant lymphoma.

In the eyes of rats, acute inflammation of the ciliary body was observed in some of the 10 and 30 mg/m^3^ male and female rats. The ciliary body is part of the uveal tract, which is an important vascular region of the eye. Since the antimony trioxide entered the blood of exposed animals, the inflammatory reaction in the ciliary body may have been secondary to irritation from systemically derived test article. Incidences of retinal atrophy were significantly increased in all exposed groups of female rats compared to the chamber controls. In 2-year rodent bioassays, especially with albino rodents, phototoxic changes are seen fairly frequently as a background change, especially in females^88^. Although there appears to have been a test article-related exacerbation of the background incidence of retinal atrophy in the female rats, it is uncertain whether this was a direct effect of the chemical or a secondary compound-related effect on one of the pathways associated with phototoxicity, such as oxidative stress or apoptosis^88^. Although the incidence of cataracts was slightly increased in female mice, the significance was uncertain because the incidence was low and without a dose response.

Arteritis was observed in multiple tissues in male and female rats. When all tissues were combined, incidences were significantly increased in an exposure concentration-dependent manner. Sites most commonly involved included mesentery, pancreas, and mediastinum. An increased incidence of arteritis has been previously described in rodents exposed to particulate matter by inhalation^89^. Although the cause of arteritis in these studies is unknown, it has been speculated that hypoxia may result in increased blood volume, creating shear stresses within arterial walls. The sites involved in this study offer some support for this hypothesis since these arteries are surrounded by less supporting tissue and might be more vulnerable to shear stresses from increased blood flow.

The incidences of renal tubule hyaline droplet accumulation were significantly increased in 30 mg/m^3^ male and female rats and in 10 mg/m^3^ female rats. The source and character of these droplets was not determined. The possibility that the droplets could be deposits of surfactant A originating from the pulmonary proteinosis was considered; however, immunohistochemical stains for surfactant A were negative. Several lines of evidence indicate that this lesion was not due to chemically bound alpha-2u globulin. The alpha-2u globulin syndrome, in which an accumulation of bound protein in the kidney leads to a cascade of events including cell death, sloughing off of cells, and finally nephropathy, only occurs in male rats. However, in the current 2-year studies, the lesion occurred in both males and females. In addition, in the alpha-2u globulin syndrome, increases in hyaline droplets typically occur following subchronic exposures and are not observed following chronic exposures as they were in the current studies. An increased incidence of nephropathy (chronic progressive nephropathy) was also noted in the 30 mg/m^3^ female rats; chronic progressive nephropathy is a spontaneously occurring disease of rats, which can be exacerbated by many chemicals in chronic toxicity studies^90^.

In the 2-year mouse study, incidences of chronic active inflammation of the epicardium in the heart were significantly increased in 10 and 30 mg/m^3^ males and females; the lesion may have been secondary to inflammation of the pleura. In addition, absolute, but not relative, heart weights were increased in 30 mg/m^3^ females at the 12-month interim evaluation. Based on reports in the literature^91; 92^, the heart is one of the major target organs following exposure to soluble antimony compounds. However, no evidence of direct toxicity to the heart was observed in the current 2-year studies.

The chronic active inflammation and ulceration of the skin in male rats and ulceration of skin in female rats occurred predominately on the plantar surfaces of the feet of both the treated and control animals and were believed to be secondary to the large size of the rats walking on the wire cages; the increased incidences of these lesions in the treated animals may have been related to exacerbation by the test article.

In order to assess the potential for genotoxicity in rats and mice following exposure to antimony trioxide, the erythrocyte micronucleus assay, measuring chromosomal damage, was performed in blood, and the comet assay was performed to assess DNA damage in lung tissue and blood leukocytes. Significant increases in micronucleated mature erythrocytes (NCEs) and DNA damage in lung cells were observed in male and female mice. The increases in micronucleated NCEs were supported by a trend toward increased frequencies of micronucleated immature erythrocytes (reticulocytes; PCEs). The increases in micronucleated erythrocytes occurred concomitantly with increases in percent reticulocytes in peripheral blood. The latter observation suggests a stimulation of erythropoiesis as a consequence of exposure to antimony trioxide, and increased cell turnover cannot be discounted as a factor in the small, but exposure concentration-related, increases in micro-nucleated NCEs observed in the mice. The increases in percent reticulocytes may have been a consequence of hypoxia that resulted from exposure to the higher concentrations of antimony trioxide, although hypoxia occurred in the rats as well (as indicated by the cyanosis), with no accompanying increases in percent reticulocytes or micronuclei. Results from the comet assay indicated that DNA damage occurred in lung cells of exposed male and female mice, as evidenced by increases in DNA migration measured as percent tail DNA. Antimony trioxide has previously been reported to be genotoxic in mammalian cells in vitro^2; 36; 38^, but not in vivo^36; 39^; however, the in vivo studies reporting negative genotoxicity test results used gavage as the route of exposure, in contrast to the studies reported here, in which antimony trioxide was administered via inhalation. Due to its insoluble nature, absorption of antimony trioxide from the gastrointestinal tract following gavage administration is poor. The patterns of nonneoplastic and neoplastic lung lesions in rats and mice were compared to the genetic toxicology data. Genotoxicity was only observed in mice. While nonneoplastic lung lesions and lung neoplasms were observed in both species, the neoplastic observations were more striking in the mice than in the rats. Collectively, these data suggest multiple mechanisms of antimony trioxide-induced genetic toxicity and carcinogenicity.

Egfr and Kras genes were evaluated for mutation frequencies in lung tumors because mutations in these genes are frequently present in human lung tumors. In both rats and mice, chronic exposure to antimony trioxide resulted in mutations in the hot spot regions of the Egfr gene within alveolar/bronchiolar adenomas and carcinomas. These Egfr mutations were not observed in spontaneous alveolar/bronchiolar adenomas and/or carcinomas from chamber control rats or mice. However, in mice (but not in rats), Kras gene mutations were observed in alveolar/bronchiolar tumors of both chamber control and antimony trioxide exposed animals, and most of these mutations were G to A transitions. Mutations in Kras and Egfr are commonly observed in human nonsmall cell lung cancer and occur in a mutually exclusive manner. Both KRAS and EGFR are major components of the MAPK signaling pathway. In the rats, the antimony trioxide-induced alveolar/bronchiolar tumors preferentially harbored Egfr mutations, whereas the alveolar/bronchiolar tumors in mice contained roughly equal numbers of Kras and Egfr mutations. This association suggests that altered EGFR signaling may play an important role in the pulmonary carcinogenesis resulting from chronic antimony trioxide exposure in both rats and mice.

In the 2-week studies, antimony trioxide lung burdens increased with increasing exposure concentration in rats and mice. Deviations from dose proportionality were small with less than proportional increases occurring at the higher exposure concentrations, and were resolved to an extent in the 4-week postexposure females. Lung clearance half-lives were estimated in females using data generated immediately after the end of exposure and at 4 weeks postexposure and were approximately twice as long in female rats (approximately 4 months) compared to female mice (approximately 2 months); these half-lives were included as time points in the chronic tissue burden studies in rats and mice. Steady-state lung burdens were not reached during the 2-week studies and would have required exposure durations of at least 7 to 21 months of exposure by a similar regimen to be reached. In female rats, blood antimony concentrations increased during the recovery period, indicating that antimony from the lung was entering the bloodstream. It is not clear whether this was the result of direct absorption or occurred following mucociliary clearance. In female mice, blood antimony concentrations decreased during the recovery period with half-lives of 22 to 32 days.

In the 2-year studies, only female rats and mice were evaluated for tissue burden because deposition patterns were similar between the sexes of both species in the 2-week studies. Lung burdens increased in proportion to exposure concentration and duration of exposure in rats and mice. In the 3 and 10 mg/m^3^ rat groups, model-predicted lung steady-state burdens in rats were similar to those actually observed at 551 days, indicating that they approached steady-state. In contrast, predicted steady state burdens in the 30 mg/m^3^ rat group were approximately 30% greater than observed burdens at 551 days, and thus did not approach steady state at this concentration. In rats, lung deposition rates were proportional to exposure concentration and were indicative of deposition efficiencies that approximately increased from 3% to 5% of the inhaled antimony trioxide. The calculated doses to the lung of rats after 551 days on study were 9.2, 24.4, and 65.6 mg/lung in the 3, 10, and 30 mg/m^3^ groups, respectively. The lung clearance half-lives in rats doubled between the 3 and 30 mg/m^3^ groups; the 3 mg/m^3^ half-life was similar to that observed during the 2-week study. As a result, only approximately one-half of the antimony trioxide dose to the lung was cleared over the course of the study in the 10 and 30 mg/m^3^ groups versus approximately two-thirds in the 3 mg/m^3^ group over the course of the study. In all exposed groups of mice, lung burdens increased steadily throughout the studies, reaching unexpectedly high values by the end of the studies, indicating that mouse lung burdens did not approach steady state and precluding modeling of lung burden data in this species.

In the 2-year studies, blood antimony concentrations increased with increasing exposure concentration in both rats and mice. In rats, concentrations also increased with exposure duration. In contrast, mouse blood concentrations appeared to be at or near steady state over most of the study in all exposed groups. Normalized blood concentrations decreased with increasing exposure concentration in both species, suggesting that as exposure concentrations (and lung burdens) increased, the rate or capacity of antimony trioxide dissolution and transport to the blood became progressively less, or that the rate of clearance from the blood increased. Although the blood concentration data were not modeled to discern blood antimony deposition and clearance rates, the blood concentration results, at least in rats, were consistent with the fact that clearance rates of antimony trioxide from the lungs also became progressively slower in rats as exposure concentrations increased.

Based on the relatively long clearance half-lives at 10 and 30 mg/m^3^ and high lung burdens at 30 mg/m^3^ in rats, and the unexpectedly high lung burdens at 551 days in mice, which precluded the mouse data from being modeled, it was hypothesized that lung overload occurred in rats and mice^74-76^. Calculations were made to determine if volumetric- or surface area-based overload occurred in either species. These calculations yielded generally similar results for the two interpretations of overload. Notably, lung overload did not occur at 3 mg/m^3^ in either species using either metric but did occur at 10 and 30 mg/m^3^, with the degree of overload increasing with exposure concentration. These data are consistent with available guidance for chronic inhalation study exposure concentration selection and data interpretation for particles, which indicates that both concentrations predicted to induce and those predicted not to induce lung overload should be selected and that all data (both in presence and absence of overload) should be utilized in the interpretation of carcinogenicity data^93^.

The lung overload hypothesis is considered to be applicable to poorly soluble particles of low intrinsic toxicity (e.g., carbon black, talc, coal dust, diesel soot, and titanium dioxide). In rats, lung overload is associated with pulmonary inflammation, fibrosis, epithelial hyperplasia, and lung tumors^93^. There is no similar association between exposure to these particles and occurrence of lung tumors in mice or hamsters. It is noteworthy that humans clear insoluble particles less readily than rodents, and with one such insoluble particle, coal dust, lung burdens similar to those that have been observed in rats with lung overload have been observed in humans. Both rats and humans develop fibrosis. While coal dust induces lung tumors in rats, the relationship is uncertain in humans^93^. Several lines of evidence from the current studies are in contrast with other particles that induce lung overload, as follows. In the current studies, the evidence for increases in lung tumors following antimony trioxide exposure was more apparent in mice than in rats with higher incidences and a predominance of malignant tumors in mice. In both species, there were increased incidences of lung neoplasms and/or nonneoplastic lesions at 3 mg/m^3^, an exposure concentration that did not result in overload. In addition, there were no significant differences in the incidences or types of Kras or Egfr mutations in rat and mouse alveolar/bronchiolar adenomas and carcinomas from exposures that did and did not approach the threshold for pulmonary overload suggesting overload did not alter the mutation spectra of the observed neoplasms. Finally, antimony trioxide exposure resulted in genotoxicity in both the lung and blood of male and female mice. Collectively, these lines of evidence indicate that antimony trioxide displays at least some intrinsic toxicity, and that the observed lung tumors could not be explained only by the high lung burdens in the study animals. In addition, these studies demonstrated significantly increased toxicity and/or carcinogenicity at exposure concentrations as low as 3 mg/m^3^, the lowest concentration tested.