# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TR-590.

## Rats

### Two-week Study

All rats survived to the end of the study (Table 2). The final mean body weights and body weight gains of exposed groups of males and females were similar to those of the chamber control groups. There were no clinical findings related to antimony trioxide exposure.

Table 2 Survival and Body Weights of Rats in the Two-week Inhalation Study of Antimony Trioxide^a^

Concentration (mg/m^3^) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 5/5 | 137 ± 2 | 227 ± 6 | 90 ± 4
3.75 | 5/5 | 136 ± 2 | 217 ± 5 | 81 ± 3 | 95
7.5 | 5/5 | 138 ± 3 | 226 ± 5 | 88 ± 3 | 99
15 | 5/5 | 136 ± 1 | 220 ± 5 | 84 ± 6 | 97
30 | 5/5 | 135 ± 4 | 210 ± 7 | 75 ± 4 | 92
60 | 5/5 | 139 ± 5 | 224 ± 9 | 86 ± 5 | 99
Female
0 | 5/5 | 123 ± 3 | 158 ± 3 | 34 ± 1
3.75 | 5/5 | 120 ± 4 | 160 ± 3 | 40 ± 1 | 102
7.5 | 5/5 | 122 ± 2 | 160 ± 3 | 38 ± 2 | 102
15 | 5/5 | 121 ± 4 | 156 ± 5 | 35 ± 2 | 99
30 | 5/5 | 119 ± 3 | 156 ± 1 | 37 ± 2 | 99
60 | 5/5 | 120 ± 4 | 158 ± 7 | 38 ± 3 | 100

^a^ Weights and weight changes are given as mean ± standard error.

^b^ Number of animals surviving at 16 days/number initially in group.

Relative lung weights of 30 mg/m^3^ males and absolute and relative lung weights of 60 mg/m^3^ males and 30 and 60 mg/m^3^ females were significantly greater than those of the chamber controls (Table 3 and Table F-1). Relative liver weights of 7.5 and 15 mg/m^3^ males were significantly decreased compared to the chamber controls, but the relationship to toxicity was uncertain. There were no gross observations associated with exposure to antimony trioxide noted at necropsy.

Table 3 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Two-week Inhalation Study of Antimony Trioxide^a^

| Chamber Control | 3.75 mg/m^3^ | 7.5 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
n | 5 | 5 | 5 | 5 | 5 | 5
Male
Necropsy body wt. | 227 ± 6 | 217 ± 5 | 226 ± 5 | 220 ± 5 | 210 ± 7 | 224 ± 9
Liver
Absolute | 10.05 ± 0.25 | 8.53 ± 0.32 | 8.84 ± 0.39 | 8.55 ± 0.47 | 8.56 ± 0.56 | 9.40 ± 0.41
Relative | 44.330 ± 1.402 | 39.406 ± 1.436 | 39.133 ± 1.363* | 38.715 ± 1.306* | 40.698 ± 1.534 | 41.859 ± 0.728
Lung
Absolute | 1.99 ± 0.11 | 1.93 ± 0.14 | 2.04 ± 0.15 | 2.08 ± 0.12 | 2.28 ± 0.19 | 2.56 ± 0.10**
Relative | 8.758 ± 0.530 | 8.919 ± 0.592 | 9.038 ± 0.609 | 9.416 ± 0.402 | 10.871 ± 0.806* | 11.423 ± 0.351**
Female
Necropsy body wt. | 158 ± 3 | 160 ± 3 | 160 ± 3 | 156 ± 5 | 156 ± 1 | 158 ± 7
Lung
Absolute | 1.39 ± 0.09 | 1.33 ± 0.08 | 1.52 ± 0.15 | 1.51 ± 0.11 | 1.70 ± 0.07* | 1.71 ± 0.10*
Relative | 8.849 ± 0.511 | 8.320 ± 0.391 | 9.508 ± 0.927 | 9.626 ± 0.445 | 10.911 ± 0.385* | 10.865 ± 0.388*

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Incidences of minimal squamous metaplasia of the epithelium lining the base of the epiglottis in the larynx occurred in two male rats in each of the 30 and 60 mg/m^3^ exposure groups, and were present in one or more female rats at each exposure level (Table 4). Significantly increased incidences of foreign body, presumed to be the test article, occurred in the lungs of all exposed groups of males and females compared to the chamber controls. The foreign bodies appeared as refractile gold to brown granules within the cytoplasm of alveolar macrophages and lying free within the alveolar spaces. Incidences of chronic active inflammation in the lungs were significantly increased in 30 and 60 mg/m^3^ males and females compared to the chamber controls. Chronic active inflammation was characterized by increased numbers of alveolar macrophages and perivascular infiltrates of lymphocytes, monocytes, and neutrophils. In areas of more intense inflammation, the alveolar architecture was sometimes obscured by inflammatory cells, cell debris, and fibrin, and was accompanied by Type 2 alveolar epithelial cell hyperplasia.

Table 4 Incidences of Selected Nonneoplastic Lesions of the Respiratory System in Rats in the Two-week Inhalation Study of Antimony Trioxide

| Chamber Control | 3.75 mg/m^3^ | 7.5 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
Male
Larynx^a^ | 5 | 0 | 0 | 5 | 5 | 5
Epiglottis, Metaplasia, Squamous^b^ | 0 | − | − | 0 | 2 (1.0)^c^ | 2 (1.0)
Lung | 5 | 5 | 5 | 5 | 5 | 5
Foreign Body | 0 | 5** | 5** | 5** | 5** | 5**
Inflammation, Chronic Active | 0 | 0 | 0 | 0 | 5** (2.2) | 5** (2.2)
Female
Larynx | 5 | 5 | 5 | 5 | 4 | 5
Epiglottis, Metaplasia, Squamous | 0 | 1 (1.0) | 1 (1.0) | 1 (1.0) | 2 (1.0) | 3 (1.0)
Lung | 5 | 5 | 5 | 5 | 5 | 5
Foreign Body | 0 | 5** | 5** | 5** | 5** | 5**
Inflammation, Chronic Active | 0 | 0 | 0 | 0 | 5** (2.4) | 5** (2.6)

** Significantly different (P ≤ 0.01) from the chamber control group by the Fisher exact test.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Exposure Concentration Selection Rationale: The 2-year rat inhalation study was designed following a review of the current 2-week study as well as the subchronic and chronic (1-year exposure duration) inhalation study data from the literature. These data were considered sufficient to design a 2-year study without conducting a 3-month NTP study. The highest exposure concentration selected for the 2-year study (30 mg/m^3^) was selected based on similar toxicity observed in the 2-week rat study in the 30 and 60 mg/m^3^ groups, and the lack of in-life toxicity that might be anticipated to limit survival in the previous chronic studies at exposure concentrations of up to 45 mg/m^3^. Exposure concentrations were spaced in half-log intervals, such that the lowest exposure concentration of 3 mg/m^3^ was slightly lower than the concentration that produced modest toxicity and was negative for carcinogenicity after 1 year of exposure (4.5 mg/m^3^; Newton et al.^16^). A 12-month interim evaluation was included in the 2-year study to provide a means of comparison to the previous 1-year exposures.

### Two-year Study

#### Survival

Estimates of 2-year survival probabilities for male and female rats are shown in Table 5 and in the Kaplan-Meier survival curves (Figure 2). Survival of 10 and 30 mg/m^3^ females was significantly less than that of the chamber control group. The decrease in survival of females was attributed primarily to lung proteinosis. In males, the trend towards reduced survival was attributed primarily to lung inflammation and proteinosis.

Table 5 Survival of Rats in the Two-year Inhalation Study of Antimony Trioxide

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Male
Animals initially in study | 60 | 60 | 60 | 60
Twelve-month interim evaluation^a^ | 10 | 10 | 10 | 10
Moribund | 15 | 19 | 22 | 29
Natural deaths | 5 | 1 | − | 3
Animals surviving to study termination | 30 | 30 | 28 | 18
Percent probability of survival at end of study^b^ | 60 | 60 | 56 | 36
Mean survival (days)^c^ | 672 | 669 | 673 | 668
Survival analysis^d^ | P = 0.025 | P = 1.000 | P = 1.000 | P = 0.084
Female
Animals initially in study | 60 | 60 | 60 | 60
Twelve-month interim evaluation^a^ | 10 | 10 | 10 | 10
Moribund | 11 | 12 | 20 | 27
Natural deaths | − | − | 2 | 3
Animals surviving to study termination | 39 | 38 | 28^e^ | 20^e^
Percent probability of survival at end of study | 78 | 76 | 56 | 40
Mean survival (days) | 704 | 704 | 686 | 663
Survival analysis | P < 0.001 | P = 0.968 | P = 0.032 | P < 0.001

^a^ Excluded from survival analyses.

^b^ Kaplan-Meier determinations.

^c^ Mean of all deaths (uncensored, censored, and terminal kill).

^d^ The result of the life table trend test^50^ is in the chamber control column, and the results of the life table pairwise comparisons^49^ with the chamber controls are in the exposed group columns.

^e^ Includes one animal that died during the last week of the study.

Figure 2

Kaplan-Meier Survival Curves for Rats Exposed to Antimony Trioxide by Inhalation for Two Years

#### Body Weights, Clinical Findings, and Organ Weights

Mean body weights of 30 mg/m^3^ males were at least 10% less than those of the chamber control group after week 69 and 20% less than that of the chamber control group by the end of the study (Table 6 and Figure 3). Mean body weights of 3, 10, and 30 mg/m^3^ females were at least 10% less than those of the chamber control group after weeks 99, 81, and 65, respectively, and those of 10 and 30 mg/m^3^ females were 20% and 28% less, respectively, than that of the chamber controls by the end of the study (Table 7 and Figure 3).

Table 6 Mean Body Weights and Survival of Male Rats in the Two-year Inhalation Study of Antimony Trioxide

Day | Chamber Control | | 3 mg/m^3^ | | | 10 mg/m^3^ | | | 30 mg/m^3^
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 120 | 60 | 119 | 99 | 60 | 119 | 100 | 60 | 118 | 99 | 60
8 | 163 | 60 | 160 | 98 | 60 | 162 | 100 | 60 | 158 | 97 | 60
16 | 209 | 60 | 205 | 98 | 60 | 209 | 100 | 60 | 203 | 97 | 60
22 | 242 | 60 | 238 | 99 | 60 | 241 | 100 | 60 | 234 | 97 | 60
29 | 272 | 60 | 269 | 99 | 60 | 272 | 100 | 60 | 265 | 98 | 60
36 | 297 | 60 | 294 | 99 | 60 | 296 | 100 | 60 | 289 | 97 | 60
43 | 317 | 60 | 314 | 99 | 60 | 317 | 100 | 60 | 309 | 97 | 60
50 | 337 | 60 | 332 | 98 | 60 | 336 | 100 | 60 | 327 | 97 | 60
57 | 351 | 60 | 346 | 99 | 60 | 350 | 100 | 60 | 340 | 97 | 60
64 | 364 | 60 | 358 | 99 | 60 | 362 | 99 | 60 | 352 | 97 | 60
71 | 374 | 60 | 368 | 98 | 60 | 370 | 99 | 60 | 361 | 96 | 60
78 | 383 | 60 | 378 | 99 | 60 | 379 | 99 | 60 | 369 | 97 | 60
85 | 390 | 60 | 384 | 99 | 60 | 387 | 99 | 60 | 377 | 97 | 60
113 | 418 | 60 | 412 | 99 | 60 | 415 | 99 | 59 | 402 | 96 | 60
141 | 436 | 60 | 428 | 98 | 60 | 432 | 99 | 59 | 419 | 96 | 60
169 | 451 | 60 | 444 | 99 | 60 | 449 | 100 | 58 | 434 | 96 | 60
197 | 466 | 60 | 459 | 99 | 60 | 465 | 100 | 58 | 447 | 96 | 60
225 | 477 | 60 | 470 | 98 | 60 | 478 | 100 | 58 | 458 | 96 | 60
253 | 491 | 60 | 482 | 98 | 60 | 490 | 100 | 58 | 470 | 96 | 60
281 | 502 | 60 | 493 | 98 | 60 | 501 | 100 | 58 | 480 | 96 | 60
309 | 516 | 60 | 503 | 98 | 60 | 515 | 100 | 58 | 489 | 95 | 60
337 | 526 | 60 | 511 | 97 | 60 | 522 | 99 | 58 | 497 | 95 | 60
365 | 535 | 60 | 519 | 97 | 59 | 531 | 99 | 58 | 503 | 94 | 60
393^a^ | 545 | 49 | 524 | 96 | 49 | 537 | 98 | 48 | 501 | 92 | 50
421 | 554 | 49 | 532 | 96 | 49 | 544 | 98 | 48 | 507 | 92 | 49
449 | 563 | 48 | 541 | 96 | 49 | 553 | 98 | 48 | 512 | 91 | 49
477 | 565 | 46 | 547 | 97 | 49 | 557 | 99 | 48 | 516 | 91 | 48
505 | 572 | 46 | 553 | 97 | 47 | 562 | 98 | 47 | 516 | 90 | 47
533 | 580 | 46 | 552 | 95 | 43 | 569 | 98 | 47 | 517 | 89 | 47
561 | 583 | 45 | 559 | 96 | 40 | 577 | 99 | 45 | 518 | 89 | 44
589 | 587 | 41 | 565 | 96 | 39 | 573 | 98 | 42 | 516 | 88 | 42
618 | 601 | 37 | 565 | 94 | 37 | 569 | 95 | 41 | 512 | 85 | 39
645 | 601 | 37 | 566 | 94 | 37 | 565 | 94 | 41 | 507 | 84 | 38
659 | 607 | 34 | 567 | 93 | 36 | 568 | 94 | 39 | 501 | 83 | 36
673 | 604 | 34 | 566 | 94 | 35 | 566 | 94 | 39 | 497 | 82 | 33
687 | 600 | 31 | 566 | 94 | 33 | 566 | 94 | 36 | 491 | 82 | 28
701 | 604 | 30 | 566 | 94 | 31 | 557 | 92 | 34 | 493 | 82 | 24
715 | 606 | 30 | 561 | 93 | 31 | 559 | 92 | 31 | 483 | 80 | 20
Mean for Weeks
1–13 | 294 | | 290 | 99 | | 292 | 100 | | 285 | 97
14–52 | 476 | | 467 | 98 | | 474 | 100 | | 455 | 96
53–103 | 582 | | 553 | 95 | | 559 | 96 | | 506 | 87

^a^ Interim evaluation occurred during week 53.

Figure 3

Growth Curves for Rats Exposed to Antimony Trioxide by Inhalation for Two Years

Table 7 Mean Body Weights and Survival of Female Rats in the Two-year Inhalation Study of Antimony Trioxide

Day | Chamber Control | | 3 mg/m^3^ | | | 10 mg/m^3^ | | | 30 mg/m^3^
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 106 | 60 | 106 | 99 | 60 | 105 | 99 | 60 | 105 | 99 | 60
8 | 128 | 60 | 127 | 100 | 60 | 127 | 99 | 60 | 126 | 99 | 60
16 | 146 | 60 | 146 | 100 | 60 | 146 | 100 | 60 | 145 | 99 | 60
22 | 159 | 60 | 159 | 100 | 60 | 159 | 100 | 60 | 159 | 100 | 60
29 | 172 | 60 | 171 | 99 | 60 | 173 | 100 | 60 | 171 | 99 | 60
36 | 182 | 60 | 180 | 99 | 60 | 182 | 100 | 60 | 181 | 99 | 60
43 | 190 | 60 | 189 | 99 | 60 | 190 | 100 | 60 | 188 | 99 | 60
50 | 197 | 60 | 195 | 99 | 60 | 195 | 99 | 60 | 194 | 99 | 60
57 | 203 | 60 | 202 | 100 | 60 | 203 | 100 | 60 | 201 | 99 | 60
64 | 209 | 60 | 206 | 99 | 60 | 206 | 99 | 60 | 205 | 98 | 60
71 | 214 | 60 | 210 | 98 | 60 | 210 | 98 | 60 | 209 | 98 | 60
78 | 217 | 60 | 213 | 98 | 60 | 214 | 98 | 60 | 213 | 98 | 60
85 | 220 | 60 | 216 | 98 | 60 | 218 | 99 | 60 | 216 | 99 | 60
113 | 232 | 60 | 229 | 99 | 60 | 230 | 99 | 60 | 227 | 98 | 60
141 | 241 | 60 | 236 | 98 | 60 | 236 | 98 | 60 | 234 | 97 | 60
169 | 247 | 60 | 243 | 99 | 60 | 244 | 99 | 60 | 241 | 98 | 60
197 | 252 | 60 | 248 | 98 | 60 | 249 | 99 | 60 | 246 | 98 | 60
225 | 260 | 60 | 254 | 98 | 60 | 255 | 98 | 60 | 253 | 98 | 60
253 | 267 | 60 | 260 | 97 | 60 | 263 | 99 | 60 | 260 | 97 | 60
281 | 271 | 60 | 265 | 98 | 60 | 270 | 99 | 60 | 264 | 97 | 60
309 | 280 | 60 | 274 | 98 | 60 | 277 | 99 | 60 | 273 | 98 | 60
337 | 287 | 60 | 279 | 97 | 60 | 285 | 99 | 60 | 279 | 97 | 60
365 | 294 | 60 | 287 | 98 | 60 | 290 | 99 | 60 | 283 | 96 | 60
393^a^ | 304 | 49 | 292 | 96 | 50 | 299 | 98 | 50 | 289 | 95 | 50
421 | 316 | 49 | 298 | 94 | 50 | 310 | 98 | 50 | 294 | 93 | 50
449 | 325 | 48 | 303 | 94 | 50 | 311 | 96 | 50 | 298 | 92 | 48
477 | 332 | 48 | 312 | 94 | 50 | 317 | 96 | 50 | 299 | 90 | 48
505 | 342 | 48 | 321 | 94 | 50 | 322 | 94 | 48 | 301 | 88 | 47
533 | 352 | 48 | 330 | 94 | 48 | 324 | 92 | 48 | 301 | 86 | 46
561 | 362 | 47 | 339 | 94 | 47 | 328 | 91 | 47 | 303 | 84 | 41
589 | 371 | 46 | 345 | 93 | 45 | 327 | 88 | 45 | 303 | 82 | 40
618 | 378 | 46 | 347 | 92 | 44 | 332 | 88 | 38 | 298 | 79 | 36
645 | 383 | 44 | 351 | 92 | 43 | 329 | 86 | 38 | 293 | 77 | 33
659 | 384 | 44 | 353 | 92 | 42 | 325 | 85 | 37 | 288 | 75 | 32
673 | 387 | 44 | 353 | 91 | 42 | 321 | 83 | 36 | 285 | 74 | 32
687 | 388 | 44 | 353 | 91 | 41 | 320 | 82 | 35 | 284 | 73 | 31
701 | 392 | 41 | 353 | 90 | 41 | 319 | 81 | 33 | 286 | 73 | 27
715 | 396 | 40 | 355 | 90 | 39 | 315 | 80 | 30 | 286 | 72 | 25
Mean for Weeks
1–13 | 180 | | 178 | 99 | | 179 | 99 | | 178 | 99
14–52 | 260 | | 254 | 98 | | 256 | 99 | | 253 | 97
53–103 | 356 | | 331 | 93 | | 318 | 90 | | 293 | 83

^a^ Interim evaluation occurred during week 53.

Exposure-related clinical findings included abnormal breathing, cyanosis, and thinness in male and female rats. Increases over chamber controls were noted in exposed rats primarily in the 10 and 30 mg/m^3^ groups. These findings generally appeared during the second year of the study. Appendage ulcer/abscesses were recorded in chamber control and exposed groups of males with equal incidences, apparently related to housing heavier male rats on wire caging.

Absolute and relative lung weights were significantly increased in all exposed groups of males and females at the 12-month interim evaluation (Table 8 and Table F-2). Lung weights increased with exposure concentration in both males and females. Due at least in part to the decreases in body weight in females, group mean relative lung weights were much greater in exposed females than in males. Small, but statistically significant increases in relative liver weights were observed in the 10 and 30 mg/m^3^ males; the increases were of uncertain toxicologic significance.

Table 8 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats at the 12-month Interim Evaluation in the Two-year Inhalation Study of Antimony Trioxide^a^

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
n | 10 | 10 | 10 | 10
Male
Necropsy body wt. | 522 ± 16 | 531 ± 17 | 540 ± 20 | 534 ± 13
Liver
Absolute | 14.08 ± 0.64 | 14.78 ± 0.43 | 15.81 ± 0.61 | 15.75 ± 0.70
Relative | 26.908 ± 0.582 | 27.910 ± 0.458 | 29.294 ± 0.508* | 29.452 ± 0.886**
Lung
Absolute | 2.79 ± 0.18 | 3.65 ± 0.19* | 4.32 ± 0.28** | 6.57 ± 0.29**
Relative | 5.368 ± 0.326 | 6.897 ± 0.312* | 8.040 ± 0.490** | 12.313 ± 0.484**
Female
Necropsy body wt. | 278 ± 10 | 293 ± 11 | 272 ± 7 | 278 ± 6
Lung
Absolute | 1.78 ± 0.09 | 2.89 ± 0.16** | 4.20 ± 0.22** | 5.48 ± 0.28**
Relative | 6.451 ± 0.335 | 9.898 ± 0.448** | 15.528 ± 0.975** | 19.719 ± 0.901**

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

At necropsy, most of the exposed rats had lungs that were mottled or mottled pale, and many had lungs that were enlarged when compared to those of the chamber control groups. These gross changes corresponded to the proteinosis and/or chronic active inflammation seen microscopically.

#### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions of the lung, adrenal medulla, nose, larynx, trachea, bone marrow, lymph nodes (bronchial and mediastinal), arterial vessels (of the mediastinum, pancreas, mesentery, lung, and kidney), kidney, eye, prostate gland, skin, forestomach, thymus, uterus, pituitary gland, and mammary gland. Summaries of the incidences of neoplasms and/or nonneoplastic lesions, statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group, and historical control incidences for the neoplasms mentioned in this section are presented in Appendix A for male rats and Appendix B for female rats.

Lung: At the 12-month interim evaluation, a single incidence of alveolar/bronchiolar adenoma occurred in a 30 mg/m^3^ female (Table 9 and Table B-1).

Table 9 Incidences of Neoplasms and Nonneoplastic Lesions of the Lung in Rats in the Two-year Inhalation Study of Antimony Trioxide

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Male
Twelve-month Interim Evaluation
Number Examined Microscopically | 10 | 10 | 10 | 10
Foreign Body^a^ | 0 | 10** | 10** | 10**
Inflammation, Chronic Active | 1 (1.0)^b^ | 10** (2.1) | 10** (2.9) | 10** (3.0)
Alveolus, Inflammation, Suppurative | 0 | 1 (1.0) | 2 (1.0) | 2 (1.5)
Perivascular, Infiltration Cellular, Lymphocyte | 0 | 4* (1.0) | 4* (1.0) | 3 (1.0)
Proteinosis | 0 | 9** (1.0) | 10** (1.4) | 10** (2.4)
Alveolar Epithelium, Hyperplasia | 0 | 10** (1.2) | 10** (1.9) | 10** (2.2)
Bronchiole, Epithelium, Hyperplasia | 0 | 5** (1.0) | 5** (1.0) | 6** (1.0)
Fibrosis | 0 | 10** (1.1) | 10** (1.8) | 10** (1.8)
Two-year Study
Number Examined Microscopically | 50 | 50 | 50 | 50
Foreign Body | 1 | 50** | 50** | 50**
Inflammation, Chronic Active | 18 (1.0) | 50** (2.5) | 50** (2.7) | 50** (2.8)
Alveolus, Inflammation, Suppurative | 0 | 12** (1.2) | 24** (1.4) | 28** (1.7)
Perivascular, Infiltration Cellular, Lymphocyte | 3 (1.7) | 25** (1.1) | 19** (1.2) | 9 (1.1)
Proteinosis | 0 | 47** (1.3) | 50** (1.9) | 50** (2.7)
Alveolar Epithelium, Hyperplasia | 4 (1.3) | 50** (1.8) | 48** (2.1) | 49** (2.2)
Bronchiole, Epithelium, Hyperplasia | 3 (1.0) | 34** (1.0) | 36** (1.1) | 33** (1.5)
Fibrosis | 2 (1.0) | 50** (1.4) | 49** (1.6) | 49** (1.7)
Alveolar/bronchiolar Adenoma, Multiple | 0 | 1 | 0 | 3
Alveolar/bronchiolar Adenoma (includes multiple)^c^
Overall rate^d^ | 3/50 (6%) | 4/50 (8%) | 6/50 (12%) | 8/50 (16%)
Adjusted rate^e^ | 7.1% | 9.8% | 13.8% | 19.7%
Terminal rate^f^ | 1/30 (3%) | 4/30 (13%) | 2/28 (7%) | 4/18 (22%)
First incidence (days) | 369 | 729 (T) | 534 | 649
Poly-3 test^g^ | P = 0.057 | P = 0.478 | P = 0.253 | P = 0.083
Alveolar/bronchiolar Carcinoma^h^
Overall rate | 0/50 (0%) | 0/50 (0%) | 2/50 (4%) | 0/50 (0%)
Adjusted rate | 0.0% | 0.0% | 4.7% | 0.0%
Terminal rate | 0/30 (0%) | 0/30 (0%) | 1/28 (4%) | 0/18 (0%)
First incidence (days) | –^i^ | – | 719 | –
Poly-3 test | P = 0.702N | –^j^ | P = 0.245 | –
Alveolar/bronchiolar Adenoma or Carcinoma^c^
Overall rate | 3/50 (6%) | 4/50 (8%) | 8/50 (16%) | 8/50 (16%)
Adjusted rate | 7.1% | 9.8% | 18.4% | 19.7%
Terminal rate | 1/30 (3%) | 4/30 (13%) | 3/28 (11%) | 4/18 (22%)
First incidence (days) | 369 | 729 (T) | 534 | 649
Poly-3 test | P = 0.067 | P = 0.478 | P = 0.104 | P = 0.083
Female
Twelve-month Interim Evaluation
Number Examined Microscopically | 10 | 10 | 10 | 10
Foreign Body | 0 | 10** | 10** | 10**
Inflammation, Chronic Active | 2 (1.0) | 10** (2.0) | 10** (2.0) | 10** (2.3)
Alveolus, Inflammation, Suppurative | 0 | 1 (1.0) | 0 | 3 (1.0)
Perivascular, Infiltration Cellular, Lymphocyte | 0 | 4* (1.0) | 5* (1.0) | 3 (1.0)
Proteinosis | 0 | 10** (1.7) | 10** (2.8) | 10** (3.0)
Alveolar Epithelium, Hyperplasia | 0 | 10** (1.0) | 10** (1.2) | 10** (1.4)
Bronchiole, Epithelium, Hyperplasia | 0 | 1 (1.0) | 0 | 3 (1.0)
Fibrosis | 0 | 10** (1.0) | 10** (1.0) | 10** (1.1)
Alveolar/bronchiolar Adenoma | 0 | 0 | 0 | 1
Two-year Study
Number Examined Microscopically | 50 | 50 | 50 | 50
Foreign Body | 0 | 50** | 50** | 50**
Inflammation, Chronic Active | 21 (1.0) | 50** (2.3) | 50** (2.2) | 50** (2.2)
Alveolus, Inflammation, Suppurative | 0 | 5* (1.0) | 6* (1.0) | 5* (1.2)
Perivascular, Infiltration Cellular, Lymphocyte | 0 | 18** (1.1) | 11** (1.1) | 8** (1.0)
Proteinosis | 0 | 50** (2.4) | 50** (2.9) | 50** (3.1)
Alveolar Epithelium, Hyperplasia | 5 (1.6) | 50** (1.9) | 49** (1.9) | 50** (2.1)
Bronchiole, Epithelium, Hyperplasia | 6 (1.0) | 26** (1.1) | 25** (1.0) | 27** (1.1)
Alveolar Epithelium, Metaplasia, Squamous | 0 | 5* (1.8) | 3 (2.3) | 1 (2.0)
Fibrosis | 1 (1.0) | 50** (1.5) | 50** (1.5) | 49** (1.4)
Alveolar/bronchiolar Adenoma, Multiple | 0 | 0 | 1 | 0
Alveolar/bronchiolar Adenoma (includes multiple)^k^
Overall rate | 0/50 (0%) | 2/50 (4%) | 6/50 (12%) | 5/50 (10%)
Adjusted rate | 0.0% | 4.4% | 13.8% | 12.4%
Terminal rate | 0/39 (0%) | 2/38 (5%) | 4/28 (14%) | 2/20 (10%)
First incidence (days) | – | 730 (T) | 534 | 534
Poly-3 test | P = 0.029 | P = 0.235 | P = 0.012 | P = 0.021
Cystic Keratinizing Epithelioma^k^ | 0 | 0 | 0 | 2
Squamous Cell Carcinoma^k^ | 0 | 0 | 0 | 1
Cystic Keratinizing Epithelioma or Squamous Cell Carcinoma^k^
Overall rate | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 7.4%
Terminal rate | 0/39 (0%) | 0/38 (0%) | 0/28 (0%) | 1/20 (5%)
First incidence (days) | – | – | – | 554
Poly-3 test | P = 0.006 | – | – | P = 0.096

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact test (interim evaluation) or the Poly-3 test (2-year study).

** P ≤ 0.01.

(T) = terminal kill.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical incidence for 2-year inhalation studies with chamber control groups (mean ± standard deviation): 4/150 (2.7% ± 3.1%), range 0%–6%; all routes: 4/299 (1.3% ± 2.4%), range 0%–6%.

^d^ Number of animals with neoplasm per number of animals with lung examined microscopically.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal kill.

^g^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend is indicated by N.

^h^ Historical incidence for inhalation studies: 0/150; all routes: 0/299.

^i^ Not applicable; no neoplasms in animal group.

^j^ Value of statistic cannot be computed.

^k^ Historical incidence for inhalation studies: 0/150; all routes: 0/300.

In the 2-year study, the incidences of alveolar/bronchiolar adenoma were slightly increased without statistical significance in 10 and 30 mg/m^3^ males (Table 9, Table A-1, and Table A-2). Also, incidences of multiple alveolar/bronchiolar adenoma occurred in 3 and 30 mg/m^3^ males, but not in chamber control males. Two alveolar/bronchiolar carcinomas occurred in 10 mg/m^3^ male rats. In all exposed groups of male rats, the incidences of alveolar/bronchiolar adenoma and alveolar/bronchiolar adenoma or carcinoma (combined) exceeded the historical control ranges for inhalation studies and for all routes of administration (Table 9 and Table A-3). In female rats, incidences of alveolar/bronchiolar adenoma occurred with a positive trend (Table 9, Table B-1, and Table B-2). The incidences of alveolar/bronchiolar adenoma in 10 and 30 mg/m^3^ females were significantly increased compared to that in the chamber controls. A single incidence of multiple alveolar/bronchiolar adenoma occurred in one 10 mg/m^3^ female. No alveolar/bronchiolar carcinomas occurred in female rats. However, a single incidence of squamous cell carcinoma occurred in one 30 mg/m^3^ female and cystic keratinizing epithelioma occurred in two 30 mg/m^3^ females; neither of these neoplasms have occurred in historical control Wistar Han rats (Table 9 and Table B-3).

Microscopically, alveolar/bronchiolar adenomas were densely cellular, expansile masses, composed of closely spaced epithelial cells that primarily followed alveolar outlines, but also contained solid cellular clusters that extended into or obliterated alveolar spaces (Figure 6). The proliferative cells showed only minor atypia, and mitoses were few. Alveolar/bronchiolar carcinomas often contained several patterns within the same mass and exhibited more cellular pleomorphism than seen in adenomas. The squamous cell carcinoma present in one 30 mg/m^3^ female rat was a solid mass composed of islands of pleomorphic squamous cells, sometimes with central keratin pearls, and separated by small to moderate amounts of fibrous stroma, infiltrating and obliterating the normal pulmonary architecture (Figure 6). On the other hand, the cystic keratinizing epitheliomas in female rats were cystic masses filled with keratin and lined by squamous epithelium that exhibited limited proliferation of mildly atypical squamous epithelium at the periphery (Figure 6).

Figure 6

Epithelial Hyperplasia and Neoplasia in the Rat Lung (H&E)

A) A relatively circumscribed zone of alveolar epithelial hyperplasia (arrows) was noted in a female Wistar Han rat exposed to 10 mg antimony trioxide/m^3^ by inhalation for 2 years. B) This alveolar/bronchiolar adenoma in a female Wistar Han rat exposed to 30 mg antimony trioxide/m^3^ by inhalation for 2 years was compact, cellular, and displayed papillary projections into the alveolar lumens. C) Cystic keratinizing epithelioma found in the lung of a female Wistar Han rat exposed to 30 mg antimony trioxide/m^3^ by inhalation for 2 years, characterized by a central, keratin-filled cavity (asterisk) with a thick, irregular outer wall of proliferating squamous epithelium (arrow). D) This squamous cell carcinoma in the lung of a female Wistar Han rat exposed to 30 mg antimony trioxide/m^3^ by inhalation for 2 years formed a predominately solid mass, composed of coalescing nests of pleomorphic squamous cells infiltrating the pulmonary parenchyma.

A spectrum of nonneoplastic lung lesions occurred that was similar at the 12-month interim evaluation and in the 2-year study for exposed groups of male and female rats (Table 9, Table A-4, and Table B-4). Foreign body occurred in all exposed male and female rats and in none of the chamber controls. The foreign particles, presumed to be the test article, were present in alveolar macrophages, and often extracellularly in the proteinaceous fluid of the alveoli, of all exposed animals. The foreign particles were small, round to oval, refractile, nonpolarizing, golden brown material with central pallor, measuring approximately 1 micron in diameter (Figure 7). Occasionally, the foreign particles were noted within the cytoplasm of alveolar lining cells and/or within the interstitium of the alveolar walls. The response of the lung to the presence of this foreign material consisted of alveolar histiocytosis (macrophages), inflammation, alveolar proteinosis, alveolar and bronchiolar epithelial hyperplasia, and fibrosis (Figure 7, Figure 8, Figure 9, Figure 10, and Figure 11). The increased alveolar macrophages were often clustered in multifocal aggregates accompanied by smaller numbers of neutrophils and sometimes cellular debris, and were incorporated in the diagnosis of chronic active inflammation. Significantly increased incidences of mild to moderate chronic active inflammation occurred in all exposed groups of male and female rats, and incidences of minimal inflammation were observed in some chamber control rats. In addition, in some of the males and females, particularly the 10 and 30 mg/m^3^ males, there were more concentrated intra-alveolar aggregates of intact and degenerate neutrophils and macrophages, associated with abundant karyorrhectic debris and foreign particles (presumed to be the test article), and these inflammatory aggregates were diagnosed as alveolus, inflammation, suppurative. A third type of inflammation, characterized by minimal perivascular infiltrates of lymphocytes, was observed in exposed males and females. These incidences of perivascular, infiltration cellular, lymphocytes were significantly increased compared to those in the chamber control groups at the 12-month interim evaluation in 3 and 10 mg/m^3^ males and females and in the 2-year study in 3 and 10 mg/m^3^ males and all exposed groups of females.

Figure 7

Foreign Body (Presumed Test Article) in the Lung of a Male Wistar Han Rat Exposed to 30 mg Antimony Trioxide/m^3^ by Inhalation for Two Years (H&E)

A) The foreign particles were located within alveolar macrophages (arrow) as well as extracellularly in the alveolar proteinotic material (arrowhead). B) At higher magnification (100×), the particles were noted to be round to ovoid, golden brown, approximately 1 μm in diameter, and refractile. C) The foreign particles were sometimes seen within alveolar epithelial cells (arrowhead) and D) within interstitial macrophages (arrowheads).

Figure 8

Nonneoplastic Changes in the Lung of a Male Wistar Han Rat Exposed to 30 mg Antimony Trioxide/m^3^ by Inhalation for Two Years (H&E)

A) This low power view revealed extensive filling of alveolar spaces by alveolar proteinosis (asterisks) and inflammation (arrows). B) With higher magnification, two additional features of the reaction to the chemical were noted: alveolar epithelial hyperplasia (arrows) and increased alveolar macrophages containing foreign body particles (arrowheads).

Figure 9

Inflammation in the Lung of a Male Wistar Han Rat Exposed to 30 mg Antimony Trioxide/m^3^ by Inhalation for Two Years (H&E)

A) Chronic active inflammation was the predominant pattern, characterized by increased numbers of alveolar macrophages and lesser numbers of neutrophils. B) Two additional inflammatory patterns noted in this and other treated rats are depicted in this image: aggregates of alveolar neutrophils and karyorrhectic debris (arrows) and perivascular clusters of lymphocytes (asterisk).

Figure 10

Alveolar Proteinosis in the Rat Lung

A) Normal lung of a chamber control female Wistar Han rat in the 2-year study of antimony trioxide by inhalation for comparison with the B) pulmonary alveolar proteinosis filling the alveolar spaces in the lung of a female Wistar Han rat exposed to 30 mg antimony trioxide/m^3^ by inhalation for 2 years. (H&E) C) Immunohistochemical staining for surfactant A in the lung of a chamber control female Wistar Han rat showed staining of type II alveolar pneumocytes (arrowhead), bronchiolar Clara cells (arrow), and alveolar macrophages, but no staining of the alveolar spaces, whereas D) similar staining in the lung of the exposed female Wistar Han rat revealed strong, diffuse staining of the alveolar proteinotic material, indicating that accumulation of surfactant A was the cause of the proteinosis. Immunohistochemical staining for surfactant C in E) the lung of the same chamber control female Wistar Han rat, and in F) the lung of the same exposed female Wistar Han rat showed staining only of the type II alveolar pneumocytes with no staining of the alveolar spaces or of the proteinotic material.

Figure 11

Fibrosis in the Lung

A) Many of the alveolar walls of this area were thickened by increased collagenous matrix (arrows) in a male Wistar Han rat exposed to 3 mg antimony trioxide/m^3^ by inhalation for 2 years. The visceral pleura was also thickened (arrowhead). (H&E) B) Masson trichrome stain of the same area shown in A imparted a bluish cast to the increased collagen in the alveolar walls and the pleura. C) Zones of more extensive nodular fibrosis (arrows) were noted in a male Wistar Han rat exposed to 30 mg antimony trioxide/m^3^ by inhalation for 2 years. (H&E) D) Masson trichrome stain of the same area shown in C highlighted the increase in blue staining collagen fibers within the parenchyma and the overlying pleura. Note that the foreign body, visible as black particulate material, was concentrated within the areas of fibrosis in both A and C.

Significantly increased incidences with increased exposure concentration-related severities of alveolar proteinosis occurred in all exposed groups of rats at the 12-month interim evaluation and in the 2-year study (Table 9, Table A-4, and Table B-4). The appearance of the proteinosis ranged from pale eosinophilic, wispy material in rare alveolar spaces to sheets of brightly eosinophilic, amorphous material filling numerous alveolar spaces. Immunohistochemical staining for surfactant A revealed strong staining of the proteinaceous material, Type 2 alveolar pneumocytes, and bronchiolar Clara cells for surfactant A. In contrast, immunohistochemical staining for surfactant C was limited to the Type 2 alveolar pneumocytes, and was not seen in the proteinotic material. The accumulation of surfactant A was probably related to both excessive production by the Type 2 alveolar epithelial cells due to the inflammation and to impaired clearance of the surfactant by the alveolar macrophages due to the foreign body.

The incidences of mild alveolar epithelium hyperplasia in all exposed groups of male and female rats at the 12-month interim evaluation and in the 2-year study were significantly increased compared to those in the chamber control groups (Table 9, Table A-4, and Table B-4). Hyperplasia was usually noted within areas of chronic active inflammation, and was characterized by hypertrophy and crowding of the Type 2 pneumocytes. In addition, relatively circumscribed, typically circular foci of epithelial hyperplasia were occasionally noted in which all of the alveolar walls within a region were lined by enlarged, cuboidal epithelial cells (Figure 6A). Bronchiolar epithelium hyperplasia with minimal severity occurred in all exposed groups of rats (except 10 mg/m^3^ females) at the 12-month interim evaluation and in the 2-year study, and the incidences were significantly increased in all exposed groups of males and females, except for females at the 12-month interim evaluation. Incidences of squamous metaplasia of alveolar epithelium occurred in all exposed female groups in the 2-year study, and the incidence of this lesion was significantly increased in the 3 mg/m^3^ group.

The incidences of fibrosis were significantly increased in all exposed groups of males and females at the 12-month interim evaluation and in the 2-year study compared to those in the chamber control groups (Table 9, Table A-4, and Table B-4). These incidences of fibrosis were minimal to mild and occurred multifocally in the interstitium of the alveolar walls of almost all exposed 12-month interim evaluation and 2-year study rats. Fibrosis was usually manifested by slight thickening of the collagenous stroma within the alveolar walls, whereas some foci were characterized by nodular collagenous stromal thickening resulting in distortion of the normal lung architecture. Areas of subpleural fibrosis were sometimes noted. In areas of minimally increased collagen deposition within the alveolar walls, the fibrosis was highlighted by Masson trichrome staining in a subset of animals. Although the fibrosis was most often seen in areas of chronic active inflammation, there were some regions of fibrosis that had few to no inflammatory cells present.

Adrenal Medulla: No incidences of adrenal medullary hyperplasia or pheochromocytoma occurred in males or females at the 12-month interim evaluation (Table A-1, Table A-5, Table B-1, and Table B-5). In the 2-year study, the incidences of benign pheochromocytoma of the adrenal medulla were significantly increased in 30 mg/m^3^ females and the incidence of benign or malignant pheochromocytoma (combined) was significantly increased in 30 mg/m^3^ females compared to those in the chamber control groups and each exceeded the historical control ranges for inhalation studies and for all routes of administration (Table 10, Table B-1, Table B-2, and Table B-4). In addition, there were two occurrences of benign pheochromocytoma in each of the 3 and 10 mg/m^3^ female groups. In male rats, the trend for increases in benign or complex pheochromocytomas was positive (Table 10 and Table A-2). Microscopically, the pheochromocytomas formed well-delineated masses of medullary cells, usually arranged in solid sheets but sometimes forming trabecular cords with intervening expanded blood-filled spaces (Figure 12). Compression of adjacent cortex and/or medulla was usually noted. One malignant pheochromocytoma, penetrating through the adrenal capsule, occurred in a 30 mg/m^3^ female.

Table 10 Incidences of Neoplasms and Nonneoplastic Lesions of the Adrenal Medulla in Rats in the Two-year Inhalation Study of Antimony Trioxide

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Male
Two-year Study
Number Examined Microscopically | 49 | 50 | 49 | 50
Hyperplasia^a^ | 1 (3.0)^b^ | 2 (3.5) | 4 (1.5) | 8* (1.5)
Benign Pheochromocytoma^c^ | 1 | 0 | 2 | 7*
Benign or Complex Pheochromocytoma^d^
Overall rate^e^ | 2/49 (4%) | 0/50 (0%) | 2/49 (4%) | 7/50 (14%)
Adjusted rate^f^ | 4.9% | 0.0% | 4.8% | 17.2%
Terminal rate^g^ | 1/30 (3%) | 0/30 (0%) | 1/27 (4%) | 3/18 (17%)
First incidence (days) | 680 | –^i^ | 537 | 590
Poly-3 test^h^ | P = 0.003 | P = 0.236N | P = 0.681N | P = 0.078
Female
Two-year Study
Number Examined Microscopically | 49 | 49 | 49 | 50
Hyperplasia | 0 | 0 | 3 (1.3) | 5* (2.0)
Benign Pheochromocytoma^j^
Overall rate | 0/49 (0%) | 2/49 (4%) | 2/49 (4%) | 6/50 (12%)
Adjusted rate | 0.0% | 4.5% | 4.8% | 15.2%
Terminal rate | 0/38 (0%) | 1/37 (3%) | 1/27 (4%) | 4/20 (20%)
First incidence (days) | – | 719 | 698 | 705
Poly-3 test | P = 0.004 | P = 0.235 | P = 0.221 | P = 0.009
Malignant Pheochromocytoma^k^ | 0 | 0 | 0 | 1
Benign or Malignant Pheochromocytoma^l^
Overall rate | 0/49 (0%) | 2/49 (4%) | 2/49 (4%) | 7/50 (14%)
Adjusted rate | 0.0% | 4.5% | 4.8% | 17.6%
Terminal rate | 0/38 (0%) | 1/37 (3%) | 1/27 (4%) | 4/20 (20%)
First incidence (days) | – | 719 | 698 | 621
Poly-3 test | P < 0.001 | P = 0.235 | P = 0.221 | P = 0.004

* Significantly different (P ≤ 0.05) from the chamber control group by the Poly-3 test.

(T) = terminal kill.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical incidence for 2-year inhalation studies with chamber control groups (mean ± standard deviation): 5/149 (3.4% ± 4.2%), range 0%–8%; all routes: 6/297 (2.0% ± 3.1%), range 0%–8%.

^d^ Historical incidence for inhalation studies: 6/149 (4.0% ± 4.0%), range 0%–8%; all routes 7/297 (2.4% ± 3.2%), range 0%–8%.

^e^ Number of animals with neoplasm per number of animals with adrenal medulla examined microscopically.

^f^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Observed incidence at terminal kill.

^h^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in an exposure group is indicated by N.

^i^ Not applicable; no neoplasms in animal group.

^j^ Historical incidence for inhalation studies: 1/148 (0.7% ± 1.2%), range 0%–2%; all routes: 5/297 (1.7% ± 1.5%), range 0%–4%.

^k^ Historical incidence for inhalation studies: 1/148 (0.7% ± 1.2%), range 0%–2%; all routes: 1/297 (0.3% ± 0.8%), range 0%–2%.

^l^ Historical incidence for inhalation studies: 2/148 (1.4% ± 2.4%), range 0%–4%; all routes: 7/297 (2.4% ± 2.0%), range 0%–4% (includes one incidence of complex pheochromocytoma).

Figure 12

Hyperplasia and Neoplasia of the Adrenal Medulla (H&E)

A) The small focus of adrenal medullary hyperplasia (arrow) found in a male Wistar Han rat exposed to 30 mg antimony trioxide/m^3^ by inhalation for 2 years displayed increased cellularity, without compression of the surrounding medulla. B) This benign pheochromocytoma in a male Wistar Han rat exposed to 30 mg antimony trioxide/m^3^ by inhalation for 2 years exhibited a solid pattern, filled and expanded the adrenal medulla, and compressed the adjacent adrenal cortex (arrows). C) This benign pheochromocytoma in a female Wistar Han rat exposed to 30 mg antimony trioxide/m^3^ by inhalation for 2 years formed a large, vascular nodule (arrow) with a trabecular pattern and frequent mitotic figures as seen at higher magnification in D).

Incidences of adrenal medullary hyperplasia occurred with a positive trend in both males and females in the 2-year study, and the incidences were significantly increased in 30 mg/m^3^ males and females compared to those of the chamber controls (Table 10, Table A-5, and Table B-5). Microscopically, hyperplasia of the adrenal medulla was characterized by noncompressive foci that were distinct from the adjacent parenchyma due to hypercellularity, decrease in cell size, and often a change in cytoplasmic coloration imparting a more basophilic appearance (Figure 12).

Nose: At the 12-month interim evaluation, foreign body, presumably the test article, occurred in a single 10 mg/m^3^ male; incidences of this lesion were significantly increased in 30 mg/m^3^ males and females compared to the chamber controls (Table 11, Table A-5, and Table B-5). In the 2-year study, significantly increased incidences of foreign body occurred in 10 and 30 mg/m^3^ males and in all exposed groups of females. Foreign bodies occurred most commonly within macrophages adjacent to the nasal-associated lymphoid tissue along the nasopharyngeal duct of nasal Level III but were also commonly present within macrophages or entrapped within the mucous layer overlying the respiratory epithelium of the ventral-most portion of Level II.

Table 11 Incidences of Nonneoplastic Lesions of the Upper Respiratory Tract in Rats in the Two-year Inhalation Study of Antimony Trioxide

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Male
Twelve-month Interim Evaluation
Nose^a^ | 10 | 10 | 10 | 10
Foreign Body^b^ | 0 | 0 | 1 | 9**
Respiratory Epithelium, Hyperplasia | 0 | 0 | 1 (1.0)^c^ | 2 (1.0)
Larynx | 10 | 10 | 10 | 10
Foreign Body | 0 | 10** | 10** | 10**
Trachea | 10 | 10 | 10 | 10
Foreign Body | 0 | 8** | 9** | 10**
Two-year Study
Nose | 50 | 49 | 50 | 50
Foreign Body | 0 | 0 | 17** | 40**
Respiratory Epithelium, Hyperplasia | 6 (1.3) | 15* (1.1) | 13 (1.1) | 25** (1.1)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 2 (1.0) | 6* (1.7)
Larynx | 50 | 50 | 50 | 50
Foreign Body | 0 | 50** | 50** | 50**
Inflammation, Chronic Active | 2 (1.5) | 5 (1.4) | 2 (2.0) | 4 (2.0)
Metaplasia, Squamous | 0 | 2 (1.0) | 0 | 1 (1.0)
Trachea | 50 | 50 | 50 | 50
Foreign Body | 0 | 28** | 43** | 48**
Metaplasia, Squamous | 1 (1.0) | 1 (1.0) | 4 (1.0) | 3 (1.3)
Female
Twelve-month Interim Evaluation
Nose | 10 | 10 | 10 | 10
Foreign Body | 0 | 0 | 0 | 4*
Respiratory Epithelium, Hyperplasia | 0 | 1 (1.0) | 0 | 2 (1.0)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 1 (1.0)
Larynx | 10 | 10 | 10 | 10
Foreign Body | 0 | 10** | 10** | 10**
Trachea | 10 | 10 | 10 | 10
Foreign Body | 0 | 6** | 10** | 10**
Two-year Study
Nose | 50 | 50 | 50 | 50
Foreign Body | 0 | 5* | 26** | 45**
Respiratory Epithelium, Hyperplasia | 4 (1.0) | 6 (1.3) | 7 (1.3) | 16** (1.1)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 2 (1.5) | 3 (2.0) | 5* (1.2)
Larynx | 50 | 50 | 50 | 50
Foreign Body | 0 | 50** | 50** | 50**
Inflammation, Chronic Active | 0 | 8** (1.1) | 0 | 3 (1.3)
Trachea | 50 | 50 | 50 | 50
Foreign Body | 0 | 39** | 47** | 49**

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact text (interim evaluation) or the Poly-3 test (2-year study).

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Hyperplasia of the respiratory epithelium occurred in 10 and 30 mg/m^3^ males and in 3 and 30 mg/m^3^ females at the 12-month interim evaluation (Table 11, Table A-5, and Table B-5). In the 2-year study, incidences of hyperplasia of the respiratory epithelium occurred in both chamber control and exposed rats; the incidences were significantly increased in 3 and 30 mg/m^3^ males and 30 mg/m^3^ females compared to those in the chamber controls. The hyperplasia consisted of focal or multifocal hypercellularity of the epithelium along the lateral wall of Level I, the maxilloturbinates and, rarely, the nasoturbinates. The affected epithelium was composed of three or more layers of nonciliated, cuboidal to low columnar epithelium (Figure 13). A single incidence of respiratory epithelial adenoma was identified in a 30 mg/m^3^ male rat (Table A-1); no adenomas were seen in the chamber controls, and none have been reported in the historical controls for inhalation studies (0/150) or for all routes of administration (0/299).

Figure 13

Respiratory Epithelial Hyperplasia of the Ventral Septum of the Nose (Level I) (H&E)

A) Normal columnar, ciliated epithelium (arrowhead) with scattered goblet cells in a chamber control, male Wistar Han rat in the 2-year study of antimony trioxide by inhalation. B) Respiratory epithelial hyperplasia (arrowhead) in a male Wistar Han rat exposed to 30 mg/m^3^ antimony trioxide by inhalation for 2 years. The epithelium is thickened by proliferation of nonciliated, cuboidal epithelial cells with crowding of the nuclei; a reduction in the number of goblet cells is also noted. The underlying lamina propria is slightly inflamed.

Squamous metaplasia of the respiratory epithelium occurred in a 30 mg/m^3^ female at the 12-month interim evaluation, in males exposed to 10 and 30 mg/m^3^ in the 2-year study, and in all exposed groups of females in the 2-year study (Table 11, Table A-5, and Table B-5). The incidences of this lesion in the 30 mg/m^3^ males and females were significantly increased compared to those in the chamber control groups in the 2-year study.

Larynx: Incidences of foreign body, presumably the test article, occurred in all exposed males and females at the 12-month interim evaluation and in the 2-year study and the incidences were significantly increased compared to those in the chamber controls (Table 11, Table A-5, and Table B-5). The foreign bodies were predominantly located within the cytoplasm of macrophages in the lamina propria, but were also seen within the extracellular matrix, and were observed in all three Levels of the larynx. In the 2-year study, chronic active inflammation occurred in chamber control and all exposed groups of males and in 3 and 30 mg/m^3^ females; the incidence of this lesion was significantly increased in 3 mg/m^3^ females compared to that in the chamber control group.

Trachea: Significantly increased incidences of foreign body, presumably the test article, occurred in all exposed groups of males and females at the 12-month interim evaluation and in the 2-year study compared to those in the chamber control groups (Table 11, Table A-5, and Table B-5). Foreign bodies were located predominately within macrophages in the lamina propria, but were also seen within the extracellular matrix. Low incidences of minimal to mild squamous metaplasia occurred in the tracheal epithelium of the chamber control and exposed groups of males in the 2-year study.

Bone Marrow: Hyperplasia of the hematopoietic elements of the marrow was not identified in male or female rats at the 12-month interim evaluation, but was observed in chamber control females and exposed groups of males and females in the 2-year study (Table 12, Table A-5, and Table B-5). The incidences of hyperplasia in the 2-year study were significantly increased in 30 mg/m^3^ males and females compared to those in the chamber controls. The hyperplastic marrow in animals exposed to antimony trioxide often exhibited a shift in the myeloid/erythroid ratio, with a distinguishable increase in the erythroid precursors. In contrast, hyperplasia in chamber control rats often occurred with inflammatory lesions, in which the marrow generally maintained a normal myeloid to erythroid ratio, or tended towards an increase in myeloid precursors.

Table 12 Incidences of Nonneoplastic Lesions of the Hematopoietic System in Rats in the Two-year Inhalation Study of Antimony Trioxide

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Male
Twelve-month Interim Evaluation
Lymph Node, Bronchial^a^ | 9 | 8 | 10 | 10
Foreign Body^b^ | 0 | 8** | 10** | 10**
Hyperplasia, Lymphoid | 0 | 2 (1.5)^c^ | 5* (1.0) | 2 (1.5)
Lymph Node, Mediastinal | 10 | 8 | 10 | 9
Foreign Body | 0 | 8** | 6** | 6**
Hyperplasia, Lymphoid | 0 | 2 (1.0) | 6** (1.3) | 3 (1.7)
Two-year Study
Bone Marrow | 50 | 50 | 50 | 50
Hyperplasia | 0 | 3 (1.0) | 4 (1.0) | 8** (1.0)
Lymph Node, Bronchial | 41 | 40 | 48 | 47
Foreign Body | 0 | 35** | 45** | 42**
Hyperplasia, Lymphoid | 0 | 21** (1.0) | 29** (1.3) | 26** (1.3)
Pigmentation | 1 (2.0) | 4 (1.3) | 5 (1.2) | 10** (1.3)
Lymph Node, Mediastinal | 42 | 45 | 49 | 49
Foreign Body | 0 | 41** | 41** | 43**
Hyperplasia, Lymphoid | 1 (1.0) | 24** (1.3) | 30** (1.4) | 26** (1.3)
Female
Twelve-month Interim Evaluation
Lymph Node, Bronchial | 7 | 8 | 9 | 5
Foreign Body | 0 | 7** | 9** | 4**
Hyperplasia, Lymphoid | 0 | 4* (1.0) | 2 (1.0) | 1 (1.0)
Lymph Node, Mediastinal | 10 | 9 | 10 | 10
Foreign Body | 0 | 9** | 5** | 6**
Hyperplasia, Lymphoid | 0 | 8** (1.0) | 0 | 3 (1.7)
Two-year Study
Bone Marrow | 50 | 50 | 50 | 50
Hyperplasia | 8 (1.0) | 5 (1.0) | 11 (1.0) | 20** (1.0)
Lymph Node, Bronchial | 35 | 36 | 28 | 41
Foreign Body | 0 | 35** | 23** | 36**
Hyperplasia, Lymphoid | 0 | 21** (1.0) | 9** (1.6) | 11** (1.0)
Lymph Node, Mediastinal | 46 | 46 | 46 | 46
Foreign Body | 0 | 27** | 32** | 33**
Hyperplasia, Lymphoid | 0 | 14** (1.1) | 10** (1.2) | 15** (1.1)

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact text (interim evaluation) or the Poly-3 test (2-year study).

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Lymph Nodes: The incidences of foreign body, presumed to be the test article, in the bronchial and mediastinal lymph nodes of all exposed groups of males and females at the 12-month interim evaluation and in the 2-year study were significantly increased compared to those in the chamber control groups (Table 12, Table A-5, and Table B-5). Foreign bodies were noted primarily within macrophages, which variably expanded the medullary and subcapsular sinuses.

Incidences of minimal to mild lymphoid hyperplasia occurred in the bronchial and mediastinal lymph nodes of most exposed groups of male and female rats at the 12-month interim evaluation and in all exposed groups of males and females in the 2-year study (Table 12, Table A-5, and Table B-5). The incidences of lymphoid hyperplasia in the bronchial and mediastinal lymph nodes were significantly increased in 10 mg/m^3^ males and 3 mg/m^3^ females at the 12-month interim evaluation and in all exposed groups of males and females in the 2-year study compared to those in the chamber controls. The lymphoid hyperplasia was characterized by expansion of the lymphocyte populations within the paracortical and medullary regions, resulting in a significant increase in lymph node size.

Golden brown pigment, resembling hemosiderin, was observed in the macrophages of the bronchial lymph nodes in male rats in the 2-year study; the incidence of pigmentation in 30 mg/m^3^ males was significantly increased compared to that in the chamber control group (Table 12 and Table A-5).

Arterial Vessels: No vascular lesions were noted at the 12-month interim evaluation (Table A-5 and Table B-5). In the 2-year study, incidences of chronic active inflammation of small to medium sized muscular arteries occurred mostly in a few 10 mg/m^3^ males and females and many 30 mg/m^3^ males and females; the vessels affected were located primarily within the mediastinum, pancreas, and mesentery, and were observed less frequently in the kidney and lung (Table 13, Table A-5, and Table B-5). The increased incidences of chronic active inflammation in the pancreas and mesentery of 30 mg/m^3^ males and females were significant when compared to those in the chamber control groups. When the incidences of inflammatory vascular lesions in any tissue were combined, they were increased in 10 and 30 mg/m^3^ males and females with the increased incidences being significant in 10 mg/m^3^ females and in 30 mg/m^3^ males and females compared to those in the chamber controls. The inflammatory infiltrate within affected vessels was predominantly composed of lymphocytes, with lesser numbers of macrophages and granulocytes (Figure 14). There were a small number of vessels with less advanced lesions that were composed primarily of neutrophils. In addition, affected vessels often had evidence of alterations to the media, variably characterized by cell swelling, vacuolation, or necrosis occasionally resulting in hemorrhage; all of these lesions were captured under the diagnosis of necrosis. In the 2-year study, the incidence of necrosis of the artery of the pancreas was significantly increased in 30 mg/m^3^ females compared to that in the chamber controls. In two 30 mg/m^3^ females, there were mediastinal arteries with marked proliferation of capillaries in the muscular walls of the vessels; this type of lesion has been referred to as plexiform vasculopathy in the literature^72^,and is depicted in Figure 14D.

Table 13 Incidences of Nonneoplastic Lesions in the Arterial Vessels of Rats in the Two-year Inhalation Study of Antimony Trioxide

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Male
Two-year Study
Mediastinum^a^ | 0 | 1 | 2 | 10
Artery, Inflammation, Chronic Active^b^ | − | 1 (3.0)^c^ | 2 (2.5) | 10 (2.3)
Artery, Necrosis | − | 0 | 2 (3.0) | 9 (1.8)
Pancreas | 50 | 50 | 50 | 50
Artery, Inflammation, Chronic Active | 1 (2.0) | 0 | 2 (2.5) | 8* (3.1)
Artery, Necrosis | 0 | 0 | 1 (2.0) | 4 (2.0)
Mesentery | 50 | 50 | 50 | 50
Artery, Inflammation, Chronic Active | 0 | 0 | 0 | 6* (2.2)
Artery, Necrosis | 0 | 0 | 0 | 3 (1.7)
Lung | 50 | 50 | 50 | 50
Artery, Inflammation, Chronic Active | 0 | 0 | 1 (1.0) | 1 (2.0)
Kidney | 50 | 50 | 50 | 50
Artery, Inflammation, Chronic Active | 0 | 0 | 1 (1.0) | 4 (1.3)
Artery, Necrosis | 0 | 0 | 1 (2.0) | 4 (1.3)
Artery (All Tissues Combined) | 50 | 50 | 50 | 50
Artery, Inflammation, Chronic Active | 1 | 1 | 5 | 16**
Female
Two-year Study
Mediastinum | 0 | 0 | 2 | 9
Artery, Inflammation, Chronic Active | − | − | 2 (1.5) | 9 (2.3)
Artery, Necrosis | − | − | 1 (1.0) | 6 (2.2)
Pancreas | 50 | 50 | 50 | 50
Artery, Inflammation, Chronic Active | 0 | 0 | 3 (2.0) | 8** (2.5)
Artery, Necrosis | 0 | 0 | 0 | 4* (2.0)
Mesentery | 50 | 50 | 50 | 50
Artery, Inflammation, Chronic Active | 0 | 0 | 0 | 6** (2.5)
Artery, Necrosis | 0 | 0 | 0 | 3 (1.7)
Lung | 50 | 50 | 50 | 50
Artery, Inflammation, Chronic Active | 0 | 0 | 1 (2.0) | 2 (1.0)
Artery, Necrosis | 0 | 0 | 0 | 2 (1.0)
Kidney | 50 | 50 | 50 | 50
Artery, Inflammation, Chronic Active | 0 | 0 | 0 | 2 (1.5)
Artery, Necrosis | 0 | 0 | 1 (2.0) | 2 (1.5)
Artery (All Tissues Combined) | 50 | 50 | 50 | 50
Artery, Inflammation, Chronic Active | 0 | 0 | 5* | 15**

* Significantly different (P ≤ 0.05) from the chamber control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Figure 14

Arterial Inflammation (A, B, and C) and Plexiform Vasculopathy (D) (H&E)

A) The wall of this pancreatic artery in a female Wistar Han rat exposed to 30 mg antimony trioxide/m^3^ by inhalation for 2 years was markedly thickened by chronic inflammatory changes (arrow). B) The pancreatic artery in a male Wistar Han rat exposed to 30 mg antimony trioxide/m^3^ by inhalation for 2 years displayed a greatly thickened wall due to fibrosis and inflammatory infiltrate. C) This mediastinal artery in a male Wistar Han rat exposed to 30 mg antimony trioxide/m^3^ by inhalation for 2 years exhibited chronic active inflammation throughout the wall and accumulation of eosinophilic material within the intima (arrow). D) Proliferation of numerous small, endothelial lined channels, accompanied by mild inflammatory infiltrate, was noted in the media and adventitia of this mediastinal artery in a female Wistar Han rat exposed to 30 mg antimony trioxide/m^3^ by inhalation for 2 years (arrows). This type of change is sometimes referred to as plexiform or plexogenic vasculopathy.

Kidney: The incidences of hyaline droplet accumulation in the cytoplasm of renal tubule cells in 30 mg/m^3^ males and 10 and 30 mg/m^3^ females were significantly increased compared to those in the chamber controls in the 2-year study (Table 14, Table A-5, and Table B-5). The hyaline droplets were variably sized (2 to 5 microns), generally circular to ovoid, eosinophilic, and located primarily within the cytoplasm of proximal tubule epithelial cells. The possibility that the material in the renal tubule cells might be surfactant A was considered because of the accumulation of surfactant A in the lung, but immunohistochemical staining of representative animals with affected kidneys was negative for surfactant A. Hyaline droplet accumulation was not seen within the kidneys of males or females at the 12-month interim evaluation (Table A-5 and Table B-5).

Table 14 Incidences of Selected Nonneoplastic Lesions in Rats in the Two-year Inhalation Study of Antimony Trioxide

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Male
Two-year Study
Kidney^a^ | 50 | 50 | 50 | 50
Renal Tubule, Accumulation, Hyaline Droplet^b^ | 0 | 1 (4.0)^c^ | 3 (2.0) | 14** (1.3)
Eye | 49 | 49 | 50 | 49
Ciliary Body, Inflammation, Acute | 0 | 0 | 1 (1.0) | 6* (1.2)
Prostate Gland | 50 | 50 | 50 | 50
Epithelium, Hyperplasia | 9 (1.3) | 18* (2.1) | 21* (1.5) | 13 (1.7)
Female
Two-year Study
Kidney | 50 | 50 | 50 | 50
Renal Tubule, Accumulation, Hyaline Droplet | 0 | 0 | 5* (1.2) | 11** (1.7)
Nephropathy | 16 (1.4) | 15 (1.0) | 20 (1.4) | 24* (1.6)
Eye | 49 | 50 | 49 | 49
Retina, Atrophy | 6 (2.5) | 21** (2.0) | 18** (2.1) | 19** (1.9)
Ciliary Body, Inflammation, Acute | 0 | 0 | 1 (1.0) | 6** (1.0)

* Significantly different (P ≤ 0.05) from the chamber control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

In the 2-year study, the incidence of nephropathy in 30 mg/m^3^ females was significantly increased compared to that in the chamber control group (Table 14 and Table B-5). Incidences of pelvis mineralization were significantly decreased in 30 mg/m^3^ males and females compared to those in the chamber control groups (males: 16/50, 10/50, 11/50, 3/50; females: 31/50, 30/50, 24/50, 15/50; Table A-5, and Table B-5).

Eye: In the 2-year study, the incidences of retinal atrophy were significantly increased in all exposed groups of females compared to the chamber control group (Table 14 and Table B-5). The increased incidences of retinal atrophy were not exposure concentration-dependent, and there were no obvious differences between the chamber control group and exposed groups of females in either the appearance or the severity of the atrophy. The atrophy ranged from minimal focal loss of the photoreceptor layer and a portion of the outer nuclear layer to diffuse loss of all but the inner plexiform and nuclear layers and the ganglion cell layer.

In the 2-year study, incidences of minimal acute inflammation of the ciliary body occurred in males and females in the 10 and 30 mg/m^3^ groups and the incidences were significantly increased in the 30 mg/m^3^ groups of males and females compared to those in the chamber control groups (Table 14, Table A-5, and Table B-5). The lesion was characterized by infiltration of neutrophils predominantly within the ciliary processes, often accompanied by the accumulation of acellular eosinophilic material.

Prostate Gland: In the 2-year study, the incidences of epithelium hyperplasia were significantly increased in 3 and 10 mg/m^3^ males compared to those in the chamber controls; and the severities were increased in all exposed groups (Table 14 and Table A-5). Microscopically, the hyperplastic foci presented as papillary or cribriform proliferations of the epithelial cells projecting into one or more adjacent prostatic acini, but without completely filling the lumens of the affected acini, and without distorting the acinar architecture or compressing the adjacent acini.

Skin: In 2-year study males, increased incidences of chronic active inflammation (chamber control, 22/50; 3 mg/m^3^, 30/50; 10 mg/m^3^, 28/50; 30 mg/m^3^, 32/50) and ulcer (17/50, 23/50, 23/50, 28/50) occurred in all exposed groups and were significantly increased in the 30 mg/m^3^ group compared to those in the chamber control group (Table A-5). In 2-year study females, the incidences of ulcer (2/50, 5/49, 4/50, 8/50) in the chamber control and exposed groups were less than those in the males, but the incidence of this lesion was significantly increased in the 30 mg/m^3^ group compared to that in the chamber control group (Table A-5 and Table B-5).

Other Organs: In the 2-year study, incidences of various nonneoplastic lesions of uncertain significance were increased in exposed groups compared to those in the chamber control groups. Incidences of squamous hyperplasia of the forestomach (chamber control, 2/50; 3 mg/m^3^, 7/50; 10 mg/m^3^, 4/50; 30 mg/m^3^, 7/50) and cellular depletion of the thymus (5/41, 6/35, 6/47, 9/45) were slightly increased in exposed groups of males (Table A-5). In the uterus, increased incidences of cystic hyperplasia of the endometrium (9/50, 17/50, 6/50, 16/50) occurred in 3 and 30 mg/m^3^ females, and the incidence of this lesion was significantly increased in the 30 mg/m^3^ group compared to that in the chamber control group (Table B-5).

In the pituitary gland, the incidence of pars distalis adenoma was significantly decreased in 30 mg/m^3^ males compared to that in the chamber controls (14/50, 15/50, 12/50, 5/50; Table A-1 and Table A-2); the incidence of this neoplasm was slightly decreased in 30 mg/m^3^ females (19/50, 22/50, 19/50, 12/50; Table B-1 and Table B-2).

## Mice

### Two-week Study

All mice survived to the end of the study (Table 15). The final mean body weights and body weight gains of exposed groups of males and females were similar to the respective chamber control groups. There were no clinical findings related to antimony trioxide exposure.

Table 15 Survival and Body Weights of Mice in the Two-week Inhalation Study of Antimony Trioxide^a^

Concentration (mg/m^3^) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 5/5 | 24.0 ± 0.3 | 25.0 ± 0.2 | 1.0 ± 0.5
3.75 | 5/5 | 24.2 ± 0.4 | 25.3 ± 0.1 | 1.1 ± 0.3 | 101
7.5 | 5/5 | 24.4 ± 0.2 | 26.4 ± 0.5 | 2.1 ± 0.5 | 106
15 | 5/5 | 24.7 ± 0.5 | 25.9 ± 0.6 | 1.2 ± 0.7 | 104
30 | 5/5 | 24.1 ± 0.4 | 25.5 ± 0.6 | 1.4 ± 0.4 | 102
60 | 5/5 | 24.5 ± 0.4 | 26.6 ± 0.8 | 2.1 ± 0.4 | 106
Female
0 | 5/5 | 19.6 ± 0.2 | 21.2 ± 0.3 | 1.6 ± 0.4
3.75 | 5/5 | 19.4 ± 0.3 | 20.9 ± 0.2 | 1.5 ± 0.2 | 98
7.5 | 5/5 | 18.7 ± 0.3 | 20.6 ± 0.4 | 1.9 ± 0.5 | 97
15 | 5/5 | 19.5 ± 0.2 | 20.9 ± 0.2 | 1.4 ± 0.4 | 99
30 | 5/5 | 19.8 ± 0.4 | 21.0 ± 0.3 | 1.2 ± 0.3 | 99
60 | 5/5 | 19.9 ± 0.4 | 21.1 ± 0.4 | 1.2 ± 0.6 | 100

^a^ Weights and weight changes are given as mean ± standard error.

^b^ Number of animals surviving at 17 days/number initially in group.

Absolute lung weights were significantly increased in 7.5 mg/m^3^ or greater males and in females exposed to 15 mg/m^3^ or greater compared to the chamber controls (Table 16 and Table F-3). Relative lung weights were significantly increased in 60 mg/m^3^ males and in all exposed groups of females compared to the chamber control groups. There were no gross observations associated with exposure to antimony trioxide noted at necropsy.

Table 16 Lung Weights and Lung-Weight-to-Body-Weight Ratios for Mice in the Two-week Inhalation Study of Antimony Trioxide^a^

| Chamber Control | 3.75 mg/m^3^ | 7.5 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
n | 5 | 5 | 5 | 5 | 5 | 5
Male
Necropsy body wt. | 25.0 ± 0.2 | 25.3 ± 0.1 | 26.4 ± 0.5 | 25.9 ± 0.6 | 25.5 ± 0.6 | 26.6 ± 0.8
Lung
Absolute | 0.17 ± 0.01 | 0.21 ± 0.02 | 0.22 ± 0.01* | 0.21 ± 0.01* | 0.21 ± 0.01* | 0.23 ± 0.01**
Relative | 6.939 ± 0.267 | 8.086 ± 0.835 | 8.184 ± 0.443 | 8.076 ± 0.321 | 8.147 ± 0.232 | 8.725 ± 0.209**
Female
Necropsy body wt. | 21.2 ± 0.3 | 20.9 ± 0.2 | 20.6 ± 0.4 | 20.9 ± 0.2 | 21.0 ± 0.3 | 21.1 ± 0.4
Lung
Absolute | 0.16 ± 0.00 | 0.18 ± 0.01 | 0.18 ± 0.00 | 0.20 ± 0.01** | 0.20 ± 0.01** | 0.22 ± 0.01**
Relative | 7.656 ± 0.185 | 8.736 ± 0.336* | 8.734 ± 0.131* | 9.546 ± 0.308** | 9.659 ± 0.229** | 10.320 ± 0.397**

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ test.

** P ≤ 0.01.

^a^ Lung weights (absolute weights) and body weights are given in grams; lung-weight-to-body-weight ratios (relative weights) are given as mg lung weight/g body weight (mean ± standard error).

Minimal or mild squamous metaplasia of the epithelium lining the base of the epiglottis occurred in all male and female mice in the 30 and 60 mg/m^3^ groups and the incidences were significantly increased compared to those of the chamber controls (Table 17). Also, minimal incidences of squamous metaplasia of the epiglottis occurred without statistical significance in one 15 mg/m^3^ male and in several 3.75, 7.5, and 15 mg/m^3^ females. Significantly increased incidences of foreign body, presumed to be the test article, occurred in the lung of all groups of mice exposed to antimony trioxide. The foreign bodies appeared as refractile gold to brown/black granules within the cytoplasm of alveolar macrophages and lying free within the alveolar spaces.

Table 17 Incidences of Selected Nonneoplastic Lesions of the Respiratory System in Mice in the Two-week Inhalation Study of Antimony Trioxide

| Chamber Control | 3.75 mg/m^3^ | 7.5 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
Male
Larynx^a^ | 5 | 0 | 5 | 4 | 5 | 5
Epiglottis, Metaplasia, Squamous^b^ | 0 | − | 0 | 1 (1.0)^c^ | 5** (1.0) | 5** (1.8)
Lung | 5 | 5 | 5 | 5 | 5 | 5
Foreign Body | 0 | 5** | 5** | 5** | 5** | 5**
Female
Larynx | 5 | 5 | 5 | 5 | 5 | 5
Epiglottis, Metaplasia, Squamous | 0 | 2 (1.0) | 2 (1.0) | 3 (1.0) | 5** (1.0) | 5** (2.0)
Lung | 5 | 5 | 5 | 5 | 5 | 5
Foreign Body | 0 | 5** | 5** | 5** | 5** | 5**

** Significantly different (P ≤ 0.01) from the chamber control group by the Fisher exact test.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Exposure Concentration Selection Rationale: The 2-year mouse inhalation study was designed following a review of the current 2-week study as well as the subchronic and chronic (1-year exposure duration) inhalation study data for rats from the literature. These data were considered sufficient to design the 2-year study without conducting a 3-month NTP study. The highest exposure concentration selected for the 2-year study (30 mg/m^3^) and half-log exposure concentration spacing intervals were selected to match the rat study. A 12-month interim evaluation was included in the 2-year study to provide a means of comparison to the previous 1-year rat exposures and the concurrent rat study.

### Two-year Study

#### Survival

Estimates of 2-year survival probabilities for male and female mice are shown in Table 18 and in the Kaplan-Meier survival curves (Figure 4). Survival of 10 and 30 mg/m^3^ males and females was significantly less than that of the chamber control groups. Decreases in survival were attributed primarily to alveolar/bronchiolar carcinomas and inflammation of the lung in males and malignant lymphoma and lung inflammation in females.

Table 18 Survival of Mice in the Two-year Inhalation Study of Antimony Trioxide

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Male
Animals initially in study | 60 | 60 | 60 | 60
Twelve-month interim evaluation^a^ | 10 | 10 | 10 | 10
Accidental death | − | 1
Moribund | 7 | 12 | 15 | 26
Natural deaths | 5 | 7 | 8 | 7
Animals surviving to study termination | 38 | 30 | 27 | 17
Percent probability of survival at end of study^b^ | 76 | 61 | 54 | 34
Mean survival (days)^c^ | 708 | 658 | 666 | 652
Survival analysis^d^ | P < 0.001 | P = 0.134 | P = 0.027 | P < 0.001
Female
Animals initially in study | 60 | 60 | 60 | 60
Twelve-month interim evaluation^a^ | 10 | 10 | 10 | 10
Accidental death | 1 | − | − | −
Moribund | 10 | 11 | 16 | 27
Natural deaths | 3 | 8 | 8 | 8
Animals surviving to study termination | 36 | 31 | 26 | 15
Percent probability of survival at end of study | 74 | 62 | 52 | 30
Mean survival (days) | 692 | 693 | 666 | 642
Survival analysis | P < 0.001 | P = 0.303 | P = 0.032 | P < 0.001

^a^ Excluded from survival analyses.

^b^ Kaplan-Meier determinations.

^c^ Mean of all deaths (uncensored, censored, and terminal kill).

^d^ The result of the life table trend test^50^ is in the chamber control column, and the results of the life table pairwise comparisons^49^ with the chamber controls are in the exposed group columns.

Figure 4

Kaplan-Meier Survival Curves for Mice Exposed to Antimony Trioxide by Inhalation for Two Years

#### Body Weights, Clinical Findings, and Organ Weights

The mean body weights of 30 mg/m^3^ males were at least 10% less than those of the chamber controls after week 73 and 25% less than that of the chamber control group by the end of the study (Table 19 and Figure 5). Mean body weights of 30 mg/m^3^ females were at least 10% less than those of the chamber controls after week 85 and 21% less than that of the chamber control group by the end of the study (Table 20 and Figure 5).

Table 19 Mean Body Weights and Survival of Male Mice in the Two-year Inhalation Study of Antimony Trioxide

Day | Chamber Control | | 3 mg/m^3^ | | | 10 mg/m^3^ | | | 30 mg/m^3^
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 23.5 | 60 | 23.2 | 99 | 60 | 23.1 | 99 | 60 | 23.2 | 99 | 60
9 | 26.0 | 60 | 25.4 | 98 | 60 | 25.4 | 98 | 60 | 25.5 | 98 | 60
16 | 26.7 | 60 | 26.3 | 99 | 60 | 26.4 | 99 | 60 | 26.4 | 99 | 60
23 | 27.6 | 60 | 27.2 | 99 | 60 | 26.9 | 98 | 60 | 27.4 | 99 | 60
30 | 28.3 | 60 | 28.2 | 100 | 60 | 27.9 | 99 | 60 | 28.4 | 101 | 60
37 | 29.2 | 60 | 29.1 | 100 | 60 | 28.7 | 98 | 60 | 29.0 | 99 | 60
44 | 30.0 | 60 | 30.0 | 100 | 60 | 29.7 | 99 | 60 | 29.2 | 98 | 60
51 | 30.8 | 60 | 30.7 | 100 | 60 | 30.2 | 98 | 60 | 29.2 | 95 | 60
58 | 31.3 | 60 | 31.9 | 102 | 60 | 30.9 | 99 | 60 | 30.6 | 98 | 60
65 | 32.5 | 60 | 32.7 | 101 | 60 | 31.0 | 96 | 60 | 31.3 | 97 | 60
72 | 33.4 | 60 | 33.4 | 100 | 59 | 31.7 | 95 | 60 | 31.6 | 95 | 60
79 | 34.3 | 60 | 34.1 | 99 | 59 | 32.2 | 94 | 60 | 32.2 | 94 | 60
86 | 35.1 | 60 | 34.9 | 99 | 59 | 32.7 | 93 | 60 | 32.7 | 93 | 60
114 | 38.5 | 60 | 38.1 | 99 | 59 | 35.6 | 92 | 60 | 35.1 | 91 | 60
142 | 41.0 | 60 | 40.4 | 99 | 59 | 38.1 | 93 | 60 | 38.0 | 93 | 60
170 | 43.8 | 60 | 42.7 | 98 | 59 | 41.2 | 94 | 60 | 41.2 | 94 | 60
198 | 45.0 | 60 | 44.1 | 98 | 59 | 43.4 | 96 | 60 | 43.5 | 97 | 60
226 | 47.0 | 60 | 46.2 | 98 | 59 | 46.0 | 98 | 60 | 46.1 | 98 | 60
254 | 48.0 | 60 | 46.9 | 98 | 59 | 47.3 | 99 | 59 | 47.3 | 99 | 60
282 | 49.7 | 60 | 48.9 | 99 | 59 | 49.4 | 99 | 58 | 49.3 | 99 | 60
310 | 50.0 | 60 | 49.0 | 98 | 59 | 49.9 | 100 | 58 | 49.6 | 99 | 60
338 | 50.5 | 60 | 49.9 | 99 | 59 | 50.6 | 100 | 58 | 49.9 | 99 | 60
366 | 51.3 | 60 | 50.4 | 98 | 58 | 51.4 | 100 | 57 | 50.6 | 99 | 60
394^a^ | 51.8 | 50 | 51.1 | 99 | 47 | 52.0 | 100 | 47 | 50.5 | 98 | 50
422 | 51.7 | 50 | 51.2 | 99 | 47 | 51.7 | 100 | 47 | 49.6 | 96 | 50
450 | 52.1 | 50 | 51.1 | 98 | 46 | 51.9 | 100 | 47 | 49.2 | 94 | 50
478 | 51.4 | 50 | 51.1 | 99 | 44 | 51.2 | 99 | 46 | 48.1 | 93 | 48
506 | 51.8 | 50 | 51.3 | 99 | 43 | 51.0 | 98 | 45 | 47.0 | 91 | 47
534 | 52.0 | 49 | 51.3 | 99 | 42 | 51.3 | 99 | 43 | 46.1 | 89 | 44
562 | 51.5 | 49 | 50.7 | 98 | 42 | 50.8 | 99 | 42 | 45.3 | 88 | 41
590 | 51.9 | 48 | 50.8 | 98 | 40 | 50.0 | 96 | 41 | 44.8 | 86 | 38
618 | 51.0 | 47 | 48.7 | 96 | 39 | 49.7 | 97 | 39 | 42.6 | 84 | 36
646 | 50.8 | 45 | 47.3 | 93 | 36 | 48.3 | 95 | 36 | 41.8 | 82 | 27
660 | 50.0 | 45 | 46.8 | 94 | 35 | 47.2 | 94 | 35 | 40.2 | 80 | 27
674 | 51.2 | 41 | 46.9 | 92 | 35 | 46.0 | 90 | 32 | 40.8 | 80 | 23
688 | 50.6 | 40 | 46.4 | 92 | 34 | 46.0 | 91 | 29 | 38.6 | 76 | 23
702 | 51.4 | 38 | 46.1 | 90 | 34 | 46.7 | 91 | 28 | 39.9 | 78 | 19
716 | 51.2 | 38 | 47.1 | 92 | 30 | 45.5 | 89 | 28 | 38.4 | 75 | 18
Mean for Weeks
1–13 | 29.9 | | 29.8 | 100 | | 29.0 | 97 | | 29.0 | 97
14–52 | 45.9 | | 45.1 | 98 | | 44.6 | 97 | | 44.4 | 97
53–103 | 51.4 | | 49.3 | 96 | | 49.4 | 96 | | 44.6 | 87

^a^ Interim evaluation occurred during week 53.

Figure 5

Growth Curves for Mice Exposed to Antimony Trioxide by Inhalation for Two Years

Table 20 Mean Body Weights and Survival of Female Mice in the Two-year Inhalation Study of Antimony Trioxide

Day | Chamber Control | | 3 mg/m^3^ | | | 10 mg/m^3^ | | | 30 mg/m^3^
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 18.6 | 60 | 18.4 | 99 | 60 | 18.5 | 100 | 60 | 18.3 | 98 | 60
9 | 20.7 | 60 | 20.7 | 100 | 60 | 20.7 | 100 | 60 | 20.4 | 98 | 60
16 | 21.2 | 60 | 21.2 | 100 | 60 | 21.4 | 101 | 60 | 21.4 | 101 | 60
23 | 22.1 | 60 | 22.7 | 103 | 60 | 22.4 | 101 | 60 | 22.6 | 102 | 60
30 | 23.1 | 60 | 23.9 | 104 | 60 | 23.8 | 103 | 60 | 23.9 | 103 | 60
37 | 23.8 | 60 | 24.5 | 103 | 60 | 24.3 | 102 | 60 | 24.5 | 103 | 60
44 | 24.5 | 60 | 25.2 | 103 | 60 | 25.0 | 102 | 60 | 25.1 | 103 | 60
51 | 25.1 | 60 | 26.1 | 104 | 60 | 26.0 | 104 | 60 | 25.9 | 103 | 60
58 | 24.9 | 60 | 26.6 | 107 | 60 | 26.5 | 106 | 60 | 26.5 | 106 | 60
65 | 26.1 | 60 | 27.2 | 104 | 60 | 26.8 | 103 | 60 | 27.3 | 105 | 60
72 | 26.4 | 60 | 27.5 | 104 | 60 | 26.9 | 102 | 60 | 27.5 | 104 | 60
79 | 27.2 | 60 | 28.2 | 104 | 60 | 27.5 | 101 | 60 | 27.9 | 102 | 60
86 | 27.5 | 60 | 29.5 | 107 | 60 | 28.0 | 102 | 60 | 27.9 | 102 | 60
114 | 29.8 | 60 | 31.8 | 107 | 60 | 29.8 | 100 | 60 | 30.6 | 103 | 60
142 | 32.3 | 60 | 34.6 | 107 | 60 | 32.7 | 101 | 60 | 32.6 | 101 | 60
170 | 35.8 | 60 | 38.1 | 107 | 60 | 36.7 | 103 | 60 | 36.3 | 101 | 60
198 | 37.3 | 60 | 40.5 | 109 | 60 | 39.2 | 105 | 60 | 38.2 | 102 | 60
226 | 39.8 | 60 | 43.9 | 110 | 60 | 42.4 | 107 | 60 | 40.4 | 102 | 60
254 | 41.6 | 60 | 45.5 | 109 | 60 | 44.1 | 106 | 60 | 41.7 | 100 | 60
282 | 43.9 | 59 | 48.9 | 111 | 60 | 46.8 | 107 | 60 | 44.4 | 101 | 60
310 | 45.6 | 59 | 50.6 | 111 | 60 | 48.4 | 106 | 60 | 46.5 | 102 | 60
338 | 47.0 | 59 | 52.3 | 111 | 60 | 50.3 | 107 | 60 | 48.0 | 102 | 60
366 | 48.9 | 59 | 54.3 | 111 | 60 | 53.0 | 108 | 60 | 49.6 | 101 | 60
394^a^ | 51.1 | 49 | 56.6 | 111 | 50 | 54.7 | 107 | 50 | 51.1 | 100 | 50
422 | 52.5 | 48 | 57.6 | 110 | 50 | 54.5 | 104 | 49 | 51.1 | 97 | 47
450 | 53.2 | 48 | 58.9 | 111 | 49 | 55.6 | 105 | 48 | 52.1 | 98 | 46
478 | 53.8 | 47 | 59.5 | 111 | 49 | 54.4 | 101 | 48 | 51.8 | 96 | 45
506 | 54.1 | 47 | 59.2 | 110 | 49 | 54.1 | 100 | 47 | 51.0 | 94 | 43
534 | 53.9 | 47 | 58.3 | 108 | 48 | 54.8 | 102 | 42 | 50.5 | 94 | 41
562 | 53.6 | 46 | 58.5 | 109 | 46 | 53.2 | 99 | 41 | 49.9 | 93 | 40
590 | 53.2 | 45 | 58.5 | 110 | 45 | 54.1 | 102 | 39 | 49.2 | 93 | 38
618 | 51.3 | 43 | 55.1 | 108 | 43 | 51.3 | 100 | 37 | 46.2 | 90 | 33
646 | 49.8 | 42 | 52.9 | 106 | 39 | 48.9 | 98 | 35 | 44.8 | 90 | 30
660 | 49.6 | 42 | 51.8 | 105 | 38 | 48.6 | 98 | 33 | 43.2 | 87 | 30
674 | 49.3 | 42 | 51.5 | 105 | 37 | 47.4 | 96 | 32 | 41.6 | 84 | 26
688 | 49.8 | 40 | 50.7 | 102 | 36 | 46.7 | 94 | 30 | 41.0 | 82 | 24
702 | 50.4 | 39 | 50.3 | 100 | 36 | 46.3 | 92 | 30 | 42.1 | 84 | 19
716 | 49.9 | 38 | 48.4 | 97 | 33 | 45.7 | 92 | 27 | 39.2 | 79 | 18
Mean for Weeks
1–13 | 23.9 | | 24.7 | 103 | | 24.4 | 102 | | 24.6 | 102
14–52 | 39.2 | | 42.9 | 109 | | 41.2 | 105 | | 39.9 | 102
53–103 | 51.5 | | 55.1 | 107 | | 51.5 | 100 | | 47.2 | 91

^a^ Interim evaluation occurred during week 53.

Exposure-related clinical findings in male and female mice included abnormal breathing and thinness, which were increased at all exposure concentrations. These findings generally appeared during the second year of the study.

At the 12-month interim evaluation, absolute and relative lung weights were significantly increased in all exposed groups of males and females (except relative lung weight in 3 mg/m^3^ females) (Table 21 and Table F-4). In addition, absolute and relative thymus weights were significantly increased in 10 and 30 mg/m^3^ males and females and absolute thymus weight was significantly increased in 3 mg/m^3^ females. Significantly increased absolute heart and liver weights were observed in 30 mg/m^3^ females, but the relative weights were not statistically increased, and the biologic significance was uncertain.

Table 21 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice at the 12 month Interim Evaluation in the Two-year Inhalation Study of Antimony Trioxide^a^

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
n | 10 | 10 | 10 | 10
Male
Necropsy body wt. | 51.4 ± 0.3 | 51.3 ± 0.9 | 51.5 ± 0.6 | 51.9 ± 0.8
Lung
Absolute | 0.24 ± 0.01 | 0.33 ± 0.01** | 0.46 ± 0.01** | 0.66 ± 0.04**
Relative | 4.703 ± 0.113 | 6.396 ± 0.131* | 8.862 ± 0.289** | 12.857 ± 0.855**
Thymus
Absolute | 0.114 ± 0.005 | 0.126 ± 0.006 | 0.147 ± 0.008** | 0.173 ± 0.011**
Relative | 2.219 ± 0.102 | 2.450 ± 0.091 | 2.840 ± 0.151** | 3.317 ± 0.170**
Female
Necropsy body wt. | 47.3 ± 2.1 | 55.4 ± 1.7* | 50.5 ± 2.1 | 49.8 ± 1.7
Heart
Absolute | 0.17 ± 0.00 | 0.17 ± 0.00 | 0.17 ± 0.00 | 0.19 ± 0.01**
Relative | 3.552 ± 0.129 | 3.120 ± 0.062* | 3.423 ± 0.120 | 3.770 ± 0.119
Liver
Absolute | 1.73 ± 0.07 | 1.91 ± 0.06 | 1.83 ± 0.06 | 1.94 ± 0.06*
Relative | 36.653 ± 0.588 | 34.465 ± 0.634 | 36.531 ± 1.129 | 39.158 ± 1.118
Lung
Absolute | 0.23 ± 0.01 | 0.33 ± 0.01** | 0.42 ± 0.02** | 0.79 ± 0.03**
Relative | 4.799 ± 0.126 | 5.913 ± 0.169 | 8.331 ± 0.320** | 16.000 ± 0.857**
Thymus
Absolute | 0.080 ± 0.005 | 0.116 ± 0.009* | 0.112 ± 0.012* | 0.129 ± 0.010**
Relative | 1.681 ± 0.062 | 2.069 ± 0.126 | 2.216 ± 0.232* | 2.554 ± 0.127**

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

At the 12-month interim evaluation, almost all mice exposed to 10 or 30 mg/m^3^, and occasional mice exposed to 3 mg/m^3^, had lungs that were described as mottled or mottled pale. All terminal kill mice exposed to 30 mg/m^3^, many mice exposed to 10 mg/m^3^, and occasional mice exposed to 3 mg/m^3^ had similar gross findings in the lungs. These gross lesions corresponded with the chronic inflammation seen microscopically. Many exposed mice from both sexes had liver and/or lung nodules or masses at terminal kill. Metastatic masses or systemic neoplasia resulting in splenomegaly, lymphadenopathy, or masses in various organs were present in several chamber control and exposed mice at terminal kill.

#### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of malignant lymphoma and neoplasms and/or nonneoplastic lesions of the lung, skin, nose, larynx, trachea, hematopoietic system (bronchial, mediastinal, and mandibular lymph nodes; spleen; bone marrow; and thymus), heart, forestomach, adrenal medulla, liver, and eye. Summaries of the incidences of neoplasms and nonneoplastic lesions, statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group, and historical control incidences for the neoplasms mentioned in this section are presented in Appendix C for male mice and Appendix D for female mice.

Lung: At the 12-month interim evaluation, alveolar/bronchiolar adenoma occurred in two 10 mg/m^3^ males and in one 30 mg/m^3^ female, and alveolar/bronchiolar carcinoma occurred in one 10 mg/m^3^ male and two 30 mg/m^3^ males (Table 22, Table C-1, and Table D-1). No lung neoplasms occurred in chamber controls at the 12-month interim evaluation.

Table 22 Incidences of Neoplasms and Nonneoplastic Lesions of the Lung in Mice in the Two-year Inhalation Study of Antimony Trioxide

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Male
Twelve-month Interim Evaluation
Number Examined Microscopically | 10 | 10 | 10 | 10
Infiltration Cellular, Lymphocyte^a^ | 0 | 10** (1.0)^b^ | 10** (1.9) | 10** (2.5)
Foreign Body | 0 | 10** | 10** | 10**
Inflammation, Chronic Active | 0 | 10** (2.1) | 10** (3.2) | 10** (3.8)
Alveolus, Fibrosis | 0 | 4* (1.0) | 7** (1.9) | 10** (1.8)
Pleura, Fibrosis | 0 | 5** (1.0) | 10** (1.2) | 10** (1.8)
Pleura, Inflammation | 0 | 7** (1.0) | 10** (1.3) | 10** (1.8)
Alveolar Epithelium, Hyperplasia | 0 | 9** (1.0) | 10** (1.7) | 10** (1.9)
Bronchiole, Epithelium, Hyperplasia | 0 | 9** (1.0) | 9** (1.2) | 9** (1.7)
Alveolar/bronchiolar Adenoma | 0 | 0 | 2 | 0
Alveolar/bronchiolar Carcinoma | 0 | 0 | 1 | 2
Two-year Study
Number Examined Microscopically | 50 | 50 | 50 | 50
Infiltration Cellular, Lymphocyte | 13 (1.2) | 47** (1.4) | 48** (2.1) | 45** (2.9)
Foreign Body | 0 | 50** | 50** | 50**
Inflammation, Chronic Active | 0 | 48** (2.3) | 50** (3.1) | 50** (3.7)
Alveolus, Fibrosis | 0 | 12** (1.1) | 30** (1.6) | 37** (1.9)
Pleura, Fibrosis | 0 | 36** (1.1) | 46** (1.4) | 50** (2.4)
Pleura, Inflammation | 1 (1.0) | 40** (1.0) | 47** (1.3) | 48** (1.8)
Alveolar Epithelium, Hyperplasia | 6 (1.2) | 39** (1.1) | 45** (1.8) | 49** (1.9)
Bronchiole, Epithelium, Hyperplasia | 0 | 32** (1.2) | 44** (1.3) | 44** (1.6)
Alveolar/bronchiolar Adenoma, Multiple | 3 | 3 | 2 | 4
Alveolar/bronchiolar Adenoma (includes multiple)^c^
Overall rate^d^ | 10/50 (20%) | 14/50 (28%) | 9/50 (18%) | 14/50 (28%)
Adjusted rate^e^ | 21.5% | 32.9% | 21.8% | 34.6%
Terminal rate^f^ | 9/38 (24%) | 7/30 (23%) | 6/27 (22%) | 4/17 (24%)
First incidence (days) | 702 | 449 | 646 | 530
Poly-3 test^g^ | P = 0.190 | P = 0.165 | P = 0.592 | P = 0.129
Alveolar/bronchiolar Carcinoma, Multiple | 0 | 5* | 6** | 11**
Alveolar/bronchiolar Carcinoma (includes multiple)^h^
Overall rate | 4/50 (8%) | 18/50 (36%) | 20/50 (40%) | 27/50 (54%)
Adjusted rate | 8.5% | 40.9% | 46.2% | 62.8%
Terminal rate | 2/38 (5%) | 9/30 (30%) | 11/27 (41%) | 12/17 (71%)
First incidence (days) | 590 | 449 | 509 | 490
Poly-3 test | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001
Alveolar/bronchiolar Adenoma or Carcinoma^i^
Overall rate | 13/50 (26%) | 29/50 (58%) | 28/50 (56%) | 34/50 (68%)
Adjusted rate | 27.5% | 64.5% | 63.6% | 75.3%
Terminal rate | 10/38 (26%) | 16/30 (53%) | 16/27 (59%) | 12/17 (71%)
First incidence (days) | 590 | 449 | 509 | 490
Poly-3 test | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001
Female
Twelve-month Interim Evaluation
Number Examined Microscopically | 10 | 10 | 10 | 10
Infiltration Cellular, Lymphocyte | 3 (1.0) | 10** (1.7) | 10** (2.0) | 9** (3.1)
Foreign Body | 0 | 10** | 10** | 10**
Inflammation, Chronic Active | 0 | 10** (1.9) | 10** (2.8) | 10** (4.0)
Alveolus, Fibrosis | 0 | 2 (1.0) | 6** (1.3) | 10** (2.4)
Pleura, Fibrosis | 0 | 6** (1.0) | 9** (1.2) | 10** (1.1)
Pleura, Inflammation | 0 | 7** (1.1) | 10** (1.3) | 10** (1.8)
Alveolar Epithelium, Hyperplasia | 0 | 8** (1.1) | 10** (1.6) | 10** (2.1)
Bronchiole, Epithelium, Hyperplasia | 0 | 5** (1.0) | 10** (1.4) | 10** (1.5)
Alveolar/bronchiolar Adenoma | 0 | 0 | 0 | 1
Two-year Study
Number Examined Microscopically | 50 | 50 | 50 | 50
Infiltration Cellular, Lymphocyte | 7 (1.1) | 37** (1.5) | 37** (2.4) | 26** (3.2)
Foreign Body | 0 | 50** | 50** | 50**
Inflammation, Chronic Active | 1 (1.0) | 50** (2.2) | 50** (3.2) | 50** (3.5)
Alveolus, Fibrosis | 0 | 13** (1.2) | 30** (1.4) | 38** (2.2)
Pleura, Fibrosis | 1 (1.0) | 39** (1.1) | 50** (1.4) | 50** (2.2)
Pleura, Inflammation | 4 (1.3) | 27** (1.4) | 42** (1.6) | 38** (2.2)
Alveolar Epithelium, Hyperplasia | 1 (1.0) | 36** (1.2) | 49** (1.7) | 48** (2.0)
Bronchiole, Epithelium, Hyperplasia | 1 (1.0) | 34** (1.1) | 48** (1.3) | 45** (1.7)
Alveolar/bronchiolar Adenoma, Multiple | 0 | 3 | 3 | 1
Alveolar/bronchiolar Adenoma (includes multiple)^j^
Overall rate | 1/50 (2%) | 10/50 (20%) | 19/50 (38%) | 8/50 (16%)
Adjusted rate | 2.3% | 22.8% | 44.9% | 20.3%
Terminal rate | 1/36 (3%) | 7/31 (23%) | 12/26 (46%) | 1/15 (7%)
First incidence (days) | 731 (T) | 708 | 519 | 404
Poly-3 test | P = 0.137 | P = 0.003 | P < 0.001 | P = 0.009
Alveolar/bronchiolar Carcinoma, Multiple | 0 | 7** | 6* | 4*
Alveolar/bronchiolar Carcinoma (includes multiple)k
Overall rate | 2/50 (4%) | 14/50 (28%) | 11/50 (22%) | 11/50 (22%)
Adjusted rate | 4.4% | 31.2% | 26.8% | 28.8%
Terminal rate | 1/36 (3%) | 9/31 (29%) | 7/26 (27%) | 5/15 (33%)
First incidence (days) | 472 | 511 | 526 | 493
Poly-3 test | P = 0.065 | P < 0.001 | P = 0.003 | P = 0.002
Alveolar/bronchiolar Adenoma or Carcinoma^l^
Overall rate | 3/50 (6%) | 22/50 (44%) | 27/50 (54%) | 18/50 (36%)
Adjusted rate | 6.6% | 48.8% | 62.6% | 43.5%
Terminal rate | 2/36 (6%) | 15/31 (48%) | 17/26 (65%) | 5/15 (33%)
First incidence (days) | 472 | 511 | 519 | 404
Poly-3 test | P = 0.019 | P < 0.001 | P < 0.001 | P < 0.001

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact test (interim evaluation) or the Poly-3 test (2-year study).

** P ≤ 0.01.

(T) = terminal kill.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical incidence for 2-year inhalation studies with chamber control groups (mean ± standard deviation): 35/250 (14.0% ± 3.7%), range 10%–20%; all routes: 83/550 (15.1% ± 5.9%), range 8%–26%.

^d^ Number of animals with neoplasm per number of animals with lung examined microscopically.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal kill.

^g^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

^h^ Historical incidence for inhalation studies: 42/250 (16.8% ± 5.4%), range 8%–22%; all routes: 75/550 (13.6% ± 6.4%), range 4%–22%.

^i^ Historical incidence for inhalation studies: 69/250 (27.6% ± 2.6%), range 26%–32%; all routes: 147/550 (26.7% ± 6.5%), range 16%–38%.

^j^ Historical incidence for inhalation studies: 12/249 (4.8% ± 2.7%), range 2%–8%; all routes: 27/549 (4.9% ± 3.5%), range 0%–10%.

^k^ Historical incidence for inhalation studies: 17/249 (6.8% ± 3.7%), range 2%–10%; all routes: 24/549 (4.4% ± 3.5%), range 0%–10%.

^l^ Historical incidence for inhalation studies: 28/249 (11.3% ± 5.5%), range 6%–18%; all routes: 50/549 (9.1% ± 5.2%), range 2%–18%.

In the 2-year study, significantly increased incidences of alveolar/bronchiolar carcinoma occurred in all exposed groups of males compared to that in the chamber controls; these incidences occurred in an exposure concentration-dependent manner and exceeded the historical control ranges for inhalation studies and for all routes of administration (Table 22, Table C-1, Table C-2, and Table C-3). Incidences of multiple alveolar/bronchiolar carcinoma occurred in approximately one-third of exposed males with carcinoma, whereas no incidences of multiple carcinoma occurred in the chamber control males. Slightly increased incidences of alveolar/bronchiolar adenoma in 3 and 30 mg/m^3^ males exceeded the historical control ranges for inhalation studies and for all routes of administration. Combined incidences of alveolar/bronchiolar adenoma or carcinoma were significantly increased in all groups of exposed males compared to that in the chamber controls, and the incidences exceeded the historical control ranges for inhalation studies and for all routes of administration. In female mice, the incidences of alveolar/bronchiolar adenoma, alveolar/bronchiolar carcinoma, and alveolar/bronchiolar adenoma or carcinoma (combined) were significantly increased in all exposed groups compared to those in the chamber controls and exceeded the historical control ranges for inhalation studies and for all routes of administration (Table 22, Table D-1, Table D-2, and Table D-3). Incidences of multiple alveolar/bronchiolar adenoma occurred in a few females in each exposed group, and incidences of multiple alveolar/bronchiolar carcinoma occurred in almost half of females with carcinoma in each exposed group; neither multiple alveolar/bronchiolar adenoma nor carcinoma were observed in female chamber controls. Of the exposed mice with alveolar/bronchiolar carcinoma, 20% of the males and 19% of the females were found to have metastases, whereas metastases were not identified in any of the male or female chamber control mice. Bronchial and mediastinal lymph nodes were the most common sites of metastasis.

Microscopically, alveolar/bronchiolar adenomas and carcinomas in the exposed groups (Figure 15) were morphologically similar to those in the chamber control groups. Alveolar/bronchiolar adenomas were usually smaller than the carcinomas, well-differentiated cytologically, and often papillary or occasionally solid in pattern. Alveolar/bronchiolar carcinomas were expansile masses which typically exhibited several histologic patterns within the same tumor, and a greater degree of cytologic pleomorphism than seen in the adenomas.

Figure 15

Epithelial Neoplasia in the Mouse Lung (H&E)

A) and B) Alveolar/bronchiolar adenoma, forming a relatively circumscribed proliferation of well-differentiated alveolar epithelial cells, focally replaced the normal lung parenchyma in a female B6C3F1/N mouse exposed to 30 mg antimony trioxide/m^3^ by inhalation for 2 years. C) This alveolar/bronchiolar carcinoma presented as a solid, densely cellular mass in the lung of a female B6C3F1/N mouse exposed to 30 mg antimony trioxide/m^3^ by inhalation for 2 years. D) Higher magnification of the tumor in C revealed cellular pleomorphism and a mixed growth pattern.

A spectrum of nonneoplastic lesions occurred in the lung of mice that was similar at the 12-month interim evaluation and in the 2-year study (Table 22, Table C-7, and Table D-8). Incidences of peribronchial and perivascular lymphocytic cellular infiltrates, ranging from minimal to marked, occurred in all exposed groups of males and females, and often extended from the hilar to the peripheral portions of the lung. The incidences of this lesion were significantly increased compared to those in the chamber controls in all exposed groups of males and females at the 12-month interim evaluation and in the 2-year study. Generally, the extent and distribution of vessel and airway cuffing by the lymphoid cells were proportional to exposure concentration, as reflected in the severity grades. The lymphocytes in these infiltrates were mature in appearance, and were composed of a mixture of B and T lymphocytes, as demonstrated in immunohistochemical stained sections of representative animals (Figure 16). Although the aggregates of B cells and the aggregates of T cells were contiguous and slightly intermingled, they often appeared to remain within relatively separate domains, as shown by staining of serial sections for B and T cells with antibodies to PAX5 and CD3, respectively. In some of the exposed mice at the 12-month interim evaluation, the lymphocytes in the infiltrates exhibited mild variation in size and shape, but with retention of nonneoplastic features such as follicle formation, admixture of plasma cells, and variable numbers of macrophages sometimes containing the presumed test article; however, in three 30 mg/m^3^ females, the lymphocytic infiltrates exhibited more obvious cytologic atypicality, absence of follicle formation, and radial and longitudinal expansion of the perivascular and peribronchial lymphoid populations, indicative of malignant lymphoma. In the 2-year study, similarly and to a greater extent, some males and many females in the chamber control and exposed groups exhibited infiltration of malignant lymphoma in a predominantly perivascular and peribronchial distribution that often obscured or replaced the nonneoplastic lymphocytic infiltrates. In a few other exposed male and female mice, the nonneoplastic lymphocytic infiltrates were obscured or replaced by histiocytic sarcoma infiltrating in the same perivascular and peribronchial distribution.

Figure 16

Lymphoid Hyperplasia in the Mouse Lung

A) Marked peribronchial and perivascular infiltration of small, well-differentiated lymphocytes in a male B6C3F1/N mouse exposed to 30 mg antimony trioxide/m^3^ by inhalation for 2 years. (H&E) B) Immunohistochemical staining for B cells with anti-PAX5 revealed focal clusters of B cells within the infiltrates (arrows). C) Immunohistochemical staining for T cells with anti-CD3 demonstrated the presence of abundant T cells as well (arrowheads). Note that the B cells in B and the T cells in C occupy separate domains. D) Immunohistochemical staining for F4/80, a macrophage marker, showed a few scattered macrophages located primarily in the T cell regions.

Incidences of foreign body, presumed to be the test article, occurred in the cytoplasm of alveolar macrophages, as well as free in alveolar spaces, of all exposed groups of mice; incidences of this lesion were significantly increased compared to those in the chamber controls in all exposed groups of males and females at the 12-month interim evaluation and in the 2-year study (Table 22, Table C-7, and Table D-8). The foreign particles were round to oval, approximately one micron in diameter, dark brown at the periphery and light brown in the center, and refractile but not birefringent with polarizing lenses.

Mild to moderate chronic active inflammation that consisted of clusters of macrophages often containing the foreign body, lesser numbers of both viable and degenerate neutrophils, and cellular debris were noted primarily within the alveolar spaces of almost all exposed mice at the 12-month interim evaluation and in the 2-year study (Table 22, Table C-7, and Table D-8). The incidences of chronic active inflammation were significantly increased compared to those in the chamber control groups in exposed groups of males and females at the 12-month interim evaluation and in the 2-year study. The inflammation was variably associated with minimal to mild alveolus fibrosis in the majority of the 10 and 30 mg/m^3^ males and females at the 12-month interim evaluation and in the 2-year study, and a minimal degree of alveolus fibrosis occurred in some of the 3 mg/m^3^ males and females at the 12-month interim evaluation and in the 2-year study. The fibrosis was manifested by slight thickening of the alveolar walls by fine tendrils of collagen, imparting a more rigid appearance to the walls with hematoxylin and eosin (Figure 17), and accentuated by the Masson trichrome stain. Incidences of alveolus fibrosis were significantly increased at the 12-month interim evaluation in all exposed groups of males and in 10 and 30 mg/m^3^ females; incidences of this lesion were significantly increased in all exposed groups of males and females in the 2-year study. Minimal to mild chronic inflammation and fibrosis of the visceral pleura of the lungs occurred in most exposed mice at the 12-month interim evaluation and in the 2-year study. Foreign body particles were sometimes seen individually within the fibrotic pleural matrix but were more frequently seen in aggregates within the cytoplasm of alveolar macrophages lying just beneath the fibrotic pleura. In addition, focal clusters of macrophages containing aggregates of foreign particles were seen randomly scattered within the fibrotic pleura, particularly in areas of lymphocytic and plasmacellular inflammation. Incidences of pleural fibrosis and pleural inflammation were significantly increased in all exposed groups of males and females at the 12-month interim evaluation and in the 2-year study.

Figure 17

Epithelial Hyperplasia and Fibrosis in the Lung (H&E)

A) Prominent hyperplasia and hypertrophy of the alveolar epithelial cells (arrows) were noted in this section of lung from a female B6C3F1/N mouse exposed to 10 mg antimony trioxide/m^3^ by inhalation for 2 years. Increased alveolar macrophages were also seen. B) Hyperplasia and hypertrophy of terminal bronchiolar epithelial cells (arrows) were sometimes observed, as seen in a female B6C3F1/N mouse exposed to 10 mg antimony trioxide/m^3^ by inhalation for 2 years. Lymphocytic infiltrate was present in the adjacent lung (arrowhead). C) Interstitial fibrosis of alveolar walls, characterized by thickening of the walls by increased collagenous matrix (arrows), was present in this region of the lung from a female B6C3F1/N mouse exposed to 30 mg antimony trioxide/m^3^ by inhalation for 2 years. Increased alveolar macrophages containing foreign particles, and a few neutrophils, were also present in the alveolar spaces. D) Fibrosis of the visceral pleura (arrows) was focally marked in this female B6C3F1/N mouse exposed to 10 mg antimony trioxide/m^3^ by inhalation for 2 years. Perivascular and peribronchial lymphocytic infiltrates were also present (arrowheads).

In the areas of chronic active inflammation, alveolar epithelium hyperplasia often occurred, ranging from minimal to mild, and this lesion occurred in most exposed male and female mice at the 12-month interim evaluation and in the 2-year study (Table 22, Table C-7, and Table D-8). Minimal to mild bronchiole epithelium hyperplasia occurred in the terminal bronchioles of most exposed mice at the 12-month interim evaluation and in the 2-year study, and was characterized either by crowding and piling up of the epithelium, and/or enlarged epithelial cells with karyomegaly and prominent nucleoli (Figure 17). The incidences of alveolar epithelium hyperplasia and bronchiole epithelium hyperplasia were significantly increased in all exposed groups of males and females compared to the chamber controls at the 12-month interim evaluation and in the 2-year study.

Malignant Lymphoma: At the 12-month interim evaluation, malignant lymphoma occurred in three 30 mg/m^3^ females (Table 23 and Table D-1). In the 2-year study, incidences of malignant lymphoma were significantly increased in exposed groups of females compared to those in the chamber control group and the incidences increased in an exposure concentration-related manner (Table 23, Table D-1, and Table D-2). In 10 and 30 mg/m^3^ females, the incidences of malignant lymphoma exceeded the historical control ranges for inhalation studies and for all routes of administration; in 3 mg/m^3^ females, incidences of this neoplasm were at the upper end of the historical control ranges for inhalation studies and for all routes of administration (Table 23 and Table D-4). Although the incidences of malignant lymphoma were not significantly increased in exposed groups of males compared to that in the chamber controls in the 2-year study (chamber control, 4/50; 3 mg/m^3^, 4/50; 10 mg/m^3^, 3/50; 30 mg/m^3^, 6/50; Table C-1 and Table C-2), the incidence of malignant lymphoma in 30 mg/m^3^ males was at the upper end of the historical control ranges for inhalation studies and for all routes of administration (Table C-4).

Table 23 Incidences of Malignant Lymphoma in Female Mice in the Two-year Inhalation Study of Antimony Trioxide

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Twelve-month Interim Evaluation
Number Necropsied | 10 | 10 | 10 | 10
All Organs: Malignant Lymphoma^a^ | 0 | 0 | 0 | 3
Two-year Study
All Organs: Malignant Lymphoma^b^
Overall rate^c^ | 7/50 (14%) | 17/50 (34%) | 20/50 (40%) | 27/50 (54%)
Adjusted rate^d^ | 15.6% | 38.1% | 47.5% | 60.7%
Terminal rate^e^ | 5/36 (14%) | 15/31 (48%) | 12/26 (46%) | 5/15 (33%)
First incidence (days) | 677 | 558 | 512 | 404
Poly-3 test^f^ | P < 0.001 | P = 0.013 | P < 0.001 | P < 0.001

^a^ Number of animals with neoplasm.

^b^ Historical incidence for 2-year inhalation studies with chamber control groups (mean ± standard deviation): 63/250 (25.2% ± 8.4%), range 14%–36%; all routes: 109/550 (19.8% ± 7.9%), range 12%–36%.

^c^ Number of animals with neoplasm per number of animals necropsied.

^d^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^e^ Observed incidence at terminal kill.

^f^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

In most of the affected animals, lymphoma occurred in both the spleen and the lung, and in many animals the thymus, mediastinal lymph nodes, and/or bronchial lymph nodes were also involved. In the spleen, the lymphoma was usually manifested by marked expansion of the white pulp areas by a mixed population of small and large, irregularly shaped atypical lymphocytes, while in the lung the lymphomatous infiltrate was distributed in the same perivascular and peribronchial pattern that characterized the nonneoplastic lymphocytic infiltrates but with marked radial and longitudinal expansion, and sometimes with foci of pleural involvement (Figure 18). Most frequently, in the lung, thymus, and lymph nodes involved, the lymphomatous infiltrates were composed of a mixed small and large atypical lymphocyte population, similar to that noted in the spleen. In some mice, however, the lymphomatous cells were more uniform in size, appearing either moderate or large cytologically, and some of the large cell lymphomas exhibited prominent cytologic pleomorphism. Immunohistochemical stains for B and T cell markers (PAX5 and CD3, respectively) were performed in selected mice, and showed a predominance of B cells with a significant admixture of T cells in both the spleen and the lung.

Figure 18

Malignant Lymphoma in the Mouse Lung

A) Malignant lymphoma, distributed primarily in peribronchial and perivascular regions, was found throughout the lung of a female B6C3F1/N mouse exposed to 30 mg antimony trioxide/m^3^ by inhalation for 2 years. In comparison to lymphoid hyperplasia, such as that depicted in Figure 15, the lymphomatous infiltrates formed broader and more compact (densely cellular) cuffing of the bronchi and vessels and were distributed more widely throughout the lung. (H&E) B) Higher magnification of this infiltrate revealed a predominance of large lymphoid cells, along with lesser numbers of small lymphocytes. (H&E) C) Immunohistochemical staining for B cells with anti-PAX5 showed that most of the cells in the infiltrates were B cells. D) Immunohistochemical staining for T cells with anti-CD3 demonstrated a significant admixture of T cells in the infiltrates. Note that the B and T cells seem to be randomly admixed in this lymphomatous infiltrate, in contrast to the separate B and T cell domains seen with the lymphoid hyperplasia in Figure 15.

Skin: Slight exposure concentration-related increases in the incidences of fibrous histiocytoma occurred in exposed groups of males in the 2-year study; the incidence of this neoplasm was significantly increased in 30 mg/m^3^ males compared to that in the chamber control group and exceeded the historical control ranges for inhalation studies and for all routes of administration (Table 24, Table C-1, Table C-2, and Table C-5). In addition, two incidences of fibrosarcoma occurred in 10 mg/m^3^ males, which exceeded the historical control ranges for inhalation studies and for all routes of administration (Table 24, Table C-1, and Table C-5). The combined incidences of fibrous histiocytoma or fibrosarcoma were also significantly increased in 30 mg/m^3^ males compared to that in the chamber control group and exceeded the historical control ranges for inhalation studies and for all routes of administration (Table 24, Table C-1, Table C-2, and Table C-5). The fibrous histiocytomas were circumscribed dermal tumors composed of histiocyte-like cells and spindle cells, sometimes accompanied by multinucleated giant cells or hemosiderin containing macrophages, and occasionally exhibiting storiform patterns. Although showing some similarity to the fibrous histiocytomas, the fibrosarcomas differed in several respects, including the predominance of spindle cells, hypercellularity, pleomorphism, frequent mitotic figures, foci of necrosis, and often epidermal ulceration or invasion of fat or skeletal muscle. Two incidences of squamous cell carcinoma of the skin occurred in 30 mg/m^3^ females, which exceeded the historical control ranges for inhalation studies and for all routes of administration (Table 24, Table D-1, and Table D-5).

Table 24 Incidences of Neoplasms of the Skin in Mice in the Two-year Inhalation Study of Antimony Trioxide

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Male
Two-year Study
Number of Animals Necropsied | 50 | 50 | 50 | 50
Fibrous Histiocytoma^a^
Overall rate^b^ | 0/50 (0%) | 1/50 (2%) | 1/50 (2%) | 4/50 (8%)
Adjusted rate^c^ | 0.0% | 2.5% | 2.5% | 10.6%
Terminal rate^d^ | 0/38 (0%) | 1/30 (3%) | 1/27 (4%) | 2/17 (12%)
First incidence (days) | –^f^ | 729 (T) | 729 (T) | 612
Poly-3 test^e^ | P = 0.012 | P = 0.473 | P = 0.474 | P = 0.039
Fibrosarcoma^a^ | 0 | 0 | 2 | 0
Fibrous Histiocytoma or Fibrosarcoma (Combined)^g^
Overall rate | 0/50 (0%) | 1/50 (2%) | 3/50 (6%) | 4/50 (8%)
Adjusted rate | 0.0% | 2.5% | 7.3% | 10.6%
Terminal rate | 0/38 (0%) | 1/30 (3%) | 2/27 (7%) | 2/17 (12%)
First incidence (days) | – | 729 (T) | 468 | 612
Poly-3 test | P = 0.023 | P = 0.473 | P = 0.100 | P = 0.039
Female
Two-year Study
Number of Animals Necropsied | 50 | 50 | 50 | 50
Squamous Cell Carcinoma^h^ | 0 | 0 | 0 | 2

(T) = terminal kill.

^a^ Historical incidence for 2-year inhalation studies with chamber control groups (mean ± standard deviation): 1/250 (0.4% ± 0.9%), range 0%–2%; all routes: 2/550 (0.4% ± 0.8%), range 0%–2%.

^b^ Number of animals with neoplasm per number of animals necropsied.

^c^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^d^ Observed incidence at terminal kill.

^e^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

^f^ Not applicable; no neoplasms in animal group.

^g^ Historical incidence for inhalation studies: 2/250 (0.8% ± 1.1%), range 0%–2%; all routes: 5/550 (0.9% ± 1.0%), range 0%–2% (includes one incidence of sarcoma).

^h^ Historical incidence for inhalation studies: 0/250; all routes: 0/550.

Nose: Incidences of foreign body, presumably the test article, were significantly increased in all exposed groups of males and females at the 12-month interim evaluation and in the 2-year study compared to those in the chamber control groups (Table 25, Table C-7, and Table D-8). The foreign particles were most often seen in the nasal-associated lymphoid tissue of Level III, and less often in the subepithelial tissue of Levels I and II in association with small numbers of lymphocytes.

Table 25 Incidences of Nonneoplastic Lesions of the Upper Respiratory Tract in Mice in the Two-year Inhalation Study of Antimony Trioxide

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Male
Twelve-month Interim Evaluation
Nose^a^ | 10 | 10 | 10 | 10
Foreign Body^b^ | 0 | 8** | 10** | 9**
Larynx | 10 | 10 | 10 | 10
Foreign Body | 0 | 3 | 5** | 10**
Respiratory Epithelium, Hyperplasia | 0 | 1 (1.0)^c^ | 4* (1.0) | 6** (1.2)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 2 (1.0) | 3 (1.0)
Trachea | 10 | 10 | 10 | 10
Foreign Body | 0 | 0 | 2 | 4*
Two-year Study
Nose | 50 | 49 | 49 | 50
Foreign Body | 0 | 48** | 48** | 49**
Respiratory Epithelium, Inflammation, Chronic Active | 3 (2.3) | 9* (1.2) | 9* (1.1) | 6 (1.5)
Larynx | 50 | 50 | 50 | 50
Foreign Body | 0 | 15** | 29** | 44**
Respiratory Epithelium, Hyperplasia | 1 (1.0) | 3 (1.3) | 15** (1.1) | 30** (1.2)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 8** (1.0) | 18** (1.1)
Squamous Epithelium, Hyperplasia | 2 (1.0) | 0 | 4 (1.3) | 13** (1.2)
Trachea | 49 | 50 | 50 | 50
Foreign Body | 0 | 3 | 1 | 20**
Epithelium, Hyperplasia | 0 | 0 | 2 (1.5) | 5* (1.2)
Female
Twelve-month Interim Evaluation
Nose | 10 | 10 | 10 | 10
Foreign Body | 0 | 6** | 9** | 10**
Larynx | 10 | 9 | 10 | 10
Foreign Body | 0 | 2 | 7** | 7**
Respiratory Epithelium, Hyperplasia | 0 | 1 (1.0) | 4* (1.0) | 0
Respiratory Epithelium, Metaplasia, Squamous | 1 (2.0) | 0 | 1 (1.0) | 8** (1.5)
Trachea | 10 | 10 | 10 | 10
Foreign Body | 0 | 0 | 2 | 4*
Two-year Study
Nose | 50 | 49 | 50 | 50
Foreign Body | 1 | 44** | 45** | 48**
Respiratory Epithelium, Inflammation, Chronic Active | 2 (1.5) | 3 (1.3) | 4 (1.0) | 5 (1.0)
Respiratory Epithelium, Inflammation, Acute | 2 (1.5) | 7 (1.1) | 7 (1.0) | 5 (1.0)
Respiratory Epithelium, Metaplasia, Squamous | 0 | 3 (1.3) | 2 (1.0) | 4* (1.3)
Larynx | 50 | 50 | 50 | 50
Foreign Body | 0 | 25** | 39** | 48**
Respiratory Epithelium, Hyperplasia | 2 (1.0) | 0 | 14** (1.1) | 18** (1.1)
Respiratory Epithelium, Metaplasia, Squamous | 1 (1.0) | 0 | 5 (1.2) | 24** (1.1)
Squamous Epithelium, Hyperplasia | 4 (1.3) | 1 (1.0) | 1 (1.0) | 12* (1.1)
Trachea | 50 | 50 | 50 | 50
Foreign Body | 0 | 7** | 14** | 20**

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact text (interim evaluation) or the Poly-3 test (2-year study).

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

In the 2-year study, chronic active inflammation occurred in the respiratory epithelium of a few mice in every exposure group; the incidences of this lesion were significantly increased in 3 and 10 mg/m^3^ males compared to those in the chamber control group (Table 25, Table C-7, and Table D-8). Low incidences of acute inflammation of the respiratory epithelium occurred in all exposure groups of females in the 2-year study. A few incidences of minimal to mild squamous metaplasia of the respiratory epithelium occurred in all exposed groups of females in the 2-year study, and the incidence of this lesion was significantly increased in the 30 mg/m^3^ group.

Larynx: Incidences of foreign body, presumably the test article, occurred in many mice in all exposed groups at the 12-month interim evaluation and in the 2-year study (Table 25, Table C-7, and Table D-8). The incidences of foreign body were significantly increased in 10 and 30 mg/m^3^ males and females at the 12-month interim evaluation and in all exposed groups of males and females in the 2-year study compared to those in the chamber control groups. The foreign body was most often recognized in the subepithelial tissue of Level I.

Incidences of minimal respiratory epithelium hyperplasia and/or squamous metaplasia occurred in the base of the epiglottis overlying the submucosal glands in some of the 10 and 30 mg/m^3^ mice at the 12-month interim evaluation and in the 2-year study (Table 25, Table C-7, and Table D-8). The incidences of respiratory epithelium hyperplasia were significantly increased in 10 and 30 mg/m^3^ males and in 10 mg/m^3^ females at the 12-month interim evaluation and in 10 and 30 mg/m^3^ males and females in the 2-year study compared to those in the chamber control groups. The incidences of respiratory epithelium squamous metaplasia were significantly increased in 30 mg/m^3^ females at the 12-month interim evaluation and in 10 and 30 mg/m^3^ males and 30 mg/m^3^ females in the 2-year study (Figure 19). Both epithelial lesions presented repetitively in this location as minor degrees of increased cellularity, with the distinction between the two usually based upon flattening at the surface in squamous metaplasia. Incidences of minimal to mild hyperplasia of the squamous epithelium overlying the arytenoid cartilages in Level I were significantly increased in 30 mg/m^3^ males and females compared to those in the chamber controls (Table 25, Table C-7, and Table D-8).

Figure 19

Squamous Metaplasia of the Base of the Epiglottis (H&E)

A) Normal columnar, ciliated epithelium (arrowhead) lining the base of the epiglottis of the larynx (Level 1) in a chamber control female B6C3F1/N mouse in the 2-year study of antimony trioxide by inhalation. B) A multilayered, squamous metaplastic epithelium has replaced the columnar epithelium in this female B6C3F1/N mouse exposed to 30 mg/m^3^ antimony trioxide by inhalation for 2 years. Note the yellow-brown granular foreign body (presumed test article) within the stroma of the lamina propria (arrow) and within an adjacent subepithelial macrophage. Normal submucosal glands are noted in both A) and B).

Trachea: Incidences of foreign body occurred at the 12-month interim evaluation in a few 10 and 30 mg/m^3^ males and females and in the 2-year study in all exposed groups of males and females (Table 25, Table C-7, and Table D-8). The incidences of foreign body were significantly increased in 30 mg/m^3^ males and females at the 12-month interim evaluation and in 30 mg/m^3^ males and all exposed groups of females in the 2-year study compared to those in the chamber control groups.

Epithelium hyperplasia occurred in several 10 and 30 mg/m^3^ males in the 2-year study; the incidence of this lesion was significantly increased in the 30 mg/m^3^ group (Table 25 and Table C-7).

Hematopoietic System [Lymph Nodes (Bronchial, Mediastinal, and Mandibular), Spleen, Bone Marrow, and Thymus]: Incidences of lymphoid hyperplasia of the bronchial lymph nodes were significantly increased in all exposed groups of male and female mice compared to those in the chamber controls at the 12-month interim evaluation and in the 2-year study (Table 26, Table C-7, and Table D-8). Incidences of lymphoid hyperplasia of the mediastinal lymph nodes were significantly increased in 30 mg/m^3^ males at the 12-month interim evaluation and in 10 and 30 mg/m^3^ males and females in the 2-year study. In females, the incidences of lymphoid hyperplasia of the spleen were significantly increased in all exposed groups at the 12-month interim evaluation but the incidence of this lesion was decreased in all exposed groups of females in the 2-year study and was significantly decreased in 3 mg/m^3^ females (chamber control, 16/50; 3 mg/m^3^, 6/50; 10 mg/m^3^, 8/50; 30 mg/m^3^, 7/50) in the 2-year study (Table 26 and Table D-8). The decreased incidence of hyperplasia at 2 years correlates with the increased incidence of malignant lymphoma, suggesting either neoplastic transformation of the hyperplastic cells, or overgrowth and replacement by the malignant cells. Lymphoid hyperplasia in the lymph nodes was characterized primarily by expansion of the paracortical areas, with occasional formation of lymphoid follicles with germinal centers.

Table 26 Incidences of Nonneoplastic Lesions of the Hematopoietic System in Mice in the Two-year Inhalation Study of Antimony Trioxide

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Male
Twelve-month Interim Evaluation
Lymph Node, Bronchial^a^ | 8 | 10 | 10 | 10
Hyperplasia, Lymphoid^b^ | 0 | 7** (1.0)^c^ | 9** (1.8) | 10** (2.7)
Foreign Body | 0 | 10** | 10** | 10**
Lymph Node, Mediastinal | 4 | 8 | 10 | 10
Hyperplasia, Lymphoid | 0 | 1 (1.0) | 4 (1.5) | 9** (2.0)
Foreign Body | 0 | 1 | 8* | 10**
Two-year Study
Lymph Node, Bronchial | 30 | 43 | 47 | 41
Hyperplasia, Lymphoid | 2 (2.0) | 21** (1.5) | 26** (1.8) | 13** (1.8)
Foreign Body | 0 | 34** | 47** | 38**
Infiltration Cellular, Histiocyte | 0 | 2 (1.5) | 4 (1.0) | 6* (1.2)
Lymph Node, Mediastinal | 37 | 45 | 48 | 49
Hyperplasia, Lymphoid | 2 (1.5) | 8 (1.6) | 17** (1.6) | 34** (1.9)
Foreign Body | 0 | 32** | 42** | 48**
Infiltration Cellular, Histiocyte | 0 | 4 (1.0) | 13** (1.1) | 34** (1.7)
Lymph Node, Mandibular | 27 | 26 | 28 | 26
Foreign Body | 0 | 7** | 8** | 16**
Bone Marrow | 49 | 50 | 48 | 50
Hyperplasia | 10 (1.0) | 19* (1.0) | 27** (1.0) | 33** (1.1)
Thymus | 41 | 38 | 43 | 39
Depletion Cellular | 15 (2.5) | 14 (2.6) | 32** (2.9) | 32** (3.5)
Female
Twelve-month Interim Evaluation
Lymph Node, Bronchial | 5 | 10 | 9 | 10
Hyperplasia, Lymphoid | 0 | 6* (1.7) | 9** (1.9) | 10** (2.1)
Foreign Body | 0 | 10** | 9** | 10**
Infiltration Cellular, Histiocyte | 0 | 1 (1.0) | 6* (1.0) | 4 (1.0)
Lymph Node, Mediastinal | 4 | 7 | 8 | 10
Hyperplasia, Lymphoid | 0 | 1 (2.0) | 4 (1.5) | 4 (2.0)
Foreign Body | 0 | 2 | 2 | 9**
Spleen | 10 | 10 | 10 | 10
Hyperplasia, Lymphoid | 0 | 4* (1.8) | 6** (1.3) | 5** (1.4)
Two-year Study
Lymph Node, Bronchial | 41 | 47 | 48 | 49
Hyperplasia, Lymphoid | 2 (1.0) | 15** (1.5) | 17** (1.7) | 11** (1.7)
Foreign Body | 0 | 34** | 46** | 43**
Infiltration Cellular, Histiocyte | 0 | 2 (1.0) | 7** (1.0) | 7** (1.1)
Lymph Node, Mediastinal | 46 | 48 | 49 | 50
Hyperplasia, Lymphoid | 0 | 3 (2.7) | 16** (1.8) | 18** (1.9)
Foreign Body | 0 | 28** | 45** | 44**
Infiltration Cellular, Histiocyte | 0 | 6* (1.3) | 11** (1.5) | 16** (1.1)
Lymph Node, Mandibular | 41 | 28 | 38 | 39
Foreign Body | 0 | 5** | 9** | 3
Spleen | 50 | 50 | 50 | 50
Hematopoietic Cell Proliferation | 17 (2.0) | 19 (2.0) | 20 (1.8) | 35** (2.2)
Hyperplasia, Lymphoid | 16 (1.6) | 6 (1.3) | 8 (1.4) | 7 (1.6)
Bone Marrow | 50 | 50 | 50 | 50
Hyperplasia | 3 (1.0) | 5 (1.0) | 15** (1.0) | 28** (1.2)
Thymus | 47 | 49 | 49 | 49
Depletion Cellular | 9 (1.9) | 18* (2.9) | 23** (2.8) | 29** (2.3)

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact text (interim evaluation) or the Poly-3 test (2-year study).

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Incidences of foreign body, presumably the test article, occurred in the bronchial, mediastinal, and mandibular lymph nodes of exposed groups of males and females (Table 26, Table C-7, and Table D-8). The incidences of foreign body in the bronchial lymph node were significantly increased in all exposed groups of males and females compared to those in the chamber controls at the 12-month interim evaluation and in the 2-year study. The incidences of foreign body in the mediastinal lymph node were significantly increased in 10 and 30 mg/m^3^ males and 30 mg/m^3^ females at the 12-month interim evaluation and all exposed groups of males and females in the 2-year study. The incidences of foreign body in the mandibular lymph node were significantly increased in all exposed groups of males and in 3 and 10 mg/m^3^ females in the 2-year study. Infiltrates of histiocytes occurred within the bronchial and mediastinal lymph nodes of most exposed groups of males and females at the 12-month interim evaluation and in the 2-year study. In the bronchial lymph node, the incidences of histiocytic cellular infiltration were significantly increased in 10 mg/m^3^ females at the 12-month interim evaluation and in 30 mg/m^3^ males and 10 and 30 mg/m^3^ females in the 2-year study. In the mediastinal lymph nodes, the incidences of histiocytic cellular infiltration were significantly increased in 10 and 30 mg/m^3^ males and in all exposed groups of females in the 2-year study.

In the 2-year study, the incidence of hematopoietic cell proliferation in the spleen was significantly increased in 30 mg/m^3^ females compared to that in the chamber controls (Table 26 and Table D-8).

Incidences of bone marrow hyperplasia did not occur in mice at the 12-month interim evaluation, but in the 2-year study, the incidences of this lesion were significantly increased in all exposed groups of males and in 10 and 30 mg/m^3^ females (Table 26, Table C-7, and Table D-8). Bone marrow hyperplasia was predominantly of myeloid cell type and may have been secondary to inflammation in the lung.

In the 2-year study, the incidences of cellular depletion of the thymus were significantly increased in 10 and 30 mg/m^3^ males and in all exposed groups of females (Table 26, Table C-7, and Table D-8).

Heart: Incidences of minimal to mild chronic active inflammation of the epicardium occurred in a few mice in all exposed groups in the 2-year study, and may have been secondary to inflammation in the pleura (Table 27, Table C-7, and Table D-8). The incidences of chronic active inflammation of the epicardium were significantly increased in 10 and 30 mg/m^3^ males and females compared to those in the chamber control groups.

Table 27 Incidences of Selected Nonneoplastic Lesions in Mice in the Two-year Inhalation Study of Antimony Trioxide

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Male
Two-year Study
Heart^a^ | 50 | 50 | 50 | 50
Epicardium, Inflammation, Chronic Active^b^ | 0 | 2 (1.0)^c^ | 7** (1.4) | 16** (1.3)
Stomach, Forestomach | 50 | 50 | 49 | 50
Inflammation, Chronic Active | 2 (1.0) | 4 (1.0) | 4 (1.3) | 7* (1.3)
Female
Two-year Study
Heart | 50 | 50 | 50 | 50
Epicardium, Inflammation, Chronic Active | 0 | 2 (1.0) | 7** (1.4) | 7** (1.6)
Stomach, Forestomach | 50 | 50 | 50 | 50
Inflammation, Chronic Active | 0 | 1 (1.0) | 0 | 3 (1.0)

* Significantly different (P ≤ 0.05) from the chamber control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Forestomach: Exposure concentration-related increases in the incidences of chronic active inflammation occurred in exposed groups of males in the 2-year study; the incidence of this lesion in 30 mg/m^3^ males was significantly increased compared to that in the chamber control group (Table 27 and Table C-7). Incidences of chronic active inflammation occurred in a single 3 mg/m^3^ female and in three 30 mg/m^3^ females in the 2-year study (Table 27 and Table D-8).

Adrenal Medulla: At the 12-month interim evaluation, an incidence of malignant pheochromocytoma was observed in one 30 mg/m^3^ female (chamber control, 0/10; 3 mg/m^3^, 0/10; 10 mg/m^3^, 0/10; 30 mg/m^3^, 1/10; Table D-1). In the 2-year study, benign pheochromocytomas occurred in one 10 mg/m^3^ male, two 3 mg/m^3^ females, and three 30 mg/m^3^ females (males: 0/49, 0/50, 1/46, 0/49; females: 0/50, 2/50, 0/48, 3/49; Table C-1, Table D-1, and Table D-2); the incidence of this neoplasm in 30 mg/m^3^ females exceeded the historical control ranges for inhalation studies and for all routes of administration (Table D-6).

Liver: In the 2-year study, the incidence of hepatocellular adenoma was significantly increased in 10 mg/m^3^ males compared to that in the chamber control group (30/50; 31/50; 36/49; 33/50; Table C-1 and Table C-2), and it was at the upper end of the historical control range for inhalation studies (Table C-6). In addition, the incidence of hepatocellular carcinoma was significantly increased in 3 mg/m^3^ males in the 2-year study (15/50, 23/50, 14/49, 20/50; Table C-1 and Table C-2). The incidence of hepatocellular adenoma or carcinoma (combined) was significantly increased in 10 mg/m^3^ females in the 2-year study (14/50, 22/50, 22/50, 19/50; Table D-1 and Table D-2) but within the historical control ranges for inhalation studies and for all routes of study (Table D-7). Because there was no dose response and the increases were not outside of the historical control ranges, these increases were considered not related to treatment.

Eye: Slight increases in the incidences of cataract occurred in exposed groups of females in the 2-year study (1/49, 4/47, 2/49, 4/49; Table D-8).

## Genetic Toxicology

In male and female Wistar Han rats, the reticulocyte population (polychromatic erythrocytes or PCEs), which is the only red blood cell population that can be accurately assessed for micronucleus frequency in peripheral blood of rats due to efficient splenic scavenging of damaged erythrocytes, did not show an increase in micronucleated cells following 12 months of inhalation exposure to antimony trioxide (0, 3, 10, or 30 mg/m^3^) (Table E-1). In addition, no significant alterations in the percent reticulocytes in peripheral blood were observed in either male or female rats, suggesting no bone marrow toxicity or effect on erythropoiesis associated with exposure to antimony trioxide.

Micronucleus frequencies in mature erythrocytes (normochromatic erythrocytes or NCEs) of male and female B6C3F1/N mice exposed to antimony trioxide (0, 3, 10, or 30 mg/m^3^) for 12 months via inhalation were significantly increased, based on significant trend tests and significantly elevated frequencies of micronucleated erythrocytes at the highest exposure concentration (Table E-2). Using flow cytometry, approximately 1 million erythrocytes were scored per animal for the presence of micronuclei, making this a highly sensitive method of scoring and allowing small increases in the endpoint to be detected. In mice, the micronucleus response in the reticulocyte population, indicative of damage induced in the bone marrow within the last 48 hours prior to sampling, was slightly increased with increasing exposure concentration, but the increase was not statistically significant. However, the trend toward increased frequencies of micronucleated reticulocytes in the mice is supportive of the observations in the mature erythrocyte population. In addition, significant increases in the percent reticulocytes were seen in both male and female mice, suggesting a stimulation of erythropoiesis in mice exposed to antimony trioxide. It should be noted that stimulation of erythropoiesis may, in some instances, result in elevated levels of micronucleated red blood cells due to an increase in mitotic errors associated with rapid cell division, although in in vivo micronucleus studies conducted by the National Toxicology Program, no consistent association between increases in percent reticulocytes and increases in micronuclei has been observed.

In addition to evaluating the potential for chromosomal damage, manifested as micronuclei resulting from exposure to antimony trioxide, the potential for DNA damage was assessed using the comet assay in the same animals in which micronucleus induction was evaluated. DNA damage was assessed in blood leukocytes and lung tissue samples. No increases in DNA damage were seen in blood leukocytes or lung cell samples in male or female Wistar Han rats exposed to antimony trioxide (Table E-3). In male and female B6C3F1/N mice, significant increases in DNA damage, measured as percent tail DNA, were seen in lung tissue samples; no increases in percent tail DNA were observed in leukocytes (Table E-4).

In summary, exposure to antimony trioxide for 12 months by inhalation resulted in increases in micronucleated erythrocytes and lung cell DNA damage in male and female mice, but not in male or female rats.

## Tissue Burden

Tissue burden results are presented in Appendix G. In the 2-week studies, lung weights (g) and lung and blood antimony concentrations (μg Sb/g) were determined in male and female rats and mice following the end of exposures and in additional female rats and mice held for 4 weeks after exposure ended. Lung burdens of antimony (μg Sb/lung) and antimony trioxide (μg Sb_2_O_3_/lung) and exposure concentration-normalized lung burdens (μg Sb_2_O_3_/lung per mg Sb_2_O_3_/m^3^) and blood concentrations (μg Sb/g per mg Sb_2_O_3_/m^3^) were calculated. In the 2-year studies, similar data were collected in female rats and mice following 61, 124, 269 (mice), 271 (rats), 369, or 551 days of exposure. In the 2-week and 2-year studies, lung weights generally increased with exposure concentration and duration (Table G-1, Table G-3, Table G-6, and Table G-8). Because of the increased lung weights in exposed rats and mice, lung burdens rather than concentrations were used for calculation of toxicokinetic parameters.

### Two-week Tissue Burden Results in Rats and Mice

Total antimony trioxide lung burdens increased with increasing exposure concentration in male and female rats and mice (Table G-1 and Table G-6). In females held for 4 weeks postexposure, lung burdens decreased to approximately 77% to 85% (rats) or 66% to 73% (mice) of those found at terminal kill, with no relationship to exposure concentration in either species. Male and female rat lung antimony trioxide normalized lung burdens were generally similar among exposure groups, particularly at the lower concentrations (≤15 mg/m^3^) indicating proportionality with exposure concentration. Although normalized burdens appeared to be slightly less than proportional at 30 and 60 mg/m^3^, the observed differences were small and became less apparent in females following the 4-week recovery period.

Blood antimony concentrations increased with exposure concentration in male and female rats and mice (Table G-1 and Table G-6). At 4 weeks postexposure in females, blood antimony concentrations increased to approximately 190%, 181%, 169%, 165%, and 162% (rats) or decreased to approximately 41%, 49%, 49%, 55%, and 49% (mice) of the concentrations at terminal kill for the 3.75, 7.5, 15, 30, and 60 mg/m^3^ groups, respectively. In both rats and mice, normalized blood concentrations decreased with exposure concentration, particularly at higher exposure concentrations (≥15 mg/m^3^), indicating that increases in blood concentration were less than proportional with exposure concentration. This pattern persisted to the postexposure time point in females.

Kinetic parameters were determined in females using lung burden data generated at the end of exposure and 4 weeks postexposure. Because there were only two time points for kinetic estimates, variability was high and no statistical comparisons were made. Clearance half-lives ranged from 73 to 122 days in rats or 47 to 62 days in mice (Table G-2 and Table G-7). There was no clear exposure concentration-related trend in rats or mice, except that the shortest half-life was in the lowest exposure concentration group in mice. Deposition rates (µg Sb_2_O_3_/day) were approximately proportional to slightly less than proportional to exposure concentration, with a 16-fold increase in exposure concentration resulting in 15-fold (rats) or 13-fold (mice) increases in deposition rate. Steady-state lung burdens were proportional to exposure concentration in mice (16-fold increase in exposure concentration resulted in a 15-fold increase in steady-state lung burden) but less than proportional over the range of exposure concentrations in rats (16-fold increase in exposure concentration resulted in an 11-fold increase in steady-state lung burden). Based on estimated steady-state lung burdens, steady state was not reached during the postexposure period in rats or mice. Steady-state lung burdens are expected to be reached after about five clearance half-lives; the expected half-lives ranged from approximately 365 to 610 days in rats or approximately 235 to 310 days in mice without clear exposure concentration-related trends in either species.

In female rats, kinetic analysis (data not shown) of blood antimony concentration data (Table G-1) indicated negative clearance half-lives due to the continuing increase in antimony concentrations in the recovery rats. This was not unexpected because antimony trioxide lung burdens after 4 weeks of recovery were still approximately 77% to 85% of the lung burdens at terminal kill. Kinetic analysis of blood antimony concentration data from female mice indicated elimination half-lives from 22 to 32 days (Table G-7); the pattern of increases with exposure concentration was generally similar to that observed in the lung. Blood and lung mean antimony concentrations were compared at 30 mg/m^3^; these comparisons were made for data at the end of the 2-week studies in males and females and at 4 weeks postexposure in females. In these comparisons, blood concentrations were 0.8% of lung concentrations in male and female rats at the end of exposure, and 2% of lung concentrations in female rats at 4 weeks postexposure (Table G-1). In male mice, the blood concentration was 0.004% of the lung concentration at the end of the study; in female mice, blood concentrations were 0.005% of lung concentrations at both time points (Table G-6).

### Two-year Tissue Burden Results in Rats and Mice

Antimony trioxide lung burdens increased with exposure concentration and duration in rats and mice (Table G-3 and Table G-8). Lung burdens in 30 mg/m^3^ rats and all exposed groups of mice failed to achieve or approach steady state and instead increased steadily over time, achieving mean values as high as approximately 35 mg Sb_2_O_3_/lung in rats and 6 mg Sb_2_O_3_/lung in mice, following 551 days of exposure to 30 mg/m^3^. Normalized lung burdens were similar at each time point, indicating that lung burdens increased in a manner that was approximately proportional to exposure concentration and duration of exposure. However, a trend towards increased normalized lung burdens with exposure concentration was apparent at 551 days in rats. In mice, normalized burdens at 10 and 30 mg/m^3^ were generally greater than those at 3 mg/m^3^ and exposure durations greater than 124 days.

Figures presenting individual animal antimony trioxide lung burdens plotted versus days on study along with the fit of the lung burden model to the data are presented in Figure G-1, Figure G-2, Figure G-3, and Figure G-4. Rat deposition and clearance parameters calculated from antimony trioxide lung burden data for each exposure are presented in Table G-4. In mice, when all exposure durations were included, the model did not fit the data well for any exposure concentration as the day 551 lung burdens were considerably higher than the curves generated with the model fit; similarly poor model fits were obtained when the day 551 data were excluded. As a result, meaningful deposition and clearance parameters could not be calculated for any of the exposure concentrations in mice. In rats, the model-predicted deposition rates (D) of approximately 17, 44, and 119 µg Sb_2_O_3_/total lung per day were consistent with the measured lung burden data, indicating good proportionality with the exposure concentrations of 3, 10, and 30 mg/m^3^. Based on these deposition rates and a literature value for the minute volume of adult male Sprague Dawley rats (0.33 L/min; Whalan et al.^73^), the calculated percent deposition efficiencies were approximately 3.3%, 3.7%, and 4.7% for the 3, 10, and 30 mg/m^3^ groups, respectively. Model-estimated clearance half-lives (t_1/2_) increased with exposure concentration with durations of 136, 203, and 262 days at 3, 10, and 30 mg/m^3^, respectively.

In rats, the plots of lung burden over time superimposed with the model fits demonstrate that lung burdens in the 30 mg/m^3^ group did not achieve steady state but increased steadily over time, showing little curvature over the course of the study, while the lung burdens in the 3 and 10 mg/m^3^ exposure groups nearly reached steady state (Figure G-1). This pattern is also apparent when comparing the model-predicted steady-state lung burden data (Table G-4) to the day 551 measured lung burden data (Table G-3). Steady-state lung burdens (L_ss_) were approximately proportional to increases in exposure concentration. Although steady-state lung burdens were not reached during this study, it should be recognized that these calculated steady-state lung burdens are only theoretical values that would certainly never be achieved in reality. It would take approximately five half-lives to reach these L_ss_ values, about 680, 1,015, and 1,310 days at 3, 10, and 30 mg/m^3^, respectively, or longer than the normal life span of a Wistar Han rat for the two highest concentrations.

In rats and mice, blood antimony concentrations increased with exposure concentration (Table G-3 and Table G-8). While blood concentrations also increased with exposure duration in rats, they did not consistently increase over time in mice. These data indicate that in mice, blood antimony concentrations were at or near steady state throughout most of the study. Normalized concentrations decreased with exposure concentration at all time points, indicating that proportionately less antimony was present in the blood as exposure concentrations increased. In rats, this trend became more apparent over time, particularly between the 10 and 30 mg/m^3^ groups. The normalized data suggest that as exposure concentrations (and lung burdens) increased, the rate or capacity of antimony trioxide dissolution and transport to the blood became progressively less, or that the rate of clearance from the blood increased. No attempts were made to model the blood concentration data to discern blood antimony deposition and clearance rates. However, this result, at least in rats, is consistent with the fact that clearance rates of antimony trioxide from the lungs also became progressively slower. In the 2-year studies, blood-to-lung mean antimony concentration comparisons were made using the day 551 data for 30 mg/m^3^ females. In these comparisons, the rat blood concentration was 7% of the lung concentration and the mouse blood concentration was 0.002% of the lung concentration.

Based primarily on the relatively long clearance half-lives in the 10 and 30 mg/m^3^ rats in the 2-year study as compared to the 3 mg/m^3^ group in the present rat study and in the 2-week rat study and the unexpectedly high lung burdens in mice following 551 days of exposure, it was hypothesized that the reduced pulmonary clearance was associated with lung overload. Accordingly, calculations were performed to determine if lung overload occurred in either species, on the basis of particle volume or surface area^74-76^. The required assumptions and calculations are described in detail in Appendix G. Briefly, with volumetric overload, pulmonary clearance is thought to slow as the volume of particles in the lung reaches 6% of the alveolar macrophage (AM) volume (1X; 1.8 × 10^9^ µm^3^ in rats or 2.4 × 10^8^ µm^3^ in mice), with clearance ceasing when the particle volume reaches 60% of the AM volume (10X). Surface area-based overload is independent of the AM volume, and is thought to occur when the surface area of particles reaches 300 cm^2^ in rats scaled to 40 cm^2^ for mice (1X). These calculations demonstrated a graded onset of overload with similar results regardless of whether particle volume or surface area was used (Table G-5 and Table G-9). Overload was not reached at 3 mg/m^3^ in either species, with lung burdens generally at 0.3X to 0.4X. At 10 mg/m^3^, volumetric-based overload occurred in both species. In rats, overload was calculated to occur by day 418 of exposure, with a particle volume of 1.1X at 551 days; corresponding values in mice were day 369 and 1.8X at 551 days, respectively. In rats, the particle surface area required for overload was nearly reached (approximately 97% of the required surface area; data not shown). In mice, the surface-area results were similar to the volume-based overload results. At 30 mg/m^3^, volume-based overload was more apparent, occurring in rats by day 94 of exposure with a particle volume of 3.5X at 551 days; corresponding values in mice were day 124 and 4.7X at 551 days. Surface-area based overload results were similar to the volume-based results for rats and mice.

## Molecular Pathology

In rats chronically exposed to antimony trioxide, point mutations in Kras [4% (1/26)] and Egfr [50% (13/26)] were noted in the alveolar/bronchiolar tumors, and none were found in spontaneously arising alveolar/bronchiolar adenomas in chamber control rats. The single Kras mutation that occurred (A to G transition) was present in exon 1, codon 16, a non-hot spot location for Kras mutations. The Egfr mutations were localized within exons 18 to 21 and all of them were transition mutations. The results for the molecular analyses are presented in Appendix K.

In mice chronically exposed to antimony trioxide, point mutations in Kras [43% (34/80)], and Egfr [46% (37/80)] were noted in the alveolar/bronchiolar tumors. Kras mutations [33% (3/9)] were also noted in the spontaneous alveolar/bronchiolar carcinomas in the chamber controls. However, the majority of the Kras mutations in alveolar/bronchiolar tumors in exposed and chamber control mice were located in codon 12 and were G to A transitions. Egfr mutations were found only in alveolar/bronchiolar tumors in exposed mice, were located primarily within exons 18 and 20, and were transition mutations. The results for the molecular analyses are presented in Appendix K.