# Materials and Methods

## Procurement and Characterization of Antimony Trioxide

Antimony trioxide was obtained from 3N International, Inc. (Akron, OH), in one lot (3N-06159) that was used in the 2-week and 2-year studies. Identity and purity analyses were conducted by the analytical chemistry laboratories at H&M Analytical Services, Inc. [Allentown, NJ; X-ray diffraction (XRD)], and Chemir Analytical Services, Inc. [Maryland Heights, MO; redox titration and ultraviolet (UV) spectrophotometry], and by the study laboratory at Battelle Toxicology Northwest [Richland, WA; inductively coupled plasma/atomic emission spectroscopy (ICP/AES)] (Appendix H). Reports on analyses performed in support of the antimony trioxide studies are on file at the National Institute of Environmental Health Sciences.

Lot 3N-06159 of the chemical, a finely divided white powder, was identified as antimony trioxide by XRD. The purity of lot 3N-06159 was determined using ICP/AES. In addition, redox titration and UV spectrophotometry of bulk chemical samples determined the oxidation state of antimony in the test article.

The ICP/AES analysis indicated a purity of 101.9% based on a theoretical content of 83.5% antimony in antimony trioxide. Of the 18 minor elements measured by ICP/AES, only arsenic (~0.019%) and lead (~0.016%) were detected above 0.01% relative to antimony trioxide. Redox titration and UV spectroscopy confirmed that antimony was present in the +3 oxidation state, consistent with antimony trioxide. The overall purity of lot 3N-06159 was determined to be greater than 99.9%.

To ensure stability, the bulk chemical was stored at room temperature in amber glass containers with Teflon^®^-lined lids. Periodic reanalyses of the bulk chemical were performed by the study laboratory using ICP/AES and the analytical chemistry laboratory using XRD, and no degradation of the bulk chemical was detected.

## Aerosol Generation and Exposure System

For the 2-year studies, male and female rats were housed in separate chambers; female rat chambers also housed male and female mice from the concurrent study. For the 2-week and 2-year studies, the generation system used a linear feed device designed and built by Battelle to meter antimony trioxide into a Trost jet mill for aerosolization and particle size reduction. The linear feed device consisted of a slide bar, a body, a delivery tube, and a test article reservoir.

The compressed air driven slide bar slid back and forth during generation, and as the slide bar moved to the dispersing position, the metering port was aligned with a compressed air port in the body. A puff of air from the port dispersed the test article from the metering port. The output of the linear feeder was regulated by adjusting the shuttle bar cadence. Initial particle size reduction was accomplished within the Trost jet mill. From the jet mill, aerosol was directed to the main distribution line where it was diluted with humidified air then conveyed from the exposure control center to the exposure room where it passed through a cyclone separator to further reduce particle size. On exiting the cyclone, the aerosol-laden air was directed to either of two smaller branch lines. The distribution line pressure was continuously monitored and maintained slightly negative to the exposure room.

From the branch line, aerosol was delivered to each exposure chamber by a sampling tube. The aerosol then entered the chamber inlet duct where it was further diluted with conditioned chamber air to achieve the desired exposure concentration. During exposure periods, there was a small excess of aerosol in each branch line over that needed to maintain chamber concentrations. A high-efficiency particulate air (HEPA) filter was placed before the endline flow control assembly of each branch to remove aerosol from the airstream prior to exhausting from the room.

The study laboratory designed the inhalation exposure chambers so that uniform aerosol concentrations could be maintained throughout the chambers with the catch pans in place. The total volume of each chamber was 2.3 m^3^ with an active mixing volume of 1.7 m^3^. Tests showed that aerosol concentration could be reliably maintained homogenous within 8% throughout the chambers, provided the aerosol was uniformly mixed before passing through the chamber inlet and provided the test material did not react to a significant extent with animals, animal excrement, or the chamber interior^41^.

## Aerosol Concentration Monitoring

Summaries of the chamber aerosol concentrations are given in Table H-1 and Table H-2. The concentration of antimony trioxide in the exposure chambers and room air was monitored using three real-time aerosol monitors (RAMs) (MicroDust pro, Casella USA, Amherst, NH). The monitors were connected to the chambers by a sampling system designed by Battelle incorporating a valve that multiplexed each RAM to a 0 mg/m^3^ chamber or the room, a HEPA-filtered air blank, and two exposure chambers. The output (voltage) of the RAM was recorded by a program designed by Battelle (Battelle Exposure Data Acquisition and Control) to select the correct sample stream and acquire a raw voltage signal from each RAM. Equations for the calibration curves resided within the program and were used to convert the measured RAM voltages to exposure chamber concentrations. Concentration control limits within the program were compared to each measured concentration and, if limits were exceeded, an audible alarm was triggered or, in extreme cases, exposure was terminated.

Each RAM was calibrated by constructing a response curve using the measured RAM voltages and antimony concentrations that were determined from filter samples that were collected daily from the exposure chambers, extracted with concentrated hydrochloric acid, sonicated, and analyzed using ICP/AES. The ICP/AES instrument was calibrated against serially diluted NIST traceable 10 mg/mL spectrometric standards of antimony trioxide and the internal standard yttrium. Quality control standards and a reagent blank were analyzed after calibration, after approximately every tenth sample, and at the end of the analysis to determine accuracy and calibration drift during analysis.

## Chamber Atmosphere Characterization

Particle size distribution was determined once prior to the 2-week and 2-year studies (3.75 and 60 mg/m^3^ chambers), once during the 2-week studies, and monthly during the 2-year studies. Cascade impactor samples were taken from each exposure chamber using a Mercer-style seven-stage impactor and the stages (coverslips lightly coated with silicone for stages 1 to 7 or filters for stage 8) were analyzed for antimony using ICP/AES after antimony trioxide was extracted from the slides or filters with concentrated hydrochloric acid and sonication. The mass of antimony trioxide collected was calculated based on the theoretical percent of antimony in antimony trioxide (83.5%). The relative mass of test article collected on each stage was analyzed by the NEWCAS impactor analysis program developed at Battelle based on probit analysis^42^. The resulting estimates of the mass median aerodynamic particle diameter (MMAD) and the geometric standard deviation (GSD) of each set of samples are given in Table H-3, Table H-4, and Table H-5. Across exposure concentrations, MMAD ranged from 1.3 to 1.5 μm with GSD of 1.9 in the 2-week studies. MMAD ranged from 0.9 to 1.5 μm and GSD from 1.7 to 2.2 across exposure concentration and time in the 2-year studies. These data are consistent with NTP Specifications, which requires that particles have an MMAD of less than 3 μm with a GSD of less than 3. In addition, when feasible, NTP prefers to test particles with an MMAD of 1 to 2 μm and a GSD of less than 2 in order to maximize deposition in the lower respiratory tract^43^. This is particularly the case when mice are included in the studies.

Buildup and decay rates for chamber aerosol concentrations were determined with (all studies) and without (2-year studies) animals present in the chambers. At a chamber airflow rate of 15 air changes per hour, the theoretical value for the time to achieve 90% of the target concentration after the beginning of aerosol generation (T_90_) was approximately 9.4 minutes. A T_90_ value of 12 minutes was selected for all studies.

The uniformity of aerosol concentration in the inhalation exposure chambers without animals present was evaluated before each of the studies began; in addition, concentration uniformity with animals present in the chambers was measured once during the 2-week studies, and every 2 to 3 months during the 2-year studies. Concentrations were measured at all 12 sample ports; one in front and one in back for each of six possible cage unit positions per chamber. Chamber concentration uniformity was maintained throughout the studies.

The persistence of antimony trioxide in the exposure chambers after aerosol delivery ended was determined by monitoring the aerosol concentration in the 60 mg/m^3^ chambers in the 2-week studies with animals present and the 30 mg/m^3^ chambers in the 2-year studies, with and without animals present. In the 2-week studies, the concentration decreased to 1% of the starting concentration within 17 minutes. In the 2-year study of male rats, the concentration decreased to 1% of the starting concentration within 23 minutes with animals present and within 18 minutes without animals. In the 2-year studies of female rats and male and female mice, the concentration decreased to 1% of the starting concentration within 16 minutes with animals present and within 15 minutes without animals.

Stability studies of antimony trioxide in the generation and exposure system were performed before (2-year studies only) and during the studies. In these studies, XRD analyses performed by the analytical chemistry laboratory consistently indicated that the samples contained antimony trioxide in the diamond cubic crystalline phase senarmontite at greater than 99% of the test sample; ICP/AES analyses conducted by the study laboratory detected levels of 18 minor elemental contaminants at generally less than 0.1% each. Taken together, these results demonstrated that the exposure atmosphere and generator reservoir samples were in good agreement with the bulk test article, the composition of antimony trioxide was stable in the exposure system, and contamination from metal materials in the exposure system did not occur.

## Animal Source

For the 2-week and 2-year studies, male and female Wistar Han [Crl:WI(Han)] rats, referred to as Wistar Han rats in this report, were obtained from Charles River Laboratories, Inc. (Raleigh, NC), and male and female B6C3F1/N mice were obtained from the NTP colony maintained at Taconic Farms, Inc. (Germantown, NY). The rationale for change of rat strain from F344/N to F344/NTac was a programmatic decision. For many years NTP used the inbred F344/N rat for its toxicity and carcinogenicity studies. Over a period of time, the F344/N rat exhibited sporadic seizures and idiopathic chylothorax, and consistently high rates of mononuclear cell leukemia and testicular neoplasia. Because of these issues in the F344/N rat and NTP’s desire to find a more fecund rat model that could be used in both reproductive and carcinogenesis studies for comparative purposes, a change in the rat model was explored. Following a workshop in 2005, the F344 rat from the Taconic commercial colony (F344/NTac) was used for a few NTP studies to allow NTP time to evaluate different rat models between 2005 and 2006^44^. The Wistar Han rat, an outbred rat stock, was then selected because it was projected to have a long lifespan, resistance to disease, large litter size, and low neonatal mortality.

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by the Association for the Assessment and Accreditation of Laboratory Animal Care International. Studies were approved by the Battelle Toxicology Northwest Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Two-week Studies

The 2-week toxicity and tissue burden studies in rats and mice were designed following a review of the existing inhalation study data from the literature; a 4-week postexposure hold followed the 2-week exposure in tissue burden study females. These studies were performed to generate short-term toxicity data in rats and mice under the conditions of an NTP inhalation study to aid in the design of the 2-year studies, including the selection of exposure concentrations and time points for pulmonary retention and clearance studies. Generation of short-term data was of particular importance for mice, as no inhalation toxicology studies have been reported in that species. The highest exposure concentration in the current 2-week studies (60 mg/m^3^) was selected to be slightly higher than the highest exposure concentration (45 mg/m^3^) used in the Groth et al.^35^ study where no exposure-related decreases in survival or body weights greater than 10% were observed. Exposure concentrations were spaced by half to examine the exposure-concentration response relationship.

On receipt, the rats and mice were approximately 4 weeks old. Animals were quarantined for 12 or 13 days and were approximately 5 to 6 weeks old on the first day of the studies. Before the studies began, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix J). All test results were negative.

Groups of five male and five female core study rats and mice were exposed by whole body inhalation to antimony trioxide aerosol at concentrations of 0, 3.75, 7.5, 15, 30, or 60 mg/m^3^ for 6 hours plus T_90_ (12 minutes) per day, 5 days per week for 12 (rats) or 13 (mice) exposure days during a 16- (rats) or 17- (mice) day period. Additional groups of five female tissue burden study rats and mice were exposed to the same concentrations for 16 (rats) or 17 (mice) days then held for 28 days without exposure. Feed was available ad libitum except during exposure periods, and water was available ad libitum. Rats and mice were housed individually. Clinical findings were recorded twice daily and at terminal kill for core study rats and mice. The core study animals were weighed on days 1, 6, 13, and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 1.

Table 1 Experimental Design and Materials and Methods in the Inhalation Studies of Antimony Trioxide

Two-week Studies | Two-year Studies
Study Laboratory
Battelle Toxicology Northwest (Richland, WA) | Battelle Toxicology Northwest (Richland, WA)
Strain and Species
Wistar Han [Crl:WI(Han)] rats B6C3F1/N mice | Wistar Han [Crl:WI(Han)] rats B6C3F1/N mice
Animal Source
Rats: Charles River Laboratories, Inc. (Raleigh, NC) | Rats: Charles River Laboratories, Inc. (Raleigh, NC)
Mice: Taconic Farms, Inc. (Germantown, NY) | Mice: Taconic Farms, Inc. (Germantown, NY)
Time Held Before Studies
Rats: 13 days Mice: 12 days | 12 days
Average Age When Studies Began
Rats: 6 weeks Mice: 5 weeks | 6 weeks
Date of First Exposure
December 3, 2007 | Rats: September 22, 2008 Mice: October 6, 2008
Duration of Exposure
6 hours plus T_90_ (12 minutes) per day, 5 days per week, for 12 (rats) or 13 (mice) exposure days during a 16- (rats) or 17- (mice) day period | 6 hours plus T_90_ (12 minutes) per day, 5 days per week, for up to 105 weeks
Date of Last Exposure
Rats: December 18, 2007 Mice: December 19, 2007 | Rats: September 22, 2010 Mice: October 6, 2010
Necropsy Dates
Rats: December 18, 2007 (core study) Mice: December 19, 2007 (core study) | Rats: September 20-23, 2010 Mice: October 4-7, 2010
Average Age at Necropsy
8 weeks | 110 weeks
Size of Study Groups
Five males and five females (core study) Five females (tissue burden study) | 60 males and 60 females (core study; including 10 males and 10 females evaluated at 12 months) 25 females (tissue burden study)
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as 2-week studies
Animals per Cage
1 | 1
Method of Animal Identification
Tail tattoo | Tail tattoo
Diet
Irradiated NTP-2000 wafer diet (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, except during exposure periods, changed daily | Same as 2-week studies
Water
Tap water (Richland, WA, municipal supply) via automatic watering system (Edstrom Industries, Waterford, WI), available ad libitum | Same as 2-week studies
Cages
Stainless steel wire bottom (Lab Products, Inc., Seaford, DE), changed weekly with chambers, rotated daily in chambers | Same as 2-week studies, except changed and rotated weekly
Cageboard
Untreated paper excreta pan liner (Techboard Ultra, Shepherd Specialty Papers, Watertown, TN), changed daily | Same as 2-week studies
Chamber Air Supply Filters
Single HEPA (open stock), charcoal (RSE, Inc., New Baltimore, MI), Purafil (Environmental Systems, Lynnwood, WA), all new at study start | Same as 2-week studies, except HEPA filter changed annually
Chambers
Stainless steel, excreta pan at each of six levels (Lab Products, Inc., Seaford, DE); chamber changed weekly; excreta pans changed daily | Same as 2-week studies
Chamber Environment
Temperature: 75° ± 3°F Relative humidity: 55% ± 15% Room fluorescent light: 12 hours/day Chamber air changes: 15 ± 2/hour | Same as 2-week studies
Exposure Concentrations
0, 3.75, 7.5, 15, 30, or 60 mg/m^3^ | 0, 3, 10, or 30 mg/m^3^
Type and Frequency of Observation
Observed twice daily; core study animals were weighed on days 1, 6, 13, and at the end of the studies; clinical findings were recorded twice daily and at terminal kill. | Observed twice daily; core study animals were weighed initially, weekly for the first 13 weeks, every 4 weeks through week 93, every 2 weeks thereafter, and at terminal kill; clinical findings were recorded every 4 weeks through week 93, every 2 weeks thereafter, and at terminal kill.
Method of Kill
Carbon dioxide asphyxiation | Same as 2-week studies
Necropsy
Necropsies were performed on all core study rats and mice. Following blood collection, the heart, right kidney, liver, lung, right testis, and thymus were weighed. In addition, blood and the right lung plus the mainstem bronchi were weighed. For tissue burden study rats and mice, the lungs with mainstem bronchi were removed and weighed and the right and left lobes were collected and weighed together. Samples were stored in containers at approximately −70°C until analyzed for antimony concentration. | Necropsies were performed on all core study animals; organs weighed at the 12-month interim evaluations were heart, right kidney, liver, lung, right testis, and thymus.
Histopathology
Histopathology was performed on 0 and 60 mg/m^3^ core study rats and mice. In addition to gross lesions and tissue masses, the following tissues were examined to a no-effect level: larynx, lung, lymph nodes (mediastinal and tracheobronchial), nose, and trachea. | Complete histopathology was performed on all core study rats and mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder (mice), harderian gland, heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, larynx, liver, lung, lymph nodes (bronchial, mandibular, mesenteric, and mediastinal), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, trachea, urinary bladder, and uterus.
Tissue Burden Studies
Blood was collected from the retroorbital plexus (rats) or retroorbital sinus (mice) of core study rats and mice at terminal kill and from tissue burden study female rats and female mice after a 4-week recovery period. The right lung with mainstem bronchi was collected (the whole lung with mainstem bronchi was weighed) from core study animals, and the whole lung with mainstem bronchi was collected and weighed from the tissue burden study animals. The blood and both lung lobes trimmed from the trachea and mainstem bronchi were weighed and analyzed for antimony concentrations. | On days 61, 124, 271 (rats) or 269 (mice), 369, and 551 (equivalent to 2, 4, 9, 12, and 18 months), blood was collected from the retroorbital plexus (rats) or retroorbital sinus (mice) from up to five female tissue burden study rats and mice per group. Lungs with mainstem bronchi were collected and weighed. The blood and both lung lobes trimmed from the trachea and mainstem bronchi were weighed and analyzed for antimony concentrations.
Mutation Analysis of Alveolar/Bronchiolar Adenomas and Carcinomas
None | DNA was extracted from formalin-fixed, paraffin-embedded rat and mouse alveolar/bronchiolar adenomas and carcinomas. The samples were subjected to seminested polymerase chain reaction (PCR) to amplify hot spot regions of Kras and Egfr genes. The lyophilized PCR products were sequenced, and the resulting electropherograms were compared to identify mutations in alveolar/bronchiolar adenomas and carcinomas that either arose spontaneously or were due to exposure to antimony trioxide.

For tissue burden studies, blood was collected from the retroorbital plexus (rats) or retroorbital sinus (mice) of core study animals at terminal kill and tissue burden animals at the end of a 4-week recovery period. Animals were anesthetized by CO_2_. Blood was placed in tubes containing potassium EDTA as the anticoagulant. After exsanguination the whole lung was collected and weighed; the right lung of core study animals and both lungs of tissue burden animals were trimmed from the mainstem bronchi and weighed. Blood and lung samples were stored at −70°C until analyses. Blood and lung samples were weighed, lung samples were homogenized, and all samples were placed into Teflon Xpress microwave digestion vessels (CEM Corporation, Matthews, NC) in a nitric acid and hydrochloric acid solution with an antimony spiking solution, predigested for at least 15 minutes at 200°C, digested in a CEM Corporation MARS5 Sample Preparation System, diluted with deionized water, centrifuged until clear or filtered with syringe filters (Acrodisc 0.45 µm PTFE filter, Pall Life Sciences, Ann Arbor, MI), and diluted again with a nitric acid and hydrochloric acid solution. Analyses of the blood for antimony concentrations were performed using an Agilent 7500ce inductively coupled plasma-mass spectrometer (Agilent Technologies, Palo Alto, CA). Analyses of the lung samples for antimony concentrations were performed using a Thermo Elemental IRIS Intrepid II inductively coupled plasma-atomic emission spectrometer (Thermo Electron Corporation, Waltham, MA).

Necropsies were performed on all core study rats and mice. The heart, right kidney, liver, lung, right testis, and thymus were weighed. Histopathologic examinations were performed on 0 and 60 mg/m^3^ core study rats and mice. Table 1 lists the tissues and organs routinely examined.

## Two-year Studies

### Study Design

Groups of 60 male and 60 female core study rats and mice were exposed by whole body inhalation to antimony trioxide aerosol at concentrations of 0, 3, 10, or 30 mg/m^3^ for 6 hours plus T_90_ (12 minutes) per day, 5 days per week for up to 105 weeks. Ten male and 10 female rats and mice from each core study exposure group were randomly selected for micronuclei evaluation, comet assay, organ weights, necropsy, and histopathology at 12 months. Additional groups of 25 tissue burden study female rats and mice were exposed to the same concentrations of antimony trioxide for up to 79 weeks.

Rats and mice were approximately 4 weeks old on receipt. The animals were quarantined for 12 days before the beginning of the studies. Five male and five female rats and mice were randomly selected for parasite evaluation and gross observation of disease. Rats and mice were approximately 6 weeks old at the beginning of the studies. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix J). All test results were negative.

Rats and mice were housed individually. Feed and water were available ad libitum, except feed was withheld during exposure periods. Chambers and cages were rotated weekly. Further details of animal maintenance are given in Table 1. The feed was analyzed for contaminants and found acceptable. Information on feed composition and contaminants is provided in Appendix I.

### Clinical Examinations and Pathology

All animals were observed twice daily. Core study animal body weights were recorded on day 1, weekly for the first 13 weeks, every 4 weeks through week 93, every 2 weeks thereafter, and at terminal kill. Clinical findings were recorded every 4 weeks through week 93, then every 2 weeks, and at terminal kill.

Complete necropsies and microscopic examinations were performed on all core study rats and mice. At the 12-month interim evaluations, the heart, right kidney, liver, lung, right testis, and thymus of rats and mice were weighed. At necropsy, all organs and tissues were examined for grossly visible lesions, and all major tissues were fixed and preserved in 10% neutral buffered formalin (except eyes were first fixed in Davidson’s solution and testes were first fixed in modified Davidson’s solution; lungs were perfused using a blunted needle and Marriott bottle apparatus until flow stopped due to equalization of pressures, ~25 cm water pressure), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin for microscopic examination. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. Tissues examined microscopically are listed in Table 1.

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The report, slides, paraffin blocks, residual wet tissues, and pathology data were sent to the NTP Archives for inventory, slide/block match, wet tissue audit, and storage. The slides, individual animal data records, and pathology tables were evaluated by an independent quality assessment (QA) laboratory. The individual animal records and tables were compared for accuracy, the slide and tissue counts were verified, and the histotechnique was evaluated. For the 2-year studies, a QA pathologist evaluated slides from all tumors and all potential target organs, which included the bone marrow, larynx, lung, bronchial lymph node, mediastinal lymph node, nose, and trachea of rats and mice; arteries and spleen of rats; and heart, liver, mandibular lymph node, and thymus of mice.

The QA report and the reviewed slides were submitted to the NTP Pathology Working Group (PWG) coordinator, who reviewed the selected tissues and addressed any inconsistencies in the diagnoses made by the laboratory and QA pathologists. Representative histopathology slides containing examples of lesions related to chemical administration, examples of disagreements in diagnoses between the laboratory and QA pathologists, or lesions of general interest were presented by the coordinator to the PWG for review. The PWG consisted of the QA pathologist and other pathologists experienced in rodent toxicologic pathology. This group examined the tissues without any knowledge of dose groups. When the PWG consensus differed from the opinion of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist(s), and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman^45^ and Boorman et al.^46^. For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of McConnell et al.^47^.

### Tissue Burden Study

Up to five female tissue burden study rats and mice per group were randomly selected after exposure to antimony trioxide on days 61, 124, 271 for rats or 269 for mice, 369, and 551 (equivalent to 2, 4, 9, 12, and 18 months). At each time point, rats and mice were weighed and anesthetized by CO_2_. Blood was collected from the retroorbital plexus (rats) or retroorbital sinus (mice), placed in tubes containing potassium EDTA as the anticoagulant, and stored at approximately −70°C until analyzed for antimony concentration as described for the 2-week studies. After exsanguination, the lungs with mainstem bronchi were removed and weighed and then both lung lobes were trimmed from the trachea and mainstem bronchi, weighed, and stored at approximately −70°C until analyzed for antimony concentration as described for the 2-week studies.

### Mutation Analysis of Alveolar/Bronchiolar Adenomas and Carcinomas

After histopathology examination, formalin-fixed, paraffin-embedded (FFPE) tissue blocks from alveolar/bronchiolar adenomas and carcinomas that arose either spontaneously (in chamber controls) or due to antimony trioxide exposure were selected from rats and mice for mutation analysis of commonly altered genes in lung cancer (Kras and Egfr). DNA was extracted from the FFPE tissues and subjected to a seminested polymerase chain reaction (PCR) to amplify hot spot regions of Kras (exons 1 and 2) and Egfr (exons 18 to 21). The lyophilized PCR products were sequenced, and the resulting electropherograms were compared to identify mutations in alveolar/bronchiolar adenomas and carcinomas that arose spontaneously or were due to exposure to antimony trioxide. The results are presented in Appendix K.

## Statistical Methods

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier^48^ and is presented in the form of graphs. Animals found dead of other than natural causes were censored; animals dying from natural causes were not censored. Statistical analyses for possible dose-related effects on survival used Cox’s^49^ method for testing two groups for equality and Tarone’s^50^ life table test to identify dose-related trends. All reported P values for the survival analyses are two sided.

### Calculation of Incidence

The incidences of neoplasms or nonneoplastic lesions are presented in Table A-1, Table A-5, Table B-1, Table B-5, Table C-1, Table C-7, Table D-1, and Table D-8 as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. For calculation of statistical significance, the incidences of most neoplasms (Table A-2, Table B-2, Table C-2, and Table D-2) and all nonneoplastic lesions are given as the numbers of animals affected at each site examined microscopically. However, when macroscopic examination was required to detect neoplasms in certain tissues (e.g., mesentery, pleura, peripheral nerve, skeletal muscle, tongue, tooth, and Zymbal’s gland) before microscopic evaluation, the denominators consist of the number of animals that had a gross abnormality. When neoplasms had multiple potential sites of occurrence (e.g., leukemia or lymphoma), the denominators consist of the number of animals on which a necropsy was performed. Table A-2, Table B-2, Table C-2, and Table D-2 also give the survival-adjusted neoplasm rate for each group and each site-specific neoplasm. This survival-adjusted rate (based on the Poly-3 method described below) accounts for differential mortality by assigning a reduced risk of neoplasm, proportional to the third power of the fraction of time on study, only to site-specific, lesion-free animals that do not reach terminal kill.

### Analysis of Neoplasm and Nonneoplastic Lesion Incidences

The Poly-k test^51-53^ was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to take survival differences into account. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight. This value is one if the animal had a lesion at that site or if it survived until terminal kill; if the animal died prior to terminal kill and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the kth power.

This method yields a lesion prevalence rate that depends only upon the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time^51^. Unless otherwise specified, a value of k = 3 was used in the analysis of site-specific lesions. This value was recommended by Bailer and Portier^51^ following an evaluation of neoplasm onset time distributions for a variety of site-specific neoplasms in control F344/N rats and B6C3F1/N mice^54^. Bailer and Portier^51^ showed that the Poly-3 test gave valid results if the true value of k was anywhere in the range from 1 to 5. A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams^55^.

Tests of significance included pairwise comparisons of each dosed group with controls and a test for an overall dose-related trend. Continuity-corrected Poly-3 tests were used in the analysis of lesion incidence, and reported P values are one sided. The significance of lower incidences or decreasing trends in lesions is represented as 1 − P with the letter N added (e.g., P = 0.99 is presented as P = 0.01N). For neoplasms and nonneoplastic lesions detected at the interim evaluation, the Fisher exact test^56^, a procedure based on the overall proportion of affected animals, was used.

### Analysis of Continuous Variables

Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^57^ and Williams^58; 59^. Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^60^ were examined by NTP personnel, and implausible values were eliminated from the analysis.

### Historical Control Data

The concurrent control group represents the most valid comparison to the treated groups and is the only control group analyzed statistically in NTP bioassays. However, historical control data are often helpful in interpreting potential treatment-related effects, particularly for uncommon or rare neoplasm types. For meaningful comparisons, the conditions for studies in the historical control database must be generally similar. Significant factors affecting the background incidences of neoplasms at a variety of sites are diet, sex, strain/stock, and route of exposure. The NTP historical control database contains all 2-year studies for each species, sex, and strain/stock with histopathology findings in control animals completed within the most recent 5-year period^61-63^. In general, the historical control database for a given study includes studies using the same route of administration, and the overall incidences of neoplasms in controls for all routes of administration are included for comparison, including the current study.

## Quality Assurance Methods

The 2-week and 2-year studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations.^64^ In addition, the 2-year study reports were audited retrospectively by an independent QA contractor against study records submitted to the NTP Archives. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Technical Report.

## Genetic Toxicology

The genetic toxicity of antimony trioxide was assessed by testing the ability of the chemical to induce increases in the frequency of micronucleated erythrocytes in rat and mouse peripheral blood and DNA damage in blood and lung of rats and mice. Micronuclei (literally “small nuclei” or Howell-Jolly bodies) are biomarkers of induced structural or numerical chromosomal alterations and are formed when acentric fragments or whole chromosomes fail to incorporate into either of two daughter nuclei during cell division^65; 66^. The protocols for these studies and the results are given in Appendix E.

The genetic toxicity studies have evolved from an earlier effort by NTP to develop a comprehensive database permitting a critical anticipation of a chemical’s carcinogenicity in experimental animals based on numerous considerations, including the molecular structure of the chemical and its observed effects in short-term in vitro and in vivo genetic toxicity tests (structure-activity relationships). The short-term tests were originally developed to clarify proposed mechanisms of chemical-induced DNA damage based on the relationship between electrophilicity and mutagenicity^67^ and the somatic mutation theory of cance^68; 69^. However, it should be noted that not all cancers arise through genotoxic mechanisms.

DNA reactivity carries the potential for carcinogenicity. In these studies with antimony, due to the insoluble nature of the compound and the exposure route employed in the 2-year studies, no bacterial mutagenicity studies were conducted. Instead, genotoxicity, in the form of chromosomal damage (micronuclei) and DNA damage (measured using the comet assay) was evaluated in an independent cohort of mice and rats after 12 months of inhalation exposure.

The predictivity for rodent carcinogenicity of clearly positive results in long-term peripheral blood micronucleus tests is high; a weak response in one sex only or negative results in both sexes of one species in this assay do not correlate well with either negative or positive results in rodent carcinogenicity studies^70^. NTP has not yet conducted an evaluation of the relationship between DNA damage assessed in the comet assay with rodent carcinogenicity, although others have demonstrated a correlation^71^. However, because of the theoretical and observed associations between induced genetic damage and adverse effects in somatic and germ cells, the determination of in vivo genetic effects is important to the overall understanding of the risks associated with exposure to a particular chemical.