# Introduction

Figure 1

Antimony Trioxide (CASRN 1309-64-4; Chemical Formula: Sb_2_O_3;_ Molecular Weight: 291.5)

Synonyms: A1530; A1582; a1588 lp; antimonious oxide; antimony oxide; antimony (III) oxide; antimony peroxide; antimony sesquioxide; antimony white; AP 50; biantimony trioxide; C.I. pigment white 11; dechlorane a-o; diantimony trioxide; exitelite; flowers of antimony; nyacol a 1530; senarmontite; valentinite; weisspiessglanz.

Trade names: FireShield^®^, Microfine^®^, Montana Brand, Thermoguard^®^, Timonox, TMS^®^, Trutint^®^, Ultrafine^®^, White Star.

## Chemical and Physical Properties

Antimony trioxide (Sb_2_O_3_) is the primary form of antimony in the atmosphere and also occurs naturally as the ores of valentinite, senarmontite, exitelite, and weisspiessglanz. At 1,500°C, antimony trioxide exists in vapor phase as dimeric Sb_4_O_6_^1^. Commercially, antimony trioxide is available as an odorless, white crystalline powder. Antimony trioxide has minimal solubility (0.017 mg/L) in water and is amphoteric with solubility in alkaline hydroxide solutions as well as in hydrochloric, tartaric, and acetic acids^1; 2^. While typically white in color, suspensions of antimony trioxide develop a darker color following absorption of ultraviolet radiation below 325 nm, possibly due to peroxide radical formation on the crystal surface^3^. The white color of the suspension slowly returns when light is removed.

Aerosolized antimony trioxide particles do not readily change chemical composition, particle size, or morphology after emission, although a coating of sulfate may form on the particle surface^3^. Methylation of antimony trioxide may occur in water-logged soil. Three organoantimony biotransformation products have been identified in natural sediment containing antimony trioxide (10 or 100 ppm) following incubation for 60 days under aerobic and anaerobic conditions. Two of the organoantimony products, methylstibonic acid and dimethylstibonic acid were identified, and less than 0.1% of the antimony in the incubates was transformed.

Antimony is a group 15 metalloid that occurs in the earth’s crust at 0.2 to 1 mg/kg and in seawater at approximately 2 × 10^−4^ mg/kg^4^. Four allotropes of antimony have been identified with metallic antimony being the only stable allotrope. Metallic antimony is a brittle, silver-white shiny metal^4^. Although native antimony occurs naturally, antimony predominantly exists as a mineral with over 100 mineral species identified^5^. Stibnite (Sb_2_S_3_) is the primary ore for industrial purposes^5^. Antimony has three oxidation states, +3, −3, and +5^3^. When metallic antimony (0) is burned in air, it oxidizes to antimony (+3) trioxide^3^. Aerosolized antimony reacts with atmospheric oxidants and rapidly oxidizes to antimony trioxide. Antimony oxidation generally occurs in aerobic surface soils as well.

## Production, Use, and Human Exposure

Antimony trioxide is the most commercially significant form of antimony. Antimony trioxide is predominantly produced by two methods: 1) oxidation of stibnite ore via furnace roasting or 2) furnace oxidation of metallic antimony. Antimony trioxide can also be produced from the reaction of antimony trichloride (SbCl_3_) with water or by alkaline hydrolysis of stibene (SbH_3_). Commercially available antimony trioxide typically has a purity between 99.2% and 99.5%^5^. Trace impurities include arsenic, copper, iron, lead, and nickel with up to 0.3% of both lead and arsenic^6; 7^.

Antimony trioxide is used as a flame retardant in canvas, textiles, paper, and plastics and in combination with some chlorinated or brominated flame retardants on commercial furniture, draperies, wall coverings, and carpets (typically 2% to 10% by weight)^1; 8^. It is commonly used with tetrabromobisphenol-A to enhance flame retardancy in printed circuit boards^7^. Antimony trioxide is also used as a catalyst in the production of polyethylene terephthalate (PET) plastic^5^. Antimony trioxide is added to phosphorescent light sources (fluorescent tubes and television/computer screens) to reinforce the photogenic capacity of phosphorus^8^.

Antimony metal is used in the electronics industry in the production of silicon wafers and diodes^5^. Lead-antimony alloys have a variety of uses including use in batteries, ammunition, corrosion resistant pumps and pipes, tank linings, roofing sheets, solder, cable sheaths, and antifriction bearings^5^. Medicinally, antimony compounds have been historically used as emetics and to treat protozoan and parasitic infections. Potassium antimonyl tartrate is a powerful emetic that was once used to treat schistosomiasis. Currently, pentavalent antimonials are used to treat leishmaniasis^9^. The estimated worldwide distribution of antimony uses is: flame retardants, 72%; transportation, including batteries, 10%; chemicals, 10%; ceramics and fiberglass, 4%; and other, 4%^5^.

Most atmospheric releases of antimony substances result from high-temperature industrial processes, the combustion of petroleum, petroleum products, and coal and the incineration of products that contain antimony. Antimony is oxidized at the high temperatures used in these processes resulting in the formation of antimony trioxide and possibly antimony tetraoxide and antimony pentoxide^6^. Antimony compounds can also leach from mining and smelting waste products discarded in large tailing piles. Acid conditions, often created in the tailing piles by the oxidation of pyrites, increase the potential for leaching^3^. High levels of antimony trioxide (>300 ppm) have been detected in ambient air downwind from a copper smelting plant^6^. The mean concentration of antimony in rainwater downwind from a copper smelting plant was 1.3 ppb compared with 0.03 ppb in rainwater collected upwind from the plant^3^.

Occupationally, the major sources of exposure to antimony exist in the metal ore smelting and mining industries. Additional worker exposure potential exists in industries where antimony trioxide is used in the production of ceramics, glass, and alloys. Inhalation and dermal contact with dusts are the most common routes of exposure^6^. For workers exposed to antimony, a mean body burden of 7.9 mg antimony has been estimated^3^. Antimony concentrations up to 600 mg/L were measured in urine samples collected from workers at a smelter plant. Firemen and emergency workers may also be exposed to antimony that is released from the combustion of materials containing antimony trioxide associated with flame retardants. Up to 543 ppm antimony has been identified in soot and tracheal specimens collected from cadavers of fire victims^3^.

The average daily intake of antimony from food and water has been estimated to be 100 μg/day^3^. Another evaluation reported that the antimony concentration for a mixed diet is 9.3 ppb, which corresponds to 4.6 μg antimony per day based on consumption of approximately 3,000 g diet/day^10^. Separate reports indicate that antimony concentrations in a variety of foods including meats, seafood, and vegetables range from 0.22 to 2.81 ppb, while another evaluation study reported that median levels of antimony in eight food groups were less than 10 ppb (wet weight)^3^. In pooled human milk, antimony concentration has been reported to be 13 ppm^3^. For drinking water, the USEPA maximum contaminant level is 6 μg/L^6^. A mean body burden of 0.7 mg antimony has been reported based on autopsy data from unexposed Japanese adults. In urine samples collected from the National Health and Nutrition Examination Survey, the geometric mean antimony concentration was 0.133 μg/L with 0.380 μg/L for the 95th percentile^11^.

## Regulatory Status

An occupational exposure limit of 0.5 mg/m^3^ has been established for antimony [8-hour time-weighted average (TWA) threshold limit value^12^; NIOSH 10-hour TWA recommended exposure limit and OSHA 8-hour TWA permissible exposure limit^13^]. The current United States Environmental Protection Agency^14^ inhalation reference concentration for antimony trioxide is 0.2 μg/m^3^.

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

In laboratory animals, the lung deposition, retention, and clearance of aerosols containing antimony following inhalation exposure depend on particle size and solubility^15^. In general, aerosols of antimony oxides with small particle sizes and low water solubility are retained in the lungs longer than larger particles with high water solubility (antimony tartrates). In a chronic inhalation study, Fischer 344 rats were exposed to antimony trioxide for 12 months at 0.06, 0.51, or 4.50 mg/m^3^ followed by a 12-month observation period^16^. At the end of the 12-month exposure period, antimony lung burdens in female rats were approximately 11.3, 129.5, and 2,010 µg in the 0.06, 0.51, and 4.50 mg/m^3^ exposure groups, respectively, and declined to approximately 2%, 15%, or 44% of the original lung burden. The resulting half-lives were 2.3, 3.6, and 9.5 months, respectively, for the 0.06, 0.51, and 4.50 mg/m^3^ groups, suggesting that the clearance is dependent on the lung burden.

Experiments in laboratory animals have shown that aerosols of trivalent antimony (tartrate) are distributed primarily to the lung, bone, liver, pelt, and thyroid gland following inhalation exposure and are excreted both in the feces and in the urine^17; 18^. In a comparison of the distribution of trivalent versus pentavalent antimony inhaled as the tartrate in hamsters, trivalent antimony accumulated in liver greater than pentavalent antimony. The opposite pattern was observed in the skeleton. Trivalent antimony in blood concentrated almost exclusively in the erythrocytes, whereas pentavalent antimony in blood was found to a greater extent in the plasma during the first 2 hours postexposure, after which, pentavalent antimony also concentrated in the erythrocytes^19^. Following intratracheal instillation of antimony trioxide (1.52 mg/kg) in hamsters, the clearance of antimony from the lung was biphasic with half-lives of 40 hours and 20 to 40 days for the first and second phases, respectively^15^.

### Humans

Antimony trioxide is absorbed after inhalation exposure as indicated by elevated blood and urine levels of antimony measured in occupationally exposed workers^6^. Urine concentrations of antimony remained elevated in smelter plant workers after exposure had ceased^20-23^. Samples collected from retired (for approximately 20 years) and deceased smelter plant workers suggest that antimony has a long biological half-life in the lung. Antimony measured in the lungs of deceased smelter workers (n = 40) was 12 times greater (312 mg/kg) than control samples, and antimony concentration in the lungs did not decrease with length of exposure cessation^24^. A separate series of studies evaluated trace elements in human lung tissue collected from deceased individuals not occupationally exposed to antimony^25-27^. In these studies, antimony accumulation in lung tissue correlated with age, presumably due to inhalation of environmental contaminants. Antimony trioxide is poorly absorbed from the gastrointestinal tract in humans^6^.

Antimony compounds are eliminated mainly in the urine, with small amounts appearing in feces via bile after conjugation with glutathione. A significant amount of antimony excreted in bile undergoes enterohepatic circulation. A renal elimination half-life of 4 days following inhalation of antimony trioxide was estimated in 21 employees of a starter battery manufacturing plant^6^.

## Toxicity

### Experimental Animals

In one study, Fischer 344 rats were exposed via whole body inhalation to target concentrations of up to 25 mg antimony trioxide/m^3^ (measured concentrations of up to 23.46 mg/m^3^) for 13 weeks (6 hours per day, 5 days per week) with some animals held for 27 weeks postexposure^16^. In this study, particle sizes were considerably higher in the exposure atmospheres [mass median aerodynamic particle diameter (MMAD) 5.7 µm] than in the test material prior to exposure (MMAD 3.4 µm). Body weights in animals exposed to 23.46 mg/m^3^ during the exposure and most of the recovery periods were lower than controls; however, the differences were less than 10%. Nonneoplastic lesions that were found at higher incidences in exposed animals included the presence of particulate material in alveolar/intra-alveolar macrophages and perivascular and/or peribronchial lymph node aggregates at the end of exposure and in the recovery period. In addition, incidences of chronic inflammation of the interstitium, granulomatous inflammation, interstitial fibrosis, and alveolar/bronchiolar hyperplasia were higher in exposed animals following the recovery period; increases in these lesions were primarily limited to the two highest exposure concentrations. In an extended study by these investigators, Fischer 344 rats were exposed via whole body inhalation to antimony trioxide target concentrations up to 5.0 mg/m^3^ (measured concentrations of up to 4.5 mg/m^3^) for 1 year (6 hours per day, 5 days per week) with some animals held for 1 year postexposure^16^. Depending on the method used, the particle size was 3.76 ± 0.84 µm with a geometric standard deviation (GSD) of 1.79 ± 0.32 (TSI Aerodynamic Particle Sizer) or 4.55 µm with a GSD of 1.80 (Cascade Impactor). Following the 1-year exposure, exposure-related lesions were limited primarily to increases in particle-laden alveolar/intraalveolar macrophages, and the presence of foreign particulate material in perivascular/peribronchiolar aggregates of lymphoid cells and in peribronchial lymph node macrophages. After the 1-year postexposure period, relatively modest exposure-related increases in chronic inflammation of the interstitium were also observed. Mild, compound-related ocular irritation was noted at 6 months, but no indications of compound-related ocular disease were noted at 12 or 18 months.

Hext et al.^28^ reported a subchronic study in which male and female Wistar rats of the Alpk:APSD strain were fed diets containing 0, 1,000, 5,000, or 20,000 ppm antimony trioxide. No in-life toxicity was observed. Some small (≤10%) changes in hematology and clinical chemistry parameters and liver weights and slight increases in histopathologic findings, including pituitary cysts and plasma cell infiltration in the cervical lymph node, were observed; however, the relationship of these changes to toxicity was uncertain.

### Humans

Antimony trioxide dust and fumes cause irritation to the respiratory tract and mucous membranes^6^. Chronic occupational exposure to antimony trioxide is associated with antimony pneumoconiosis characterized on chest X rays by the presence of diffuse, densely distributed punctate opacities that are round, polygonal, or irregular in shape^21; 29; 30^. In a study by McCallum^23^, pneumoconiosis was identified in asymptomatic antimony smelter workers and the degree of radiographic abnormalities was correlated with the amount of antimony retained in the lungs and duration of exposure. In a study by McCallum et al.^31^, radiographic abnormalities were observed after just a few years of exposure. In this study, antimony (as antimony trioxide) aerosol concentrations averaged 5 mg/m^3^ with concentrations up to 37 mg/m^3^ measured during tapping operations. In the Cooper et al.^21^ study, antimony pneumoconiosis was diagnosed in three of the 13 smelter workers exposed to antimony ore and antimony trioxide (0.08 to 138 mg antimony/m^3^) for 1 to 15 years. Pulmonary function examinations were also conducted in this study, and no consistent pattern of abnormalities was observed. The Potkonjak and Pavlovich^30^ study evaluated smelter workers (n = 51) who had been employed for 9 to 31 years. The evaluation included physical examination, laboratory analysis, chest X ray, and pulmonary function studies. In this study, the airborne dust concentrations measured 17 to 86 mg/m^3^ and were composed of 39% to 89% antimony trioxide, 2% to 8% antimony pentoxide and less than 5% free silica. Other agents present in the dust included less than 4% ferric trioxide and less than 7% arsenic oxide. Pulmonary function testing identified no specific pattern of abnormalities. Chronic coughing was identified in 61% of the workers and antimony pneumoconiosis was identified by chest X ray in 67% of the smelter workers. The chest X ray lesions in smelter workers (dense, irregular opacities with diameters < 1 mm in mid and lower lung) differ from the chest X ray lesions of silicosis observed in antimony miners (round opacities with diameters >3 mm in upper and mid lung) where airborne dust samples containing nearly 80% free silica have been identified^30^.

Antimony toxicity following oral exposure in humans has been reported following medicinal use of potassium antimonyl tartrate^32^. Accidental ingestion of antimony has been reported due to leaching from ceramic containers into acidic beverages. In one incident, more than 50 people were hospitalized after consuming a beverage contaminated with antimony (13 mg/L). Symptoms included a burning sensation in the stomach, colic, nausea, vomiting, and collapse^6^.

Chronic occupational exposure to antimony trioxide on exposed skin causes dermatitis with papular and pustular lesions developing on the arms and legs^6^. The skin lesions primarily occur during the summer and develop around sweat and sebaceous glands with areas of eczema. The lesions invaginate, crust, and eventually desquamate with residual hyperpigmentation^30^.

## Reproductive and Developmental Toxicity

### Experimental Animals

Female rats were exposed by inhalation to antimony trioxide at 250 mg/m^3^ for up to 2 months (4 hours per day)^33^. Exposure began 3 to 5 days before estrus and continued through mating and gestation until 3 to 5 days prior to delivery. All of the chamber control rats (n = 10) and 16 of 24 exposed rats became pregnant. The average litter size was 6.2 in the exposed rats and 8.3 in the chamber control rats. No data were presented on the incidences of postimplantation loss. No teratogenic effects were observed in the fetuses of the exposed animals. No testicular toxicity was identified in rats or mice following oral gavages of antimony trioxide or antimony potassium tartrate up to 1,200 mg/kg body weight^34^.

### Humans

Women (number not specified) occupationally exposed to dust containing metallic antimony, antimony trioxide, and antimony pentasulfide were evaluated over a period of 2 years^33^. The level of exposure and selection criteria of the control group were not specified. Disturbances of the menstrual cycle and increased incidences of spontaneous abortion and premature birth were reported in exposed women. Antimony was detected in the blood of the exposed workers at levels 10 times higher than in the controls. Antimony also was measured in the urine, breast milk, amniotic fluid, placental tissue, and umbilical cord blood of the exposed workers.

## Carcinogenicity

### Experimental Animals

Inhalation studies of antimony trioxide have identified increased incidences of lung tumors in rats.^14; 35^. In one study, female CR Fischer rats (n = 50) were exposed to 1.9 or 5.0 mg/m^3^ antimony trioxide (6 hours per day, 5 days per week) for 1 year followed by a postexposure period of 1 year or longer^14^. In this study, antimony trioxide exposure resulted in the induction of lung tumors including adenomas, scirrhous carcinomas, and squamous cell carcinomas. Other reports have indicated that, while the reported high exposure concentration was 5.0 mg/m^3^, the actual exposure concentration based on histopathologic examination in comparison to another study of antimony trioxide was probably considerably higher and that the MMAD and GSD for that study were 5.06 µm and 2.13, respectively^16^. In another study^35^, male and female Wistar rats (n = 90/sex) were exposed via whole body inhalation to either antimony trioxide (45 mg/m^3^; MMAD: 2.80 μm) or antimony ore (36 to 40 mg/m^3^; MMAD: 4.78 μm) for up to 1 year (7 hours per day, 5 days per week) with a 20-week postexposure period. Increases in lung tumor incidences (squamous cell carcinomas, scirrhous carcinomas, and bronchoalveolar adenomas and carcinomas with antimony trioxide) over controls were observed in female rats exposed to antimony trioxide (19/70) or antimony ore (17/68). In the Newton et al.^16^ whole body inhalation study, antimony trioxide exposure at concentrations of 0.05, 0.5 and 5.0 mg/m^3^ (measured at 0.06, 0.51 and 4.5 mg/m^3^, respectively) for 1 year, followed by a 1-year postexposure period, did not increase tumor incidence in male or female Fischer 344 rats (N = 65/sex per group). Three lung tumors were observed in this study with one in a control group male, one in a mid-exposure group female, and one in a high-exposure group male.

### Humans

No studies examining the carcinogenic potential of antimony trioxide in humans were identified in a review of the literature.

## Genetic Toxicity

In bacterial mutagenicity assays, antimony trioxide (purity reported to be >99.9%) was negative in Salmonella typhimurium strains TA98, TA100, TA1535, and TA1537 and Escherichia coli strains WP2P and WP2PuvrA with or without induced rat liver S9 activation enzymes (S9 mix) at concentrations up to 5,000 µg/plate^36^. Antimony trioxide (purity >99.9%) was also reported to be negative in TA98 and TA100 with or without S9 mix at concentrations up to 1.71 µg/plate^2^. In the Bacillus subtilis rec assay, in which differential cytotoxicity between strains H17 (rec^+^) and M45 (rec^–^) is used as a measure of compound-induced DNA damage, antimony trioxide was positive at concentrations of 0.6 and 1.1 µg/disk^2^. In an earlier rec assay, antimony trioxide (purity not specified) was reported to be positive at a concentration of 50 mM^37^. Both of these rec assays were performed without S9 mix.

Antimony trioxide was also tested for genotoxicity in mammalian cell assays. Antimony trioxide induced sister chromatid exchanges (SCEs) in the absence of S9 at concentrations of 0.9, 0.17, and 0.34 µg/mL in cultured Chinese hamster ovary cells^2^. In a second study, antimony trioxide was reported to induce SCEs in cultured human lymphocytes at concentrations of 0.5, 1, and 2 µM in the absence of S9^38^. Significant increases in chromosomal aberrations were seen in cultured human lymphocytes exposed to 100 µg/mL antimony trioxide with or without S9 mix^36^; no increases in aberrations were seen at lower concentrations of antimony trioxide, and no alterations in mitotic index were seen at any of the concentrations used in this study. Antimony trioxide was negative in the L5178Y mouse lymphoma cell Tk^+/−^ mutation assay with and without S9 mix at concentrations up to 50 µg/mL^36^.

In vivo, no significant increases in micronucleated polychromatic erythrocytes (PCEs) were observed in bone marrow samples from male and female CD-1 mice given a single dose of 5,000 mg/kg antimony trioxide by oral gavage, and no significant increases in micronucleated PCEs were seen after repeated dosing with 400, 667, or 1,000 mg/kg per day by oral gavage for 8, 15, or 22 days^36^. No increases in chromosomal aberrations or micronucleated PCE frequencies were seen in bone marrow of a single cohort of male and female Sprague Dawley Crl:CD rats given antimony trioxide (purity >99.9%) at doses of 250, 500, or 1,000 mg/kg per day by oral gavage for 21 days^39^; inductively coupled plasma atomic emission spectroscopy was used to verify the concentration of solubilized antimony trioxide in the dosing solutions. Furthermore, these investigators used a toxicokinetic approach to confirm the presence of antimony trioxide in the bone marrow of exposed rats. Antimony trioxide was also negative in a liver DNA repair assay conducted using male Alderley Park Alpk:APfSD (Wistar-derived) rats exposed to a single dose of antimony trioxide (3,200 or 5,000 mg/kg) and assessed 2 or 16 hours after dosing^36^.

The genotoxic effects of occupational exposure to antimony trioxide were studied in workers at a factory that produced fireproof textiles for car upholstery^40^. The study compared SCEs, micronuclei, and DNA damage levels (detected by the comet assay) in peripheral blood lymphocytes among 1) workers who prepared suspensions of antimony trioxide, 2) workers who had a different task at the factory, and 3) an unexposed control group. Biomonitoring equipment showed only a small difference in antimony trioxide exposure levels between the two groups of workers and the levels of exposure recorded in this study were approximately 4,000 times lower than the occupational exposure limit. No differences in the three indicators of genotoxicity were observed among any of the three groups of workers that were evaluated in this study.

To summarize, antimony trioxide was not mutagenic in bacterial reverse mutation assays or in the mouse lymphoma assay, but results from the bacterial rec assay and mammalian cell SCE and chromosomal aberration assays suggest that antimony trioxide can damage DNA in vitro. However, results of chromosomal damage assays in laboratory animals and exposed workers were negative.

## Study Rationale

Antimony trioxide was nominated by the Consumer Product Safety Commission and the National Institute of Environmental Health Sciences for National Toxicology Program testing due to the potential for substantial human exposure in occupational settings and the lack of adequate 2-year exposure carcinogenicity studies. Three 1-year inhalation exposure studies in rats are reported in the literature^14; 16; 35^; however, the methodologies and lung carcinogenicity results were inconsistent among the three studies. In response, NTP conducted 2-week and 2-year inhalation studies on antimony trioxide to determine if antimony trioxide poses a carcinogenic hazard in rats, to generate data in a second species, and to characterize the exposure-concentration responses in rats and mice. A 12-month interim evaluation was added as a means of comparison to previous inhalation studies. Inhalation exposure was selected because this is most common route of occupational exposure to antimony trioxide in humans. This Technical Report summarizes the results of the 2-week and 2-year toxicity and carcinogenicity studies conducted in male and female Wistar Han rats and B6C3F1/N mice.