# Appendix L Summary of Peer Review Panel Comments

On February 16, 2016, the draft Technical Report on the toxicology and carcinogenesis studies of antimony trioxide received public review by the National Toxicology Program’s Technical Reports Peer Review Panel. The review meeting was held at the National Institute of Environmental Health Sciences, Research Triangle Park, NC.

Dr. M.D. Stout, NIEHS, introduced the toxicology and carcinogenesis studies of antimony trioxide by describing the uses of the chemical, the study designs, and the results of the studies in rats and mice, including nonneoplastic and neoplastic lesions in test animals. The proposed conclusions were some evidence of carcinogenic activity of antimony trioxide in male and female Wistar Han rats and clear evidence of carcinogenic activity of antimony trioxide in male and female B6C3F1/N mice.

Dr. Pino, the first primary reviewer, stated the studies in both rats and mice were well conducted, and the results overall supported NTP’s conclusions regarding the long-term toxicity and carcinogenicity of antimony trioxide. He suggested adding mention of foreign body in the summary findings in the abstract, providing solubility of antimony trioxide in water, clarifying the paragraph about animal source, and discussing whether or not cataracts observed in female mice were considered related to exposure. He also suggested giving the reasons why the findings in the prostate gland and skin of rats and the adrenal medullary pheochromocytomas in mice were not considered exposure related. He disagreed that the incidence of mammary gland carcinoma in rats was meaningfully decreased. He also made several specific editorial corrections and comments. He suggested changes to the report’s conclusions, including rewriting a sentence in the first paragraph to indicate that the incidence of fibrous histiocytoma alone is also increased and replacing “lesions of” with “findings in” in the second paragraph. He noted that there was no increase in reticulocytes in the micronucleus test in rats at 12 months to correlate with the bone marrow increase in erythroid precursors at 2 years. This was in contrast to observations in the mouse. He suggested hematology should have been performed to determine what was happening with circulating erythrocytes. He agreed with the discussion in the report that significance of increased micronuclei in mice was of questionable significance. Dr. Pino suggested that a brief sentence discussing foreign body observations would be helpful. Dr. Stout concurred. For Dr. Pino’s other suggestions, Dr. Stout agreed with his comments and noted that sections of the report would be updated accordingly. Dr. Pinkerton, the second primary reviewer, stated the study design, conduct, and findings were excellent. He noted that the conclusions made by NTP were scientifically sound and logical. While he did not recommend deleting any information from the report, he suggested that tables should be adjusted to provide a clear designation of the total number of animals examined. He suggested adding a definition of “thinness” for the animals. He asked for more information on inflammation of the pleura and appreciated the report’s inclusion of the rationale for changing the rat model. Dr. Stout said he would ensure that the number of animals is included in all tables. Regarding “thinness,” he said it is a general body shape observation. Dr. G.P. Flake, NIEHS, discussed pleural inflammation, stating that particles in or below the pleura appeared to cause the fibrosis that had been observed. Dr. Pinkerton asked if it was dose related. Dr. Flake replied that it was.

Dr. Singal, the third primary reviewer, stated that overall the study design was appropriate and suggested improvements to enhance the report’s thoroughness and additional endpoints that could have been added to the studies. She asked for more information about how the material affected the system as a whole. She suggested that urinary excretion could have been added. She asked for further evaluation of the difference in thymus weight increases between rats and mice. She suggested lung lavage data would have been informative of the proteinaceous/cellular changes in the lungs. She asked for further evaluation of the observation regarding karyorrhectic debris, as well as evaluation of lymphocytic infiltrates in rats. She noted that skin lesions had been observed in mice and suggested that future studies should include a more detailed evaluation of dermal changes due to the relevance for effects observed in humans. She suggested further investigation of hyaline droplet formation in the kidney. She suggested inclusion of comet assay data, as it is mentioned in the text and not shown, to allow a basis for comparison of the differing DNA damage results in mice and rats. In reference to the discussion in the report about potential intrinsic toxicity of antimony trioxide, she noted that particle surface chemistry may contribute to free radical generation and asked for further investigation. Regarding microscopic image slides, she asked for more information about the collection and fixing process and the method of sectioning. She suggested adding proper labeling with magnification information. She recommended adding images of sections of the upper respiratory tract. She noted that there was reference to deposition and clearance modeling without data or methodology. She said her observations would enhance the report and not detract from the study’s findings. Dr. Stout stated that urinary excretion is not typically assessed in these types of studies and acknowledged that it might have been useful in this case. He said that lung lavage data are typically obtained in satellite studies. Dr. Flake addressed Dr. Singal’s comment regarding arterial inflammation, noting that the cause was unknown and there are several possibilities. Regarding Dr. Singal’s question about pulmonary edema, he noted that the associated histologic changes were not observed. He proposed the vascular changes were most likely related to increased blood volume. Regarding the karyorrhectic debris, he said it was related to the neutrophils and alveolar macrophages in the lung, which tend to form aggregates and ultimately break down to form the debris seen. Regarding the lymphocytic infiltrates in the rats, he said it was a less prominent reaction than in the mice. Dr. Stout concurred about cytokine analysis being useful to include; however, he said the molecular analyses were retrospective; therefore, there was not an opportunity to collect specimens for cytokine analysis. He agreed that the skin effects warranted further investigation. He said Dr. Singal’s suggestion regarding hyaline droplet accumulation was noteworthy. Regarding the DNA damage results, he noted that the genotoxicity data are publicly available on the website and that there were no observed explanations for the difference between the results in the rats and the mice. He said that the issue of particle surface chemistry in the study of metal particles could be important to investigate in better understanding the toxicity. He said that the final magnification was not shown on the photos because it could be different when it is published. He stated that collecting and fixing sections of the lungs followed standard NTP practices. He agreed that it would be helpful to add more detail about the inflation fixing pressure and that images of the upper respiratory tract would be helpful. He noted that deposition and clearance information had been included in the report’s appendix and would be checked for completeness.

Dr. Mirsalis noted receipt and distribution to the panel of written comments from Dr. Craig Boreiko of CJB Risk Analysis, LLC on behalf of the International Antimony Association. He then recognized Dr. Boreiko for oral public comments. Dr. Boreiko spoke on behalf of the International Antimony Association and noted he would be touching on highlights of the written comments he had previously submitted. He said there was no question that something was happening in the mouse; however, he proposed that the question of why remained largely unresolved in the report. He was surprised by the results in the rat. He speculated that deep alveolar loading was likely to be significantly greater in the rat studies than that seen in previous studies. He noted that particle overload had been discussed in the body of the report; however it was not in the abstract. He questioned interpretation of the comet assay data, and asked whether the micronucleus data were actually biologically significant. He questioned the conclusion of clear evidence of lymphoma in female mice.

Dr. Brock asked whether the panelists’ discussions and reviews would be captured and processed for inclusion in the final reports and future studies. Dr. C.R. Blystone, NIEHS, replied that all comments are discussed and addressed, and suggestions are taken into account. Dr. Brock asked if there was a process for protocol review. Dr. Blystone said that there are multiple steps for protocol review and reviewer comments are considered. Dr. Brock said that he had found the exposure concentration justification weak given the results of the study. He suggested enhancing the justification in the report.

Dr. Elwell asked whether the adenoma in the nose (listed in the summary tables in the appendix) of one of the highest exposure male rats should be mentioned in the body of the report, given that it was at a target site. He asked about the incidence of adenomas in males at the highest dose in the lung; the table in the report indicated that there were eight, which did not seem to agree with the incidence in the summary table of the report. Dr. Stout noted that eight is the correct number.

Dr. Mirsalis stated that following standard regulatory guidelines, the genotoxicity data would be considered negative. Regarding the micronucleus data, he said that it is important to consider the historical control data for comparison. He emphasized that contrary to language in the report, there was a lack of genotoxic carcinogen response. He recommended toning down that section of the report. Ms. Kristine Witt, NIEHS, genetic toxicology group leader in the Biomolecular Screening Branch of DNTP, noted that the report reflected what had been observed. The level of response was low, and the historic control data were taken into account.

Dr. Brock moved to accept the conclusions as written, and Dr. Pinkerton seconded the motion. Dr. Pino suggested adding the phrase “incidence of fibrous histiocytoma and the” to the second bullet point under the male mice. In the discussion of nonneoplastic issues, Dr. Pino suggested changing the word “lesions” to “findings,” and the addition of “the kidney and” between “and” and “eye” later in the sentence.

Given Dr. Pino’s suggestions, Dr. Brock withdrew his original motion. Dr. Pino moved to accept the conclusions as revised. Dr. Pinkerton seconded the motion. Dr. Mirsalis called for a vote on the motion. The panel voted unanimously to accept the motion.