# Appendix K Analysis of Kras and Egfr Mutations in Wistar Han Rat and B6C3F1/N Mouse Alveolar/Bronchiolar Tumors Resulting from Chronic Inhalation Exposure to Antimony Trioxide

## K.1 Introduction

In the current studies, chronic exposure of Wistar Han rats and B6C3F1/N mice to antimony trioxide particulates for 2 years resulted in increased incidences of alveolar/bronchiolar adenomas and carcinomas. The incidences of alveolar/bronchiolar adenoma or carcinoma (combined) in Wistar Han rats (males and females, respectively) from each exposure group were 0 mg/m^3^ (6%, 0%), 3 mg/m^3^ (8%, 4%), 10 mg/m^3^ (16%, 12%), and 30 mg/m^3^ (16%, 10%) (Table A-2 and Table B-2). The incidences of alveolar/bronchiolar carcinoma in B6C3F1/N mice (males and females, respectively) from each exposure group were 0 mg/m^3^ (8%, 4%), 3 mg/m^3^ (36%, 28%), 10 mg/m^3^ (40%, 22%), and 30 mg/m^3^ (54%, 22%) (Table C-2 and Table D-2).

Somatic mutations in some oncogenes such as Kras and Egfr are commonly noted in human lung cancers. These mutations are also observed in rodent lung tumors that either arise spontaneously or are due to chemical exposure. Most often, the mutation spectra are conserved in tumors resulting from certain chemical exposures and these signatures often serve as biomarkers of exposure and disease. For example, G to T transversions in codon 12 of Kras genes are commonly noted in lung cancers resulting from tobacco smoke exposure and also in rodent lung tumors resulting from chronic oxidative stress.

In human non-small cell lung cancer, the incidence of Kras mutations is approximately 26% (67/254)^111^. Of these, 86% of the mutations arise within codon 12, and 14% occur in codon 13. Point mutations in codons 12, 13, and 61 of Kras are activating mutations that result in constitutive activation of the KRAS protein, making it refractory to the inhibitory GTPase activating proteins, which results in stimulus-independent, persistent activation of downstream effectors, in particular the RAF-MEK-ERK cascade. Constitutive activation of this kinase cascade results in promotion of cellular proliferation and transformation^112; 113^.

The incidence of Egfr mutations in the non-small cell lung cancer subtype of adenocarcinoma in humans is about 9% (22/254) with the majority (70%) of the mutations located within exons 19 and 21111. EGFR is a transmembrane receptor, which upon ligand binding, dimerizes and activates the cytosolic kinase domain of the receptor tyrosine kinase resulting in activation of signaling pathways that support cancer development and progression. These signaling pathways include the PI3K pathway, which when activated leads to AKT activation and apoptosis inhibition, and the GRB2-SOS pathways, which lead to activation of P21RAS, resulting in cell cycle progression^114^.

In the current studies, increased lung weights in the exposed animals were related to the antimony trioxide exposure concentration and duration (Table F-2, Table F-4, Table G-3, and Table G-8). Antimony trioxide lung burden modeling studies in female Wistar Han rats and B6C3F1/N mice suggested that mid and high exposure concentration groups (10 and 30 mg/m^3^) in both species may have approached the threshold needed for pulmonary overload (Appendix G). Pulmonary overload is characterized by prolonged pulmonary clearance half-lives, markedly increased lung burdens of the inhaled particulates, and subsequent compromise of pulmonary function. Reduced clearance and marked pulmonary inflammation resulting from inhalation of very high doses of minimally soluble particulates may contribute to neoplasia in the rat^93; 115^.

The objective of this study was to determine the somatic point mutations relevant to human lung cancer in lung tumors occurring in rats and mice due to chronic inhalation of antimony trioxide and also to evaluate any differences in mutations in lung tumors arising in the exposed groups that may have approached the threshold for pulmonary overload.

## K.2 Materials and Methods

### K.2.1 Lung Tumors

After inhalation exposure to antimony trioxide for 2 years, alveolar/bronchiolar adenomas and carcinomas were obtained from male Wistar Han rats and female B6C3F1/N mice, and alveolar/bronchiolar carcinomas were obtained from female Wistar Han rats and male B6C3F1/N mice. In addition, spontaneous alveolar/bronchiolar neoplasms and nontumor normal lung tissues were acquired from chamber control animals at study termination. Formalin-fixed, paraffin-embedded (FFPE) tissues were used for mutation analysis. The mouse tumors that were selected for mutation analysis were generally greater than 5 mm in diameter, whereas the rat tumors were smaller and scattered throughout the pulmonary parenchyma. The alveolar/bronchiolar tumors were selected for molecular biology analysis based on their overall size and viability (minimal to no necrosis or hemorrhage microscopically) in order to maximize the amount and quality of DNA obtained from the FFPE sections. DNA quality was measured using a Nanodrop spectrophotometer (Thermo Scientific, Wilmington, DE) to calculate the 260/280 nm absorbance ratio, and DNA samples with a purity range of 1.7 to 2.0 were used for analysis. Samples falling outside of this range were reisolated from FFPE sections until a suitable purity measure was obtained or were discarded.

### K.2.2 DNA Extraction, Polymerase Chain Reaction, Autosequencing, and Mutation Analysis

Alveolar/bronchiolar tumors (carcinomas from B6C3F1/N mice; adenomas and carcinomas from Wistar Han rats) representing all antimony trioxide exposed groups, spontaneous alveolar/bronchiolar tumors (2 rat adenomas and 9 mouse carcinomas), and nontumor lung tissue from chamber control rats (11) and mice (10) were evaluated for hot spot mutations within specific codons or exons in Kras and Egfr genes that are relevant in human lung cancer. FFPE sections at 10 µm thickness were collected on glass slides. The neoplasms (single or multiple from the same lung) were dissected with a sharp microtome blade and collected into screw-top tubes. In some cases (especially in rats) where the alveolar/bronchiolar tumors had a miliary distribution and were scattered throughout the pulmonary parenchyma, the entire lung section was used for DNA isolation. DNA was isolated from these FFPE dissected neoplasm tissue sections with the DNeasy^®^ Tissue Kit (Qiagen, Valencia, CA). Amplification reactions were carried out by seminested polymerase chain reaction (PCR) using primer sets designed for Kras (exons 1 and 2), and Egfr (exons 18 to 21) (Table K-1 and Table K-2). Controls lacking template DNA were run with all sets of reactions. PCR products were purified using a QIAquick^®^ Gel Extraction Kit (Qiagen). The purified products were cycled with Terminal Ready Reaction Mix-Big Dye^®^ (PerkinElmer, Foster City, CA), and the extension products were purified with the DyeEx^®^ 2.0 SpinKit (Qiagen). The lyophilized PCR products were sequenced with an automatic sequencer (Perkin-Elmer ABI Model 3100)116. The resulting electropherograms were compared to identify mutations in alveolar/bronchiolar neoplasms that either arose spontaneously or were due to antimony trioxide exposure.

### K.2.3 Statistics

To test for significance of exposure concentration-related trends in the incidences of mutations, a one-sided Cochran-Armitage trend test was conducted. One-sided Fisher’s exact tests were conducted to test for significant differences in the proportions of mutations between the chamber control and various exposed groups.

## K.3 Results

### K.3.1 Rats

The incidences of Kras and Egfr mutations in alveolar/bronchiolar tumors in Wistar Han rats exposed to antimony trioxide by inhalation for 2 years were 4% (1/26) and 50% (13/26), respectively (Table K-3, Table K-4, and Table K-5). No Kras or Egfr mutations were noted in alveolar/bronchiolar tumors that arose spontaneously or in age-matched nontumor lung tissues. The Kras mutation (A to G transition) that occurred in the single antimony trioxide exposed alveolar/bronchiolar tumor was in exon 1, codon 16, a non-hot spot location for Kras mutations. The Egfr mutations were localized within exons 18 to 21 and all of them were transition mutations.

The tissue burden modeling studies (Appendix G) estimated that the mid- and high-exposure concentration groups may have approached the threshold for pulmonary overload. The incidences of Kras mutations in alveolar/bronchiolar tumors in groups without (3 mg/m^3^) and with (10 and 30 mg/m^3^) pulmonary overload were 0% (0/5) and 5% (1/21), respectively, whereas, the incidences of Egfr mutations in alveolar/bronchiolar tumors in groups without (3 mg/m^3^) and with (10 and 30 mg/m^3^) pulmonary overload were 60% (3/5) and 48% (10/21), respectively (Table K-3).

### K.3.2 Mice

The incidences of Kras and Egfr mutations in alveolar/bronchiolar tumors in B6C3F1/N mice exposed to antimony trioxide by inhalation for 2 years were 43% (34/80) and 46% (37/80), respectively (Table K-3, Table K-7, and Table K-8). The majority of the Kras mutations were located in codon 12 and were G to A transitions. The Egfr mutations were mainly located within exons 18 and 20 and were transition mutations. The incidences of Kras mutations were 33% (3/9) and 0% (0/10) in spontaneous alveolar/bronchiolar carcinomas and age-matched nontumor lung tissues, respectively. All three Kras mutations in spontaneous alveolar/bronchiolar carcinomas were G to A transitions. No Egfr mutations were noted in either spontaneous alveolar/bronchiolar carcinomas or non-tumor lung tissues.

The tissue burden modeling studies (Appendix G) estimated that the mid- and high-dose groups may have approached the threshold for pulmonary overload. The incidences of Kras mutations in alveolar/bronchiolar tumors in groups without (3 mg/m^3^) and with (10 and 30 mg/m^3^) pulmonary overload were 32% (9/28) and 48% (25/52), respectively, whereas, the incidences of Egfr mutations in alveolar/bronchiolar tumors in groups without (3 mg/m^3^) and with (10 and 30 mg/m^3^) pulmonary overload were 39% (11/28) and 50% (26/52), respectively (Table K-6).

## K.4 Discussion

Kras mutations were common in antimony trioxide-exposed alveolar/bronchiolar tumors in B6C3F1/N mice but not in alveolar/bronchiolar tumors in Wistar Han rats. The only Kras mutation in the single alveolar/bronchiolar tumor in the rats was present in the atypical codon 12. In contrast, Kras mutations in mouse alveolar/bronchiolar tumors that occurred due to chronic exposure to antimony trioxide were located mainly in codon 12 and were mainly G to A transitions. These G to A transitions of Kras mutations are also common in spontaneous alveolar/bronchiolar carcinomas^116^ and suggest that antimony trioxide exposure may have enhanced the proliferation of clones harboring the spontaneous mutations. Rat and mouse alveolar/bronchiolar adenomas and carcinomas from exposures that did and did not approach the threshold for pulmonary overload did not have significant differences in the incidences or types of Kras or Egfr mutations.

Interestingly, the alveolar/bronchiolar tumors resulting from chronic antimony trioxide exposure in both rats and mice harbored mutations in the Egfr gene. Both KRAS and EGFR are major components of the MAPK signaling pathway, but the antimony trioxide induced tumors seem to preferentially harbor Egfr mutations in both species. These results suggest that EGFR signaling plays an important role in the pulmonary carcinogenesis resulting from chronic antimony trioxide exposure in both rats and mice. These findings may be relevant in the context of human lung cancers since the demographics, etiology, and prognosis of lung cancers harboring Egfr mutations are different from those harboring Kras mutations^117-119^.

Table K-1 Primers Used to Amplify the Hot Spot Regions of Rat Kras and Egfr Genes

Exon | Codon | Primer | Strand | Sequence
1 | Kras-12-13 | RKrasF25849 | Sense | 5´-AAAGTACTTGATAATTCTTGTGTGG-3´
| | RKrasR25489 | Antisense | 5´-AGAAGTGGGGTTCCTTGCACCG-3´
| | RKrasR25497 | Antisense | 5´-GGTTCCTTGCACCGATGGTTCCC-3´
2 | Kras-61 | RKrasF14399 | Sense | 5´-GCTCTGCCTATTTGGACTGGG-3´
| | RKrasF14444 | Sense | 5´-CGAGTGCTTGCTGACCACTTG-3´
| | RKrasR13986 | Antisense | 5´-CAGGAATTCTACATACTTGACAC-3´
18 | Egfr-689-729 | REgfr18F144600 | Sense | 5´-TGCGTGTAGCATATTGTG-3´
| | REgfr18F144640 | Sense | 5´-GTCTGCTCCCTTCTTCAC-3´
| | REgfr18R144843 | Antisense | 5´-GGAGAGTACAGCAAATAC-3´
| | REgfr18R144823 | Antisense | 5´-GTTCCCAGAAGCCTAGTC-3´
19 | Egfr-730-762 | REgfr19F146377 | Sense | 5´-ACAAGGCAACATGCTGCTG-3´
| | REgfr19F146412 | Sense | 5´-TTAATGTCAGCCCTCTTC-3´
| | REgfr19R146605 | Antisense | 5´-ACACAAACTAAGGAAGCAAGAC-3´
| | REgfr19R146583 | Antisense | 5´-TGACTATAGGAAACCGTG-3´
20 | Egfr-763-824 | REgfr20F150643 | Sense | 5´-ACATGTGTTGTCCTTACC-3´
| | REgfr20R150924 | Antisense | 5´-ATTCATCCTGCTTCTGAAACC-3´
| | REgfr20R150905 | Antisense | 5´-CCTGCTATTGGCTCTTTG-3´
21 | Egfr-825-876 | REgfr21F162616 | Sense | 5´-TGGTTCACTTCCCTCACTG-3´
| | REgfr21R162634 | Antisense | 5´-AAGCGTCTTCTGTGTTTC-3´
| | REgfr21R162838 | Antisense | 5´-ATGCTTCCTGACTTATTCTC-3´

Table K-2 Primers Used to Amplify the Hot Spot Regions of Mouse Kras and Egfr Genes

Exon | Codon | Primer | Strand | Sequence
1 | Kras-12-13 | MKras12AOS | Sense | 5´-TTATTGTAAGGCCTGCTGAA-3´
| | MKras12AOA | Antisense | 5´-GCAGCGTTACCTCTATCGTA-3´
| | MKras12AIS | Sense | 5´-ATGACTGAGTATAAACTTGT-3´
| | MKras12AIA | Antisense | 5´-TCGTACTCATCCACAAAGTG-3´
2 | Kras-61 | MKras61OS | Sense | 5´-TTCTCAGGACTCCTACAGGA-3´
| | MKras61OA | Antisense | 5´-ACCCACCTATAATGGTGAAT-3´
| | MAPK61IS | Sense | 5´-TACAGGAAACAAGTAGTAATTGATGGAGAA-3´
| | MAPK61IA | Antisense | 5´-ATAATGGTGAATATCTTCAAATGATTTAGT-3´
18 | Egfr-688-728 | MEgfr18F138871 | Sense | 5´-ATGCTATTAGGAGTTGGA-3´
| | MEgfr18F138893 | Sense | 5´-CTGGCTCAGAATGAATCTAC-3´
| | MEgfr18R139205 | Antisense | 5´-CACAGCAAACACTGGTTC-3´
| | MEgfr18R139157 | Antisense | 5´-GTCTCCAGGAAGCCTAGT-3´
19 | Egfr-729-761 | MEgfr19F140736 | Sense | 5´-CCAGCTCACAAGGCAACA-3´
| | MEgfr19F140773 | Sense | 5´-TCAAGTTAATGTCAGCCC-3´
| | MEgfr19R140986 | Antisense | 5´-GAACTAAGGAAGCAAGATTG-3´
20 | Egfr-762-823 | MEgfr20F144618 | Sense | 5´-CCAGAAAGGGATATGCGT-3´
| | MEgfr20F144669 | Sense | 5´-CATCTATTGTCCTTACCTTG-3´
| | MEgfr20R144989 | Antisense | 5´-GGAAGACCACAAGTCAAAG-3´
| | MEgfr20R144917 | Antisense | 5´-CTTTGGGTACTTCAGTGG-3´
21 | Egfr-824-875 | MEgfr21F152001 | Sense | 5´-GTGGATTTAACCCTGTGTTC-3´
| | MEgfr21F152063 | Sense | 5´-GATGGTTCACTCCCTCAC-3´
| | MEgfr21R152302 | Antisense | 5´-TGGGCTGTCAGGAAAATG-3´

Table K-3 Summary of Kras and Egfr Mutations in Nontumor Lung Tissue and Alveolar/Bronchiolar Adenomas and Carcinomas from Wistar Han Rats in the Two-year Inhalation Study of Antimony Trioxide^a^

Tissue: | Antimony Trioxide Concentration | Mutation Frequency^b^ | | Kras Codon | Egfr Exons
Tissue: | Antimony Trioxide Concentration | Kras | Egfr | 16 | 18 | 19 | 20 | 21
Nontumor lung: | 0 mg/m^3^ | 0/11 (0) | 0/11 (0) | 0 | 0 | 0 | 0 | 0
Lung tumors: | 0 mg/m^3^ | 0/4 (0) | 0/4 (0) | 0 | 0 | 0 | 0 | 0
| 3 mg/m^3^ | 0/5 (0) | 3^c^/5 (60) | 0 | 2 | 2 | 0 | 1
| 10 mg/m^3^ | 1/11 (9) | 6/11 (55) | 1 | 2 | 2 | 1 | 1
| 30 mg/m^3^ | 0/10 (0) | 4/10 (40) | 0 | 0 | 1 | 2 | 1
All exposed groups combined | | 1/26 (4) | 13^c^/26 (50) | 1 | 4 | 5 | 3 | 3
Without pulmonary overload | | 0/5 (0) | 3^c^/5 (60) | 0 | 2 | 2 | 0 | 1
With pulmonary overload | | 1/21 (5) | 10/21 (48) | 1 | 2 | 3 | 3 | 2

^a^ Male and female Wistar Han rats were exposed to 0, 3, 10, or 30 mg/m^3^ antimony trioxide daily by inhalation for 2 years. Silent mutations are not included. There were no significant differences from the chamber control group by the one-sided Fisher’s exact test and no significant exposure-concentration trend by the Cochran-Armitage trend test.

^b^ Number of tissues with mutations/number of tissues assayed (% with mutation).

^c^ Same animal with double mutations (M246 with Egfr 19 and 21; M257 with Egfr 18 and 19).

Table K-4 Kras and Egfr Mutations in Nontumor Lung Tissue and Alveolar/Bronchiolar Adenomas and Carcinomas from Male Wistar Han Rats in the Two-year Inhalation Study of Antimony Trioxide^a^

Sample/ Animal # | Dose (mg/m^3^)/ Dx | Kras | | Egfr
Sample/ Animal # | Dose (mg/m^3^)/ Dx | Codon 16 | Codon 57 | Exon 18 | Exon 19 | Exon 20 | Exon 21
1/M4 | 0 N | NM | NM | NM | NM | NM | NM
2/M12 | 0 N | NM | NM | NM | NM | NM | NM
3/M14 | 0 N | NM | NM | NM | NM | NM | NM
4/M15 | 0 N | NM | NM | NM | NM | NM | NM
5/M16 | 0 N | NM | NM | NM | NM | NM | NM
6/M17 | 0 N | NM | NM | NM | NM | NM | NM
7/M25 | 0 N | NM | NM | NM | NM | NM | NM
8/M21 | 0 N | NM | NM | NM | NM | NM | NM
9/M22 | 0 N | NM | NM | NM | NM | NM | NM
10/M50 | 0 N | NM | NM | NM | NM | NM | NM
11/M20 | 0 Ad | NM | NM | NM | NM | NM | NM
12/M24 | 0 Ad | NM | NM | NM | Codon 736 | NM | NM
| | | | | GGC→GGT
| | | | | (Gly→Gly)
13/M59 | 0 N | NM | NM | NM | NM | NM | NM
14/M246 | 3 Ad | NM | NM | NM | Codon 761 | NM | Codon 858
| | | | | CTT→CCT | | GGA→AGA
| | | | | (Leu→Pro) | | (Gly→Arg)
15/M257 | 3 Ad | NM | NM | Codon 720 | Codon 749 | NM | NM
| | | | GGT→AGT | AGA→AAA
| | | | (Gly→Ser) | (Arg→Lys)
16/M426 | 10 Ad | NM | NM | Codon 691 | NM | NM | NM
| | | | GAA→AAA
| | | | (Glu→Lys)
17/M452 | 10 Ad | NM | NM | Codon 723 | NM | NM | Codon 870
| | | | GCA→GTA | | | TAC→TAT
| | | | (Ala→Val) | | | (Tyr→Tyr)
18/M404 | 10 Ca | NM | NM | NM | Codon 742 | NM | NM
| | | | | CCT→CTT
| | | | | (Pro→Leu)
19/M412 | 10 Ad | NM | NM | NM | NM | NM | NM
20/M417 | 10 Ca | NM | NM | NM | NM | NM | NM
21/M425 | 10 Ad | NM | NM | NM | NM | Codon 787 | NM
| | | | | | GTC→GCC
| | | | | | (Val→Ala)
22/M611 | 30 Ad | NM | GAC→GAT | NM | NM | NM | NM
| | | (Asp→Asp)
23/M624 | 30 Ad | NM | NM | NM | Codon 742 | NM | NM
| | | | | CCT→CTT
| | | | | (Pro→Leu)
24/M626 | 30 Ad | NM | NM | NM | NM | NM | Codon 836
| | | | | | | CAC→CGC
| | | | | | | (His→Arg)
25/M632 | 30 Ad | NM | NM | NM | NM | NM | NM
26/M658 | 30 Ad | NM | NM | NM | NM | NM | NM

^a^ Rats were exposed to 0, 3, 10, or 30 mg/m^3^ antimony trioxide daily by inhalation for 2 years. Alveolar/bronchiolar adenomas and carcinomas were included.

N = no neoplasm; NM = no mutation; Ad = adenoma; Ca = carcinoma. No Kras mutations were detected at codon 12, 13, or 61.

Table K-5 Kras and Egfr Mutations in Alveolar/Bronchiolar Adenomas and Carcinomas from Female Wistar Han Rats in the Two-year Inhalation Study of Antimony Trioxide^a^

Sample/ Animal # | Dose (mg/m^3^)/ Dx | Kras | | Egfr
Sample/ Animal # | Dose (mg/m^3^)/ Dx | Codon 16 | Codon 57 | Exon 18 | Exon 19 | Codon 16 | Codon 57
1/F316 | 3/Ad | NM | NM | Codon 697 | NM | NM | NM
| | | | GGA→GAA
| | | | (Gly→Glu)
2/F319 | 3/Ad | NM | NM | NM | NM | NM | NM
3/F342 | 3/Ad* | NM | NM | NM | Codon 755 | NM | NM
| | | | | AAA→AAG
| | | | | (Lys→Lys)
4/F512 | 10/Ad | NM | NM | NM | Codon 741 | Codon 804 | NM
| | | | | ATC→ACC | CGA→AGA
| | | | | (Ile→Thr) | (Arg→Arg)
5/F529 | 10/Ad | NM | NM | NM | NM | NM | NM
6/F535 | 10/Ad | NM | NM | NM | NM | NM | NM
7/F541 | 10/Ad | AAG→GAG | NM | NM | NM | NM | Codon 861
| | (Lys→Glu) | | | | | AAA→GAA
| | | | | | | (Lys→Glu)
8/F512 | 10/Ad | NM | NM | NM | NM | NM | NM
9/F737 | 30/Ad | NM | NM | NM | NM | NM | NM
10/F720 | 30/Ad | NM | NM | NM | NM | NM | NM
11/F725 | 30/Ad | NM | NM | NM | NM | Codon 808 | NM
| | | | | | GAC→GGC
| | | | | | (Asp→Gly)
12/F760 | 30/Ca* | NM | NM | NM | NM | Codon 820 | NM
| | | | | | GTG→ATG
| | | | | | (Val→Met)
13/F711 | 30/Ad | NM | NM | NM | NM | NM | NM

^a^ Rats were exposed to 0, 3, 10, or 30 mg/m^3^ antimony trioxide daily by inhalation for 2 years. Alveolar/bronchiolar adenomas and carcinomas were included.

NM = no mutation; Ad = adenoma; Ca = carcinoma.

* Pathology Working Group downgraded the diagnosis to marked hyperplasia. No Kras mutations were detected at codon 12, 13, or 61.

Table K-6 Summary of Kras and Egfr Mutations in Nontumor Lung Tissue and Alveolar/Bronchiolar Carcinomas from B6C3F1/N Mice in the Two-year Inhalation Study of Antimony Trioxide^a^

Tissue: | Antimony Trioxide Concentration | Mutation Frequency^b^ | | Kras Codons | | | | | Egfr Exons
Tissue: | Antimony Trioxide Concentration | Kras | Egfr | 12 | 13 | 14 | 60 | 61 | 18 | 19 | 20 | 21
Nontumor lung: | 0 mg/m^3^ | 0/10 (0) | 0/10 (0) | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0
Lung tumors: | 0 mg/m^3^ | 3/9 (33) | 0/9 (0)^#^ | 3 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0
| 3 mg/m^3^ | 9/28 (32) | 11/28 (39)* | 4 | 0 | 0 | 1 | 4 | 5 | 0 | 4 | 2
| 10 mg/m^3^ | 15/26 (58) | 11^c^/26 (42)* | 11 | 0 | 0 | 0 | 4 | 2 | 1 | 8 | 1
| 30 mg/m^3^ | 10/26 (38) | 15^c^/26 (58)** | 8 | 1 | 1 | 0 | 0 | 4 | 7 | 4 | 1
All exposed groups combined | | 34/80 (43) | 37^c^/80 (46)** | 23 | 1 | 1 | 1 | 8 | 11 | 8 | 16 | 4
Without pulmonary overload | | 9/28 (32) | 11/28 (39)* | 4 | 0 | 0 | 0 | 4 | 5 | 0 | 4 | 2
With pulmonary overload | | 25/52 (48) | 26^c^/52 (50)** | 19 | 1 | 1 | 0 | 4 | 6 | 8 | 12 | 2

* Significantly different (P ≤ 0.05) from the chamber control group by the one-sided Fisher’s exact test.

** P ≤ 0.005.

^#^ Significant exposure-concentration trend (P ≤ 0.01) by the Cochran-Armitage trend test.

^a^ Male and female B6C3F1/N mice were exposed to 0, 3, 10, or 30 mg/m^3^ antimony trioxide daily by inhalation for 2 years. Silent mutations are not included.

^b^ Number of tissues with mutation/number of tissues assayed (% with mutation).

^c^ Same animal with double mutations (M449 with Egfr 20 and 21; M623 with Egfr 19 and 21).

Table K-7 Kras and Egfr Mutations in Nontumor Lung Tissue and Alveolar/Bronchiolar Carcinomas from Male B6C3F1/N Mice in the Two-year Inhalation Study of Antimony Trioxide^a^

Sample/ Animal # | Dose (mg/m^3^)/ Dx | Kras | | | Egfr
Sample/ Animal # | Dose (mg/m^3^)/ Dx | Codon 12 | Codon 13 | Codon 61 | Exon 18 | Exon 19 | Exon 20 | Exon 21
1/M14 | 0/N | NM | NM | NM | NM | NM | NM | NM
2/M15 | 0/N | NM | NM | NM | NM | NM | NM | NM
3/M20 | 0/N | NM | NM | NM | NM | NM | NM | NM
4/M22 | 0/N | NM | NM | NM | NM | NM | NM | NM
5/M26 | 0/N | NM | NM | NM | NM | NM | NM | NM
6/M28 | 0/N | NM | NM | NM | NM | NM | NM | NM
7/M33 | 0/N | NM | NM | NM | NM | NM | NM | NM
8/M34 | 0/N | NM | NM | NM | NM | NM | NM | NM
9/M40 | 0/N | NM | NM | NM | NM | NM | NM | NM
10/M47 | 0/N | NM | NM | NM | NM | NM | NM | NM
11/M10 | 0/Ca | NM | NM | NM | NM | NM | NM | NM
12/M13 | 0/Ca | GGT→GAT | NM | NM | NM | NM | NM | NM
| | (Gly→Asp)
13/M25 | 0/Ca | NM | NM | NM | NM | NM | NM | NM
14/M58 | 0/Ca | NM | NM | NM | NM | NM | NM | NM
15/M205 | 3/Ca | NM | NM | NM | NM | NM | NM | NM
16/M210 | 3/Ca | NM | NM | NM | Codon 723 | NM | NM | NM
| | | | | GGA→AGA
| | | | | (Gly→Arg)
17/M211 | 3/Ca | NM | NM | NM | NM | NM | NM | NM
18/M219 | 3/Ca | NM | NM | NM | Codon 713 | NM | NM | NM
| | | | | GAA→AAA
| | | | | (Glu→Lys)
19/M220 | 3/Ca | NM | NM | NM | NM | NM | NM | NM
20/M225 | 3/Ca | NM | NM | NM | NM | NM | NM | NM
21/M228 | 3/Ca | NM | NM | NM | NM | NM | NM | NM
22/M242 | 3/Ca | NM | NM | NM | NM | NM | NM | Codon 859
| | | | | | | | GGG→AGG
| | | | | | | | (Gly→Arg)
23/M247 | 3/Ca | NM | NM | NM | NM | NM | Codon 796 | NM
| | | | | | | CCC→CCT
| | | | | | | (Pro→Pro)
24/M251 | 3/Ca | GGT→GAT | NM | NM | NM | NM | NM | Codon 866
| | (Gly→Asp) | | | | | | GCT→ACT
| | | | | | | | (Ala→Thr)
25/M252 | 3/Ca | NM | NM | Codon 60 | Codon 713 | NM | NM | NM
| | | | GGT→GAT | GAA→AAA
| | | | (Gly→Asp) | (Glu→Lys)
26/M253 | 3/Ca | NM | NM | NM | NM | NM | NM | NM
27/M255 | 3/Ca | NM | NM | NM | NM | NM | NM | Codon 876
| | | | | | | | GGC→GGT
| | | | | | | | (Gly→Gly)
28/M256 | 3/Ca | NM | NM | CAA→CTA | NM | NM | NM | NM
| | | | (Gln→Leu)
29/M259 | 3/Ca | NM | NM | NM | NM | NM | NM | NM
30/M402 | 10/Ca | NM | NM | NM | NM | NM | NM | NM
31/M404 | 10/Ca | GGT→GTT | NM | CAA→CAT | NM | NM | NM | NM
| | (Gly→Val) | | (Gln→His)
32/M406 | 10/Ca | NM | NM | NM | NM | NM | Codon 772 | NM
| | | | | | | GAC→GAT
| | | | | | | (Asp→Asp)
33/M418 | 10/Ca | NM | NM | NM | NM | NM | Codon 782 | NM
| | | | | | | ATC→ACC
| | | | | | | (Ile→Thr)
34/M421 | 10/Ca | NM | NM | NM | NM | NM | NM | NM
35/M422 | 10/Ca | NM | NM | NM | NM | NM | Codon 807 | NM
| | | | | | | CAC→TAC
| | | | | | | (His→Tyr)
36/M424 | 10/Ca | GGT→GAT | NM | NM | NM | NM | NM | NM
| | (Gly→Asp)
37/M426 | 10/Ca | GGT→GAT | NM | NM | NM | NM | NM | NM
| | (Gly→Asp)
38/M429 | 10/Ca | GGT→GAT | NM | NM | NM | NM | Codon 810 | NM
| | (Gly→Asp) | | | | | AAC→CAC
| | | | | | | (Asn→His)
39/M435 | 10/Ca | NM | NM | NM | NM | NM | Codon 771 | Codon 837
| | | | | | | GTG→GAG | CAC→CAT
| | | | | | | (Val→Glu) | (His→His)
40/M437 | 10/Ca | NM | NM | NM | NM | Codon 752 | NM | NM
| | | | | | GCC→GAC
| | | | | | (Ala→Asp)
41/M445 | 10/Ca | NM | NM | CAA→CTA | NM | NM | Codon 807 | NM
| | | | (Gln→Leu) | | | CAC→TAC
| | | | | | | (His→Tyr)
42/M449 | 10/Ca | NM | NM | NM | NM | NM | Codon 799 | Codon 870
| | | | | | | TCG→CGC | GAA→AAA
| | | | | | | (Cys→Arg) | (Glu→Lys)
43/M451 | 10/Ca | NM | NM | NM | NM | NM | NM | NM
44/M456 | 10/Ca | NM | NM | CAA→CAC | NM | NM | Codon 813 | NM
| | | | (Gln→His) | | | TCC→CCC
| | | | | | | (Ser→Pro)
45/M458 | 10/Ca | NM | NM | NM | NM | NM | NM | NM
46/M602 | 30/Ca* | NM | NM | NM | NM | Codon 758 | NM | NM
| | | | | | AAC→AAT
| | | | | | (Asn→Asn)
47/M605 | 30/Ca | GGT→GAT | NM | NM | Codon 691 | NM | NM | NM
| | (Gly→Asp) | | | GTG→GAG
| | | | | (Val→Glu)
48/M614 | 30/Ca | NM | NM | NM | NM | NM | Codon 788 | NM
| | | | | | | GTC→GTA
| | | | | | | (Val→Val)
49/M615 | 30/Ca | NM | GGC→CGC | NM | NM | NM | NM | NM
| | | Gly→Arg)
50/M620 | 30/Ca | GGT→GAT | NM | NM | NM | NM | Codon 810 | NM
| | (Gly→Asp) | | | | | CAC→AAC
| | | | | | | (His→Asn)
51/M622 | 30/Ca | GGT→GAT | NM | NM | NM | NM | Codon 771 | Codon 849
| | (Gly→Asp) | | | | | GTG→GTA | ACA→ACG
| | | | | | | (Val→Val) | (Thr→Thr)
52/M623 | 30/Ca | NM | NM | NM | NM | Codon 751 | NM | Codon 841
| | | | | | GAA→GGA | | GCA→GTA
| | | | | | (Glu→Gly) | | (Ala→Val)
53/M628 | 30/Ca | GGT→GAT | NM | NM | NM | Codon 744 | NM | NM
| | (Gly→Asp) | | | | GTG→GAG
| | | | | | (Val→Glu)
54/M633 | 30/Ca | NM | NM | NM | NM | Codon 737 | NM | Codon 859
| | | | | | GGT→GAT | | GGG→GGT
| | | | | | (Gly→Asp) | | (Gly→Gly)
55/M641 | 30/Ca | NM | NM | NM | Codon 706 | NM | Codon 799 | NM
| | | | | TTG→CTG | | TGC→CGC
| | | | | (Leu→Leu) | | (Cys→Arg)
56/M642 | 30/Ca | GGT→GTT | NM | Codon 14 | NM | NM | NM | NM
| | (Gly→Val) | | GTA→ATA
| | | | (Val→Ile)
57/M643 | 30/Ca | GGT→GAT | NM | NM | NM | Codon 752 | NM | NM
| | (Gly→Asp) | | | | GCC→GAC
| | | | | | (Ala→Asp)
58/M644 | 30/Ca | NM | NM | NM | NM | NM | Codon 812 | NM
| | | | | | | GGC→GGT
| | | | | | | (Gly→Gly)
| | | | | | | Codon 813
| | | | | | | TCC→CCC
| | | | | | | (Ser→Pro)
59/M646 | 30/Ca | NM | NM | NM | NM | Codon 732 | NM | NM
| | | | | | CTC→CTT
| | | | | | (Leu→Leu)
60/M656 | 30/Ca | NM | NM | NM | NM | Codon 745 | NM | NM
| | | | | | GCC→GTC
| | | | | | (Ala→Val)
61/M657 | 30/Ca | NM | NM | NM | NM | NM | NM | Codon 877
| | | | | | | | AAA→AAG
| | | | | | | | (Lys→Lys)

^a^ Mice were exposed to 0, 3, 10, or 30 mg/m^3^ antimony trioxide daily by inhalation for 2 years. Alveolar/bronchiolar carcinomas were included.

N = no neoplasm; NM = no mutation; Ca = carcinoma; *Pathology Working Group downgraded the diagnosis to hyperplasia.

Table K-8 Kras and Egfr Mutations in Alveolar/Bronchiolar Carcinomas from Female B6C3F1/N Mice in the Two-year Inhalation Study of Antimony Trioxide^a^

Sample/ Animal # | Dose (mg/m^3^)/ Dx | Kras | | | Egfr
Sample/ Animal # | Dose (mg/m^3^)/ Dx | Codon 12 | Codon 13 | Codon 61 | Exon 18 | Exon 19 | Exon 20 | Exon 21
1/F113 | 0/Ca | GGT→GAT | NM | NM | NM | Codon 758 | NM | NM
| | (Gly→Asp) | | | | AAC→AAT
| | | | | | (Asn→Asn)
2/F122 | 0/Ca | NM | NM | NM | NM | NM | NM | NM
3/F147 | 0/Ca | NM | NM | NM | NM | NM | NM | NM
4/F155 | 0/Ca | GGT→GAT | NM | NM | NM | NM | NM | NM
| | (Gly→Asp)
5/F156 | 0/Ca | NM | NM | NM | NM | NM | Codon 815 | NM
| | | | | | | TAC→TAT
| | | | | | | (Tyr→Tyr)
6/F303 | 3/Ca | NM | NM | NM | NM | NM | Codon 801 | Codon 861
| | | | | | | CTG→CAG | GCC→GCT
| | | | | | | (Leu→Gln) | (Ala→Ala)
7/F310 | 3/Ca | NM | NM | NM | NM | NM | NM | NM
8/F312 | 3/Ca | NM | NM | CAA→CAT | NM | NM | Codon 822 | NM
| | | | (Gln→His) | | | CAG→CGG
| | | | | | | (Gln→Arg)
9/F318 | 3/Ca | GGT→GAT | NM | CAA→CAG | NM | NM | NM | NM
| | (Gly→Asp) | | Gln→Gln)
10/F326 | 3/Ca | GGT→GAT | NM | CAA→CTA | NM | NM | NM | NM
| | (Gly→Asp) | | (Gln→Leu)
11/F333 | 3/Ca | NM | NM | NM | NM | NM | NM | NM
12/F334 | 3/Ca | NM | NM | CAA→CAC | NM | NM | Codon 811 | NM
| | | | (Gln→His) | | | ATT→ACT
| | | | | | | (Ile→Thr)
13/F338 | 3/Ca | NM | NM | NM | NM | NM | NM | NM
14/F339 | 3/Ca | NM | NM | NM | Codon 696 | NM | NM | NM
| | | | | CCC→GCC
| | | | | (Pro→Ala)
15/F353 | 3/Ca | NM | NM | NM | NM | NM | Codon 815 | NM
| | | | | | | TAC→TCC
| | | | | | | (Ile→Thr)
16/F354 | 3/Ca | NM | NM | NM | NM | NM | NM | NM
17/F355 | 3/Ca | GGT→GTT | NM | NM | Codon 690 | NM | NM | NM
| | (Gly→Val) | | | CTC→TTC
| | | | | (Leu→Phe)
18/F356 | 3/Ca | NM | NM | NM | NM | NM | NM | NM
19/F503 | 10/Ca | GGT→GAT | NM | CAA→CAG | NM | NM | NM | NM
| | (Gly→Asp) | | (Gln→Gln)
20/F504 | 10/Ca | GGT→GTT | NM | NM | NM | NM | NM | NM
| | (Gly→Val)
21/F508 | 10/Ca | NM | NM | NM | Codon 724 | NM | NM | NM
| | | | | GCA→GTA
| | | | | (Ala→Val)
22/F516 | 10/Ca | GGT→GAT | NM | NM | NM | NM | NM | NM
| | (Gly→Asp)
23/F523 | 10/Ca | GGT→GAT | NM | CAA→CGA | NM | NM | Codon 801 | NM
| | (Gly→Asp) | | (Gln→Arg) | | | CTG→CAG
| | | | | | | (Leu→Gln)
24/F525 | 10/Ca | NM | NM | NM | NM | NM | NM | NM
25/F538 | 10/Ca | GGT→GAT | NM | NM | NM | NM | NM | NM
| | (Gly→Asp)
26/F555 | 10/Ca | GGT→GAT | NM | NM | NM | NM | NM | NM
| | (Gly→Asp)
27/F556 | 10/Ca | NM | NM | NM | Codon 701 | NM | NM | NM
| | | | | CCA→TCA
| | | | | (Pro→Ser)
28/F558 | 10/Ca | GGT→GAT | NM | NM | NM | NM | NM | NM
| | (Gly→Asp)
29/F706 | 30/Ca | NM | NM | NM | NM | NM | NM | NM
30/F707 | 30/Ca | NM | NM | NM | NM | Codon 747 | NM | NM
| | | | | | AAG→AGG
| | | | | | (Lys→Arg)
31/F725 | 30/Ca | GGT→CGT | NM | NM | NM | Codon 752 | NM | NM
| | (Gly→Arg) | | | | GCC→GTC
| | | | | | (Ala→Val)
32/F740 | 30/Ca | NM | NM | NM | NM | NM | NM | NM
33/F742 | 30/Ca | NM | NM | NM | NM | NM | Codon 812 | NM
| | | | | | | GGC→GGT
| | | | | | | (Gly→Gly)
| | | | | | | Codon 813
| | | | | | | TCC→CCC
| | | | | | | (Ser→Pro)
34/F744 | 30/Ca | NM | NM | NM | Codon 691 | NM | NM | NM
| | | | | GTG→GAG
| | | | | (Val→Glu)
35/F749 | 30/Ca | NM | NM | NM | NM | NM | NM | NM
36/F753 | 30/Ca | GGT→GTT | NM | NM | NM | NM | NM | NM
| | (Gly→Val)
37/F755 | 30/Ca | NM | NM | NM | Codon 806 | NM | NM | NM
| | | | | GAA→GGA
| | | | | (Glu→Gly)
38/F759 | 30/Ca | NM | NM | NM | Codon 712 | NM | NM | NM
| | | | | ACA→ATA
| | | | | (Thr→Ile)

^a^ Mice were exposed to 0, 3, 10, or 30 mg/m^3^ antimony trioxide daily by inhalation for 2 years. Alveolar/bronchiolar carcinomas were included.

NM = no mutation; Ca = carcinoma.