# Appendix J Sentinel Animal Program

## J.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicologic evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or dosed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

Blood samples were collected from each animal and allowed to clot and the serum was separated. Additionally, fecal samples were collected and tested for Helicobacter species. All samples were processed appropriately with serology testing performed in-house or sent to the Research Animal Diagnostic Laboratory, University of Missouri, Columbia, MO, for determination of the presence of pathogens. The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Blood was collected from five animals per sex per time point except for the following: 18-month collection – five male rats and four female rats; 18-month collection – four male mice and five female mice.

Table J-1 Laboratory Methods and Agents Tested for in the Sentinel Animal Program

Method and Test | Time of Collection
Rats
Two-week Study
ELISA
Mycoplasma pulmonis | 2 weeks
PVM (pneumonia virus of mice) | 2 weeks
RCV/SDA(rat coronavirus/sialodacryoadenitis virus) | 2 weeks
RPV (rat parvovirus) | 2 weeks
Sendai | 2 weeks
Two-year Study
ELISA
M. pulmonis | 2 weeks
PVM | 2 weeks
RCV/SDA | 2 weeks
RPV | 2 weeks
Sendai | 2 weeks
Multiplex Fluorescent Immunoassay
KRV (Kilham’s rat virus) | 6, 12, and 18 months, study termination
M. pulmonis | 6, 12, and 18 months, study termination
Parvo NS-1 | 6, 12, and 18 months, study termination
PVM | 6, 12, and 18 months, study termination
RCV/SDA | 6, 12, and 18 months, study termination
RMV (rat minute virus) | 6, 12, and 18 months, study termination
RPV | 6, 12, and 18 months, study termination
RTV (rat theilovirus) | 6, 12, and 18 months, study termination
Sendai | 6, 12, and 18 months, study termination
TMEV (Theiler’s murine encephalomyelitis virus) | 6, 12, and 18 months, study termination
Toolan’s H-1 virus | 6, 12, and 18 months, study termination
Immunofluorescence Assay
KRV | Study termination
RTV | Study termination
Mice
Two-week Study
ELISA
MHV (mouse hepatitis virus) | 2 weeks
MPV (mouse parvovirus) | 2 weeks
M. pulmonis | 2 weeks
PVM | 2 weeks
Sendai | 2 weeks
TMEV GDVII (Theiler’s murine encephalomyelitis virus – mouse poliovirus, strain GDVII) | 2 weeks
Two-year Study
ELISA
MHV | 2 weeks
MPV | 2 weeks
M. pulmonis | 2 weeks
PVM | 2 weeks
Sendai | 2 weeks
TMEV GDVII | 2 weeks
Multiplex Fluorescent Immunoassay
Ectromelia virus | 6, 12, and 18 months, study termination
EDIM (epizootic diarrhea of infant mice) | 6, 12, and 18 months, study termination
LCMV (lymphocytic choriomeningitis virus) | 6, 12, and 18 months, study termination
M. pulmonis | 6, 12, and 18 months, study termination
MHV | 6, 12, and 18 months, study termination
MNV (mouse norovirus) | 6, 12, and 18 months, study termination
Parvo NS-1 | 6, 12, and 18 months, study termination
MPV | 6, 12, and 18 months, study termination
MVM (minute virus of mice) | 6, 12, and 18 months, study termination
PVM | 6, 12, and 18 months, study termination
Reovirus | 6, 12, and 18 months, study termination
Sendai | 6, 12, and 18 months, study termination
TMEV GDVII | 6, 12, and 18 months, study termination
Immunofluorescence Assay
MNV | 18 months
TMEV GDVII | 18 months
EDIM | Study termination
MVM | Study termination
Polymerase Chain Reaction
Helicobacter species | 18 months

## J.2 Results

All test results were negative.