# Appendix I Ingredients, Nutrient Composition, and Contaminant Levels in NTP-2000 Rat and Mouse Ration

Table I-1 Ingredients of NTP-2000 Rat and Mouse Ration

Ingredients | Percent by Weight
Ground hard winter wheat | 22.26
Ground #2 yellow shelled corn | 22.18
Wheat middlings | 15.0
Oat hulls | 8.5
Alfalfa meal (dehydrated, 17% protein) | 7.5
Purified cellulose | 5.5
Soybean meal (49% protein) | 5.0
Fish meal (60% protein) | 4.0
Corn oil (without preservatives) | 3.0
Soy oil (without preservatives) | 3.0
Dried brewer’s yeast | 1.0
Calcium carbonate (USP) | 0.9
Vitamin premix^a^ | 0.5
Mineral premix^b^ | 0.5
Calcium phosphate, dibasic (USP) | 0.4
Sodium chloride | 0.3
Choline chloride (70% choline) | 0.26
Methionine | 0.2

^a^ Wheat middlings as carrier.

^b^ Calcium carbonate as carrier.

Table I-2 Vitamins and Minerals in NTP-2000 Rat and Mouse Ration^a^

| Amount | Source
Vitamins
A | 4,000 IU | Stabilized vitamin A palmitate or acetate
D | 1,000 IU | D-activated animal sterol
K | 1.0 mg | Menadione sodium bisulfite complex
α-Tocopheryl acetate | 100 IU | –
Niacin | 23 mg | –
Folic acid | 1.1 mg | –
d-Pantothenic acid | 10 mg | d-Calcium pantothenate
Riboflavin | 3.3 mg | –
Thiamine | 4 mg | Thiamine mononitrate
B12 | 52 µg | –
Pyridoxine | 6.3 mg | Pyridoxine hydrochloride
Biotin | 0.2 mg | d-Biotin
Minerals
Magnesium | 514 mg | Magnesium oxide
Iron | 35 mg | Iron sulfate
Zinc | 12 mg | Zinc oxide
Manganese | 10 mg | Manganese oxide
Copper | 2.0 mg | Copper sulfate
Iodine | 0.2 mg | Calcium iodate
Chromium | 0.2 mg | Chromium acetate

^a^ Per kg of finished product.

Table I-3 Nutrient Composition of NTP-2000 Rat and Mouse Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by weight) | 14.6 ± 0.53 | 13.7–15.9 | 26
Crude fat (% by weight) | 8.3 ± 0.24 | 7.7–8.6 | 26
Crude fiber (% by weight) | 9.3 ± 1.02 | 7.1–11.8 | 26
Ash (% by weight) | 5.1 ± 0.14 | 4.9–5.4 | 26
Amino Acids (% of total diet)
Arginine | 0.789 ± 0.071 | 0.67–0.97 | 24
Cystine | 0.219 ± 0.023 | 0.15–0.25 | 24
Glycine | 0.700 ± 0.039 | 0.62–0.80 | 24
Histidine | 0.349 ± 0.075 | 0.27–0.68 | 24
Isoleucine | 0.546 ± 0.042 | 0.43–0.66 | 24
Leucine | 1.095 ± 0.064 | 0.96–1.24 | 24
Lysine | 0.703 ± 0.114 | 0.31–0.86 | 24
Methionine | 0.409 ± 0.044 | 0.26–0.49 | 24
Phenylalanine | 0.628 ± 0.038 | 0.54–0.72 | 24
Threonine | 0.507 ± 0.041 | 0.43–0.61 | 24
Tryptophan | 0.151 ± 0.028 | 0.11–0.20 | 24
Tyrosine | 0.409 ± 0.064 | 0.28–0.54 | 24
Valine | 0.664 ± 0.042 | 0.55–0.73 | 24
Essential Fatty Acids (% of total diet)
Linoleic | 3.96 ± 0.250 | 3.49–4.55 | 24
Linolenic | 0.30 ± 0.031 | 0.21–0.35 | 24
Vitamins
Vitamin A (IU/kg) | 3,795 ± 92 | 2,110–5,720 | 26
Vitamin D (IU/kg) | 1,000^a^ | – | –
α-Tocopherol (ppm) | 79.7 ± 21.28 | 27.0–124.0 | 24
Thiamine (ppm)^b^ | 7.3 ± 1.17 | 5.3–11.0 | 26
Riboflavin (ppm) | 7.9 ± 2.96 | 4.20–17.50 | 24
Niacin (ppm) | 78.9 ± 8.86 | 66.4–98.2 | 24
Pantothenic acid (ppm) | 27 ± 12.08 | 17.4–81.0 | 24
Pyridoxine (ppm)^b^ | 9.58 ± 1.91 | 6.44–13.7 | 24
Folic acid (ppm) | 1.6 ± 0.47 | 1.15–3.27 | 24
Biotin (ppm) | 0.32 ± 0.10 | 0.20–0.704 | 24
Vitamin B12 (ppb) | 52.8 ± 38.0 | 18.3–174.0 | 24
Choline (ppm)^b^ | 2,733 ± 608 | 1,160–3,790 | 24
Minerals
Calcium (%) | 0.910 ± 0.043 | 0.810–0.994 | 26
Phosphorus (%) | 0.557 ± 0.031 | 0.490–0.630 | 26
Potassium (%) | 0.669 ± 0.031 | 0.626–0.733 | 24
Chloride (%) | 0.384 ± 0.038 | 0.300–0.474 | 24
Sodium (%) | 0.193 ± 0.024 | 0.160–0.283 | 24
Magnesium (%) | 0.217 ± 0.059 | 0.185–0.490 | 24
Sulfur (%) | 0.170 ± 0.029 | 0.116–0.209 | 14
Iron (ppm) | 188 ± 38.3 | 135–311 | 24
Manganese (ppm) | 51.2 ± 9.99 | 21.0–73.1 | 24
Zinc (ppm) | 59.02 ± 27.84 | 43.3–184 | 24
Copper (ppm) | 7.28 ± 2.635 | 3.21–16.3 | 24
Iodine (ppm) | 0.504 ± 0.197 | 0.158–0.972 | 24
Chromium (ppm) | 0.683 ± 0.270 | 0.330–1.380 | 24
Cobalt (ppm) | 0.242 ± 0.162 | 0.094–0.864 | 24

^a^ From formulation.

^b^ As hydrochloride (thiamine and pyridoxine) or chloride (choline).

Table I-4 Contaminant Levels in NTP-2000 Rat and Mouse Ration^a^

| Mean ± Standard Deviation^b^ | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.24 ± 0.039 | 0.16–0.31 | 26
Cadmium (ppm) | 0.06 ± 0.010 | 0.04–0.01 | 26
Lead (ppm) | 0.1 ± 0.160 | 0.06–0.89 | 26
Mercury (ppm) | <0.02 | – | 26
Selenium (ppm) | 0.2 ± 0.045 | 0.14–0.34 | 26
Aflatoxins (ppb) | <5.00 | – | 26
Nitrate nitrogen (ppm)c | 19.89 ± 7.81 | 10.0–35.9 | 26
Nitrite nitrogen (ppm)c | <0.61 | – | 26
BHA (ppm)d | <1.0 | – | 26
BHT (ppm)d | <1.0 | – | 26
Aerobic plate count (CFU/g) | 10 ± 0.0 | 10 | 26
Coliform (MPN/g) | 3.0 ± 0.0 | 3.0 | 26
Escherichia coli (MPN/g) | <10 | – | 26
Salmonella (MPN/g) | Negative | – | 26
Total nitrosoamines (ppb)e | 9.5 ± 4.20 | 2.0–17.2 | 26
N-Nitrosodimethylamine (ppb)e | 2.9 ± 2.70 | 0.9–11.1 | 26
N-Nitrosopyrrolidine (ppb)e | 7.2 ± 2.80 | 1.0–11.2 | 26
Pesticides (ppm)
α-BHC | <0.01 | – | 26
β-BHC | <0.02 | – | 26
γ-BHC | <0.01 | – | 26
δ-BHC | <0.01 | – | 26
Heptachlor | <0.01 | – | 26
Aldrin | <0.01 | – | 26
Heptachlor epoxide | <0.01 | – | 26
DDE | <0.01 | – | 26
DDD | <0.01 | – | 26
DDT | <0.01 | – | 26
HCB | <0.01 | – | 26
Mirex | <0.01 | – | 26
Methoxychlor | <0.05 | – | 26
Dieldrin | <0.01 | – | 26
Endrin | <0.01 | – | 26
Telodrin | <0.01 | – | 26
Chlordane | <0.05 | – | 26
Toxaphene | <0.10 | – | 26
Estimated PCBs | <0.20 | – | 26
Ronnel | <0.01 | – | 26
Ethion | <0.02 | – | 26
Trithion | <0.05 | – | 26
Diazinon | <0.10 | – | 26
Methyl chlorpyrifos | 0.131 ± 0.120 | 0.020–0.553 | 26
Methyl parathion | <0.02 | – | 26
Ethyl parathion | <0.02 | – | 26
Malathion | 0.117 ± 0.094 | 0.02–0.40 | 26
Endosulfan I | <0.01 | – | 26
Endosulfan II | <0.01 | – | 26
Endosulfan sulfate | <0.03 | – | 26

^a^ All samples were irradiated. CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride.

^b^ For values less than the limit of detection, the detection limit is given as the mean.

^c^ Sources of contamination: alfalfa, grains, and fish meal.

^d^ Sources of contamination: soy oil and fish meal.

^e^ All values were corrected for percent recovery.