# Appendix H Chemical Characterization and Generation of Chamber Concentrations

## H.1 Procurement and Characterization of Antimony Trioxide

Antimony trioxide was obtained from 3N International, Inc. (Akron, OH), in one lot (3N-06159) that was used in the 2-week and 2-year studies. Identity and purity analyses were conducted by the analytical chemistry laboratories at H&M Analytical Services, Inc. [Allentown, NJ; X-ray diffraction (XRD)], and Chemir Analytical Services, Inc. [Maryland Heights, MO; redox titration and ultraviolet (UV) spectrophotometry], and by the study laboratory at Battelle Toxicology Northwest [Richland, WA; inductively coupled plasma/atomic emission spectroscopy (ICP/AES)]. Reports on analyses performed in support of the antimony trioxide studies are on file at the National Institute of Environmental Health Sciences.

Lot 3N-06159 of the chemical, a finely divided white powder, was identified as antimony trioxide by the analytical chemistry laboratory using XRD. XRD patterns were consistent with library reference patterns (Joint Center for Powder Diffraction Studies/International Centre for Diffraction Data) for the diamond cubic structure of antimony trioxide, senarmontite, at 99.9%, with a trace amount of lead dioxide (0.1%) based on the XRD Rietveld method. A representative XRD pattern is presented in Figure H-1.

The purity of lot 3N-06159 was determined using ICP/AES by system A. In addition, redox titration and UV spectrophotometry of bulk chemical samples dissolved in hydrochloric acid (HCl) determined the oxidation state of antimony in the test article. Redox titration was performed with a standardized iodine solution and a freshly prepared starch indicator solution. UV spectrophotometry measured absorbance (330 nm) of iodoantimonous acid formed by the addition of potassium iodide reagent to the antimony tartrate salt of the test article.

A. For ICP/AES, samples were dissolved in concentrated HCl. National Institute of Standards and Technology (NIST)-traceable standards of yttrium (224.306 nm) and indium (325.609 nm) were added to each sample as internal standards for analyses of antimony (206.833 nm) and 18 minor elemental contaminants (aluminum, arsenic, beryllium, cadmium, cobalt, chromium, copper, iron, magnesium, manganese, molybdenum, nickel, lead, sulfur, selenium, tin, tungsten, and zirconium), respectively. Analyses were performed on a Thermo Elemental IRIS Intrepid II inductively coupled plasma/atomic emission spectrometer (Thermo Electron Corporation, Waltham, MA), and the results were normalized against those of NIST-traceable reference standards.

For lot 3N-06159, ICP/AES analysis by system A indicated a purity of 101.9% based on a theoretical content of 83.5% antimony in antimony trioxide. Of the 18 minor elements measured by ICP/AES, only arsenic (~0.019%) and lead (~0.016%) were detected above 0.01% relative to antimony trioxide. Redox titration and UV spectroscopy confirmed that antimony was present in the +3 oxidation state, consistent with antimony trioxide. The overall purity of lot 3N-06159 was determined to be greater than 99.9%.

To ensure stability, the bulk chemical was stored at room temperature in amber glass containers with Teflon^®^-lined lids. Periodic reanalyses of the bulk chemical were performed by the study laboratory using ICP/AES by system A and the analytical chemistry laboratory using XRD and no degradation of the bulk chemical was detected.

## H.2 Aerosol Generation and Exposure System

A schematic diagram of the antimony trioxide generation and distribution system used during the 2-week and 2-year studies is shown in Figure H-2. For the 2-year studies, male and female rats were housed in separate chambers; female rat chambers also housed male and female mice from the concurrent study. The generation system used a linear feed device designed and built by Battelle to meter antimony trioxide into a Trost jet mill (Garlock, Inc., Newtown, PA) for aerosolization and particle size reduction. The linear feed device consisted of a slide bar, a body, a delivery tube, and a test article reservoir.

The compressed air driven slide bar slid back and forth during generation. As the slide bar moved to the filling position, the metering port on the shuttle bar was aligned with the reservoir opening and was filled with a small metered amount of test article. A stainless steel screen at the bottom of the metering port held the material within the port. A slight vacuum was applied to the metering port to assist with filling. As the slide bar moved to the dispersing position, the metering port was aligned with a compressed air port in the body. A puff of air from the port dispersed the test article from the metering port. The output of the linear feeder was regulated by adjusting the shuttle bar cadence.

Initial particle size reduction was accomplished within the Trost jet mill. Opposing nitrogen and air gas streams drove the jet mill. All components of the generation system were housed within a glove box located within the exposure control center.

From the jet mill, aerosol was directed to the main distribution line where it was diluted with humidified air then conveyed from the exposure control center to the exposure room where it passed through a cyclone separator to further reduce particle size. On exiting the cyclone, the aerosol-laden air was directed to either of two smaller branch lines. The main distribution and branch lines were made of stainless steel, bonded and grounded to prevent the buildup of electrostatic charge. The distribution line pressure was continuously monitored and maintained slightly negative to the exposure room.

From the branch line, aerosol was delivered to each exposure chamber by a sampling tube. The flow through the sampling tube was induced by a stainless steel ejector pump designed and fabricated at Battelle. The flow rate and configuration of the ejector pumps were chosen to optimize the efficiency of the delivery system. The aerosol then entered the chamber inlet duct where it was further diluted with conditioned chamber air to achieve the desired exposure concentration.

During exposure periods, there was a small excess of aerosol in each branch line over that needed to maintain chamber concentrations. This additional aerosol was available for making adjustments to the chamber aerosol delivery flow rates and was controlled using house vacuum regulated by a filter-protected flow meter. A second flow control system was available during off-exposure periods. This system consisted of a vacuum transducer pump (Air-Vac Engineering Company, Inc., Seymour, CT) of higher flow capacity positioned in parallel with each branch line flow meter control assembly that became operational only during critical shut-down periods. This backup pump was intended to create sufficient vacuum in the branch line to overcome the negative pressure in the chambers and prevent the flow of aerosol-laden air from the branch line to the chambers as the air supply to each chamber ejector pump was shut off. A high-efficiency particulate air (HEPA) filter was placed before the endline flow control assembly of each branch to remove aerosol from the airstream prior to exhausting from the room.

The study laboratory designed the inhalation exposure chambers (Lab Products, Inc., Seaford, DE) so that uniform aerosol concentrations could be maintained throughout the chambers with the catch pans in place. The total volume of each chamber was 2.3 m^3^ with an active mixing volume of 1.7 m^3^. There were three levels of caging, each level split into two tiers that were offset from each other and from the chamber walls. Drawer-like stainless steel cage units composed of individual animal cages were suspended in the space above each tier. Stainless steel catch pans for the collection of urine and feces were suspended below each cage unit.

Incoming air that contained a uniform mixture of test chemical was diverted so that it flowed vertically along the inner surfaces of the chambers. Eddies were formed at each tier as the aerosol flowed past the catch pans. Stagnant zones that would normally exist above each pair of catch pans were cleared by exhaust flow through the space between the tiers. Aerosol reaching the lowest level was deflected across the bottom tiers by metal strips in the space between the catch pan and the wall. Tests showed that aerosol concentration could be reliably maintained homogenous within 8% throughout the chambers, provided the aerosol was uniformly mixed before passing through the chamber inlet and provided the test material did not react to a significant extent with animals, animal excrement, or the chamber interior.^41^

## H.3 Aerosol Concentration Monitoring

Summaries of the chamber aerosol concentrations are given in Table H-1 and Table H-2. The concentration of antimony trioxide in the exposure chambers and room air was monitored using three real-time aerosol monitors (RAMs) (MicroDust pro, Casella USA, Amherst, NH). The monitors were connected to the chambers by a sampling system designed by Battelle incorporating a valve that multiplexed each RAM to a 0 mg/m^3^ chamber or the room, a HEPA-filtered air blank, and two exposure chambers. The output (voltage) of the RAM was recorded by a program designed by Battelle (Battelle Exposure Data Acquisition and Control) to select the correct sample stream and acquire a raw voltage signal from each RAM. Equations for the calibration curves resided within the program and were used to convert the measured RAM voltages to exposure chamber concentrations. Concentration control limits within the program were compared to each measured concentration and, if limits were exceeded, an audible alarm was triggered or, in extreme cases, exposure was terminated.

Each RAM was calibrated by constructing a response curve using the measured RAM voltages (voltage readings were corrected by subtracting the RAM zero-offset voltage from measured RAM voltages) and antimony concentrations that were determined by analyzing duplicate 25 mm Pallflex TX40HI20WW Emfab, 0.45 µm Teflon^®^-coated, glass-fiber filters (Pall Corporation, East Hills, NY) collected daily from the exposure chambers. Antimony trioxide was extracted from the filters with concentrated hydrochloric acid, sonicated, and analyzed using ICP/AES by system A.

The ICP/AES instrument was calibrated against serially diluted NIST-traceable 10 mg/mL spectrometric standards of antimony trioxide and the internal standard yttrium. Quality control standards and a reagent blank were analyzed after calibration, after approximately every tenth sample, and at the end of the analysis to determine accuracy and calibration drift during analysis.

## H.4 Chamber Atmosphere Characterization

Particle size distribution was determined once prior to the 2-week and 2-year studies, once during the 2-week studies, and monthly during the 2-year studies. Cascade impactor samples were taken from each exposure chamber using a Mercer-style seven-stage impactor (In-Tox Products, Moriarty, NM) and the stages [22 mm glass coverslips lightly coated with silicone to prevent particle bounce for stages 1 to 7, or 25 mm Pallflex TX40HI20WW Emfab Teflon^®^-coated glass-fiber filters (Pall Corporation) for stage 8] were analyzed for antimony using ICP/AES by system A after antimony trioxide was extracted from the slides or filters with concentrated HCl and sonication. The mass of antimony trioxide collected was calculated based on the theoretical percent of antimony in antimony trioxide (83.5%). The relative mass of test article collected on each stage was analyzed by the NEWCAS impactor analysis program developed at Battelle based on probit analysis^42^. The resulting estimates of the mass median aerodynamic particle diameter and the geometric standard deviation of each set of samples are given in Table H-3, Table H-4, and Table H-5. All samples were within the 1 to 3 µm range required by the protocol.

Buildup and decay rates for chamber aerosol concentrations were determined with (all studies) and without (2-year studies) animals present in the chambers. At a chamber airflow rate of 15 air changes per hour, the theoretical value for the time to achieve 90% of the target concentration after the beginning of aerosol generation (T90) and the time for the chamber concentration to decay to 10% of the target concentration after aerosol generation was terminated (T10) was approximately 9.4 minutes. For rats and mice in the 2-week studies with animals present, T90 values ranged from 8 to 12 minutes; T10 values ranged from 7 to 10 minutes. For rats and mice in the 2-year studies, T90 values ranged from 11 to 18 minutes without animals present and from 12 to 17 minutes with animals; T10 values ranged from 5 to 10 minutes without animals present and from 8 to 12 minutes with animals. A T90 value of 12 minutes was selected for all studies.

The uniformity of aerosol concentration in the inhalation exposure chambers without animals present was evaluated before each of the studies began; in addition, concentration uniformity with animals present in the chambers was measured once during the 2-week studies, and every 2 to 3 months during the 2-year studies. Aerosol concentrations were measured using the on-line monitor with the stream-selection valve fixed in one position to allow continuous monitoring from a single input line. Concentrations were measured at all 12 sample ports; one in front and one in back for each of six possible cage unit positions per chamber. Chamber concentration uniformity was maintained throughout the studies.

The persistence of antimony trioxide in the exposure chambers after aerosol delivery ended was determined by monitoring the aerosol concentration in the 60 mg/m^3^ chambers in the 2-week studies with animals present and the 30 mg/m^3^ chambers in the 2-year studies, with and without animals present. In the 2-week studies, the concentration decreased to 1% of the starting concentration within 17 minutes. In the 2-year study of male rats, the concentration decreased to 1% of the starting concentration within approximately 23 minutes with animals present and within 18 minutes without animals. In the 2-year studies of female rats and male and female mice, the concentration decreased to 1% of the starting concentration within 16 minutes with animals present and within 15 minutes without animals.

Stability studies of antimony trioxide in the generation and exposure system were performed before (2-year studies only) and during the studies by the study laboratory (ICP/AES) and H&M Analytical Services, Inc. (XRD). On each sample collection day, a sample of antimony trioxide powder was collected before filling the generator reservoir, and a sample of the powdered test article from the generator reservoir was collected at the end of the generation day; additional test material was added to the generator each day. Before (except for the 2-week studies) and during each study, microporous filters [25 mm A/E glass-fiber filters (Pall Corporation)] were collected from the aerosol distribution line and the 3.75 mg/m^3^ and 60 mg/m^3^ chambers (2-week studies) or the 3 mg/m^3^ and 30 mg/m^3^ chambers (2-year studies) to obtain samples for XRD analyses. Separate sets of filters [25 mm GH Polypro, 0.45 µm (Pall Corporation)] were collected from the distribution line and the same chambers to obtain samples for ICP/AES analyses. Generator reservoir and filter samples were analyzed using multiple but similar XRD systems and ICP/AES by system A to determine if inorganic impurities were introduced into the test atmosphere by the exposure generation system. Powder and filter samples for XRD analyses required no additional processing; those for ICP/AES analyses were dissolved in concentrated HCl and assayed for antimony and 18 minor elemental contaminants as in the initial bulk chemical purity assessment.

During the 2-week studies, XRD with Rietveld analysis indicated that the samples taken from the generation and exposure system contained antimony trioxide (99.6% to 99.9%) and lead dioxide (0.1% to 0.4%). Relative to antimony trioxide, ICP/AES detected aluminum, arsenic, beryllium, cadmium, chromium, copper, manganese, selenium, tungsten, and zirconium at less than 0.1%, cobalt, iron, magnesium, molybdenum, nickel, lead, and tin at less than 0.2%, and sulfur at less than 0.3%.

Before the 2-year studies, XRD with Rietveld analysis indicated the presence of a single crystalline phase of antimony trioxide, the diamond cubic structure senarmontite. The detection limits were approximately 0.1%, 0.2%, and 1.0% for the generator reservoir bulk material samples, the chamber filter samples, and the distribution line filter samples, respectively. Relative to antimony trioxide, ICP/AES detected sulfur at less than 0.2% and the other 17 measured minor elemental contaminants at less than 0.1%.

XRD analyses of test chemical stability in the generation and exposure system were performed at 2 (mice) or 4 (rats) weeks, 1 year, and the end of the 2-year studies. XRD with Rietveld analysis of the generator reservoir bulk material and filter samples indicated a single crystalline phase, that of antimony trioxide in the diamond cubic structure senarmontite. The detection limit for impurity phases ranged from 0.05% to 0.1% for the powder samples and 0.1% to 0.3% for the filter samples. ICP/AES analyses of test chemical stability in the generation and exposure system were performed on generator reservoir bulk material and filter samples collected at 2 (mice) or 4 (rats) weeks during the 2-year studies; all 18 measured minor elemental contaminants were detected at less than or equal to 0.1% relative to antimony trioxide.

Taken together, these results demonstrated that the exposure atmosphere and generator reservoir samples were in good agreement with the bulk test article, the composition of antimony trioxide was stable in the exposure system, and contamination from metal materials in the exposure system did not occur.

Table H-1 Summary of Chamber Concentrations in the Two-week Inhalation Studies of Antimony Trioxide

| Target Concentration (mg/m^3^) | Total Number of Readings | Average Concentration^a^ (mg/m^3^)
Rat Chambers | 3.75 | 113 | 3.72 ± 0.26
| 7.5 | 116 | 7.42 ± 0.40
| 15 | 113 | 14.7 ± 1.0
| 30 | 113 | 30.2 ± 1.4
| 60 | 116 | 59.5 ± 2.9
Mouse Chambers | 3.75 | 123 | 3.71 ± 0.27
| 7.5 | 126 | 7.43 ± 0.39
| 15 | 123 | 14.7 ± 1.1
| 30 | 123 | 30.2 ± 1.4
| 60 | 126 | 59.4 ± 2.9

^a^ Mean ± standard deviation.

Table H-2 Summary of Chamber Concentrations in the Two-year Inhalation Studies of Antimony Trioxide

| Target Concentration (mg/m^3^) | Total Number of Readings | Average Concentration^a^ (mg/m^3^)
Male Rat Chambers | 3 | 4,914 | 3.0 ± 0.2
| 10 | 4,916 | 9.9 ± 0.7
| 30 | 4,937 | 29.7 ± 2.1
Female Rat Chambers | 3 | 4,953 | 3.0 ± 0.2
| 10 | 4,951 | 9.9 ± 0.6
| 30 | 4,932 | 30.1 ± 1.9
Mouse Chambers | 3 | 4,947 | 3.0 ± 0.2
| 10 | 4,945 | 9.9 ± 0.6
| 30 | 4,928 | 30.1 ± 1.9

^a^ Mean ± standard deviation.

Table H-3 Summary of Aerosol Size Measurements for the Rat and Mouse Exposure Chambers in the Two-week Inhalation Studies of Antimony Trioxide

Target Concentration (mg/m^3^) | Mass Median Aerodynamic Diameter (µm) | Geometric Standard Deviation
3.75 | 1.4 | 1.9
7.5 | 1.3 | 1.9
15 | 1.5 | 1.9
30 | 1.4 | 1.9
60 | 1.4 | 1.9

Table H-4 Summary of Aerosol Size Measurements for the Male Rat Exposure Chambers in the Two-year Inhalation Study of Antimony Trioxide

Date of Test | Target Concentration (mg/m^3^) | Mass Median Aerodynamic Diameter (µm) | Geometric Standard Deviation
September 2008 | 3 | 1.1 | 2.2
| 10 | 1.2 | 2.0
| 30 | 1.3 | 1.8
November 2008 | 3 | 1.4 | 2.2
| 10 | 1.1 | 2.0
| 30 | 1.1 | 1.9
December 2008 | 3 | 1.2 | 1.8
| 10 | 1.2 | 2.0
| 30 | 1.2 | 2.0
January 2009 | 3 | 1.2 | 1.9
| 10 | 1.2 | 1.9
| 30 | 1.2 | 1.9
February 2009 | 3 | 1.1 | 1.9
| 10 | 1.1 | 2.0
| 30 | 1.2 | 1.9
March 2009 | 3 | 1.1 | 1.9
| 10 | 1.1 | 1.9
| 30 | 1.2 | 1.8
April 2009 | 3 | 1.1 | 2.0
| 10 | 1.2 | 1.9
| 30 | 1.1 | 1.9
May 2009 | 3 | 1.0 | 1.9
| 10 | 1.1 | 1.9
| 30 | 1.1 | 1.9
June 2009 | 3 | 1.1 | 1.9
| 10 | 1.2 | 1.9
| 30 | 1.3 | 1.9
July 2009 | 3 | 1.2 | 1.9
| 10 | 1.3 | 1.9
| 30 | 1.4 | 1.9
August 2009 | 3 | 1.1 | 2.0
| 10 | 1.2 | 2.0
| 30 | 1.4 | 1.9
September 2009 | 3 | 1.1 | 2.0
| 10 | 1.1 | 1.9
| 30 | 1.2 | 1.9
October 2009 | 3 | 1.2 | 1.9
| 10 | 1.3 | 2.0
| 30 | 1.3 | 1.9
November 2009 | 3 | 1.1 | 1.9
| 10 | 1.3 | 1.9
| 30 | 1.3 | 1.9
December 2009 | 3 | 1.2 | 2.0
| 10 | 1.3 | 1.9
| 30 | 1.3 | 1.9
January 2010 | 3 | 1.2 | 1.9
| 10 | 1.3 | 1.8
| 30 | 1.3 | 1.9
February 2010 | 3 | 1.3 | 1.8
| 10 | 1.2 | 2.0
| 30 | 1.4 | 1.9
March 2010 | 3 | 1.1 | 1.9
| 10 | 1.2 | 1.9
| 30 | 1.1 | 1.9
April 2010 | 3 | 1.2 | 2.1
| 10 | 1.3 | 2.0
| 30 | 1.3 | 1.9
May 2010 | 3 | 1.2 | 2.0
| 10 | 1.3 | 1.9
| 30 | 1.3 | 1.9
June 2010 | 3 | 1.2 | 1.9
| 10 | 1.3 | 2.0
| 30 | 1.4 | 1.8
July 2010 | 3 | 1.3 | 1.9
| 10 | 1.2 | 2.0
| 30 | 1.3 | 1.9
August 2010 | 3 | 1.2 | 2.0
| 10 | 1.3 | 1.9
| 30 | 1.4 | 1.9
September 2010 | 3 | 1.2 | 1.9
| 10 | 1.2 | 1.9
| 30 | 1.3 | 1.9
Range | 3 | 1.0–1.4 | 1.8–2.2
| 10 | 1.1–1.3 | 1.8–2.0
| 30 | 1.1–1.4 | 1.8–2.0

Table H-5 Summary of Aerosol Size Measurements for the Female Rat and Male and Female Mouse Exposure Chambers in the Two-year Inhalation Studies of Antimony Trioxide

Date of Test | Target Concentration (mg/m^3^) | Mass Median Aerodynamic Diameter (µm) | Geometric Standard Deviation
October 2008 | 3 | 1.3 | 1.8
| 10 | 1.3 | 1.9
| 30 | 1.2 | 1.9
November 2008 | 3 | 0.9 | 2.0
| 10 | 1.1 | 1.9
| 30 | 0.9 | 2.0
December 2008 | 3 | 1.3 | 1.9
| 10 | 1.3 | 1.9
| 30 | 1.3 | 1.9
January 2009 | 3 | 1.2 | 1.9
| 10 | 1.3 | 1.9
| 30 | 1.3 | 1.8
February 2009 | 3 | 1.1 | 2.0
| 10 | 1.2 | 1.9
| 30 | 1.2 | 2.0
March 2009 | 3 | 1.2 | 1.9
| 10 | 1.3 | 1.9
| 30 | 1.2 | 1.9
April 2009 | 3 | 1.1 | 1.9
| 10 | 1.1 | 2.0
| 30 | 1.2 | 2.0
May 2009 | 3 | 1.1 | 2.0
| 10 | 1.1 | 2.0
| 30 | 1.3 | 2.0
June 2009 | 3 | 1.1 | 1.9
| 10 | 1.2 | 2.0
| 30 | 1.3 | 2.0
July 2009 | 3 | 1.1 | 1.9
| 10 | 1.2 | 1.9
| 30 | 1.2 | 2.0
August 2009 | 3 | 1.2 | 2.0
| 10 | 1.0 | 2.0
| 30 | 1.1 | 2.0
September 2009 | 3 | 1.4 | 1.9
| 10 | 1.0 | 2.0
| 30 | 1.3 | 1.9
October 2009 | 3 | 1.1 | 2.0
| 10 | 1.1 | 2.0
| 30 | 1.2 | 1.9
November 2009 | 3 | 1.2 | 2.0
| 10 | 1.4 | 1.7
| 30 | 1.2 | 2.0
December 2009 | 3 | 1.2 | 1.9
| 10 | 1.3 | 1.9
| 30 | 1.4 | 1.9
January 2010 | 3 | 1.0 | 2.0
| 10 | 1.1 | 2.0
| 30 | 1.2 | 1.9
February 2010 | 3 | 1.2 | 1.9
| 10 | 1.4 | 2.0
| 30 | 1.2 | 1.9
March 2010 | 3 | 1.4 | 1.9
| 10 | 1.3 | 2.0
| 30 | 1.3 | 2.0
April 2010 | 3 | 1.1 | 2.0
| 10 | 1.2 | 1.9
| 30 | 1.0 | 2.1
May 2010 | 3 | 1.1 | 2.0
| 10 | 1.3 | 1.9
| 30 | 1.4 | 1.9
June 2010 | 3 | 1.4 | 2.1
| 10 | 1.3 | 1.9
| 30 | 1.4 | 1.9
July 2010 | 3 | 1.2 | 1.9
| 10 | 1.3 | 2.0
| 30 | 1.3 | 2.0
August 2010 | 3 | 1.5 | 2.0
| 10 | 1.4 | 1.9
| 30 | 1.5 | 1.9
September 2010 | 3 | 1.2 | 1.9
| 10 | 1.2 | 1.9
| 30 | 1.3 | 1.8
Range | 3 | 0.9–1.5 | 1.8–2.1
| 10 | 1.0–1.4 | 1.7–2.0
| 30 | 0.9–1.5 | 1.8–2.1

Figure H-1

X-ray Diffraction Pattern of Antimony Trioxide

Figure H-2

Schematic of the Aerosol Generation and Delivery System in the Inhalation Studies of Antimony Trioxide

The exposure chamber configuration shown is for the 2-year studies.