# Appendix G Tissue Burden Results

## G.1 Blood and Lung Deposition and Clearance Equations Used in the Two-week Inhalation Studies of Antimony Trioxide

Lung and blood clearance rates were calculated using Equation (1):

Equation (1): A_(t)_ = A_o_(e^–kt^)

where, A_(t)_ is the lung burden (μg Sb_2_O_3_/lung) or blood concentration (μg Sb/g) at time t (t = 4 weeks postexposure), A_o_ is the lung burden or blood concentration at terminal sacrifice (0 days postexposure), and k is the lung or blood clearance rate constant [fraction cleared per day (day^−1^)].

Lung and blood clearance half-lives in days (t_½_) were calculated from Equation (2), where ln 2 is the Naperian logarithm of 2:

Equation (2): t_½_ = ln 2/k

Deposition rates were calculated from lung burdens using Equation (3). The lung antimony trioxide burden at terminal sacrifice and the calculated lung clearance rate constant were used to solve for the deposition rate, α (μg Sb_2_O_3_/day).

Equation (3):A_(t)_ = α/k(1 – e^–kt^)

In Equation (3), A_(t)_ is the lung burden at time t [t = 16 (rats) or 17 (mice) days on study]; α is the antimony trioxide deposition rate; and k is the first-order clearance rate constant derived from Equation (1). Steady-state or equilibrium lung burdens A_e_ (μg Sb_2_O_3_/lung) were calculated according to Equation (4):

Equation (4): A_e_ = α/k

## G.2 Lung Deposition and Clearance Equations Used in the Two-year Inhalation Studies of Antimony Trioxide

The lung burden model used for these studies assumed a zero-order (constant) deposition rate and a first-order (with respect to lung burden) clearance rate as shown in Equation (5):

Equation (5): L_(t)_ = (D/k)(1 – e^–kt^)

In Equation (5), L_(t)_ is the retained antimony trioxide lung burden (μg Sb_2_O_3_/lung) at any time t (days on study); D represents the deposition rate (μg Sb_2_O_3_/lung per day); and k is the lung clearance rate constant (days^−1^). The equation also contains a boundary condition that at t = 0, the mass of antimony trioxide in the lung is zero.

This model was fit to the antimony trioxide lung burden data collected during the in-life part of the chronic studies. The model was fit to the individual animal data from each exposure group using KaleidaGraph (Synergy Software, Reading, PA). All results are presented from model fits using 1/variance weighting.

The model did not fit the mouse data well; when all the data were included the model would not calculate meaningful deposition and clearance parameters. Accordingly, the mouse data were remodeled excluding the day 551 data, but the model still fit the data poorly and thus no calculated deposition and clearance parameter estimates are provided for the mouse study.

For the rat study, the model fits provided direct estimates of D and k along with their standard errors for each exposure group. Parameters estimated by the model fit were used to calculate additional quantities for each exposure group along with their standard errors using propagation of error techniques and Equations (6) and (7):

Equation (6): t_1/2 _= ln 2/k

Equation (7): L_SS_ = D/k

In Equations (6) and (7), t_1/2_ is the clearance half-life in days; ln 2 is the Naperian logarithm of 2; and L_SS_ is the predicted steady-state lung burden (µg Sb_2_O_3_/lung).

The deposition efficiency (%E) was calculated for each exposure group as defined in Equation (8):

Equation (8): %E = [D/(0.33C × 360)] × 100%

In Equation (8), D is the deposition rate (μg Sb_2_O_3_/lung per day) determined from the model fit; 0.33 is the minute volume of a mature Sprague Dawley rat^73^ in L/minute; C is the exposure concentration (μg Sb_2_O_3_/L); and 360 is the exposure duration in minutes/day. Because their minute volumes are expected to be similar, the minute volume for Sprague Dawley rats was used in the calculations, even though Wistar Han rats were used for the current tissue burden study.

The total lung dose (in mg Sb_2_O_3_/lung) administered to each exposed group was calculated as defined in Equation (9):

Equation (9): Total dose = 551 × D/1,000

In Equation (9), 551 is the total number of study days for tissue burden study rats; D is the deposition rate; and dividing by 1,000 converts from μg to mg. Also calculated for each exposure group was the total amount of antimony trioxide cleared from the lungs during the study, which was the difference between the calculated dose (in mg Sb_2_O_3_/lung) and the calculated lung burden (in mg Sb_2_O_3_/lung) on study day 551. This was expressed as both an absolute value and as a percentage relative to the total dose.

## G.3 Lung Overload Evaluation Used in the Two-year Inhalation Studies of Antimony Trioxide

Lung overload refers to the situation in which respirable, relatively insoluble particles are deposited in the lungs at a rate in excess of the rate at which the alveolar macrophages (AM) can clear the particles from the lung.^74; 75; 105; 106^. Morrow^74^ proposed a mechanism by which such overload may occur. Based on empirical observation, when the volume of particulate material in the lung reaches approximately 6% of the total volume available in the lung AM pool, the mobility of the AM begins to become compromised and lung clearance of deposited particulate material slows. This is a progressive process; as more particulate material is deposited in the lung, the lung AM become increasingly engorged with particles, and AM mediated clearance becomes increasingly slower up to the point where the volume of particulate material in the lung reaches approximately 60% of the total volume available in the AM pool. At this point, AM mediated particle clearance essentially ceases. As clearance slows, the particle burden in the lung continues to increase with increased exposure. Thus, very long lung clearance half-lives and dramatically increased lung burdens are hallmarks of lung overload.

Data on the macrophage pool volume in F344 rat lungs have been reported^74; 107; 108^ based on experimental observations, and similar data have been reported by other investigators using different strains of rat^109; 110^. Morrow^74^ estimated the AM pool in the F344 rat lung is approximately 2.5 × 10^7^ cells, each with a volume of around 1,000 µm^3^/AM. Taking 6% of this volume as 60 µm^3^ and multiplying by the number of cells in the rat lung AM pool, the lung burden volume at which overload begins to occur is 1.5 × 10^9^ µm^3^. The lung burden volume at which clearance ceases is 10 times greater (600 µm^3^/AM) or 1.5 × 10^10^ µm^3^. As pointed out by Morrow^74^, for a particulate material with a density of 1.0 g/cm^3^ the volume of 1.5 × 10^9^ µm^3^ (onset of overload) corresponds to a lung burden of approximately 1.5 mg/lung. Ten times this amount would be a lung burden of 15 mg/lung and would correspond to the condition when the volume of the lung burden is 60% of the available volume in the AM pool (clearance ceases). As burdens increase from 1.5 to 15 mg, particle clearance is expected to become progressively slower.

However, it is noteworthy that the amounts of 1.5 and 15 mg given above apply only to a material of unit density. Because the antimony trioxide used in these studies has a density of 5.47 g/cm^3^ the test chemical occupies a smaller volume per unit mass than a material of unit density. Additionally, the above hypothesis is based on the macrophage population in the lungs of F344 rats. Masse et al.^109^ estimated that the AM population in 300 g Sprague Dawley rats is approximately 3.0 × 10^7^ cells. Thus, the above calculations can be made more specific to the test systems in this study by using the AM volume for the Sprague Dawley rat, which is similar to the Wistar Han, and accounting for the density of antimony trioxide. Assuming a pool of 3.0 × 10^7^ cells, each with a volume of 1,000 µm^3^/cell, gives a total AM pool volume of 3.0 × 10^10^ µm^3^. Using 6% of this the total AM volume gives a volume for onset of overload of 1.8 × 10^9^ µm^3^. Given an antimony trioxide density of 5,470 mg/cm^3^, this would correspond to 9.8 mg of antimony trioxide in the lungs. Similarly 60% of the AM pool volume (where lung clearance ceases) would be 1.8 × 10^10^ µm^3^ and would correspond to an antimony trioxide lung burden of 98 mg.

No literature values for AM populations in mouse lungs were found. The AM population in B6C3F1 mice was estimated to be approximately 4.0 × 10^6^ cells. This value was calculated by multiplying the Sprague Dawley rat AM population by the mean lung weight ratio of B6C3F1 mice to Wistar Han rats from chamber control animals from the 18-month time point in the 2-year antimony trioxide studies. Wistar Han rats were assumed to have a similar AM population as Sprague Dawley rats. Thus, the above calculations can be made more specific to the test systems in this study by using the estimated AM volume for the B6C3F1 mouse and accounting for the density of antimony trioxide. Assuming a pool of 4.0 × 10^6^ cells, each with a volume of 1,000 µm^3^/cell, gives a total AM pool volume of 4.0 × 10^9^ µm^3^. Using 6% of the total AM volume gives a volume for onset of overload of 2.4 × 10^8^ µm^3^. Given an antimony trioxide density of 5,470 mg/cm^3^, this would correspond to 1.3 mg of antimony trioxide in the lungs. Similarly 60% of the AM pool volume (where lung clearance ceases) would be 2.4 × 10^9^ µm^3^ and would correspond to an antimony trioxide lung burden of 13 mg.

As described above a model was fit to the antimony trioxide lung burden data to estimate the deposition and clearance rates of antimony trioxide during the current study. This model was employed to calculate retained lung burdens over the course of the study. In rats, these calculated lung burdens were converted to an equivalent volume of antimony trioxide and compared to the threshold volume required to reach overload. In mice, the mean measured lung burden values at each collection time point were converted to an equivalent volume of antimony trioxide and compared to the threshold volume required to reach overload.

Lung burdens in these tissue burden studies did not achieve steady state, as evidenced by very high lung burdens in both rats and mice by the end of the studies. These results indicated the possibility that lung overload may have occurred in some of the exposed groups, and additional calculations were undertaken to evaluate this possibility. In this evaluation, lung burdens of antimony trioxide at each collection time point were converted to equivalent volumes and surface areas of antimony trioxide and compared to the thresholds required to reach lung overload.

Using Equation (10), the density of antimony trioxide and the measured lung burden were used to calculate the total volume of antimony trioxide (μm^3^) in the lungs for each time point:

Equation (10): V_p_(t) = [10^−3^ × L(t)/ρ] × 10^12^

In Equation (10), V_p_(t) is the volume of the retained lung burden in μm^3^ at any time t (days on study); L(t) is the measured lung burden (converted to mg by multiplying by 10^−3^ mg/μg) at time t; ρ is the density of antimony trioxide (5,470 mg/cm^3^); and the factor 10^12^ converts cm^3^ to μm^3^.

Through an iterative calculation, the ratio R(t) was calculated using Equation (11):

Equation (11): R(t) = V_p_(t)/V*

In Equation (11), V_p_(t) is the volume of retained antimony trioxide lung burden at time t, and V* is the threshold volume required for the onset of lung overload [6% of the alveolar macrophage (AM) pool volume]; V* is estimated to be 1.8 × 10^9^ μm^3^ in the Sprague Dawley rat and 2.4 × 10^8^ µm^3^ in the B6C3F1/N mouse.

These calculated ratios were used to determine the time of onset of lung overload and the extent of overload achieved over the course of the studies. The time of onset of the overload condition (t*, days) was determined as the earliest time (days on study) for which R(t) > 1.0. Thus, t* is the time point when the volume of the lung burden first exceeded 6% of the volume of the AM pool. The maximum value of the ratio (R_max_) was used to determine the extent of overload that occurred by the end of the study. Since lung burdens increased throughout the studies, R_max_ was necessarily the value of R at 551 days on study (the terminal sacrifice for tissue burden study animals).

As noted above, the time point when the volume of retained lung burden first exceeds 6% of the AM pool volume or when the overload condition first occurs during the study is defined at t*. Experimental studies have indicated that this should occur at an antimony trioxide lung burden slightly greater than 9.8 mg/lung in Wistar Han rats and at slightly greater than 1.3 mg/lung in B6C3F1/N mice. R_max_ is the multiplicative factor by which the threshold volumes were exceeded over the duration of the studies. For example, a value of R_max_ of 10 would indicate a lung burden volume that is 60% of the AM pool volume, which would occur near lung burdens of 98 mg Sb_2_O_3_/lung in Wistar Han rats or 13 mg Sb_2_O_3_/lung in B6C3F1/N mice.

As discussed by Tran et al.^76^, in some cases the surface area of the retained lung burden (as opposed to the volume) has been a more robust indicator of whether overload has occurred. In this regard, these investigators determined that the threshold for lung overload in rats occurs when the surface area of the retained lung burden reaches 200 to 300 cm^2^/lung; no corresponding value is available for mice in the literature, but for the current study, the threshold surface area for lung overload in mice was estimated to be 40 cm^2^/lung. This value was calculated by multiplying the threshold surface area value for rats (300 cm^2^/lung) by the mean lung weight ratio of B6C3F1/N mice to Wistar Han rats from chamber control animals in the current 2-year antimony trioxide studies.

The surface area of retained lung burdens was calculated using Equation (12):

Equation (12): α(t) = 2.54[L(t)/10^3^] × 10^4^

In Equation (12), α(t) is the surface area (cm^2^ Sb_2_O_3_/lung) of the retained lung burden at time t (days on study); 2.54 is the specific surface area of the antimony trioxide test chemical in m^2^/g; L(t) is the measured lung burden (mg Sb_2_O_3_/lung) at time t; 10^3^ converts mg to g; and 10^4^ converts m^2^ to cm^2^.

The ratio of α(t) to the determined or estimated threshold surface areas (300 and 40 cm^2^/lung for rats and mice, respectively) was calculated and determined the time point when this ratio first exceeded 1.0 as the time point when the overload threshold surface area was first exceeded. This ratio was also calculated at 551 days to determine to what extent the threshold surface area was exceeded by the end of the study.

Table G-1 Lung Weights, Antimony Concentrations and Burdens, and Antimony Trioxide Burdens for Rats in the Two-week Inhalation Study of Antimony Trioxide^a^

| Chamber Control | 3.75 mg/m^3^ | 7.5 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
n | 5 | 5 | 5 | 5 | 5 | 5
Male
Blood
μg Sb/g blood
Day 16 | 0.020 ± 0.001 | 1.297 ± 0.045** | 2.405 ± 0.141** | 3.967 ± 0.227** | 6.148 ± 0.405** | 11.802 ± 0.649**
μg Sb/g blood per mg Sb_2_O_3_/m^3^
Day 16 | NA | 0.346 ± 0.012 | 0.321 ± 0.019 | 0.264 ± 0.015 | 0.205 ± 0.014 | 0.197 ± 0.011
Lung^b^
Absolute lung wt. (g)
Day 16 | 1.985 ± 0.109 | 1.934 ± 0.144 | 2.043 ± 0.150 | 2.078 ± 0.120 | 2.282 ± 0.186 | 2.559 ± 0.102**
μg Sb/g lung
Day 16 | 0.052 ± 0.010 | 142.568 ± 13.635** | 301.569 ± 25.638** | 546.957 ± 54.568** | 728.835 ± 64.918** | 1,444.030 ± 55.892**
μg Sb/lung
Day 16 | 0.105 ± 0.023 | 270.211 ± 18.232** | 602.680 ± 25.519** | 1,112.528 ± 59.870** | 1,616.755 ± 23.888** | 3,687.600 ± 166.239**
μg Sb_2_O_3_/lung
Day 16 | 0.126 ± 0.028 | 323.490 ± 21.827** | 721.514 ± 30.551** | 1,331.890 ± 71.675** | 1,935.538 ± 28.598** | 4,414.702 ± 199.017**
μg Sb_2_O_3_/lung per mg Sb_2_O_3_/m^3^
Day 16 | NA | 86.264 ± 5.820 | 96.202 ± 4.073 | 88.793 ± 4.778 | 64.518 ± 0.953 | 73.578 ± 3.317
Female
Blood
μg Sb/g blood
Day 16 | 0.027 ± 0.004 | 1.368 ± 0.037** | 2.710 ± 0.084** | 4.473 ± 0.301** | 7.362 ± 0.339** | 13.342 ± 0.850**
Week 4 PE | 0.037 ± 0.007 | 2.594 ± 0.116** | 4.874 ± 0.318** | 7.605 ± 0.318** | 12.174 ± 0.389** | 21.589 ± 1.186**
μg Sb/g blood per mg Sb_2_O_3_/m^3^
Day 16 | NA | 0.365 ± 0.010 | 0.361 ± 0.011 | 0.298 ± 0.020 | 0.245 ± 0.011 | 0.222 ± 0.014
Week 4 PE | NA | 0.692 ± 0.031 | 0.650 ± 0.042 | 0.507 ± 0.021 | 0.406 ± 0.013 | 0.360 ± 0.020
Lung^b^
Absolute lung wt. (g)
Day 16 | 1.394 ± 0.085 | 1.334 ± 0.080 | 1.517 ± 0.145 | 1.511 ± 0.111 | 1.702 ± 0.065* | 1.711 ± 0.095*
Week 4 PE | 1.539 ± 0.133 | 1.736 ± 0.108 | 1.984 ± 0.175* | 2.023 ± 0.066* | 2.309 ± 0.134** | 2.147 ± 0.111**
μg Sb/g lung
Day 16 | 0.042 ± 0.000 | 165.730 ± 10.218** | 338.480 ± 32.598** | 638.542 ± 38.782** | 968.788 ± 51.547** | 1,865.036 ± 81.633**
Week 4 PE | 0.051 ± 0.009 | 108.658 ± 7.337** | 210.955 ± 21.354** | 360.035 ± 10.640** | 612.160 ± 49.834** | 1,201.76 ± 75.166**
μg Sb/lung
Day 16 | 0.059 ± 0.004 | 218.212 ± 6.318** | 495.395 ± 21.259** | 948.774 ± 20.889** | 1,637.570 ± 51.105** | 3,175.977 ± 159.404**
Week 4 PE | 0.078 ± 0.014 | 186.169 ± 7.635** | 404.222 ± 14.954** | 727.562 ± 26.171** | 1,390.39 ± 64.499** | 2,552.45 ± 84.325**
μg Sb_2_O_3_/lung
Day 16 | 0.070 ± 0.004 | 261.238 ± 7.563** | 593.075 ± 25.451** | 1,135.848 ± 25.007** | 1,960.458 ± 61.182** | 3,802.200 ± 190.835**
Week 4 PE | 0.094 ± 0.017 | 222.877 ± 9.141** | 483.924 ± 17.903** | 871.019 ± 31.331** | 1,664.54 ± 77.216** | 3,055.73 ± 100.951**
μg Sb_2_O_3_/lung per mg Sb_2_O_3_/m^3^
Day 16 | NA | 69.663 ± 2.017 | 79.077 ± 3.394 | 75.723 ± 1.667 | 65.349 ± 2.040 | 63.370 ± 3.181
Week 4 PE | NA | 59.434 ± 2.438 | 64.523 ± 2.387 | 58.068 ± 2.089 | 55.485 ± 2.574 | 50.929 ± 1.682

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ test.

** Significantly different (P ≤ 0.01) from the chamber control group by Williams’ test (lung weights) or Shirley’s test (tissue concentrations and burdens).

^a^ Data are presented as mean ± standard error. Statistical tests were performed only on data that were not normalized. NA = not applicable; PE = postexposure.

^b^ Lung burdens were calculated using the weights of the total lung with mainstem bronchi at collection and antimony concentrations measured in the right lung (terminal sacrifice) or the right and left lung (recovery). Lung antimony trioxide burdens (μg Sb_2_O_3_/lung) were calculated by dividing the lung antimony burden (μg Sb/lung) by the fraction of antimony in antimony trioxide (0.8353).

Table G-2 Lung Deposition and Clearance Parameter Estimates for Female Rats in the Two-week Inhalation Study of Antimony Trioxide^a^

Exposure Concentration (mg/m^3^) | k (days^−1^) | t_1/2_ (days) | α (µg Sb_2_O_3_/day) | Ae (µg Sb_2_O_3_)
3.75 | 0.0057 | 122 | 17 | 3,011
7.5 | 0.0073 | 95 | 39 | 5,405
15 | 0.0095 | 73 | 77 | 8,070
30 | 0.0058 | 119 | 128 | 21,962
60 | 0.0078 | 89 | 253 | 32,385

^a^ Statistical analyses of these data were not performed due to the limited number of time points and data points within some time points. K = first-order clearance rate constant; t_½_ = clearance half-life; α = lung deposition rate; A_e_ = steady-state lung burden.

Table G-3 Lung Weights, Antimony Concentrations and Burdens, and Antimony Trioxide Burdens for Female Rats in the Two-year Inhalation Study of Antimony Trioxide^a^

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
n | 5 | 5 | 5 | 5
Blood
μg Sb/g blood
Day 61 | 0.139 ± 0.012 | 7.352 ± 0.375** | 18.079 ± 0.793** | 43.574 ± 1.741**
Day 124 | 0.050 ± 0.002 | 16.135 ± 0.995** | 40.350 ± 1.543** | 96.082 ± 3.940**
Day 271 | 0.077 ± 0.002 | 39.590 ± 3.915** | 88.833 ± 2.210** | 175.437 ± 6.471**
Day 369 | 0.084 ± 0.008 | 50.917 ± 2.296** | 102.083 ± 2.738** | 200.239 ± 10.302**
Day 551 | 0.066 ± 0.005 | 63.297 ± 3.906** | 149.192 ± 8.472**^b^ | 231.934 ± 8.681**
μg Sb/g blood per mg Sb_2_O_3_/m^3^
Day 61 | NA | 2.451 ± 0.125 | 1.808 ± 0.079 | 1.452 ± 0.058
Day 124 | NA | 5.378 ± 0.332 | 4.035 ± 0.154 | 3.203 ± 0.131
Day 271 | NA | 13.197 ± 1.305 | 8.883 ± 0.221 | 5.848 ± 0.216
Day 369 | NA | 16.972 ± 0.765 | 10.208 ± 0.274 | 6.675 ± 0.343
Day 551 | NA | 21.099 ± 1.302 | 14.919 ± 0.847^b^ | 7.731 ± 0.289
Lung^c^
Absolute lung wt. (g)
Day 61 | 1.112 ± 0.041 | 1.558 ± 0.098** | 1.750 ± 0.086** | 1.936 ± 0.069**
Day 124 | 1.356 ± 0.099 | 1.999 ± 0.096** | 2.346 ± 0.050** | 2.851 ± 0.095**
Day 271 | 1.474 ± 0.095 | 2.631 ± 0.177** | 3.374 ± 0.100** | 4.233 ± 0.254**
Day 369 | 1.693 ± 0.174 | 2.990 ± 0.355 | 3.887 ± 0.234** | 5.409 ± 0.778**
Day 551 | 1.539 ± 0.079 | 2.748 ± 0.186 | 5.830 ± 1.106**^b^ | 9.641 ± 1.148**
μg Sb/g lung
Day 61 | 0.128 ± 0.046 | 436.686 ± 14.015** | 1,202.69 ± 51.447** | 2,894.85 ± 87.000**
Day 124 | 0.042 ± 0.000 | 689.305 ± 49.265** | 1,571.00 ± 59.097** | 3,750.99 ± 144.557**
Day 271 | 0.285 ± 0.074 | 837.475 ± 40.496** | 1,983.17 ± 92.267** | 4,610.22 ± 363.095**
Day 369 | 0.302 ± 0.031 | 765.002 ± 179.148** | 1,976.06 ± 92.704** | 4,256.31 ± 344.828**
Day 551 | 0.163 ± 0.020 | 978.770 ± 86.114** | 1,801.06 ± 277.723**^b^ | 3,261.79 ± 535.308**
μg Sb/lung
Day 61 | 0.146 ± 0.055 | 677.161 ± 35.177** | 2,098.68 ± 104.802** | 5,589.54 ± 158.053**
Day 124 | 0.057 ± 0.004 | 1,360.25 ± 48.652** | 3,686.32 ± 157.588** | 10,706.2 ± 596.172**
Day 271 | 0.427 ± 0.113 | 2,190.88 ± 143.007** | 6,675.12 ± 264.985** | 19,215.3 ± 924.889**
Day 369 | 0.493 ± 0.021 | 2,052.99 ± 136.950** | 7,596.49 ± 167.389** | 22,447.0 ± 2,309.92**
Day 551 | 0.249 ± 0.025 | 2,631.38 ± 129.598** | 9,599.82 ± 393.455**^b^ | 29,011.6 ± 1,437.94**
μg Sb_2_O_3_/lung
Day 61 | 0.175 ± 0.066 | 810.681 ± 42.113** | 2,512.49 ± 125.466** | 6,691.65 ± 189.217**
Day 124 | 0.068 ± 0.005 | 1,628.46 ± 58.245** | 4,413.16 ± 188.660** | 12,817.1 ± 713.722**
Day 271 | 0.512 ± 0.135 | 2,622.87 ± 171.204** | 7,991.29 ± 317.233** | 23,004.1 ± 1,107.25**
Day 369 | 0.591 ± 0.025 | 2,457.79 ± 163.953** | 9,094.32 ± 200.394** | 26,873.0 ± 2,765.38**
Day 551 | 0.298 ± 0.030 | 3,150.22 ± 155.152** | 11,492.7 ± 471.034**^b^ | 34,731.9 ± 1,721.47**
μg Sb_2_O_3_/lung per mg Sb_2_O_3_/m^3^
Day 61 | NA | 270.227 ± 14.038 | 251.249 ± 12.547 | 223.055 ± 6.307
Day 124 | NA | 542.819 ± 19.415 | 441.316 ± 18.866 | 427.238 ± 23.791
Day 271 | NA | 874.288 ± 57.068 | 799.129 ± 31.723 | 766.803 ± 36.908
Day 369 | NA | 819.264 ± 54.651 | 909.432 ± 20.039 | 895.765 ± 92.179
Day 551 | NA | 1,050.07 ± 51.717 | 1,149.27 ± 47.103^b^ | 1,157.73 ± 57.382

** Significantly different (P ≤ 0.01) from the chamber control group by Williams’ test (lung weights) or Shirley’s test (tissue concentrations and burdens).

^a^ Data are presented as mean ± standard error. Statistical tests were performed only on data that were not normalized. NA = not applicable.

^b^ n = 4.

^c^ Lung burdens were calculated using the weights of the total lung with mainstem bronchi at collection and measured concentrations of antimony in the total lung. Lung antimony trioxide burdens (μg Sb_2_O_3_/lung) were calculated by dividing the lung antimony burden (μg Sb/lung) by the fraction of antimony in antimony trioxide (0.8353).

Table G-4 Lung Deposition and Clearance Parameter Estimates for Female Rats in the Two-year Inhalation Study of Antimony Trioxide^a^

Parameter | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
D (µg Sb_2_O_3_/total lung per day) | 16.7 ± 0.7 | 44.2 ± 1.9 | 119.1 ± 3.8
k (days^−1^) | 0.0051 ± 0.0005 | 0.0034 ± 0.0003 | 0.0026 ± 0.0003
t_½_ (days) | 136 ± 11 | 203 ± 18 | 262 ± 26
Lss (µg Sb_2_O_3_/total lung) | 3,281 ± 326 | 12,964 ± 1,348 | 44,997 ± 5,226

^a^ Data are presented as mean ± standard error. D = deposition rate; k = first-order lung clearance rate constant; t_½_ = lung clearance half-life; L_SS_ = steady-state lung burden.

Table G-5 Lung Burden Overload Parameter Estimates for Female Rats in the Two-year Inhalation Study of Antimony Trioxide

Parameter | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
t* = Time when R(t) > 1 (days) | NA | 418 | 94
L(t*) = lung burden at t* (mg Sb_2_O_3_/lung) | NA | 9.8 | 9.9
Rmax = maximum R(t) at 551 days (unitless) | 0.3 | 1.1 | 3.5
Lung burden at Rmax = L(t) at 551 days (mg Sb_2_O_3_/lung) | 3.1 | 11.0 | 34.5
Total dose = deposited Sb_2_O_3_ at 551 days (mg/lung) | 9.2 | 24.4 | 65.6
Total Sb_2_O_3_ cleared = cleared Sb_2_O_3_ up through 551 days (mg/lung) | 6.1 | 13.4 | 31.1
% Total Sb_2_O_3_ cleared = total Sb_2_O_3_ cleared/total dose) × 100 (unitless) | 66 | 55 | 47

R(t) = ratio of the volume of retained Sb_2_O_3_ lung burden at time t to the threshold volume required for the onset of lung overload; NA = not applicable.

Table G-6 Lung Weights, Antimony Concentrations and Burdens, and Antimony Trioxide Burdens for Mice in the Two-week Inhalation Study of Antimony Trioxide^a^

| Chamber Control | 3.75 mg/m^3^ | 7.5 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
n | 5 | 5 | 5 | 5 | 5 | 5
Male
Blood
μg Sb/g blood
Day 17 | 0.001 ± 0.000 | 0.023 ± 0.001**^b^ | 0.040 ± 0.002**^b^ | 0.061 ± 0.001** | 0.084 ± 0.001** | 0.178 ± 0.066**^b^
μg Sb/g blood per mg Sb_2_O_3_/m^3^
Day 17 | NA | 0.006 ± 0.000b | 0.005 ± 0.000b | 0.004 ± 0.000 | 0.003 ± 0.000 | 0.003 ± 0.001b
Lung^c^
Absolute lung wt. (g)
Day 17 | 0.174 ± 0.008 | 0.205 ± 0.021 | 0.217 ± 0.013* | 0.210 ± 0.010* | 0.208 ± 0.009* | 0.231 ± 0.005**
μg Sb/g lung
Day 17 | 0.455 ± 0.000 | 317.011 ± 34.763** | 574.255 ± 39.327** | 1,229.622 ± 63.691** | 2,010.842 ± 69.131** | 3,572.798 ± 153.853**
μg Sb/lung
Day 17 | 0.079 ± 0.004 | 62.195 ± 3.222** | 122.395 ± 3.209** | 255.787 ± 9.064** | 415.521 ± 5.836** | 825.632 ± 32.596**
μg Sb_2_O_3_/lung
Day 17 | 0.095 ± 0.004 | 74.459 ± 3.857** | 146.528 ± 3.843** | 306.222 ± 10.851** | 497.451 ± 6.987** | 988.425 ± 39.023**
μg Sb_2_O_3_/lung per mg Sb_2_O_3_/m^3^
Day 17 | NA | 19.856 ± 1.029 | 19.537 ± 0.512 | 20.415 ± 0.723 | 16.582 ± 0.233 | 16.474 ± 0.650
Female
Blood
μg Sb/g blood
Day 17 | 0.001 ± 0.000b | 0.027 ± 0.001* | 0.042 ± 0.001** | 0.070 ± 0.006** | 0.088 ± 0.004**b | 0.140 ± 0.016**
Week 4 PE | 0.001 ± 0.000 | 0.011 ± 0.001** | 0.021 ± 0.000** | 0.034 ± 0.001** | 0.048 ± 0.002** | 0.068 ± 0.002**
μg Sb/g blood per mg Sb/m^3^
Day 17 | NA | 0.007 ± 0.000 | 0.006 ± 0.000 | 0.005 ± 0.000 | 0.003 ± 0.000b | 0.002 ± 0.000
Week 4 PE | NA | 0.003 ± 0.000 | 0.003 ± 0.000 | 0.002 ± 0.000 | 0.002 ± 0.000 | 0.001 ± 0.000
Lung^c^
Absolute lung wt. (g)
Day 17 | 0.162 ± 0.004 | 0.182 ± 0.006 | 0.180 ± 0.004 | 0.200 ± 0.007** | 0.203 ± 0.005** | 0.218 ± 0.010**
Week 4 PE | 0.200 ± 0.008 | 0.181 ± 0.004 | 0.204 ± 0.008 | 0.255 ± 0.023** | 0.271 ± 0.004** | 0.342 ± 0.009**
μg Sb/g lung
Day 17 | 0.455 ± 0.000 | 294.205 ± 16.022** | 635.327 ± 18.297** | 1,073.105 ± 28.121**^b^ | 1,871.826 ± 80.026** | 3,111.101 ± 173.398**
Week 4 PE | 0.637 ± 0.182 | 194.627 ± 5.879** | 409.191 ± 19.625** | 613.924 ± 54.525** | 1,011.90 ± 27.660** | 1,408.27 ± 58.728**
μg Sb/lung
Day 17 | 0.074 ± 0.002 | 53.307 ± 2.208** | 113.836 ± 1.662** | 213.298 ± 11.923**^b^ | 381.127 ± 23.682** | 673.947 ± 28.796**
Week 4 PE | 0.131 ± 0.042 | 35.247 ± 0.943** | 83.042 ± 1.892** | 151.673 ± 4.355** | 273.437 ± 4.895** | 480.060 ± 12.981**
μg Sb_2_O_3_/lung
Day 17 | 0.088 ± 0.002 | 63.818 ± 2.643** | 136.282 ± 1.990** | 255.355 ± 14.274**^b^ | 456.276 ± 28.351** | 806.832 ± 34.474**
Week 4 PE | 0.157 ± 0.051 | 42.197 ± 1.129** | 99.415 ± 2.265** | 181.579 ± 5.214** | 327.351 ± 5.860** | 574.715 ± 15.541**
μg Sb_2_O_3_/g lung per mg Sb_2_O_3_/m^3^
Day 17 | NA | 17.018 ± 0.705 | 18.171 ± 0.265 | 17.024 ± 0.952b | 15.209 ± 0.945 | 13.447 ± 0.575
Week 4 PE | NA | 11.253 ± 0.301 | 13.255 ± 0.302 | 12.105 ± 0.348 | 10.912 ± 0.195 | 9.578 ± 0.259

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ test (lung weights) or Shirley’s test (tissue concentrations and burdens).

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed only on data that were not normalized. NA = not applicable; PE = postexposure.

^b^ n = 4.

^c^ Lung burdens were calculated using the weights of the total lung with mainstem bronchi at collection and antimony concentrations measured in the right lung (terminal sacrifice) or the right and left lung (recovery). Lung antimony trioxide burdens (μg Sb_2_O_3_/lung) were calculated by dividing the lung antimony burden (μg Sb/lung) by the fraction of antimony in antimony trioxide (0.8353).

Table G-7 Blood and Lung Deposition and Clearance Parameter Estimates for Female Mice in the Two-week Inhalation Study of Antimony Trioxide^a^

Tissue | Exposure Concentration (mg/m^3^) | k (days^−1^) | t_1/2_ (days) | α (µg Sb_2_O_3_/day) | A_e_ (µg Sb_2_O_3_)
Blood | 3.75 | 0.032 | 22 | NA | NA
| 7.5 | 0.026 | 27 | NA | NA
| 15 | 0.026 | 27 | NA | NA
| 30 | 0.022 | 32 | NA | NA
| 60 | 0.026 | 27 | NA | NA
Lung | 3.75 | 0.015 | 47 | 4 | 287
| 7.5 | 0.011 | 62 | 9 | 782
| 15 | 0.012 | 57 | 17 | 1,366
| 30 | 0.012 | 58 | 30 | 2,499
| 60 | 0.012 | 57 | 53 | 4,335

^a^ Statistical analyses of these data were not performed due to the limited number of time points and data points within some time points. k = first-order clearance rate constant; t_½_ = clearance half-life; α = lung deposition rate; A_e_ = steady-state lung burden; NA = not applicable.

Table G-8 Lung Weights, Antimony Concentrations and Burdens, and Antimony Trioxide Burdens for Female Mice in the Two-year Inhalation Study of Antimony Trioxide^a^

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
n | 5 | 5 | 5 | 5
Blood
μg Sb/g blood
Day 61 | 0.001 ± 0.000 | 0.043 ± 0.002** | 0.083 ± 0.002** | 0.141 ± 0.003**
Day 124 | 0.001 ± 0.001 | 0.058 ± 0.001** | 0.089 ± 0.002** | 0.148 ± 0.005**
Day 269 | 0.001 ± 0.000 | 0.053 ± 0.006** | 0.091 ± 0.002** | 0.163 ± 0.008**^b^
Day 369 | 0.001 ± 0.000 | 0.052 ± 0.003** | 0.088 ± 0.003** | 0.137 ± 0.007**
Day 551 | 0.001 ± 0.000 | 0.061 ± 0.010** | 0.087 ± 0.004** | 0.163 ± 0.006**^b^
μg Sb/g blood per mg Sb_2_O_3_/m^3^
Day 61 | NA | 0.014 ± 0.001 | 0.008 ± 0.000 | 0.005 ± 0.000
Day 124 | NA | 0.019 ± 0.000 | 0.009 ± 0.000 | 0.005 ± 0.000
Day 269 | NA | 0.017 ± 0.002 | 0.009 ± 0.000 | 0.005 ± 0.000^b^
Day 369 | NA | 0.017 ± 0.001 | 0.009 ± 0.000 | 0.005 ± 0.000
Day 551 | NA | 0.020 ± 0.003 | 0.009 ± 0.000 | 0.005 ± 0.000^b^
Lung^c^
Absolute lung wt. (g)
Day 61 | 0.202 ± 0.006 | 0.263 ± 0.008** | 0.335 ± 0.017** | 0.398 ± 0.008**
Day 124 | 0.182 ± 0.003 | 0.279 ± 0.014** | 0.367 ± 0.004** | 0.517 ± 0.020**
Day 269 | 0.184 ± 0.008 | 0.268 ± 0.006* | 0.353 ± 0.005** | 0.646 ± 0.056**^b^
Day 369 | 0.187 ± 0.003 | 0.281 ± 0.009** | 0.354 ± 0.012** | 0.701 ± 0.025**
Day 551 | 0.204 ± 0.006 | 0.306 ± 0.022** | 0.435 ± 0.032** | 0.617 ± 0.026**^b^
μg Sb/g lung
Day 61 | 0.455 ± 0.000 | 560.526 ± 11.741** | 1,233.12 ± 42.424** | 2,687.32 ± 56.076**
Day 124 | 0.455 ± 0.000 | 682.534 ± 59.310** | 1,475.78 ± 32.782** | 2,954.05 ± 95.408**
Day 269 | 0.455 ± 0.000 | 801.719 ± 22.118** | 2,678.08 ± 135.202** | 4,132.91 ± 667.094**^b^
Day 369 | 0.455 ± 0.000 | 978.803 ± 53.661** | 3,797.88 ± 231.550** | 3,892.00 ± 248.070**
Day 551 | 0.455 ± 0.000 | 1,471.76 ± 115.654** | 4,188.07 ± 608.706** | 8,398.33 ± 609.402**^b^
μg Sb/lung
Day 61 | 0.092 ± 0.003 | 146.980 ± 3.155** | 410.431 ± 12.314** | 1,069.07 ± 32.882**
Day 124 | 0.083 ± 0.001 | 187.387 ± 8.950** | 541.373 ± 15.157** | 1,532.01 ± 95.506**
Day 269 | 0.084 ± 0.004 | 215.420 ± 9.629** | 943.736 ± 40.072** | 2,558.37 ± 180.94**^b^
Day 369 | 0.085 ± 0.002 | 275.448 ± 18.393** | 1,336.04 ± 56.473** | 2,716.81 ± 157.964**
Day 551 | 0.093 ± 0.003 | 441.294 ± 13.534** | 1,744.56 ± 188.559** | 5,136.49 ± 155.895**^b^
μg Sb_2_O_3_/lung
Day 61 | 0.110 ± 0.004 | 175.960 ± 3.777** | 491.358 ± 14.741** | 1,279.86 ± 39.365**
Day 124 | 0.099 ± 0.002 | 224.335 ± 10.714** | 648.118 ± 18.146** | 1,834.09 ± 114.338**
Day 269 | 0.100 ± 0.004 | 257.896 ± 11.527** | 1,129.82 ± 47.974** | 3,062.82 ± 216.617**^b^
Day 369 | 0.102 ± 0.002 | 329.760 ± 22.020** | 1,599.48 ± 67.608** | 3,252.50 ± 189.110**
Day 551 | 0.111 ± 0.003 | 528.306 ± 16.202** | 2,088.54 ± 225.738** | 6,149.27 ± 186.634**^b^
μg Sb_2_O_3_/lung per mg Sb_2_O_3_/m^3^
Day 61 | NA | 58.653 ± 1.259 | 49.136 ± 1.474 | 42.662 ± 1.312
Day 124 | NA | 74.778 ± 3.571 | 64.812 ± 1.815 | 61.136 ± 3.811
Day 269 | NA | 85.965 ± 3.842 | 112.982 ± 4.797 | 102.094 ± 7.221^b^
Day 369 | NA | 109.920 ± 7.340 | 159.948 ± 6.761 | 108.417 ± 6.304
Day 551 | NA | 176.102 ± 5.401 | 208.854 ± 22.574 | 204.976 ± 6.221^b^

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ test.

** Significantly different (P ≤ 0.01) from the chamber control group by Williams’ test (lung weights) or Shirley’s test (tissue concentrations and burdens).

^a^ Data are presented as mean ± standard error. Statistical tests were performed only on data that were not normalized. NA = not applicable.

^b^ n = 4.

^c^ Lung burdens were calculated using the weights of the total lung with mainstem bronchi at collection and measured concentrations of antimony in the total lung. Lung antimony trioxide burdens (μg Sb_2_O_3_/lung) were calculated by dividing the lung antimony burden (μg Sb/lung) by the fraction of antimony in antimony trioxide (0.8353).

Table G-9 Retained Lung Antimony Trioxide Burden Volumes and Surface Areas in Female Mice in the Two-year Inhalation Study of Antimony Trioxide

Parameter | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Volume of retained lung burden (µm^3^ Sb_2_O_3_/lung)
Day 61 | 3.22 × 107 | 8.98 × 107 | 2.34 × 108
Day 124 | 4.10 × 107 | 1.18 × 108 | 3.35 × 108
Day 269 | 4.71 × 107 | 1.98 × 108 | 5.60 × 108
Day 369 | 6.03 × 107 | 2.92 × 108 | 5.95 × 108
Day 551 | 9.66 × 107 | 4.23 × 108 | 1.12 × 109
Ratio of retained volume to threshold volume (µm^3^ Sb_2_O_3_/lung)/(2.4 × 108 µm^3^)^a^
Day 61 | 0.13 | 0.37 | 0.97
Day 124 | 0.17 | 0.49 | 1.40
Day 269 | 0.20 | 0.82 | 2.33
Day 369 | 0.25 | 1.22 | 2.48
Day 551 | 0.40 | 1.76 | 4.68
Surface area of retained lung burden (cm^2^ Sb_2_O_3_/lung)
Day 61 | 4 | 12 | 33
Day 124 | 6 | 16 | 47
Day 269 | 7 | 27 | 78
Day 369 | 8 | 41 | 83
Day 551 | 13 | 59 | 156
Ratio of retained surface area to threshold surface area (cm^2^ Sb_2_O_3_/lung)/(40 cm^2^/lung)^b^
Day 61 | 0.11 | 0.31 | 0.81
Day 124 | 0.14 | 0.41 | 1.16
Day 269 | 0.16 | 0.69 | 1.94
Day 369 | 0.21 | 1.02 | 2.07
Day 551 | 0.34 | 1.47 | 3.90

^a^ 2.4 × 10^8^ µm^3^ is the estimated threshold alveolar macrophage pool volume when overload should occur.

^b^ 40 cm^2^/lung is the estimated threshold lung surface area when overload should occur.

Figure G-1

Lung Antimony Trioxide Burdens in 3, 10, and 30 mg/m3 Female Rats in the Two-year Inhalation Study of Antimony Trioxide

The lines represent the fit of the lung deposition and clearance model to the data.

Figure G-2

Lung Antimony Trioxide Burdens in 3 mg/m^3^ Female Mice in the Two-year Inhalation Study of Antimony Trioxide Including All Time Points (Top) and with Day 551 Data Removed (Bottom)

The lines represent the fit of the lung deposition and clearance model to the data.

Figure G-3

Lung Antimony Trioxide Burdens in 10 mg/m^3^ Female Mice in the Two-year Inhalation Study of Antimony Trioxide Including All Time Points (Top) and with Day 551 Data Removed (Bottom)

The lines represent the fit of the lung deposition and clearance model to the data.

Figure G-4

Lung Antimony Trioxide Burdens in 30 mg/m^3^ Female Mice in the Two-year Inhalation Study of Antimony Trioxide Including All Time Points (Top) and with Day 551 Data Removed (Bottom)

The lines represent the fit of the lung deposition and clearance model to the data.