# Appendix F Organ Weights and Organ-Weight-To-Body-Weight Ratios

Table F-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Two-week Inhalation Study of Antimony Trioxide^a^

| Chamber Control | 3.75 mg/m^3^ | 7.5 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
n | 5 | 5 | 5 | 5 | 5 | 5
Male
Necropsy body wt. | 227 ± 6 | 217 ± 5 | 226 ± 5 | 220 ± 5 | 210 ± 7 | 224 ± 9
Heart
Absolute | 0.91 ± 0.03 | 0.85 ± 0.04 | 0.87 ± 0.02 | 0.87 ± 0.02 | 0.83 ± 0.03 | 0.85 ± 0.02
Relative | 4.033 ± 0.157 | 3.910 ± 0.123 | 3.848 ± 0.092 | 3.975 ± 0.113 | 3.982 ± 0.109 | 3.790 ± 0.079
R. Kidney
Absolute | 0.99 ± 0.04 | 0.94 ± 0.03 | 0.99 ± 0.04 | 0.96 ± 0.04 | 0.91 ± 0.03 | 0.98 ± 0.04
Relative | 4.370 ± 0.142 | 4.338 ± 0.054 | 4.406 ± 0.199 | 4.357 ± 0.139 | 4.362 ± 0.090 | 4.368 ± 0.039
Liver
Absolute | 10.05 ± 0.25 | 8.53 ± 0.32 | 8.84 ± 0.39 | 8.55 ± 0.47 | 8.56 ± 0.56 | 9.40 ± 0.41
Relative | 44.330 ± 1.402 | 39.406 ± 1.436 | 39.133 ± 1.363* | 38.715 ± 1.306* | 40.698 ± 1.534 | 41.859 ± 0.728
Lung
Absolute | 1.99 ± 0.11 | 1.93 ± 0.14 | 2.04 ± 0.15 | 2.08 ± 0.12 | 2.28 ± 0.19 | 2.56 ± 0.10**
Relative | 8.758 ± 0.530 | 8.919 ± 0.592 | 9.038 ± 0.609 | 9.416 ± 0.402 | 10.871 ± 0.806* | 11.423 ± 0.351**
R. Testis
Absolute | 1.465 ± 0.034 | 1.312 ± 0.056 | 1.420 ± 0.045 | 1.404 ± 0.052 | 1.293 ± 0.047 | 1.443 ± 0.078
Relative | 6.458 ± 0.157 | 6.051 ± 0.184 | 6.287 ± 0.124 | 6.382 ± 0.239 | 6.195 ± 0.294 | 6.436 ± 0.267
Thymus
Absolute | 0.759 ± 0.068 | 0.698 ± 0.030 | 0.896 ± 0.075 | 0.731 ± 0.053 | 0.739 ± 0.029 | 0.792 ± 0.044
Relative | 3.346 ± 0.303 | 3.236 ± 0.176 | 3.953 ± 0.287 | 3.308 ± 0.178 | 3.525 ± 0.066 | 3.559 ± 0.290
Female
Necropsy body wt. | 158 ± 3 | 160 ± 3 | 160 ± 3 | 156 ± 5 | 156 ± 1 | 158 ± 7
Heart
Absolute | 0.67 ± 0.02 | 0.64 ± 0.03 | 0.66 ± 0.01 | 0.63 ± 0.02 | 0.67 ± 0.02 | 0.64 ± 0.03
Relative | 4.226 ± 0.072 | 4.007 ± 0.108 | 4.115 ± 0.149 | 4.045 ± 0.069 | 4.308 ± 0.110 | 4.064 ± 0.106
R. Kidney
Absolute | 0.72 ± 0.02 | 0.67 ± 0.03 | 0.72 ± 0.02 | 0.67 ± 0.02 | 0.70 ± 0.03 | 0.75 ± 0.03
Relative | 4.545 ± 0.061 | 4.194 ± 0.099 | 4.544 ± 0.211 | 4.299 ± 0.064 | 4.501 ± 0.207 | 4.803 ± 0.155
Liver
Absolute | 5.96 ± 0.14 | 5.62 ± 0.32 | 5.96 ± 0.23 | 5.68 ± 0.21 | 5.78 ± 0.15 | 5.93 ± 0.31
Relative | 37.850 ± 0.518 | 35.041 ± 1.537 | 37.401 ± 2.077 | 36.303 ± 0.606 | 37.070 ± 0.918 | 37.602 ± 0.881
Lung
Absolute | 1.39 ± 0.09 | 1.33 ± 0.08 | 1.52 ± 0.15 | 1.51 ± 0.11 | 1.70 ± 0.07* | 1.71 ± 0.10*
Relative | 8.849 ± 0.511 | 8.320 ± 0.391 | 9.508 ± 0.927 | 9.626 ± 0.445 | 10.911 ± 0.385* | 10.865 ± 0.388*
Thymus
Absolute | 0.614 ± 0.040 | 0.570 ± 0.027 | 0.619 ± 0.056 | 0.567 ± 0.037 | 0.588 ± 0.019 | 0.633 ± 0.056
Relative | 3.909 ± 0.286 | 3.555 ± 0.116 | 3.889 ± 0.391 | 3.615 ± 0.144 | 3.774 ± 0.121 | 3.995 ± 0.212

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table F-2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats at the 12-month Interim Evaluation in the Two-year Inhalation Study of Antimony Trioxide^a^

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
n | 10 | 10 | 10 | 10
Male
Necropsy body wt. | 522 ± 16 | 531 ± 17 | 540 ± 20 | 534 ± 13
Heart
Absolute | 1.21 ± 0.05 | 1.24 ± 0.04 | 1.21 ± 0.02 | 1.29 ± 0.05
Relative | 2.321 ± 0.053 | 2.337 ± 0.077 | 2.252 ± 0.073 | 2.410 ± 0.070
R. Kidney
Absolute | 1.42 ± 0.04 | 1.39 ± 0.05 | 1.49 ± 0.05 | 1.46 ± 0.03
Relative | 2.724 ± 0.080 | 2.623 ± 0.073 | 2.769 ± 0.105 | 2.746 ± 0.062
Liver
Absolute | 14.08 ± 0.64 | 14.78 ± 0.43 | 15.81 ± 0.61 | 15.75 ± 0.70
Relative | 26.908 ± 0.582 | 27.910 ± 0.458 | 29.294 ± 0.508* | 29.452 ± 0.886**
Lung
Absolute | 2.79 ± 0.18 | 3.65 ± 0.19* | 4.32 ± 0.28** | 6.57 ± 0.29**
Relative | 5.368 ± 0.326 | 6.897 ± 0.312* | 8.040 ± 0.490** | 12.313 ± 0.484**
R. Testis
Absolute | 1.854 ± 0.113 | 1.628 ± 0.177 | 1.917 ± 0.055 | 1.958 ± 0.055
Relative | 3.559 ± 0.198 | 3.071 ± 0.329 | 3.592 ± 0.173 | 3.683 ± 0.113
Thymus
Absolute | 0.474 ± 0.037 | 0.512 ± 0.025 | 0.508 ± 0.028 | 0.477 ± 0.020
Relative | 0.906 ± 0.057 | 0.977 ± 0.063 | 0.946 ± 0.054 | 0.896 ± 0.038
Female
Necropsy body wt. | 278 ± 10 | 293 ± 11 | 272 ± 7 | 278 ± 6
Heart
Absolute | 0.82 ± 0.03 | 0.86 ± 0.03 | 0.82 ± 0.02 | 0.85 ± 0.03
Relative | 2.957 ± 0.075 | 2.956 ± 0.076 | 3.030 ± 0.054 | 3.052 ± 0.037
R. Kidney
Absolute | 0.91 ± 0.02 | 0.96 ± 0.02 | 0.92 ± 0.03 | 0.93 ± 0.03
Relative | 3.309 ± 0.104 | 3.294 ± 0.119 | 3.381 ± 0.078 | 3.342 ± 0.058
Liver
Absolute | 7.61 ± 0.19 | 8.54 ± 0.35 | 7.97 ± 0.41 | 7.81 ± 0.25
Relative | 27.588 ± 0.781 | 29.218 ± 0.728 | 29.201 ± 1.044 | 28.087 ± 0.629
Lung
Absolute | 1.78 ± 0.09 | 2.89 ± 0.16** | 4.20 ± 0.22** | 5.48 ± 0.28**
Relative | 6.451 ± 0.335 | 9.898 ± 0.448** | 15.528 ± 0.975** | 19.719 ± 0.901**
Thymus
Absolute | 0.346 ± 0.025 | 0.348 ± 0.024 | 0.343 ± 0.018 | 0.346 ± 0.017
Relative | 1.246 ± 0.074 | 1.184 ± 0.057 | 1.264 ± 0.071 | 1.245 ± 0.056

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table F-3 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Two-week Inhalation Study of Antimony Trioxide^a^

| Chamber Control | 3.75 mg/m^3^ | 7.5 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
n | 5 | 5 | 5 | 5 | 5 | 5
Male
Necropsy body wt. | 25.0 ± 0.2 | 25.3 ± 0.1 | 26.4 ± 0.5 | 25.9 ± 0.6 | 25.5 ± 0.6 | 26.6 ± 0.8
Heart
Absolute | 0.12 ± 0.00 | 0.13 ± 0.00 | 0.13 ± 0.01 | 0.13 ± 0.01 | 0.12 ± 0.01 | 0.12 ± 0.00
Relative | 4.796 ± 0.114 | 4.973 ± 0.162 | 4.838 ± 0.141 | 4.999 ± 0.176 | 4.704 ± 0.137 | 4.598 ± 0.143
R. Kidney
Absolute | 0.21 ± 0.01 | 0.23 ± 0.00 | 0.23 ± 0.01 | 0.24 ± 0.02 | 0.21 ± 0.01 | 0.23 ± 0.01
Relative | 8.390 ± 0.169 | 8.999 ± 0.093 | 8.849 ± 0.181 | 9.071 ± 0.397 | 8.315 ± 0.153 | 8.653 ± 0.259
Liver
Absolute | 1.20 ± 0.04 | 1.12 ± 0.03 | 1.19 ± 0.05 | 1.21 ± 0.08 | 1.11 ± 0.06 | 1.16 ± 0.03
Relative | 47.938 ± 1.448 | 44.364 ± 1.189 | 45.125 ± 1.498 | 46.366 ± 2.182 | 43.536 ± 1.251 | 43.723 ± 1.222
Lung
Absolute | 0.17 ± 0.01 | 0.21 ± 0.02 | 0.22 ± 0.01* | 0.21 ± 0.01* | 0.21 ± 0.01* | 0.23 ± 0.01**
Relative | 6.939 ± 0.267 | 8.086 ± 0.835 | 8.184 ± 0.443 | 8.076 ± 0.321 | 8.147 ± 0.232 | 8.725 ± 0.209**
R. Testis
Absolute | 0.096 ± 0.002 | 0.094 ± 0.002 | 0.094 ± 0.002 | 0.096 ± 0.005 | 0.091 ± 0.003 | 0.099 ± 0.002
Relative | 3.827 ± 0.066 | 3.709 ± 0.068 | 3.574 ± 0.145 | 3.714 ± 0.204 | 3.572 ± 0.145 | 3.733 ± 0.084
Thymus
Absolute | 0.040 ± 0.004 | 0.045 ± 0.004 | 0.049 ± 0.004 | 0.046 ± 0.004 | 0.048 ± 0.005 | 0.052 ± 0.004
Relative | 1.589 ± 0.143 | 1.768 ± 0.155 | 1.844 ± 0.159 | 1.772 ± 0.156 | 1.882 ± 0.208 | 1.948 ± 0.131
Female
Necropsy body wt. | 21.2 ± 0.3 | 20.9 ± 0.2 | 20.6 ± 0.4 | 20.9 ± 0.2 | 21.0 ± 0.3 | 21.1 ± 0.4
Heart
Absolute | 0.11 ± 0.00 | 0.11 ± 0.00 | 0.11 ± 0.00 | 0.12 ± 0.00 | 0.11 ± 0.00 | 0.11 ± 0.00
Relative | 5.187 ± 0.103 | 5.369 ± 0.072 | 5.363 ± 0.219 | 5.645 ± 0.199 | 5.235 ± 0.146 | 5.216 ± 0.101
R. Kidney
Absolute | 0.16 ± 0.01 | 0.16 ± 0.00 | 0.16 ± 0.00 | 0.16 ± 0.00 | 0.17 ± 0.00 | 0.16 ± 0.00
Relative | 7.455 ± 0.264 | 7.579 ± 0.200 | 7.800 ± 0.316 | 7.656 ± 0.217 | 7.901 ± 0.118 | 7.776 ± 0.178
Liver
Absolute | 1.00 ± 0.04 | 0.93 ± 0.03 | 0.93 ± 0.03 | 1.02 ± 0.02 | 0.99 ± 0.02 | 1.03 ± 0.03
Relative | 46.932 ± 1.037 | 44.760 ± 1.054 | 45.306 ± 0.747 | 48.750 ± 0.409 | 47.003 ± 0.565 | 48.841 ± 0.663
Lung
Absolute | 0.16 ± 0.00 | 0.18 ± 0.01 | 0.18 ± 0.00 | 0.20 ± 0.01** | 0.20 ± 0.01** | 0.22 ± 0.01**
Relative | 7.656 ± 0.185 | 8.736 ± 0.336* | 8.734 ± 0.131* | 9.546 ± 0.308** | 9.659 ± 0.229** | 10.320 ± 0.397**
Thymus
Absolute | 0.074 ± 0.002 | 0.071 ± 0.002 | 0.067 ± 0.003 | 0.067 ± 0.005 | 0.072 ± 0.005 | 0.075 ± 0.003
Relative | 3.481 ± 0.083 | 3.412 ± 0.093 | 3.257 ± 0.099 | 3.194 ± 0.261 | 3.410 ± 0.226 | 3.558 ± 0.117

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table F-4 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice at the 12-month Interim Evaluation in the Two-year Inhalation Study of Antimony Trioxide^a^

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
n | 10 | 10 | 10 | 10
Male
Necropsy body wt. | 51.4 ± 0.3 | 51.3 ± 0.9 | 51.5 ± 0.6 | 51.9 ± 0.8
Heart
Absolute | 0.21 ± 0.01 | 0.21 ± 0.00 | 0.22 ± 0.01 | 0.23 ± 0.01
Relative | 4.161 ± 0.108 | 4.077 ± 0.079 | 4.197 ± 0.130 | 4.474 ± 0.153
R. Kidney
Absolute | 0.42 ± 0.01 | 0.41 ± 0.01 | 0.41 ± 0.01 | 0.42 ± 0.01
Relative | 8.068 ± 0.188 | 7.913 ± 0.232 | 7.946 ± 0.244 | 8.095 ± 0.196
Liver
Absolute | 2.51 ± 0.19 | 2.29 ± 0.10 | 2.51 ± 0.25 | 2.70 ± 0.25
Relative | 48.720 ± 3.637 | 44.824 ± 2.426 | 48.812 ± 5.098 | 52.084 ± 4.884
Lung
Absolute | 0.24 ± 0.01 | 0.33 ± 0.01** | 0.46 ± 0.01** | 0.66 ± 0.04**
Relative | 4.703 ± 0.113 | 6.396 ± 0.131* | 8.862 ± 0.289** | 12.857 ± 0.855**
R. Testis
Absolute | 0.120 ± 0.002 | 0.120 ± 0.002 | 0.119 ± 0.001 | 0.120 ± 0.002
Relative | 2.332 ± 0.035 | 2.332 ± 0.051 | 2.314 ± 0.022 | 2.309 ± 0.037
Thymus
Absolute | 0.114 ± 0.005 | 0.126 ± 0.006 | 0.147 ± 0.008** | 0.173 ± 0.011**
Relative | 2.219 ± 0.102 | 2.450 ± 0.091 | 2.840 ± 0.151** | 3.317 ± 0.170**
Female
Necropsy body wt. | 47.3 ± 2.1 | 55.4 ± 1.7* | 50.5 ± 2.1 | 49.8 ± 1.7
Heart
Absolute | 0.17 ± 0.00 | 0.17 ± 0.00 | 0.17 ± 0.00 | 0.19 ± 0.01**
Relative | 3.552 ± 0.129 | 3.120 ± 0.062* | 3.423 ± 0.120 | 3.770 ± 0.119
R. Kidney
Absolute | 0.24 ± 0.01 | 0.25 ± 0.01 | 0.25 ± 0.01 | 0.25 ± 0.01
Relative | 5.060 ± 0.223 | 4.485 ± 0.133 | 4.913 ± 0.219 | 4.998 ± 0.242
Liver
Absolute | 1.73 ± 0.07 | 1.91 ± 0.06 | 1.83 ± 0.06 | 1.94 ± 0.06*
Relative | 36.653 ± 0.588 | 34.465 ± 0.634 | 36.531 ± 1.129 | 39.158 ± 1.118
Lung
Absolute | 0.23 ± 0.01 | 0.33 ± 0.01** | 0.42 ± 0.02** | 0.79 ± 0.03**
Relative | 4.799 ± 0.126 | 5.913 ± 0.169 | 8.331 ± 0.320** | 16.000 ± 0.857**
Thymus
Absolute | 0.080 ± 0.005 | 0.116 ± 0.009* | 0.112 ± 0.012* | 0.129 ± 0.010**
Relative | 1.681 ± 0.062 | 2.069 ± 0.126 | 2.216 ± 0.232* | 2.554 ± 0.127**

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).