# Appendix E Genetic Toxicology

## E.1 Rat and Mouse Peripheral Blood Micronucleus Test Protocol

A detailed discussion of this assay is presented by Torous et al.^94^ and Witt et al.^95^ At the 12-month interim evaluation in the 2-year studies of antimony trioxide, small blood samples (approximately 120 µL) were obtained from male and female Wistar Han rats and B6C3F1/N mice in EDTA tubes. Samples were immediately refrigerated, and then shipped with cold packs by overnight courier to the analytical laboratory where they were immediately fixed in ultracold methanol^96^ (MicroFlow^®^ Basic Kits, Litron Laboratories, Rochester NY) and stored in a −80°C freezer until analysis. Flow cytometric analysis was conducted using a FACSCalibur flow cytometer (Becton Dickinson, San Jose, CA). Reticulocytes were identified by the presence of an active transferrin receptor (CD71+) on the cell surface; mature erythrocytes were identified as CD71-negative. For rat blood samples, the analysis was restricted to the youngest reticulocytes (i.e., the subpopulation of erythrocytes with the highest CD71 expression) to focus on the population of reticulocytes that were least altered by the efficient action of the rat spleen in sequestering and destroying micronucleated red blood cells^97^. Using flow cytometry, micronucleated cells were detected using the DNA staining dye propidium iodide (PI) in conjunction with RNase treatment. Therefore, micronucleated reticulocytes express high levels of CD71 (CD71+) and PI-associated fluorescence, while micronucleated erythrocytes are negative for CD71 (CD71−) and show PI-associated fluorescence. Twenty thousand CD71+ reticulocytes were scored per animal for the presence of micronuclei, and approximately 1 × 10^6^ total erythrocytes were counted for the presence of micronuclei and to determine percentage of reticulocytes (percent reticulocytes) as a measure of chemical-induced bone marrow toxicity.

In this assay, the animal is the experimental unit and approximately 20,000 reticulocytes and/or 1 × 10^6^ erythrocytes are evaluated per animal for the presence of micronuclei. In addition, the percent reticulocytes was determined in approximately 1 × 10^6^ erythrocytes. The optimum number of cells to score for micronuclei using flow cytometric approaches was determined in earlier studies^98^. Data from each treatment group are summarized as the mean frequency of micronucleated reticulocytes per 1,000 reticulocytes, plus or minus the standard error of the mean. With the large number of cells counted by flow cytometry, it is assumed that the number of micronucleated cells is normally distributed. Levene’s test is used to determine if variances among treatment groups were equal. When they are, linear regression analysis is used to test for linear trend and pairwise differences with the control group are evaluated using Williams’ test, after linearizing the data by averaging data points that violate a linear trend. When variances are unequal, nonparametric methods are used to analyze the data: Jonckheere’s test is used to evaluate linear trend and Dunn’s test is used to assess the significance of pairwise differences with the control group. To maintain the overall significance level at P ≤ 0.05, the trend as well as the pairwise differences from the control group are declared statistically significant if P ≤ 0.025. Ultimately, the scientific staff determines the final call after considering the results of statistical analyses, reproducibility of any effects observed, and the magnitudes of those effects.

## E.2 Comet Assay Protocol for DNA Damage Assessment in Peripheral Blood Leukocytes and Cells from the Lung

The same animals sampled for the peripheral blood micronucleus assay were sampled for assessment of DNA damage in cells from the blood and the lung. The general tissue sample preparation procedures have been described in detail previously^99^. In brief, at the 12-month interim evaluation, lung and additional (approximately 50 µL) blood samples were collected for assessment of DNA damage using the comet assay^100-102^. Blood samples were placed into tubes containing 1 mL of mincing solution (Mg^+2^ and Ca^+2^ free Hank’s Balanced Salt Solution with 20 mM EDTA, pH 7.4 to 7.7, and 10% v/v fresh DMSO). A small portion of the lung was placed in a cryovial containing 1 mL of mincing solution and rapidly minced. Blood and tissue samples for the comet assay were flash frozen in liquid nitrogen and stored at −80°C prior to shipping on dry ice to the genetic toxicology laboratory. Upon arrival at the genetic toxicology laboratory, frozen samples were stored in a −80°C freezer until thawing and processing for DNA damage analysis.

Thawed cell samples were diluted with phosphate buffered saline (PBS), mixed with 0.5% low melting point agarose at 37°C, layered onto slides, and placed in cold lysing solution (2.5 M NaCl, 100 mM Na2EDTA, 10 mM Tris, pH 10, with freshly added 10% DMSO and 1% Triton X-100) overnight. After rinsing in 0.4 M Trizma base, pH 7.5, slides were treated with cold alkali (300 mM NaOH, 1 mM Na2EDTA, pH>13) for 20 minutes, then electrophoresed at 4° to 10°C for 20 minutes at 1.0 V/cm, 300 mA. Slides were then neutralized with 0.4 M Trizma base (pH 7.5) for 5 minutes, incubated for 5 minutes in ice-cold 100% ethanol, and allowed to air dry. Slides were stained with SYBR^®^ Gold and 100 cells were scored per tissue per animal using Comet Assay IV Imaging Software¸ Version 4.11 (Perceptive Instruments, Ltd., Suffolk, UK). For each cell, the extent of DNA migration was characterized using the percent tail DNA endpoint measurement (intensity of all tail pixels divided by the total intensity of all pixels in the comet, expressed as a percentage).

For each 100-cell sample per animal, the Shapiro-Wilk test was first used to assess normality of the control group. Data that were normally distributed were analyzed using an independent sample’s t-test to compare each dose level to the concurrent control and linear regression to determine the presence of a dose response. Normally distributed data were also tested for homogeneity of variances using the F test; for data of unequal variances, the Welch’s approximation for unequal variances t-test value was used for determination of a one-tailed significant (P ≤ 0.05) increase in DNA migration. Data that were not normally distributed were analyzed by the Mann-Whitney test^103^ comparing each dose level to the concurrent control, followed by the Kendall rank correlation test^104^ to determine the presence of a dose response. Trend tests were considered statistically significant at P ≤ 0.025 and pairwise comparisons were significant at P ≤ 0.008 (0.025/3 dose groups) to correct for multiple comparisons.

## E.3 Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The summary table in the Abstract of this Technical Report presents a result that represents a scientific judgment of the overall evidence for activity of the chemical in an assay.

## E.4 Results

In male and female Wistar Han rats, the reticulocyte population (polychromatic erythrocytes or PCEs), did not show an increase in micronucleated cells following 12 months of inhalation exposure to antimony trioxide (0, 3, 10, or 30 mg/m^3^) (Table E-1). In addition, no significant alterations in the percent reticulocytes in peripheral blood were observed in either male or female rats, suggesting no bone marrow toxicity or effect on erythropoiesis associated with exposure to antimony trioxide.

Micronucleus frequencies in mature erythrocytes (normochromatic erythrocytes or NCEs) of male and female B6C3F1/N mice exposed to antimony trioxide (0, 3, 10, or 30 mg/m^3^) for 12 months via inhalation were significantly increased, based on significant trend tests and significantly elevated frequencies of micronucleated erythrocytes at the highest exposure concentration (Table E-2). Using flow cytometry, approximately 1 million erythrocytes were scored per animal for the presence of micronuclei, making this a highly sensitive method of scoring and allowing small increases in the endpoint to be detected. In mice, the micronucleus response in the reticulocyte population, indicative of damage induced in the bone marrow within the last 48 hours prior to sampling, was slightly increased with increasing exposure concentration, but the increase was not statistically significant. However, the trend toward increased frequencies of micronucleated reticulocytes in the mice is supportive of the observations in the mature erythrocyte population. In addition, significant increases in the percent reticulocytes were seen in both male and female mice, suggesting a stimulation of erythropoiesis in mice exposed to antimony trioxide. It should be noted that stimulation of erythropoiesis may, in some instances, result in elevated levels of micronucleated red blood cells due to an increase in mitotic errors associated with rapid cell division, although in in vivo micronucleus studies conducted by the National Toxicology Program, no consistent association between increases in percent reticulocytes and increases in micronuclei has been observed.

In addition to evaluating the potential for chromosomal damage, manifested as micronuclei resulting from exposure to antimony trioxide, the potential for DNA damage was assessed using the comet assay in the same animals in which micronucleus induction was evaluated. DNA damage was assessed in blood leukocytes and lung tissue samples. No increases in DNA damage were seen in blood leukocytes or lung cell samples in male or female Wistar Han rats exposed to antimony trioxide (Table E-3). In male and female B6C3F1/N mice, significant increases in DNA damage, measured as percent tail DNA, were seen in lung tissue samples; no increases in percent tail DNA were observed in leukocytes (Table E-4).

In summary, exposure to antimony trioxide for 12 months by inhalation resulted in increases in micronucleated erythrocytes and lung cell DNA damage in male and female mice, but not in male or female rats.

Table E-1 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Rats Following Treatment with Antimony Trioxide by Inhalation for 12 Months^a^

Concentration (mg/m^3^) | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%) | P Value^c^
Male
Air^d^ | 5 | 0.98 ± 0.08 | | 0.04 ± 0.01 | | 0.632 ± 0.05
3 | 5 | 0.81 ± 0.10 | 0.6885 | 0.06 ± 0.01 | 0.2690 | 0.702 ± 0.06 | 0.8511
10 | 5 | 1.11 ± 0.15 | 0.5738 | 0.06 ± 0.01 | 0.3234 | 0.651 ± 0.03 | 0.9499
30 | 5 | 0.86 ± 0.14 | 0.6068 | 0.05 ± 0.02 | 0.3447 | 0.588 ± 0.05 | 0.6547
| | P = 0.642^e^ | | P = 0.467 | | P = 0.227
Female
Air | 5 | 1.50 ± 0.37 | | 0.05 ± 0.01 | | 0.878 ± 0.21
3 | 5 | 1.15 ± 0.33 | 0.8909 | 0.03 ± 0.00 | 0.9471 | 0.895 ± 0.11 | 1.0000
10 | 5 | 0.66 ± 0.08 | 0.9416 | 0.04 ± 0.01 | 0.9771 | 0.747 ± 0.06 | 0.9122
30 | 5 | 0.80 ± 0.15 | 0.9567 | 0.03 ± 0.00 | 0.9843 | 0.779 ± 0.13 | 0.9228
| | P = 0.936 | | P = 0.892 | | P = 0.573

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Torous et al.^94^ and Witt et al.^95^. NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the chamber control group; exposed group values are significant at P ≤ 0.025 by Williams’ test.

^d^ Chamber control.

^e^ Exposure concentration-related trend; significant at P ≤ 0.025 by linear regression.

Table E-2 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Mice Following Treatment with Antimony Trioxide by Inhalation for 12 Months^a^

Concentration (mg/m^3^) | Number of Mice with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%) | P Value^d^
Male
Air^e^ | 5 | 2.53 ± 0.14 | | 1.55 ± 0.05 | | 1.458 ± 0.07
3 | 5 | 2.37 ± 0.13 | 0.6223 | 1.59 ± 0.03 | 0.3054 | 1.504 ± 0.09 | 0.8622
10 | 5 | 2.87 ± 0.23 | 0.1622 | 1.66 ± 0.02 | 0.1198 | 2.247 ± 0.34 | 0.0273
30 | 5 | 2.78 ± 0.21 | 0.1731 | 1.93 ± 0.10 | 0.0002 | 3.544 ± 0.57 | 0.0001
| | P = 0.100^f^ | | P = 0.100^f^ | | P = 0.100^f^
Female
Air | 5 | 2.17 ± 0.19 | | 1.04 ± 0.02 | | 1.131 ± 0.22
3 | 5 | 1.77 ± 0.14 | 0.8408 | 1.08 ± 0.01 | 0.2750 | 1.215 ± 0.06 | 1.0000
10 | 5 | 2.21 ± 0.06 | 0.4985 | 1.13 ± 0.05 | 0.1462 | 1.398 ± 0.13 | 1.0000
30 | 5 | 2.38 ± 0.13 | 0.1931 | 1.38 ± 0.09 | 0.0002 | 2.660 ± 0.34 | 0.0069
| | P < 0.001^f^ | | P < 0.001^f^ | | P = 0.001^g^

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Torous et al.94 and Witt et al.95. NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the chamber control group; exposed group values are significant at P ≤ 0.025 by Williams’ test.

^d^ Pairwise comparison with the chamber control group; exposed group values are significant at P ≤ 0.025 by Williams’ (males) or Dunn’s (females) test.

^e^ Chamber control.

^f^ Exposure concentration-related trend; significant at P ≤ 0.025 by linear regression.

^g^ Exposure concentration-related trend; significant at P ≤ 0.025 by Jonckheere’s test.

Table E-3 DNA Damage in the Blood and Lung of Rats Following Treatment with Antimony Trioxide by Inhalation for 12 Months^a^

| Dose (mg/m^3^) | Number of Rats | Percent Tail DNA^b^ | P Value^c^
Male
Blood
Air^d^ | 0 | 5 | 5.4 ± 1.04
Antimony trioxide | 3 | 5 | 7.9 ± 1.05 | 0.0476
| 10 | 5 | 6.0 ± 1.23 | 0.4206
| 30 | 5 | 4.5 ± 0.72 | 0.6548
| | | P = 0.4194^e^
Lung
Air | 0 | 5 | 31.0 ± 2.32
Antimony trioxide | 3 | 5 | 34.7 ± 2.42 | 0.1518
| 10 | 5 | 25.8 ± 2.61 | 0.9142
| 30 | 5 | 29.3 ± 1.00 | 0.7412
| | | P = 0.6636
Female
Blood
Air | 0 | 5 | 2.5 ± 0.51
Antimony trioxide | 3 | 5 | 1.7 ± 0.14 | 0.9047
| 10 | 5 | 3.3 ± 1.08 | 0.2575
| 30 | 5 | 2.2 ± 0.34 | 0.6689
| | | P = 0.9566
Lung
Air | 0 | 5 | 32.2 ± 1.20
Antimony trioxide | 3 | 5 | 30.1 ± 1.28 | 0.8753
| 10 | 5 | 28.9 ± 4.03 | 0.7653
| 30 | 5 | 29.2 ± 3.03 | 0.8116
| | | P = 0.4813

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Recio et al.^99^.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the chamber control group; exposed group values are significant at P ≤ 0.008 by Student’s t-test, except male blood by the Mann-Whitney test.

^d^ Chamber control.

^e^ Exposure concentration-related trend; significant at P ≤ 0.025 by linear regression, except male blood by the Kendall Rank Correlation test.

Table E-4 DNA Damage in the Blood and Lung of Mice Following Treatment with Antimony Trioxide by Inhalation for 12 Months^a^

| Dose (mg/m^3^) | Number of Mice | Percent Tail DNA^b^ | P Value^c^
Male
Blood
Air^d^ | 0 | 5 | 3.3 ± 0.74
Antimony trioxide | 3 | 5 | 3.6 ± 0.27 | 0.3888
| 10 | 5 | 3.0 ± 0.41 | 0.6526
| 30 | 5 | 4.1 ± 1.24 | 0.3065
| | | P = 0.4538^e^
Lung
Air | 0 | 5 | 25.6 ± 0.78
Antimony trioxide | 3 | 5 | 33.7 ± 2.62 | 0.0165
| 10 | 5 | 33.5 ± 2.02 | 0.0033
| 30 | 5 | 37.5 ± 2.28 | 0.0005
| | | P = 0.0076
Female
Blood
Air | 0 | 5 | 3.5 ± 0.68
Antimony trioxide | 3 | 5 | 3.8 ± 0.40 | 0.3735
| 10 | 5 | 2.5 ± 0.20 | 0.8953
| 30 | 5 | 2.4 ± 0.28 | 0.9139
| | | P = 0.9566
Lung
Air | 0 | 5 | 32.8 ± 1.11
Antimony trioxide | 3 | 5 | 35.8 ± 2.09 | 0.1181
| 10 | 5 | 36.4 ± 2.65 | 0.1220
| 30 | 5 | 45.5 ± 2.32 | 0.0006
| | | P = 0.0002

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Recio et al.^99^.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the chamber control group; exposed group values are significant at P ≤ 0.008 by Student’s t-test.

^d^ Chamber control.

^e^ Exposure concentration-related trend; significant at P ≤ 0.025 by linear regression.