# Appendix D Summary of Lesions in Female Mice in the Two-year Inhalation Study of Antimony Trioxide

Table D-1 Summary of the Incidence of Neoplasms in Female Mice in the Two-year Inhalation Study of Antimony Trioxide^a^

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Disposition Summary
Animals initially in study | 60 | 60 | 60 | 60
Twelve-month interim evaluation | 10 | 10 | 10 | 10
Early deaths
Accidental death | 1 | – | – | –
Moribund | 10 | 11 | 16 | 27
Natural deaths | 3 | 8 | 8 | 8
Survivors
Terminal kill | 36 | 31 | 26 | 15
Animals examined microscopically | 60 | 60 | 60 | 60
Twelve-month Interim Evaluation
Alimentary System
Esophagus | (10) | (10) | (10) | (10)
Gallbladder | (10) | (10) | (10) | (10)
Intestine large, cecum | (10) | (10) | (10) | (10)
Intestine large, colon | (10) | (10) | (10) | (10)
Intestine large, rectum | (10) | (10) | (10) | (10)
Intestine small, duodenum | (10) | (10) | (10) | (10)
Intestine small, ileum | (10) | (10) | (10) | (10)
Intestine small, jejunum | (10) | (10) | (10) | (10)
Liver | (10) | (10) | (10) | (10)
Hepatocellular adenoma | – | 2 (20%) | 2 (20%) | 4 (40%)
Pancreas | (10) | (10) | (10) | (10)
Salivary glands | (10) | (10) | (10) | (10)
Stomach, forestomach | (10) | (10) | (10) | (10)
Stomach, glandular | (10) | (10) | (10) | (10)
Tooth | (1) | (0) | (0) | (0)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Adrenal medulla | (10) | (10) | (10) | (10)
Pheochromocytoma malignant | – | – | – | 1 (10%)
Islets, pancreatic | (10) | (10) | (10) | (10)
Parathyroid gland | (8) | (9) | (6) | (8)
Pituitary gland | (10) | (10) | (10) | (10)
Thyroid gland | (10) | (9) | (10) | (10)
Genital System
Clitoral gland | (10) | (9) | (7) | (7)
Ovary | (10) | (10) | (10) | (10)
Luteoma | – | 1 (10%) | – | –
Uterus | (10) | (10) | (10) | (10)
Respiratory System
Larynx | (10) | (9) | (10) | (10)
Lung | (10) | (10) | (10) | (10)
Alveolar/bronchiolar adenoma | – | – | – | 1 (10%)
Nose | (10) | (10) | (10) | (10)
Trachea | (10) | (10) | (10) | (10)
Systemic Lesions
Multiple organs^b^ | (10) | (10) | (10) | (10)
Histiocytic sarcoma | – | 1 (10%) | – | –
Lymphoma malignant | – | – | – | 3 (30%)
Systems Examined at 12 Months with No Neoplasms Observed
Cardiovascular System
General Body System
Hematopoietic System
Integumentary System
Musculoskeletal System
Nervous System
Special Senses System
Urinary System
Two-year Study
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Gallbladder | (46) | (41) | (44) | (45)
Fibrosarcoma, metastatic, pancreas | – | 1 (2%) | – | –
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | –
Intestine large, cecum | (47) | (44) | (48) | (47)
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | –
Polyp adenomatous | – | – | – | 1 (2%)
Intestine large, colon | (47) | (47) | (49) | (47)
Intestine large, rectum | (44) | (46) | (48) | (47)
Intestine small, duodenum | (47) | (44) | (45) | (45)
Fibrosarcoma, metastatic, pancreas | – | 1 (2%) | – | –
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | –
Intestine small, ileum | (47) | (45) | (47) | (45)
Hemangiosarcoma | – | 1 (2%) | – | –
Intestine small, jejunum | (47) | (43) | (46) | (44)
Adenoma | – | – | 1 (2%) | 1 (2%)
Carcinoma | – | 1 (2%) | – | –
Liver | (50) | (50) | (50) | (50)
Fibrosarcoma, metastatic, pancreas | – | 1 (2%) | – | –
Hemangioma | – | – | 1 (2%) | –
Hemangiosarcoma | – | – | 1 (2%) | –
Hepatocellular adenoma | 9 (18%) | 9 (18%) | 11 (22%) | 15 (30%)
Hepatocellular adenoma, multiple | 2 (4%) | 5 (10%) | 5 (10%) | 2 (4%)
Hepatocellular carcinoma | 4 (8%) | 10 (20%) | 9 (18%) | 3 (6%)
Hepatocellular carcinoma, multiple | 2 (4%) | 1 (2%) | 3 (6%) | 1 (2%)
Hepatocholangiocarcinoma | 1 (2%) | 2 (4%) | – | –
Mesentery | (9) | (12) | (16) | (7)
Fibrosarcoma, metastatic, pancreas | – | 1 (8%) | – | –
Granulosa cell tumor malignant, metastatic, ovary | – | – | 1 (6%) | –
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (8%) | – | –
Lipoma | 1 (11%) | – | – | –
Pancreas | (50) | (50) | (50) | (50)
Fibrosarcoma | – | 1 (2%) | – | –
Hemangiosarcoma, metastatic, liver | – | – | 1 (2%) | –
Salivary glands | (50) | (50) | (50) | (50)
Myxosarcoma | 1 (2%) | – | – | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | –
Squamous cell papilloma | 1 (2%) | – | – | –
Stomach, glandular | (50) | (49) | (50) | (50)
Fibrosarcoma, metastatic, pancreas | – | 1 (2%) | – | –
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | –
Tongue | (0) | (1) | (0) | (0)
Tooth | (0) | (2) | (2) | (1)
Cardiovascular System
Blood vessel | (50) | (48) | (47) | (46)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | 1 (2%) | –
Heart | (50) | (50) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (2%) | 1 (2%) | 1 (2%)
Pericardium, alveolar/bronchiolar carcinoma, metastatic, lung | – | – | 1 (2%) | 1 (2%)
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Adenoma | – | 1 (2%) | – | –
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Capsule, fibrosarcoma, metastatic, pancreas | – | 1 (2%) | – | –
Capsule, hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | –
Subcapsular, adenoma | 1 (2%) | – | 1 (2%) | –
Adrenal medulla | (50) | (50) | (48) | (49)
Pheochromocytoma benign | – | 2 (4%) | – | 3 (6%)
Islets, pancreatic | (50) | (49) | (49) | (49)
Adenoma | – | 1 (2%) | 1 (2%) | 1 (2%)
Fibrosarcoma, metastatic, pancreas | – | 1 (2%) | – | –
Parathyroid gland | (27) | (33) | (34) | (32)
Adenoma | – | – | – | 1 (3%)
Pituitary gland | (49) | (50) | (50) | (50)
Pars distalis, adenoma | 9 (18%) | 10 (20%) | 7 (14%) | 3 (6%)
Pars distalis, carcinoma | – | – | 1 (2%) | –
Pars intermedia, adenoma | – | 1 (2%) | 1 (2%) | –
Thyroid gland | (48) | (50) | (50) | (50)
Follicular cell, adenoma | – | – | – | 1 (2%)
Follicular cell, carcinoma | – | – | 1 (2%) | –
General Body System
Peritoneum | (0) | (0) | (1) | (0)
Genital System
Clitoral gland | (48) | (44) | (47) | (42)
Ovary | (50) | (49) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (2%) | – | –
Cystadenoma | 1 (2%) | 2 (4%) | 2 (4%) | –
Fibrosarcoma, metastatic, pancreas | – | 1 (2%) | – | –
Granulosa cell tumor malignant | 1 (2%) | – | 1 (2%) | –
Granulosa-theca tumor malignant | – | 1 (2%) | – | –
Hemangioma | – | 1 (2%) | – | 1 (2%)
Hemangiosarcoma | 1 (2%) | – | 1 (2%) | –
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | –
Luteoma | – | 1 (2%) | – | –
Oviduct | (1) | (0) | (0) | (0)
Uterus | (50) | (50) | (50) | (50)
Carcinoma | – | – | 1 (2%) | –
Granular cell tumor benign | 1 (2%) | – | – | –
Hemangiosarcoma | 1 (2%) | – | 1 (2%) | –
Leiomyoma | – | 2 (4%) | – | –
Polyp stromal | 4 (8%) | 2 (4%) | 1 (2%) | 2 (4%)
Endometrium, polyp stromal | – | – | – | 1 (2%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Mast cell tumor NOS, metastatic, uncertain primary site | – | – | – | 1 (2%)
Lymph node | (6) | (9) | (14) | (16)
Hemangioma | – | – | – | 1 (6%)
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (11%) | – | –
Lumbar, hemangiosarcoma | 1 (17%) | – | – | –
Lumbar, hepatocholangiocarcinoma, metastatic, liver | – | 1 (11%) | – | –
Pancreatic, fibrosarcoma, metastatic, pancreas | – | 1 (11%) | – | –
Pancreatic, granulosa cell tumor malignant, metastatic, ovary | – | – | 1 (7%) | –
Pancreatic, hepatocholangiocarcinoma, metastatic, liver | – | 1 (11%) | – | –
Lymph node, bronchial | (41) | (47) | (48) | (49)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 2 (4%) | 2 (4%) | –
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | –
Lymph node, mandibular | (41) | (28) | (38) | (39)
Lymph node, mediastinal | (46) | (48) | (49) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 2 (4%) | 2 (4%) | –
Hepatocellular carcinoma, metastatic, liver | 1 (2%) | – | – | –
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | –
Lymph node, mesenteric | (50) | (48) | (48) | (46)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (2%) | – | –
Fibrosarcoma, metastatic, pancreas | – | 1 (2%) | – | –
Hemangiosarcoma | – | – | – | 1 (2%)
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | –
Spleen | (50) | (50) | (50) | (50)
Hemangiosarcoma | – | 1 (2%) | – | –
Thymus | (47) | (49) | (49) | (49)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 2 (4%) | – | 1 (2%)
Hemangioma | – | – | – | 1 (2%)
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | –
Thymoma NOS | 1 (2%) | – | – | –
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Carcinoma | 1 (2%) | 2 (4%) | – | –
Squamous cell carcinoma, metastatic, skin | – | – | – | 1 (2%)
Skin | (50) | (50) | (50) | (50)
Fibrosarcoma | 1 (2%) | 1 (2%) | – | 1 (2%)
Fibrous histiocytoma | 1 (2%) | – | – | –
Hemangiosarcoma | 1 (2%) | 1 (2%) | – | 1 (2%)
Hemangiosarcoma, metastatic, liver | – | – | 1 (2%) | –
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | –
Squamous cell carcinoma | – | – | – | 2 (4%)
Musculoskeletal System
Bone | (50) | (50) | (49) | (50)
Femur, periosteum, alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Skeletal muscle | (4) | (1) | (4) | (3)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (33%)
Carcinoma, metastatic, mammary gland | – | 1 (100%) | – | –
Granulosa cell tumor malignant, metastatic, ovary | – | – | 1 (25%) | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Peripheral nerve | (3) | (0) | (2) | (1)
Spinal cord | (4) | (0) | (2) | (1)
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | 1 (2%) | 7 (14%) | 16 (32%) | 7 (14%)
Alveolar/bronchiolar adenoma, multiple | – | 3 (6%) | 3 (6%) | 1 (2%)
Alveolar/bronchiolar carcinoma | 2 (4%) | 7 (14%) | 5 (10%) | 7 (14%)
Alveolar/bronchiolar carcinoma, multiple | – | 7 (14%) | 6 (12%) | 4 (8%)
Carcinoma, metastatic, harderian gland | 1 (2%) | – | – | –
Granulosa-theca tumor malignant, metastatic, ovary | – | 1 (2%) | – | –
Hepatocellular carcinoma, metastatic, liver | 3 (6%) | 3 (6%) | – | 1 (2%)
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | –
Mast cell tumor NOS, metastatic, uncertain primary site | – | – | – | 1 (2%)
Nose | (50) | (49) | (50) | (50)
Pleura | (0) | (2) | (0) | (2)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (50%) | – | –
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Ear | (0) | (0) | (0) | (1)
Eye | (49) | (47) | (49) | (49)
Harderian gland | (49) | (50) | (50) | (50)
Adenoma | 3 (6%) | 4 (8%) | 6 (12%) | 2 (4%)
Carcinoma | 4 (8%) | – | – | 2 (4%)
Zymbal’s gland | (0) | (0) | (0) | (1)
Carcinoma | – | – | – | 1 (100%)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (2%) | 1 (2%) | 1 (2%)
Hepatocellular carcinoma, metastatic, liver | 1 (2%) | – | – | –
Urinary bladder | (50) | (50) | (50) | (50)
Hemangioma | – | 1 (2%) | – | –
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | 3 (6%) | 6 (12%) | 2 (4%) | 3 (6%)
Lymphoma malignant | 7 (14%) | 17 (34%) | 20 (40%) | 27 (54%)
Neoplasm Summary
Total animals with primary neoplasms^c^
Twelve-month interim evaluation | – | 3 | 2 | 6
Two-year study | 35 | 47 | 46 | 45
Total primary neoplasms
Twelve-month interim evaluation | – | 4 | 2 | 9
Two-year study | 66 | 111 | 108 | 97
Total animals with benign neoplasms
Twelve-month interim evaluation | – | 2 | 2 | 5
Two-year study | 25 | 35 | 35 | 31
Total benign neoplasms
Twelve-month interim evaluation | – | 3 | 2 | 5
Two-year study | 33 | 52 | 56 | 44
Total animals with malignant neoplasms
Twelve-month interim evaluation | – | 1 | – | 4
Two-year study | 25 | 40 | 35 | 41
Total malignant neoplasms
Twelve-month interim evaluation | – | 1 | – | 4
Two-year study | 32 | 59 | 52 | 53
Total animals with metastatic neoplasms
Two-year study | 7 | 13 | 5 | 7
Total metastatic neoplasms
Two-year study | 8 | 47 | 13 | 15
Total animals with uncertain neoplasms- benign or malignant
Two-year study | 1 | – | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table D-2 Statistical Analysis of Primary Neoplasms in Female Mice in the Two-year Inhalation Study of Antimony Trioxide

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Adrenal Medulla: Benign Pheochromocytoma
Overall rate^a^ | 0/50 (0%) | 2/50 (4%) | 0/48 (0%) | 3/49 (6%)
Adjusted rate^b^ | 0.0% | 4.6% | 0.0% | 8.4%
Terminal rate^c^ | 0/36 (0%) | 2/31 (7%) | 0/26 (0%) | 2/15 (13%)
First incidence (days) | –^e^ | 731 (T) | – | 701
Poly-3 test^d^ | P = 0.078 | P = 0.233 | –^f^ | P = 0.083
Harderian Gland: Adenoma
Overall rate | 3/50 (6%) | 4/50 (8%) | 6/50 (12%) | 2/50 (4%)
Adjusted rate | 6.7% | 9.1% | 14.5% | 5.5%
Terminal rate | 2/36 (6%) | 3/31 (10%) | 3/26 (12%) | 1/15 (7%)
First incidence (days) | 716 | 677 | 423 | 696
Poly-3 test | P = 0.463N | P = 0.492 | P = 0.205 | P = 0.591N
Harderian Gland: Carcinoma
Overall rate | 4/50 (8%) | 0/50 (0%) | 0/50 (0%) | 2/50 (4%)
Adjusted rate | 8.8% | 0.0% | 0.0% | 5.5%
Terminal rate | 2/36 (6%) | 0/31 (0%) | 0/26 (0%) | 1/15 (7%)
First incidence (days) | 472 | – | – | 628
Poly-3 test | P = 0.627N | P = 0.065N | P = 0.078N | P = 0.439N
Harderian Gland: Adenoma or Carcinoma
Overall rate | 7/50 (14%) | 4/50 (8%) | 6/50 (12%) | 4/50 (8%)
Adjusted rate | 15.4% | 9.1% | 14.5% | 10.9%
Terminal rate | 4/36 (11%) | 3/31 (10%) | 3/26 (12%) | 2/15 (13%)
First incidence (days) | 472 | 677 | 423 | 628
Poly-3 test | P = 0.465N | P = 0.278N | P = 0.571N | P = 0.392N
Liver: Hepatocellular Adenoma
Overall rate | 11/50 (22%) | 14/50 (28%) | 16/50 (32%) | 17/50 (34%)
Adjusted rate | 24.7% | 31.6% | 38.3% | 43.1%
Terminal rate | 11/36 (31%) | 12/31 (39%) | 10/26 (39%) | 6/15 (40%)
First incidence (days) | 731 (T) | 645 | 521 | 470
Poly-3 test | P = 0.058 | P = 0.312 | P = 0.127 | P = 0.056
Liver: Hepatocellular Carcinoma
Overall rate | 6/50 (12%) | 11/50 (22%) | 12/50 (24%) | 4/50 (8%)
Adjusted rate | 13.4% | 24.6% | 28.8% | 10.8%
Terminal rate | 4/36 (11%) | 7/31 (23%) | 6/26 (23%) | 3/15 (20%)
First incidence (days) | 684 | 613 | 512 | 513
Poly-3 test | P = 0.252N | P = 0.139 | P = 0.064 | P = 0.496N
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 14/50 (28%) | 22/50 (44%) | 22/50 (44%) | 19/50 (38%)
Adjusted rate | 31.2% | 48.9% | 51.1% | 47.4%
Terminal rate | 12/36 (33%) | 17/31 (55%) | 12/26 (46%) | 7/15 (47%)
First incidence (days) | 684 | 613 | 512 | 470
Poly-3 test | P = 0.213 | P = 0.063 | P = 0.042 | P = 0.091
Lung: Alveolar/Bronchiolar Adenoma
Overall rate | 1/50 (2%) | 10/50 (20%) | 19/50 (38%) | 8/50 (16%)
Adjusted rate | 2.3% | 22.8% | 44.9% | 20.3%
Terminal rate | 1/36 (3%) | 7/31 (23%) | 12/26 (46%) | 1/15 (7%)
First incidence (days) | 731 (T) | 708 | 519 | 404
Poly-3 test | P = 0.137 | P = 0.003 | P < 0.001 | P = 0.009
Lung: Alveolar/Bronchiolar Carcinoma
Overall rate | 2/50 (4%) | 14/50 (28%) | 11/50 (22%) | 11/50 (22%)
Adjusted rate | 4.4% | 31.2% | 26.8% | 28.8%
Terminal rate | 1/36 (3%) | 9/31 (29%) | 7/26 (27%) | 5/15 (33%)
First incidence (days) | 472 | 511 | 526 | 493
Poly-3 test | P = 0.065 | P < 0.001 | P = 0.003 | P = 0.002
Lung: Alveolar/Bronchiolar Adenoma or Carcinoma
Overall rate | 3/50 (6%) | 22/50 (44%) | 27/50 (54%) | 18/50 (36%)
Adjusted rate | 6.6% | 48.8% | 62.6% | 43.5%
Terminal rate | 2/36 (6%) | 15/31 (48%) | 17/26 (65%) | 5/15 (33%)
First incidence (days) | 472 | 511 | 519 | 404
Poly-3 test | P = 0.019 | P < 0.001 | P < 0.001 | P < 0.001
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 9/49 (18%) | 10/50 (20%) | 7/50 (14%) | 3/50 (6%)
Adjusted rate | 20.7% | 22.2% | 17.1% | 8.3%
Terminal rate | 9/35 (26%) | 6/31 (19%) | 4/26 (15%) | 3/15 (20%)
First incidence (days) | 731 (T) | 511 | 526 | 731 (T)
Poly-3 test | P = 0.065N | P = 0.535 | P = 0.442N | P = 0.109N
Pituitary Gland (Pars Distalis): Adenoma or Carcinoma
Overall rate | 9/49 (18%) | 10/50 (20%) | 8/50 (16%) | 3/50 (6%)
Adjusted rate | 20.7% | 22.2% | 19.3% | 8.3%
Terminal rate | 9/35 (26%) | 6/31 (19%) | 4/26 (15%) | 3/15 (20%)
First incidence (days) | 731 (T) | 511 | 526 | 731 (T)
Poly-3 test | P = 0.069N | P = 0.535 | P = 0.544N | P = 0.109N
Uterus: Stromal Polyp
Overall rate | 4/50 (8%) | 2/50 (4%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 8.9% | 4.6% | 2.5% | 8.2%
Terminal rate | 3/36 (8%) | 2/31 (7%) | 0/26 (0%) | 2/15 (13%)
First incidence (days) | 614 | 731 (T) | 519 | 572
Poly-3 test | P = 0.540 | P = 0.349N | P = 0.211N | P = 0.607N
All Organs: Hemangioma
Overall rate | 0/50 (0%) | 2/50 (4%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 0.0% | 4.6% | 2.5% | 8.3%
Terminal rate | 0/36 (0%) | 2/31 (7%) | 1/26 (4%) | 2/15 (13%)
First incidence (days) | – | 731 (T) | 731 (T) | 710
Poly-3 test | P = 0.095 | P = 0.233 | P = 0.478 | P = 0.086
All Organs: Hemangiosarcoma
Overall rate | 4/50 (8%) | 3/50 (6%) | 3/50 (6%) | 2/50 (4%)
Adjusted rate | 9.0% | 6.7% | 7.5% | 5.5%
Terminal rate | 3/36 (8%) | 1/31 (3%) | 3/26 (12%) | 1/15 (7%)
First incidence (days) | 725 | 606 | 731 (T) | 696
Poly-3 test | P = 0.408N | P = 0.499N | P = 0.560N | P = 0.434N
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 4/50 (8%) | 5/50 (10%) | 4/50 (8%) | 5/50 (10%)
Adjusted rate | 9.0% | 11.2% | 10.0% | 13.7%
Terminal rate | 3/36 (8%) | 3/31 (10%) | 4/26 (15%) | 3/15 (20%)
First incidence (days) | 725 | 606 | 731 (T) | 696
Poly-3 test | P = 0.351 | P = 0.501 | P = 0.582 | P = 0.377
All Organs: Histiocytic Sarcoma
Overall rate | 3/50 (6%) | 6/50 (12%) | 2/50 (4%) | 3/50 (6%)
Adjusted rate | 6.7% | 13.3% | 4.9% | 8.0%
Terminal rate | 1/36 (3%) | 3/31 (10%) | 0/26 (0%) | 0/15 (0%)
First incidence (days) | 614 | 559 | 526 | 488
Poly-3 test | P = 0.475N | P = 0.242 | P = 0.546N | P = 0.574
All Organs: Malignant Lymphoma
Overall rate | 7/50 (14%) | 17/50 (34%) | 20/50 (40%) | 27/50 (54%)
Adjusted rate | 15.6% | 38.1% | 47.5% | 60.7%
Terminal rate | 5/36 (14%) | 15/31 (48%) | 12/26 (46%) | 5/15 (33%)
First incidence (days) | 677 | 558 | 512 | 404
Poly-3 test | P < 0.001 | P = 0.013 | P < 0.001 | P < 0.001
All Organs: Benign Neoplasms
Overall rate | 25/50 (50%) | 35/50 (70%) | 35/50 (70%) | 31/50 (62%)
Adjusted rate | 55.4% | 76.5% | 77.0% | 72.1%
Terminal rate | 22/36 (61%) | 27/31 (87%) | 20/26 (77%) | 13/15 (87%)
First incidence (days) | 614 | 511 | 423 | 404
Poly-3 test | P = 0.222 | P = 0.022 | P = 0.019 | P = 0.068
All Organs: Malignant Neoplasms
Overall rate | 25/50 (50%) | 40/50 (80%) | 35/50 (70%) | 41/50 (82%)
Adjusted rate | 53.4% | 81.9% | 77.6% | 86.5%
Terminal rate | 16/36 (44%) | 25/31 (81%) | 19/26 (73%) | 12/15 (80%)
First incidence (days) | 472 | 511 | 512 | 404
Poly-3 test | P = 0.004 | P = 0.002 | P = 0.010 | P < 0.001
All Organs: Benign or Malignant Neoplasms
Overall rate | 35/50 (70%) | 47/50 (94%) | 46/50 (92%) | 46/50 (92%)
Adjusted rate | 74.8% | 95.9% | 97.0% | 94.3%
Terminal rate | 26/36 (72%) | 30/31 (97%) | 26/26 (100%) | 14/15 (93%)
First incidence (days) | 472 | 511 | 423 | 404
Poly-3 test | P = 0.037 | P = 0.002 | P < 0.001 | P = 0.006

(T) = terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal gland, liver, lung, and pituitary gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table D-3 Historical Incidence of Alveolar/Bronchiolar Neoplasms in Control Female B6C3F1/N Mice^a^

Study (Study Start) | Adenoma | Carcinoma | | Adenoma or Carcinoma
Historical Incidence: Inhalation Studies
Antimony trioxide (October 2008) | 1/50 | 2/50 | 3/50
CIMSTAR 3800 (May 2008) | 1/50 | 4/50 | 4/50
Cobalt metal (May 2006) | 3/49 | 5/49 | 8/49
Vinylidene chloride (June 2005) | 3/50 | 1/50 | 4/50
Trim VX (August 2009) | 4/50 | 5/50 | 9/50
Total (%) | 12/249 (4.8%) | 17/249 (6.8%) | 28/249 (11.2%)
Mean ± standard deviation | 4.8% ± 2.7% | 6.8% ± 3.7% | 11.3% ± 5.5%
Range | 2%–8% | 2%–10% | 6%–18%
Overall Historical Incidence: All Routes
Total (%) | 27/549 (4.9%) | 24/549 (4.4%) | 50/549 (9.1%)
Mean ± standard deviation | 4.9% ± 3.5% | 4.4% ± 3.5% | 9.1% ± 5.2%
Range | 0%–10% | 0%–10% | 2%–18%

^a^ Data as of June 2015.

Table D-4 Historical Incidence of Malignant Lymphoma in Control Female B6C3F1/N Mice^a^

Study (Study Start) | Incidence in Controls
Historical Incidence: Inhalation Studies
Antimony trioxide (October 2008) | 7/50
CIMSTAR 3800 (May 2008) | 18/50
Cobalt (May 2006) | 14/50
Vinylidene chloride (June 2005) | 14/50
Trim VX (August 2009) | 10/50
Total (%) | 63/250 (25.2%)
Mean ± standard deviation | 25.2% ± 8.4%
Range | 14%–36%
Overall Historical Incidence: All Routes
Total (%) | 109/550 (19.8%)
Mean ± standard deviation | 19.8% ± 7.9%
Range | 12%–36%

^a^ Data as of June 2015; may include data for histiocytic, lymphocytic, mixed, unspecified, or undifferentiated cell types.

Table D-5 Historical Incidence of Squamous Cell Carcinoma of the Skin in Control Female B6C3F1/N Mice^a^

Study (Study Start) | Incidence in Controls
Historical Incidence: Inhalation Studies
Antimony trioxide (October 2008) | 0/50
CIMSTAR 3800 (May 2008) | 0/50
Cobalt metal (May 2006) | 0/50
Vinylidene chloride (June 2005) | 0/50
Trim VX (August 2009) | 0/50
Total | 0/250
Overall Historical Incidence: All Routes
Total | 0/550

^a^ Data as of June 2015.

Table D-6 Historical Incidence of Benign Pheochromocytoma of the Adrenal Medulla in Control Female B6C3F1/N Mice^a^

Study (Study Start) | Incidence in Controls
Historical Incidence: Inhalation Studies
Antimony trioxide (October 2008) | 0/50
CIMSTAR 3800 (May 2008) | 1/49
Cobalt metal (May 2006) | 1/50
Vinylidene chloride (June 2005) | 1/50
Trim VX (August 2009) | 2/50
Total (%) | 5/249 (2.0%)
Mean ± standard deviation | 2.0% ± 1.4%
Range | 0%–4%
Overall Historical Incidence: All Routes
Total (%) | 6/546 (1.1%)
Mean ± standard deviation | 1.1% ± 1.4%
Range | 0%–4%

^a^ Data as of June 2015.

Table D-7 Historical Incidence of Hepatocellular Adenoma or Carcinoma (combined) in Control Female B6C3F1/N Mice^a^

Study (Study Start) | Incidence in Controls
Historical Incidence: Inhalation Studies
Antimony trioxide (October 2008) | 14/50
CIMSTAR 3800 (May 2008) | 20/50
Cobalt metal (May 2006) | 25/50
Vinylidene chloride (June 2005) | 28/50
Trim VX (August 2009) | 15/50
Total (%) | 102/250 (40.8%)
Mean ± standard deviation | 40.8% ± 12.2%
Range | 28%–56%
Overall Historical Incidence: All Routes
Total (%) | 207/549 (37.7%)
Mean ± standard deviation | 37.8% ± 16.6%
Range | 16%–73%

^a^ Data as of June 2015.

Table D-8 Summary of the Incidence of Nonneoplastic Lesions in Female Mice in the Two-year Inhalation Study of Antimony Trioxide^a^

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Disposition Summary
Animals initially in study | 60 | 60 | 60 | 60
Twelve-month interim evaluation | 10 | 10 | 10 | 10
Early deaths
Accidental death | 1 | – | – | –
Moribund | 10 | 11 | 16 | 27
Natural deaths | 3 | 8 | 8 | 8
Survivors
Terminal kill | 36 | 31 | 26 | 15
Animals examined microscopically | 60 | 60 | 60 | 60
Twelve-month Interim Evaluation
Alimentary System
Esophagus | (10) | (10) | (10) | (10)
Gallbladder | (10) | (10) | (10) | (10)
Intestine large, cecum | (10) | (10) | (10) | (10)
Intestine large, colon | (10) | (10) | (10) | (10)
Intestine large, rectum | (10) | (10) | (10) | (10)
Intestine small, duodenum | (10) | (10) | (10) | (10)
Intestine small, ileum | (10) | (10) | (10) | (10)
Intestine small, jejunum | (10) | (10) | (10) | (10)
Liver | (10) | (10) | (10) | (10)
Basophilic focus | – | 1 (10%) | – | –
Clear cell focus | – | – | 1 (10%) | –
Pancreas | (10) | (10) | (10) | (10)
Atrophy | – | – | 1 (10%) | –
Salivary glands | (10) | (10) | (10) | (10)
Stomach, forestomach | (10) | (10) | (10) | (10)
Stomach, glandular | (10) | (10) | (10) | (10)
Tooth | (1) | (0) | (0) | (0)
Dysplasia | 1 (100%) | – | – | –
Cardiovascular System
Blood vessel | (10) | (9) | (10) | (10)
Adventitia, inflammation, chronic active | 1 (10%) | – | – | –
Heart | (10) | (10) | (10) | (10)
Cardiomyopathy | – | 1 (10%) | – | –
Artery, inflammation, chronic active | – | – | 1 (10%) | –
Genital System
Clitoral gland | (10) | (9) | (7) | (7)
Ovary | (10) | (10) | (10) | (10)
Follicle, cyst | 1 (10%) | – | 1 (10%) | 1 (10%)
Uterus | (10) | (10) | (10) | (10)
Endometrium, hyperplasia, cystic | 7 (70%) | 9 (90%) | 10 (100%) | 9 (90%)
Hematopoietic System
Bone marrow | (10) | (10) | (10) | (10)
Lymph node, bronchial | (5) | (10) | (9) | (10)
Foreign body | – | 10 (100%) | 9 (100%) | 10 (100%)
Hyperplasia, lymphoid | – | 6 (60%) | 9 (100%) | 10 (100%)
Infiltration cellular, histiocyte | – | 1 (10%) | 6 (67%) | 4 (40%)
Lymph node, mandibular | (6) | (8) | (7) | (8)
Lymph node, mediastinal | (4) | (7) | (8) | (10)
Foreign body | – | 2 (29%) | 2 (25%) | 9 (90%)
Hyperplasia, lymphoid | – | 1 (14%) | 4 (50%) | 4 (40%)
Infiltration cellular, histiocyte | – | – | 2 (25%) | 3 (30%)
Lymph node, mesenteric | (9) | (10) | (10) | (10)
Spleen | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | – | – | 3 (30%) | 2 (20%)
Hyperplasia, lymphoid | – | 4 (40%) | 6 (60%) | 5 (50%)
Thymus | (10) | (9) | (10) | (9)
Medulla, hyperplasia, lymphoid | 1 (10%) | 4 (44%) | 4 (40%) | 3 (33%)
Integumentary System
Mammary gland | (9) | (10) | (10) | (10)
Skin | (10) | (10) | (10) | (10)
Dermis, infiltration cellular, mixed cell | 2 (20%) | 1 (10%) | – | 2 (20%)
Musculoskeletal System
Bone | (10) | (10) | (10) | (10)
Femur, fibro-osseous lesion | 1 (10%) | – | 1 (10%) | –
Respiratory System
Larynx | (10) | (9) | (10) | (10)
Foreign body | – | 2 (22%) | 7 (70%) | 7 (70%)
Respiratory epithelium, hyperplasia | – | 1 (11%) | 4 (40%) | –
Respiratory epithelium, metaplasia, squamous | 1 (10%) | – | 1 (10%) | 8 (80%)
Lung | (10) | (10) | (10) | (10)
Foreign body | – | 10 (100%) | 10 (100%) | 10 (100%)
Infiltration cellular, lymphocyte | 3 (30%) | 10 (100%) | 10 (100%) | 9 (90%)
Inflammation, chronic active | – | 10 (100%) | 10 (100%) | 10 (100%)
Alveolar epithelium, hyperplasia | – | 8 (80%) | 10 (100%) | 10 (100%)
Alveolus, fibrosis | – | 2 (20%) | 6 (60%) | 10 (100%)
Bronchiole, epithelium, hyperplasia | – | 5 (50%) | 10 (100%) | 10 (100%)
Pleura, fibrosis | – | 6 (60%) | 9 (90%) | 10 (100%)
Pleura, inflammation | – | 7 (70%) | 10 (100%) | 10 (100%)
Nose | (10) | (10) | (10) | (10)
Foreign body | – | 6 (60%) | 9 (90%) | 10 (100%)
Inflammation, acute | – | – | 1 (10%) | –
Olfactory epithelium, accumulation, hyaline droplet | 1 (10%) | – | – | –
Olfactory epithelium, metaplasia, respiratory | – | – | – | 1 (10%)
Respiratory epithelium, accumulation, hyaline droplet | 6 (60%) | 4 (40%) | 3 (30%) | –
Respiratory epithelium, inflammation, acute | 1 (10%) | – | – | –
Trachea | (10) | (10) | (10) | (10)
Foreign body | – | – | 2 (20%) | 4 (40%)
Inflammation, chronic active | – | 1 (10%) | – | –
Special Senses System
Eye | (10) | (10) | (10) | (10)
Harderian gland | (10) | (10) | (10) | (10)
Hyperplasia | 1 (10%) | – | – | –
Urinary System
Kidney | (10) | (10) | (10) | (10)
Nephropathy | 2 (20%) | – | 1 (10%) | 1 (10%)
Urinary bladder | (10) | (10) | (10) | (10)
Systems Examined at 12 Months with No Lesions Observed
Endocrine System
General Body System
Nervous System
Two-year Study
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Gallbladder | (46) | (41) | (44) | (45)
Inflammation, chronic | – | 1 (2%) | 1 (2%) | –
Intestine large, cecum | (47) | (44) | (48) | (47)
Inflammation, chronic active | – | 2 (5%) | 2 (4%) | –
Intestine large, colon | (47) | (47) | (49) | (47)
Necrosis | – | – | 1 (2%) | –
Intestine large, rectum | (44) | (46) | (48) | (47)
Intestine small, duodenum | (47) | (44) | (45) | (45)
Intestine small, ileum | (47) | (45) | (47) | (45)
Inflammation, chronic active | – | – | 1 (2%) | –
Peyer’s patch, hyperplasia, lymphoid | – | – | 1 (2%) | –
Intestine small, jejunum | (47) | (43) | (46) | (44)
Inflammation | – | 1 (2%) | – | –
Peyer’s patch, hyperplasia, lymphoid | 1 (2%) | – | – | –
Liver | (50) | (50) | (50) | (50)
Angiectasis | 2 (4%) | 1 (2%) | 1 (2%) | 2 (4%)
Basophilic focus | – | – | – | 1 (2%)
Clear cell focus | 6 (12%) | 5 (10%) | 3 (6%) | 2 (4%)
Cyst | – | – | 1 (2%) | –
Eosinophilic focus | 2 (4%) | 3 (6%) | 2 (4%) | –
Fatty change | – | 2 (4%) | 1 (2%) | –
Hematopoietic cell proliferation | – | – | – | 1 (2%)
Inflammation, chronic active | 4 (8%) | 3 (6%) | 1 (2%) | 2 (4%)
Mineralization | – | 1 (2%) | – | –
Mixed cell focus | 1 (2%) | – | 1 (2%) | –
Necrosis | 3 (6%) | 2 (4%) | 5 (10%) | 2 (4%)
Tension lipidosis | 4 (8%) | 3 (6%) | 3 (6%) | –
Thrombosis | – | 1 (2%) | – | –
Centrilobular, fatty change | – | 1 (2%) | – | –
Hepatocyte, periportal, hypertrophy | – | – | 1 (2%) | –
Mesentery | (9) | (12) | (16) | (7)
Cyst | – | 1 (8%) | – | –
Inflammation, suppurative | – | – | 1 (6%) | –
Inflammation, chronic | – | – | – | 1 (14%)
Necrosis, fatty | 5 (56%) | 9 (75%) | 11 (69%) | 4 (57%)
Artery, inflammation, chronic active | 2 (22%) | – | 2 (13%) | 1 (14%)
Fat, necrosis | – | – | – | 1 (14%)
Lymphatic, angiectasis | – | – | 1 (6%) | –
Pancreas | (50) | (50) | (50) | (50)
Atrophy | – | 3 (6%) | 2 (4%) | –
Hypertrophy | – | 1 (2%) | – | –
Inflammation | – | – | 2 (4%) | –
Inflammation, chronic active | – | – | – | 1 (2%)
Necrosis | – | – | 1 (2%) | –
Artery, inflammation, chronic active | – | 1 (2%) | – | 1 (2%)
Duct, cyst | – | 2 (4%) | 1 (2%) | –
Salivary glands | (50) | (50) | (50) | (50)
Inflammation, acute | – | 1 (2%) | – | –
Artery, inflammation, chronic active | – | – | 1 (2%) | 1 (2%)
Stomach, forestomach | (50) | (50) | (50) | (50)
Hyperkeratosis | 2 (4%) | – | – | –
Hyperplasia, squamous | – | – | – | 1 (2%)
Inflammation, chronic active | – | 1 (2%) | – | 3 (6%)
Mineralization | – | 1 (2%) | – | –
Perforation, chronic active | – | – | – | 1 (2%)
Stomach, glandular | (50) | (49) | (50) | (50)
Inflammation, chronic active | 1 (2%) | 1 (2%) | 3 (6%) | 2 (4%)
Mineralization | 2 (4%) | 3 (6%) | 2 (4%) | 2 (4%)
Necrosis | – | 1 (2%) | – | 1 (2%)
Ulcer | – | – | – | 1 (2%)
Artery, inflammation, chronic active | – | – | 1 (2%) | –
Tongue | (0) | (1) | (0) | (0)
Hyperkeratosis | – | 1 (100%) | – | –
Inflammation, chronic active | – | 1 (100%) | – | –
Ulcer | – | 1 (100%) | – | –
Tooth | (0) | (2) | (2) | (1)
Dysplasia | – | 1 (50%) | 1 (50%) | 1 (100%)
Inflammation, chronic active | – | 1 (50%) | – | –
Peridontal tissue, mineralization | – | – | 1 (50%) | –
Cardiovascular System
Blood vessel | (50) | (48) | (47) | (46)
Inflammation, chronic active | 1 (2%) | – | 2 (4%) | –
Mineralization | – | 1 (2%) | – | –
Thrombosis | – | – | 1 (2%) | –
Adventitia, inflammation, chronic active | – | – | 2 (4%) | 1 (2%)
Media, inflammation, chronic active | – | – | 1 (2%) | 1 (2%)
Media, mineralization | – | – | 1 (2%) | –
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 11 (22%) | 13 (26%) | 6 (12%) | 11 (22%)
Necrosis, acute | 1 (2%) | – | – | –
Thrombosis | – | 2 (4%) | – | –
Artery, inflammation, chronic active | 10 (20%) | 4 (8%) | 11 (22%) | 5 (10%)
Artery, mineralization | – | 1 (2%) | – | –
Epicardium, inflammation, chronic active | – | 2 (4%) | 7 (14%) | 7 (14%)
Epicardium, myocardium, necrosis | – | – | 1 (2%) | –
Myocardium, inflammation, acute | – | 2 (4%) | 1 (2%) | –
Myocardium, inflammation, chronic active | – | 1 (2%) | – | –
Myocardium, necrosis | – | 1 (2%) | – | –
Pericardium, hyperplasia, lymphoid | – | – | 1 (2%) | –
Pericardium, inflammation, chronic active | – | – | 1 (2%) | 1 (2%)
Valve, inflammation, chronic active | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Necrosis | – | – | 1 (2%) | –
Zona fasciculata, hypertrophy | 12 (24%) | 16 (32%) | 11 (22%) | 11 (22%)
Zona fasciculata, necrosis | – | – | 1 (2%) | –
Zona glomerulosa, hyperplasia | – | – | – | 1 (2%)
Adrenal medulla | (50) | (50) | (48) | (49)
Hyperplasia | 9 (18%) | 8 (16%) | 9 (19%) | 7 (14%)
Islets, pancreatic | (50) | (49) | (49) | (49)
Hyperplasia, adenomatous | 1 (2%) | – | – | –
Parathyroid gland | (27) | (33) | (34) | (32)
Cyst | 1 (4%) | – | – | –
Hypertrophy | 1 (4%) | – | – | –
Pituitary gland | (49) | (50) | (50) | (50)
Pars distalis, angiectasis | – | – | 1 (2%) | 2 (4%)
Pars distalis, cyst | 2 (4%) | 1 (2%) | – | –
Pars distalis, hyperplasia | 15 (31%) | 6 (12%) | 10 (20%) | 14 (28%)
Pars nervosa, inflammation, acute | – | – | – | 1 (2%)
Pars nervosa, thrombosis | – | – | 1 (2%) | –
Thyroid gland | (48) | (50) | (50) | (50)
Inflammation, chronic active | – | – | 1 (2%) | 1 (2%)
Follicular cell, hyperplasia | 1 (2%) | – | – | –
General Body System
Peritoneum | (0) | (0) | (1) | (0)
Inflammation, suppurative | – | – | 1 (100%) | –
Genital System
Clitoral gland | (48) | (44) | (47) | (42)
Inflammation, chronic active | 1 (2%) | 1 (2%) | – | 1 (2%)
Ovary | (50) | (49) | (50) | (50)
Angiectasis | 1 (2%) | – | 2 (4%) | 1 (2%)
Cyst | – | – | 1 (2%) | –
Hemorrhage | – | – | 1 (2%) | –
Inflammation, acute | 1 (2%) | – | 1 (2%) | 1 (2%)
Inflammation, chronic active | 1 (2%) | – | 1 (2%) | 1 (2%)
Mineralization | – | – | – | 1 (2%)
Necrosis, fatty | – | – | – | 1 (2%)
Artery, inflammation, chronic active | – | – | 1 (2%) | –
Bursa, cyst | 1 (2%) | 1 (2%) | 1 (2%) | 3 (6%)
Follicle, cyst | 7 (14%) | 11 (22%) | 13 (26%) | 13 (26%)
Oviduct | (1) | (0) | (0) | (0)
Uterus | (50) | (50) | (50) | (50)
Angiectasis | 2 (4%) | – | 1 (2%) | 1 (2%)
Hydrometra | – | – | 1 (2%) | –
Inflammation, chronic active | 1 (2%) | 3 (6%) | 1 (2%) | 2 (4%)
Thrombosis | 1 (2%) | – | – | –
Ulcer | – | – | – | 1 (2%)
Endometrial glands, endometrium, hyperplasia | 1 (2%) | – | – | –
Endometrium, hyperplasia, cystic | 41 (82%) | 43 (86%) | 44 (88%) | 41 (82%)
Lymphatic, angiectasis | – | – | 1 (2%) | –
Serosa, cyst | – | 1 (2%) | – | –
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Atrophy | – | – | – | 1 (2%)
Hyperplasia | 3 (6%) | 5 (10%) | 15 (30%) | 28 (56%)
Myelofibrosis | 1 (2%) | – | – | –
Necrosis | – | – | 1 (2%) | –
Lymph node | (6) | (9) | (14) | (16)
Iliac, angiectasis | – | 1 (11%) | 1 (7%) | –
Iliac, hyperplasia | – | – | – | 1 (6%)
Iliac, hyperplasia, lymphoid | – | – | 1 (7%) | –
Iliac, inflammation | – | – | – | 1 (6%)
Lumbar, angiectasis | – | – | 1 (7%) | –
Lumbar, ectasia | – | – | – | 3 (19%)
Lumbar, hematopoietic cell proliferation | – | – | – | 1 (6%)
Lumbar, hyperplasia, lymphoid | 1 (17%) | – | – | –
Renal, angiectasis | – | 3 (33%) | 1 (7%) | –
Renal, hyperplasia, lymphoid | 1 (17%) | – | – | 1 (6%)
Lymph node, bronchial | (41) | (47) | (48) | (49)
Foreign body | – | 34 (72%) | 46 (96%) | 43 (88%)
Hyperplasia, lymphoid | 2 (5%) | 15 (32%) | 17 (35%) | 11 (22%)
Infiltration cellular, histiocyte | – | 2 (4%) | 7 (15%) | 7 (14%)
Infiltration cellular, plasma cell | – | – | – | 1 (2%)
Inflammation, acute | 1 (2%) | – | – | 1 (2%)
Lymph node, mandibular | (41) | (28) | (38) | (39)
Angiectasis | – | 1 (4%) | – | –
Foreign body | – | 5 (18%) | 9 (24%) | 3 (8%)
Hyperplasia, lymphoid | 7 (17%) | 1 (4%) | 2 (5%) | 1 (3%)
Infiltration cellular, histiocyte | – | – | 2 (5%) | 1 (3%)
Lymph node, mediastinal | (46) | (48) | (49) | (50)
Angiectasis | – | 1 (2%) | – | 1 (2%)
Foreign body | – | 28 (58%) | 45 (92%) | 44 (88%)
Hyperplasia, lymphoid | – | 3 (6%) | 16 (33%) | 18 (36%)
Infiltration cellular, histiocyte | – | 6 (13%) | 11 (22%) | 16 (32%)
Infiltration cellular, plasma cell | – | – | – | 1 (2%)
Inflammation, acute | 1 (2%) | – | – | –
Pigmentation | 1 (2%) | – | – | –
Arteriole, necrosis | – | – | 1 (2%) | –
Artery, inflammation, chronic active | – | 1 (2%) | 1 (2%) | –
Medullary sinuses, dilatation | 1 (2%) | – | – | –
Lymph node, mesenteric | (50) | (48) | (48) | (46)
Angiectasis | – | 2 (4%) | 1 (2%) | –
Hematopoietic cell proliferation | – | – | – | 1 (2%)
Hyperplasia, lymphoid | – | 2 (4%) | 3 (6%) | 1 (2%)
Infiltration cellular, histiocyte | – | – | 1 (2%) | –
Infiltration cellular, mixed cell | – | 2 (4%) | 1 (2%) | –
Infiltration cellular, plasma cell | – | 1 (2%) | – | 1 (2%)
Inflammation, chronic | 1 (2%) | – | – | –
Necrosis, acute | – | – | 1 (2%) | –
Spleen | (50) | (50) | (50) | (50)
Angiectasis | – | 1 (2%) | – | –
Hematopoietic cell proliferation | 17 (34%) | 19 (38%) | 20 (40%) | 35 (70%)
Hyperplasia, lymphoid | 16 (32%) | 6 (12%) | 8 (16%) | 7 (14%)
Inflammation, chronic active | – | 1 (2%) | – | 1 (2%)
Metaplasia, osseous | – | – | 1 (2%) | –
Necrosis | – | 1 (2%) | – | –
Thymus | (47) | (49) | (49) | (49)
Angiectasis | 1 (2%) | 1 (2%) | – | –
Cyst | – | – | 1 (2%) | –
Depletion cellular | 9 (19%) | 18 (37%) | 23 (47%) | 29 (59%)
Foreign body | – | – | – | 1 (2%)
Hyperplasia, lymphoid | – | – | 1 (2%) | –
Inflammation, chronic active | 1 (2%) | 1 (2%) | 2 (4%) | –
Medulla, hyperplasia, lymphoid | 13 (28%) | 12 (24%) | 15 (31%) | 16 (33%)
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Dilatation | – | – | 1 (2%) | –
Hyperplasia | – | 2 (4%) | – | 1 (2%)
Hypertrophy | 1 (2%) | 4 (8%) | 3 (6%) | 1 (2%)
Inflammation, chronic active | – | 2 (4%) | – | 2 (4%)
Necrosis, acute | – | – | 1 (2%) | –
Skin | (50) | (50) | (50) | (50)
Hyperplasia | – | – | – | 2 (4%)
Inflammation, chronic active | 2 (4%) | 2 (4%) | 2 (4%) | 4 (8%)
Ulcer | – | – | – | 1 (2%)
Musculoskeletal System
Bone | (50) | (50) | (49) | (50)
Hyperostosis | – | – | 1 (2%) | –
Femur, fibro-osseous lesion | 21 (42%) | 16 (32%) | 10 (20%) | 6 (12%)
Maxilla, fibro-osseous lesion | – | 2 (4%) | 1 (2%) | 1 (2%)
Skeletal muscle | (4) | (1) | (4) | (3)
Hemorrhage | 1 (25%) | – | – | –
Inflammation, chronic | – | – | 1 (25%) | –
Artery, inflammation, chronic active | 1 (25%) | – | – | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Compression | 2 (4%) | 2 (4%) | 2 (4%) | 1 (2%)
Demyelination | 1 (2%) | – | – | 1 (2%)
Necrosis, acute | – | – | – | 1 (2%)
Thrombosis | – | 1 (2%) | 1 (2%) | –
Arteriole, inflammation, chronic active | 2 (4%) | – | 2 (4%) | 1 (2%)
Glial cell, hyperplasia | 1 (2%) | – | – | –
Meninges, infiltration cellular, histiocyte | – | – | 1 (2%) | –
Meninges, infiltration cellular, lymphoid | 1 (2%) | 2 (4%) | 3 (6%) | 1 (2%)
Peripheral nerve | (3) | (0) | (2) | (1)
Sciatic, degeneration | – | – | 1 (50%) | –
Spinal cord | (4) | (0) | (2) | (1)
Hemorrhage | 1 (25%) | – | – | –
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Foreign body | – | 25 (50%) | 39 (78%) | 48 (96%)
Inflammation, chronic active | 4 (8%) | 3 (6%) | 2 (4%) | 4 (8%)
Mineralization | – | 1 (2%) | – | –
Arteriole, inflammation, chronic active | 1 (2%) | – | 2 (4%) | –
Artery, inflammation, chronic active | – | 1 (2%) | – | –
Cartilage, mineralization | – | 2 (4%) | – | –
Respiratory epithelium, hyperplasia | 2 (4%) | – | 14 (28%) | 18 (36%)
Respiratory epithelium, metaplasia, squamous | 1 (2%) | – | 5 (10%) | 24 (48%)
Squamous epithelium, hyperplasia | 4 (8%) | 1 (2%) | 1 (2%) | 12 (24%)
Lung | (50) | (50) | (50) | (50)
Foreign body | – | 50 (100%) | 50 (100%) | 50 (100%)
Hemorrhage | – | 1 (2%) | – | –
Infiltration cellular, histiocyte | 1 (2%) | – | – | –
Infiltration cellular, lymphocyte | 7 (14%) | 37 (74%) | 37 (74%) | 26 (52%)
Inflammation, chronic active | 1 (2%) | 50 (100%) | 50 (100%) | 50 (100%)
Thrombosis | 1 (2%) | 1 (2%) | | 1 (2%)
Alveolar epithelium, hyperplasia | 1 (2%) | 36 (72%) | 49 (98%) | 48 (96%)
Alveolar epithelium, metaplasia, squamous | – | 1 (2%) | – | 2 (4%)
Alveolus, fibrosis | – | 13 (26%) | 30 (60%) | 38 (76%)
Alveolus, infiltration cellular, histiocyte | – | – | – | 1 (2%)
Alveolus, metaplasia, squamous | – | – | 1 (2%) | –
Artery, inflammation, acute | 1 (2%) | – | – | –
Bronchiole, epithelium, hyperplasia | 1 (2%) | 34 (68%) | 48 (96%) | 45 (90%)
Bronchiole, epithelium, goblet cell, metaplasia | – | – | 1 (2%) | 1 (2%)
Bronchus, epithelium, hyperplasia | – | – | 1 (2%) | –
Bronchus, epithelium, goblet cell, metaplasia | – | – | – | 2 (4%)
Mediastinum, inflammation, acute | 1 (2%) | – | – | –
Mediastinum, necrosis, fatty | – | – | 1 (2%) | –
Pleura, fibrosis | 1 (2%) | 39 (78%) | 50 (100%) | 50 (100%)
Pleura, inflammation | 4 (8%) | 27 (54%) | 42 (84%) | 38 (76%)
Nose | (50) | (49) | (50) | (50)
Foreign body | 1 (2%) | 44 (90%) | 45 (90%) | 48 (96%)
Artery, inflammation, chronic active | 1 (2%) | – | – | –
Glands, dilatation | – | – | – | 1 (2%)
Glands, olfactory epithelium, dilatation | 1 (2%) | – | – | –
Glands, respiratory epithelium, accumulation, hyaline droplet | – | – | 1 (2%) | –
Lumen, hyperkeratosis | 1 (2%) | – | – | –
Nasolacrimal duct, inflammation, acute | – | – | – | 1 (2%)
Nasolacrimal duct, inflammation, chronic active | – | 1 (2%) | 1 (2%) | –
Olfactory epithelium, accumulation, hyaline droplet | 18 (36%) | 9 (18%) | 12 (24%) | 8 (16%)
Olfactory epithelium, atrophy | – | 2 (4%) | 1 (2%) | 1 (2%)
Olfactory epithelium, metaplasia, respiratory | – | 1 (2%) | 3 (6%) | –
Olfactory epithelium, necrosis | 1 (2%) | – | – | –
Respiratory epithelium, accumulation, hyaline droplet | 29 (58%) | 22 (45%) | 25 (50%) | 19 (38%)
Respiratory epithelium, hyperplasia | – | – | – | 2 (4%)
Respiratory epithelium, inflammation, acute | 2 (4%) | 7 (14%) | 7 (14%) | 5 (10%)
Respiratory epithelium, inflammation, chronic active | 2 (4%) | 3 (6%) | 4 (8%) | 5 (10%)
Respiratory epithelium, metaplasia, squamous | – | 3 (6%) | 2 (4%) | 4 (8%)
Respiratory epithelium, mineralization | – | – | 1 (2%) | –
Respiratory epithelium, necrosis | 1 (2%) | 2 (4%) | – | –
Turbinate, inflammation, suppurative | 1 (2%) | – | – | –
Turbinate, necrosis | – | – | 1 (2%) | –
Vomeronasal organ, necrosis | 1 (2%) | – | – | –
Pleura | (0) | (2) | (0) | (2)
Necrosis, fatty | – | 1 (50%) | – | 1 (50%)
Trachea | (50) | (50) | (50) | (50)
Foreign body | – | 7 (14%) | 14 (28%) | 20 (40%)
Inflammation, chronic active | 2 (4%) | 4 (8%) | 4 (8%) | –
Artery, inflammation, chronic active | 1 (2%) | – | 1 (2%) | –
Cartilage, metaplasia, osseous | – | 1 (2%) | – | –
Epithelium, hyperplasia | – | – | – | 1 (2%)
Epithelium, metaplasia, squamous | – | – | 1 (2%) | 1 (2%)
Epithelium, mineralization | – | 2 (4%) | – | –
Glands, inflammation, acute | – | 1 (2%) | – | –
Glands, metaplasia, cartilaginous | 2 (4%) | – | – | –
Special Senses System
Ear | (0) | (0) | (0) | (1)
Eye | (49) | (47) | (49) | (49)
Cataract | 1 (2%) | 4 (9%) | 2 (4%) | 4 (8%)
Cornea, inflammation, chronic active | – | – | – | 1 (2%)
Retina, atrophy | 1 (2%) | – | – | –
Harderian gland | (49) | (50) | (50) | (50)
Hyperplasia | 2 (4%) | – | – | –
Inflammation, acute | – | – | 1 (2%) | –
Zymbal’s gland | (0) | (0) | (0) | (1)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Cyst | – | – | 2 (4%) | –
Infarct | 1 (2%) | 3 (6%) | – | –
Inflammation, acute | – | 2 (4%) | – | –
Metaplasia, osseous | 1 (2%) | – | 2 (4%) | 1 (2%)
Mineralization | – | 1 (2%) | – | –
Necrosis | – | 1 (2%) | – | –
Nephropathy | 35 (70%) | 30 (60%) | 29 (58%) | 32 (64%)
Artery, inflammation, chronic active | – | – | 1 (2%) | –
Urinary bladder | (50) | (50) | (50) | (50)
Hyperplasia, lymphoid | 1 (2%) | – | 1 (2%) | –
Infiltration cellular, lymphocyte, focal | – | – | – | 1 (2%)
Artery, inflammation, chronic active | 1 (2%) | – | 2 (4%) | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.