# Appendix C Summary of Lesions in Male Mice in the Two-year Inhalation Study of Antimony Trioxide

Table C-1 Summary of the Incidence of Neoplasms in Male Mice in the Two-year Inhalation Study of Antimony Trioxide^a^

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Disposition Summary
Animals initially in study | 60 | 60 | 60 | 60
Twelve-month interim evaluation | 10 | 10 | 10 | 10
Early deaths
Accidental death | – | 1 | – | –
Moribund | 7 | 12 | 15 | 26
Natural deaths | 5 | 7 | 8 | 7
Survivors
Terminal kill | 38 | 30 | 27 | 17
Animals examined microscopically | 60 | 60 | 60 | 60
Twelve-month Interim Evaluation
Alimentary System
Esophagus | (10) | (10) | (10) | (10)
Gallbladder | (8) | (10) | (9) | (9)
Intestine large, cecum | (10) | (10) | (10) | (10)
Intestine large, colon | (10) | (10) | (10) | (10)
Intestine large, rectum | (10) | (10) | (10) | (10)
Intestine small, duodenum | (10) | (10) | (10) | (10)
Intestine small, ileum | (10) | (10) | (10) | (10)
Intestine small, jejunum | (10) | (10) | (10) | (10)
Liver | (10) | (10) | (10) | (10)
Hepatocellular adenoma | 2 (20%) | 2 (20%) | 1 (10%) | 3 (30%)
Hepatocellular adenoma, multiple | 1 (10%) | – | 2 (20%) | 2 (20%)
Hepatocellular carcinoma | 1 (10%) | 1 (10%) | 1 (10%) | 2 (20%)
Mesentery | (0) | (0) | (0) | (1)
Pancreas | (10) | (10) | (10) | (10)
Salivary glands | (10) | (10) | (10) | (10)
Stomach, forestomach | (10) | (10) | (10) | (10)
Stomach, glandular | (10) | (9) | (10) | (10)
Tooth | (1) | (0) | (0) | (0)
Respiratory System
Larynx | (10) | (10) | (10) | (10)
Lung | (10) | (10) | (10) | (10)
Alveolar/bronchiolar adenoma | – | – | 2 (20%) | –
Alveolar/bronchiolar carcinoma | – | – | 1 (10%) | 2 (20%)
Nose | (10) | (10) | (10) | (10)
Trachea | (10) | (10) | (10) | (10)
Systems Examined at 12 Months with No Neoplasms Observed
Cardiovascular System
Endocrine System
General Body System
Genital System
Hematopoietic System
Integumentary System
Musculoskeletal System
Nervous System
Special Senses System
Urinary System
Two-year Study
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Hepatocholangiocarcinoma, metastatic, liver | 1 (2%) | – | – | –
Gallbladder | (44) | (41) | (38) | (40)
Intestine large, cecum | (46) | (45) | (45) | (47)
Adenoma | – | 2 (4%) | – | –
Intestine large, colon | (48) | (45) | (47) | (48)
Intestine large, rectum | (47) | (42) | (45) | (48)
Intestine small, duodenum | (45) | (45) | (42) | (46)
Adenoma | 2 (4%) | – | – | –
Intestine small, ileum | (46) | (44) | (43) | (48)
Adenoma | – | – | 1 (2%) | –
Intestine small, jejunum | (46) | (44) | (42) | (48)
Carcinoma | 1 (2%) | 1 (2%) | – | 1 (2%)
Liver | (50) | (50) | (49) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Cholangiocarcinoma | 1 (2%) | – | – | –
Cholangioma | – | – | – | 1 (2%)
Hemangiosarcoma | – | – | – | 1 (2%)
Hemangiosarcoma, metastatic, spleen | – | – | 1 (2%) | –
Hepatoblastoma | 2 (4%) | 1 (2%) | – | 4 (8%)
Hepatocellular adenoma | 12 (24%) | 15 (30%) | 22 (45%) | 15 (30%)
Hepatocellular adenoma, multiple | 18 (36%) | 16 (32%) | 14 (29%) | 18 (36%)
Hepatocellular carcinoma | 13 (26%) | 17 (34%) | 7 (14%) | 15 (30%)
Hepatocellular carcinoma, multiple | 2 (4%) | 6 (12%) | 7 (14%) | 5 (10%)
Hepatocholangiocarcinoma | 1 (2%) | – | – | –
Plasma cell tumor malignant, metastatic spleen | – | 1 (2%) | – | –
Rhabdomyosarcoma, metastatic, skeletal muscle | – | 1 (2%) | – | –
Mesentery | (7) | (4) | (4) | (5)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (25%) | – | –
Hepatocholangiocarcinoma, metastatic, liver | 1 (14%) | – | – | –
Rhabdomyosarcoma, metastatic, skeletal muscle | – | 1 (25%) | – | –
Oral mucosa | (1) | (0) | (0) | (0)
Pancreas | (49) | (49) | (49) | (50)
Hepatocellular carcinoma, metastatic, liver | – | – | – | 1 (2%)
Plasma cell tumor malignant, metastatic, spleen | – | 1 (2%) | – | –
Rhabdomyosarcoma, metastatic, skeletal muscle | – | 1 (2%) | – | –
Salivary glands | (50) | (50) | (50) | (50)
Stomach, forestomach | (50) | (50) | (49) | (50)
Squamous cell papilloma | 1 (2%) | – | – | –
Stomach, glandular | (48) | (49) | (49) | (50)
Rhabdomyosarcoma, metastatic, skeletal muscle | – | 1 (2%) | – | –
Tooth | (14) | (14) | (14) | (6)
Blood vessel | (50) | (49) | (48) | (44)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Sarcoma, metastatic, uncertain primary site | – | – | 1 (2%) | –
Heart | (50) | (50) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | 1 (2%) | 2 (4%)
Hemangioma | – | 1 (2%) | – | –
Hemangiosarcoma | – | – | 2 (4%) | –
Rhabdomyosarcoma, metastatic, skeletal muscle | – | 1 (2%) | – | –
Sarcoma, metastatic, uncertain primary site | – | – | 1 (2%) | –
Epicardium, carcinoma, metastatic, uncertain primary site | – | 1 (2%) | 1 (2%) | –
Endocrine System
Adrenal cortex | (49) | (50) | (49) | (49)
Adenoma | – | 1 (2%) | – | –
Rhabdomyosarcoma, metastatic, skeletal muscle | – | 1 (2%) | – | –
Capsule, hepatocholangiocarcinoma, metastatic, liver | 1 (2%) | – | – | –
Subcapsular, adenoma | 4 (8%) | – | 2 (4%) | –
Zona fasciculata, adenoma | – | – | 1 (2%) | –
Adrenal medulla | (49) | (50) | (46) | (49)
Pheochromocytoma benign | – | – | 1 (2%) | –
Islets, pancreatic | (49) | (49) | (49) | (50)
Adenoma | – | – | 1 (2%) | –
Parathyroid gland | (27) | (32) | (26) | (33)
Pituitary gland | (49) | (49) | (48) | (50)
Pars distalis, adenoma | – | – | 2 (4%) | –
Thyroid gland | (49) | (49) | (48) | (49)
C-cell, carcinoma | – | 1 (2%) | – | –
Follicular cell, adenoma | – | – | 1 (2%) | –
Follicular cell, carcinoma | – | – | 1 (2%) | –
General Body System
Peritoneum | (0) | (0) | (0) | (1)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (100%)
Genital System
Epididymis | (50) | (50) | (50) | (50)
Fibrosarcoma | – | – | 1 (2%) | –
Hepatocholangiocarcinoma, metastatic, liver | 1 (2%) | – | – | –
Preputial gland | (50) | (50) | (49) | (50)
Prostate | (49) | (50) | (49) | (50)
Rhabdomyosarcoma, metastatic, skeletal muscle | – | 1 (2%) | – | –
Seminal vesicle | (49) | (50) | (49) | (50)
Adenoma | 1 (2%) | – | – | –
Rhabdomyosarcoma, metastatic, skeletal muscle | – | 1 (2%) | – | –
Testes | (49) | (49) | (50) | (50)
Rhabdomyosarcoma, metastatic, skeletal muscle | – | 1 (2%) | – | –
Hematopoietic System
Bone marrow | (49) | (50) | (48) | (50)
Hemangiosarcoma, metastatic, lymph node | – | 1 (2%) | – | –
Hemangiosarcoma, metastatic, spleen | 1 (2%) | – | – | –
Rhabdomyosarcoma, metastatic, skeletal muscle | – | 1 (2%) | – | –
Lymph node | (2) | (2) | (2) | (2)
Hemangiosarcoma | – | 1 (50%) | – | –
Iliac, hemangiosarcoma | – | – | 1 (50%) | –
Pancreatic, alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (50%)
Lymph node, bronchial | (30) | (43) | (47) | (41)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 3 (7%) | 1 (2%) | 5 (12%)
Hemangiosarcoma, metastatic, heart | – | – | 1 (2%) | –
Hepatocellular carcinoma, metastatic, liver | 1 (3%) | – | – | 1 (2%)
Hepatocholangiocarcinoma, metastatic, liver | 1 (3%) | – | – | –
Plasma cell tumor malignant, metastatic, spleen | – | 1 (2%) | – | –
Rhabdomyosarcoma, metastatic, skeletal muscle | – | 1 (2%) | – | –
Sarcoma, metastatic, uncertain primary site | – | – | 1 (2%) | –
Lymph node, mandibular | (27) | (26) | (28) | (26)
Lymph node, mediastinal | (37) | (45) | (48) | (49)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 2 (4%) | 3 (6%) | 4 (8%)
Carcinoma, metastatic, uncertain primary site | – | – | 1 (2%) | –
Hemangiosarcoma, metastatic, heart | – | – | 1 (2%) | –
Hemangiosarcoma, metastatic, spleen | – | – | 1 (2%) | –
Hepatocellular carcinoma, metastatic, liver | 1 (3%) | – | – | 2 (4%)
Hepatocholangiocarcinoma, metastatic, liver | 1 (3%) | – | – | –
Plasma cell tumor malignant, metastatic, spleen | – | 1 (2%) | – | –
Rhabdomyosarcoma, metastatic, skeletal muscle | – | 1 (2%) | – | –
Sarcoma, metastatic, uncertain primary site | – | – | 1 (2%) | –
Lymph node, mesenteric | (48) | (47) | (47) | (50)
Fibrous histiocytoma, metastatic, skin | – | – | – | 1 (2%)
Hepatocellular carcinoma, metastatic, liver | – | – | 1 (2%) | –
Hepatocholangiocarcinoma, metastatic, liver | 1 (2%) | – | – | –
Plasma cell tumor malignant, metastatic, spleen | – | 1 (2%) | – | –
Rhabdomyosarcoma, metastatic, skeletal muscle | – | 1 (2%) | – | –
Spleen | (49) | (50) | (50) | (50)
Hemangiosarcoma | 2 (4%) | – | 1 (2%) | –
Hepatocellular carcinoma, metastatic, liver | 1 (2%) | – | – | –
Plasma cell tumor malignant | – | 1 (2%) | – | –
Thymus | (41) | (38) | (43) | (39)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 2 (5%) | – | 3 (8%)
Hemangiosarcoma, metastatic, heart | – | – | 1 (2%) | –
Hepatocellular carcinoma, metastatic, liver | 1 (2%) | – | – | –
Rhabdomyosarcoma, metastatic, skeletal muscle | – | 1 (3%) | – | –
Sarcoma, metastatic, uncertain primary site | – | – | 1 (2%) | –
Integumentary System
Mammary gland | (0) | (2) | (4) | (1)
Skin | (50) | (50) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Fibrosarcoma | – | – | 2 (4%) | –
Fibrous histiocytoma | – | 1 (2%) | 1 (2%) | 4 (8%)
Hemangioma | – | 1 (2%) | – | –
Sebaceous gland, carcinoma | – | – | 1 (2%) | –
Subcutaneous tissue, alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Musculoskeletal System
Bone | (50) | (50) | (49) | (50)
Hemangiosarcoma, metastatic, spleen | – | – | 1 (2%) | –
Rhabdomyosarcoma, metastatic, skeletal muscle | – | 1 (2%) | – | –
Skeletal muscle | (2) | (3) | (1) | (1)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (100%)
Hepatocholangiocarcinoma, metastatic, liver | 1 (50%) | – | – | –
Rhabdomyosarcoma | – | 1 (33%) | – | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Rhabdomyosarcoma, metastatic, skeletal muscle | – | 1 (2%) | – | –
Peripheral nerve | (1) | (1) | (0) | (0)
Spinal cord | (1) | (2) | (0) | (0)
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | 7 (14%) | 11 (22%) | 7 (14%) | 10 (20%)
Alveolar/bronchiolar adenoma, multiple | 3 (6%) | 3 (6%) | 2 (4%) | 4 (8%)
Alveolar/bronchiolar carcinoma | 4 (8%) | 13 (26%) | 14 (28%) | 16 (32%)
Alveolar/bronchiolar carcinoma, multiple | – | 5 (10%) | 6 (12%) | 11 (22%)
Hepatoblastoma, metastatic, liver | 1 (2%) | – | – | –
Hepatocellular carcinoma, metastatic, liver | 1 (2%) | 3 (6%) | 2 (4%) | 5 (10%)
Hepatocholangiocarcinoma, metastatic, liver | 1 (2%) | – | – | –
Plasma cell tumor malignant, metastatic, spleen | – | 1 (2%) | – | –
Rhabdomyosarcoma, metastatic, skeletal muscle | – | 1 (2%) | – | –
Sarcoma, metastatic, uncertain primary site | – | – | 1 (2%) | –
Nose | (50) | (49) | (49) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Pleura | (0) | (0) | (0) | (2)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (50%)
Trachea | (49) | (50) | (50) | (50)
Special Senses System
Eye | (48) | (49) | (47) | (50)
Hepatocellular carcinoma, metastatic, liver | 1 (2%) | – | – | –
Retrobulbar, alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Harderian gland | (49) | (50) | (50) | (50)
Adenoma | 5 (10%) | 5 (10%) | 4 (8%) | 3 (6%)
Adenoma, multiple | 1 (2%) | 1 (2%) | – | –
Carcinoma | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Hemangioma | – | – | – | 1 (2%)
Urinary System
Kidney | (50) | (50) | (49) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Hepatocellular carcinoma, metastatic, liver | 1 (2%) | – | 1 (2%) | 1 (2%)
Plasma cell tumor malignant | – | 1 (2%) | – | –
Rhabdomyosarcoma, metastatic, skeletal muscle | – | 1 (2%) | – | –
Ureter | (1) | (0) | (0) | (0)
Urinary bladder | (50) | (50) | (48) | (50)
Rhabdomyosarcoma, metastatic, skeletal muscle | – | 1 (2%) | – | –
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | 1 (2%) | 1 (2%) | 3 (6%) | 1 (2%)
Lymphoma malignant | 4 (8%) | 4 (8%) | 3 (6%) | 6 (12%)
Mesothelioma malignant | – | – | – | 1 (2%)
Neoplasm Summary
Total animals with primary neoplasms^c^
Twelve-month interim evaluation | 3 | 3 | 7 | 6
Two-year study | 45 | 45 | 46 | 46
Total primary neoplasms
Twelve-month interim evaluation | 4 | 3 | 7 | 9
Two-year study | 86 | 111 | 109 | 119
Total animals with benign neoplasms
Twelve-month interim evaluation | 3 | 2 | 5 | 5
Two-year study | 37 | 38 | 38 | 37
Total benign neoplasms
Twelve-month interim evaluation | 3 | 2 | 5 | 5
Two-year study | 54 | 56 | 58 | 52
Total animals with malignant neoplasms
Twelve-month interim evaluation | 1 | 1 | 2 | 4
Two-year study | 25 | 40 | 36 | 40
Total malignant neoplasms
Twelve-month interim evaluation | 1 | 1 | 2 | 4
Two-year study | 32 | 55 | 51 | 67
Total animals with metastatic neoplasms
Two-year study | 5 | 9 | 11 | 14
Total metastatic neoplasms
Two-year study | 20 | 38 | 24 | 36
Total animals with malignant neoplasms of uncertain primary site
Two-year study | – | 1 | 3 | –

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table C-2 Statistical Analysis of Primary Neoplasms in Male Mice in the Two-year Inhalation Study of Antimony Trioxide

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Adrenal Cortex: Adenoma
Overall rate^a^ | 4/49 (8%) | 1/50 (2%) | 3/49 (6%) | 0/49 (0%)
Adjusted rate^b^ | 8.7% | 2.5% | 7.3% | 0.0%
Terminal rate^c^ | 3/38 (8%) | 1/30 (3%) | 2/27 (7%) | 0/17 (0%)
First incidence (days) | 702 | 729 (T) | 666 | –^e^
Poly-3 test^d^ | P = 0.123N | P = 0.221N | P = 0.565N | P = 0.095N
Harderian Gland: Adenoma
Overall rate | 6/50 (12%) | 6/50 (12%) | 4/50 (8%) | 3/50 (6%)
Adjusted rate | 12.9% | 14.6% | 9.8% | 7.9%
Terminal rate | 5/38 (13%) | 4/30 (13%) | 4/27 (15%) | 1/17 (6%)
First incidence (days) | 663 | 514 | 729 (T) | 536
Poly-3 test | P = 0.242N | P = 0.532 | P = 0.457N | P = 0.349N
Harderian Gland: Adenoma or Carcinoma
Overall rate | 7/50 (14%) | 7/50 (14%) | 5/50 (10%) | 4/50 (8%)
Adjusted rate | 15.0% | 17.0% | 12.2% | 10.5%
Terminal rate | 5/38 (13%) | 5/30 (17%) | 4/27 (15%) | 2/17 (12%)
First incidence (days) | 663 | 514 | 576 | 536
Poly-3 test | P = 0.279N | P = 0.512 | P = 0.471N | P = 0.388N
Liver: Hepatocellular Adenoma
Overall rate | 30/50 (60%) | 31/50 (62%) | 36/49 (73%) | 33/50 (66%)
Adjusted rate | 62.8% | 68.8% | 80.2% | 76.5%
Terminal rate | 25/38 (66%) | 21/30 (70%) | 24/27 (89%) | 14/17 (82%)
First incidence (days) | 626 | 365 | 279 | 474
Poly-3 test | P = 0.105 | P = 0.344 | P = 0.043 | P = 0.106
Liver: Hepatocellular Carcinoma
Overall rate | 15/50 (30%) | 23/50 (46%) | 14/49 (29%) | 20/50 (40%)
Adjusted rate | 30.8% | 50.5% | 33.2% | 46.6%
Terminal rate | 9/38 (24%) | 12/30 (40%) | 7/27 (26%) | 7/17 (41%)
First incidence (days) | 512 | 365 | 554 | 474
Poly-3 test | P = 0.220 | P = 0.039 | P = 0.492 | P = 0.086
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 39/50 (78%) | 38/50 (76%) | 40/49 (82%) | 39/50 (78%)
Adjusted rate | 78.7% | 81.5% | 87.7% | 85.4%
Terminal rate | 30/38 (79%) | 23/30 (77%) | 25/27 (93%) | 14/17 (82%)
First incidence (days) | 512 | 365 | 279 | 474
Poly-3 test | P = 0.249 | P = 0.464 | P = 0.174 | P = 0.271
Liver: Hepatoblastoma
Overall rate | 2/50 (4%) | 1/50 (2%) | 0/49 (0%) | 4/50 (8%)
Adjusted rate | 4.3% | 2.5% | 0.0% | 10.3%
Terminal rate | 2/38 (5%) | 0/30 (0%) | 0/27 (0%) | 1/17 (6%)
First incidence (days) | 729 (T) | 604 | – | 554
Poly-3 test | P = 0.088 | P = 0.544N | P = 0.268N | P = 0.261
Liver: Hepatocellular Carcinoma or Hepatoblastoma
Overall rate | 16/50 (32%) | 24/50 (48%) | 14/49 (29%) | 21/50 (42%)
Adjusted rate | 32.8% | 52.2% | 33.2% | 49%
Terminal rate | 10/38 (26%) | 12/30 (40%) | 7/27 (26%) | 8/17 (47%)
First incidence (days) | 512 | 365 | 554 | 474
Poly-3 test | P = 0.211 | P = 0.042 | P = 0.574 | P = 0.084
Liver: Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma
Overall rate | 39/50 (78%) | 39/50 (78%) | 40/49 (82%) | 39/50 (78%)
Adjusted rate | 78.7% | 82.8% | 87.7% | 85.4%
Terminal rate | 30/38 (79%) | 23/30 (77%) | 25/27 (93%) | 14/17 (82%)
First incidence (days) | 512 | 365 | 279 | 474
Poly-3 test | P = 0.276 | P = 0.395 | P = 0.174 | P = 0.271
Lung: Alveolar/Bronchiolar Adenoma
Overall rate | 10/50 (20%) | 14/50 (28%) | 9/50 (18%) | 14/50 (28%)
Adjusted rate | 21.5% | 32.9% | 21.8% | 34.6%
Terminal rate | 9/38 (24%) | 7/30 (23%) | 6/27 (22%) | 4/17 (24%)
First incidence (days) | 702 | 449 | 646 | 530
Poly-3 test | P = 0.190 | P = 0.165 | P = 0.592 | P = 0.129
Lung: Alveolar/Bronchiolar Carcinoma
Overall rate | 4/50 (8%) | 18/50 (36%) | 20/50 (40%) | 27/50 (54%)
Adjusted rate | 8.5% | 40.9% | 46.2% | 62.8%
Terminal rate | 2/38 (5%) | 9/30 (30%) | 11/27 (41%) | 12/17 (71%)
First incidence (days) | 590 | 449 | 509 | 490
Poly-3 test | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001
Lung: Alveolar/Bronchiolar Adenoma or Carcinoma
Overall rate | 13/50 (26%) | 29/50 (58%) | 28/50 (56%) | 34/50 (68%)
Adjusted rate | 27.5% | 64.5% | 63.6% | 75.3%
Terminal rate | 10/38 (26%) | 16/30 (53%) | 16/27 (59%) | 12/17 (71%)
First incidence (days) | 590 | 449 | 509 | 490
Poly-3 test | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001
Skin: Fibrous Histiocytoma
Overall rate | 0/50 (0%) | 1/50 (2%) | 1/50 (2%) | 4/50 (8%)
Adjusted rate | 0.0% | 2.5% | 2.5% | 10.6%
Terminal rate | 0/38 (0%) | 1/30 (3%) | 1/27 (4%) | 2/17 (12%)
First incidence (days) | – | 729 (T) | 729 (T) | 612
Poly-3 test | P = 0.012 | P = 0.473 | P = 0.474 | P = 0.039
Skin: Fibrous Histiocytoma or Fibrosarcoma
Overall rate | 0/50 (0%) | 1/50 (2%) | 3/50 (6%) | 4/50 (8%)
Adjusted rate | 0.0% | 2.5% | 7.3% | 10.6%
Terminal rate | 0/38 (0%) | 1/30 (3%) | 2/27 (7%) | 2/17 (12%)
First incidence (days) | – | 729 (T) | 468 | 612
Poly-3 test | P = 0.023 | P = 0.473 | P = 0.100 | P = 0.039
Small Intestine (Site Unspecified): Adenoma or Carcinoma
Overall rate | 3/50 (6%) | 1/50 (2%) | 1/50 (2%) | 1/50 (2%)
Adjusted rate | 6.5% | 2.4% | 2.5% | 2.7%
Terminal rate | 2/38 (5%) | 0/30 (0%) | 1/27 (4%) | 1/17 (6%)
First incidence (days) | 702 | 365 | 729 (T) | 729 (T)
Poly-3 test | P = 0.386N | P = 0.349N | P = 0.354N | P = 0.387N
All Organs: Hemangiosarcoma
Overall rate | 2/50 (4%) | 1/50 (2%) | 3/50 (6%) | 1/50 (2%)
Adjusted rate | 4.3% | 2.5% | 7.2% | 2.7%
Terminal rate | 2/38 (5%) | 1/30 (3%) | 1/27 (4%) | 1/17 (6%)
First incidence (days) | 729 (T) | 729 (T) | 509 | 729 (T)
Poly-3 test | P = 0.542N | P = 0.547N | P = 0.450 | P = 0.574N
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 2/50 (4%) | 3/50 (6%) | 3/50 (6%) | 2/50 (4%)
Adjusted rate | 4.3% | 7.4% | 7.2% | 5.3%
Terminal rate | 2/38 (5%) | 2/30 (7%) | 1/27 (4%) | 1/17 (6%)
First incidence (days) | 729 (T) | 651 | 509 | 490
Poly-3 test | P = 0.595N | P = 0.441 | P = 0.450 | P = 0.621
All Organs: Histiocytic Sarcoma
Overall rate | 1/50 (2%) | 1/50 (2%) | 3/50 (6%) | 1/50 (2%)
Adjusted rate | 2.2% | 2.5% | 7.3% | 2.7%
Terminal rate | 0/38 (0%) | 1/30 (3%) | 1/27 (4%) | 1/17 (6%)
First incidence (days) | 663 | 729 (T) | 639 | 729 (T)
Poly-3 test | P = 0.574 | P = 0.728 | P = 0.263 | P = 0.709
All Organs: Malignant Lymphoma
Overall rate | 4/50 (8%) | 4/50 (8%) | 3/50 (6%) | 6/50 (12%)
Adjusted rate | 8.6% | 9.8% | 7.4% | 15.7%
Terminal rate | 3/38 (8%) | 2/30 (7%) | 3/27 (11%) | 2/17 (12%)
First incidence (days) | 670 | 590 | 729 (T) | 639
Poly-3 test | P = 0.189 | P = 0.571 | P = 0.573N | P = 0.254
All Organs: Benign Neoplasms
Overall rate | 37/50 (74%) | 38/50 (76%) | 38/50 (76%) | 37/50 (74%)
Adjusted rate | 76.7% | 82.1% | 84.6% | 81.5%
Terminal rate | 29/38 (76%) | 24/30 (80%) | 26/27 (96%) | 14/17 (82%)
First incidence (days) | 626 | 365 | 279 | 474
Poly-3 test | P = 0.425 | P = 0.343 | P = 0.228 | P = 0.372
All Organs: Malignant Neoplasms
Overall rate | 25/50 (50%) | 40/50 (80%) | 38/50 (76%) | 40/50 (80%)
Adjusted rate | 50.7% | 83.1% | 81.0% | 84.4%
Terminal rate | 16/38 (42%) | 22/30 (73%) | 20/27 (74%) | 14/17 (82%)
First incidence (days) | 512 | 365 | 468 | 474
Poly-3 test | P = 0.005 | P < 0.001 | P < 0.001 | P < 0.001
All Organs: Benign or Malignant Neoplasms
Overall rate | 45/50 (90%) | 45/50 (90%) | 47/50 (94%) | 46/50 (92%)
Adjusted rate | 90.0% | 93.4% | 97.8% | 95.6%
Terminal rate | 33/38 (87%) | 27/30 (90%) | 27/27 (100%) | 16/17 (94%)
First incidence (days) | 512 | 365 | 279 | 474
Poly-3 test | P = 0.229 | P = 0.401 | P = 0.110 | P = 0.239

(T) = terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal gland, liver, and lung; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

Table C-3 Historical Incidence of Alveolar/Bronchiolar Neoplasms in Control Male B6C3F1/N Mice^a^

Study (Study Start) | Adenoma | Carcinoma | Adenoma or Carcinoma
Historical Incidence: Inhalation Studies
Antimony trioxide (October 2008) | 10/50 | 4/50 | 13/50
CIMSTAR 3800 (May 2008) | 5/50 | 8/50 | 13/50
Cobalt metal (May 2006) | 7/50 | 11/50 | 16/50
Vinylidene chloride (June 2005) | 7/50 | 9/50 | 13/50
Trim VX (August 2009) | 6/50 | 10/50 | 14/50
Total (%) | 35/250 (14.0%) | 42/250 (16.8%) | 69/250 (27.6%)
Mean ± standard deviation | 14.0% ± 3.7% | 16.8% ± 5.4% | 27.6% ± 2.6%
Range | 10%–20% | 8%–22% | 26%–32%
Overall Historical Incidence: All Routes
Total (%) | 83/550 (15.1%) | 75/550 (13.6%) | 147/550 (26.7%)
Mean ± standard deviation | 15.1% ± 5.9% | 13.6% ± 6.4% | 26.7% ± 6.5%
Range | 8%–26% | 4%–22% | 16%–38%

^a^ Data as of June 2015.

Table C-4 Historical Incidence of Malignant Lymphoma in Control Male B6C3F1/N Mice^a^

Study (Study Start) | Incidence in Controls
Historical Incidence: Inhalation Studies
Antimony trioxide (October 2008) | 4/50
CIMSTAR 3800 (May 2008) | 3/50
Cobalt metal (May 2006) | 4/50
Vinylidene chloride (June 2005) | 2/50
Trim VX (August 2009) | 6/50
Total (%) | 19/250 (7.6%)
Mean ± standard deviation | 7.6% ± 3.0%
Range | 4%–12%
Overall Historical Incidence: All Routes
Total (%) | 35/550 (6.4%)
Mean ± standard deviation | 6.4% ± 3.4%
Range | 0%–12%

^a^ Data as of June 2015; may include data for histiocytic, lymphocytic, mixed, unspecified, or undifferentiated cell types.

Table C-5 Historical Incidence of Skin Neoplasms in Control Male B6C3F1/N Mice^a^

Study (Study Start) | Fibrous Histiocytoma | Fibrosarcoma | Fibrous Histiocytoma or Fibrosarcoma
Historical Incidence: Inhalation Studies
Antimony trioxide (October 2008) | 0/50 | 0/50 | 0/50
CIMSTAR 3800 (May 2008) | 0/50 | 0/50 | 0/50
Cobalt metal (May 2006) | 0/50 | 0/50 | 0/50
Vinylidene chloride (June 2005) | 1/50 | 0/50 | 1/50
Trim VX (August 2009) | 0/50 | 1/50 | 1/50
Total (%) | 1/250 (0.4%) | 1/250 (0.4%) | 2/250 (0.8%)
Mean ± standard deviation | 0.4% ± 0.9% | 0.4% ± 0.9% | 0.8% ± 1.1%
Range | 0%–2% | 0%–2% | 0%–2%
Overall Historical Incidence: All Routes
Total (%) | 2/550 (0.4%) | 2/550 (0.4%) | 5/550 (0.9%)^b^
Mean ± standard deviation | 0.4% ± 0.8% | 0.4% ± 0.8% | 0.9% ± 1.0%
Range | 0%–2% | 0%–2% | 0%–2%

^a^ Data as of June 2015.

^b^ Includes one incidence of sarcoma.

Table C-6 Historical Incidence of Hepatocellular Neoplasms in Control Male B6C3F1/N Mice^a^

Study (Study Start) | Adenoma | Carcinoma
Historical Incidence: Inhalation Studies
Antimony trioxide (October 2008) | 30/50 | 15/50
CIMSTAR 3800 (May 2008) | 24/50 | 11/50
Cobalt metal (May 2006) | 28/50 | 25/50
Vinylidene chloride (June 2005) | 37/50 | 26/50
Trim VX (August 2009) | 23/50 | 21/50
Total (%) | 142/250 (56.8%) | 98/250 (39.2%)
Mean ± standard deviation | 56.8% ± 11.2% | 39.2% ± 12.9%
Range | 46%–74% | 22%–52%
Overall Historical Incidence: All Routes
Total (%) | 328/550 (59.6%) | 188/550 (34.2%)
Mean ± standard deviation | 59.6% ± 11.2% | 34.2% ± 11.3%
Range | 46%–78% | 22%–52%

^a^ Data as of June 2015.

Table C-7 Summary of the Incidence of Nonneoplastic Lesions in Male Mice in the Two-year Inhalation Study of Antimony Trioxide^a^

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Disposition Summary
Animals initially in study | 60 | 60 | 60 | 60
Twelve-month interim evaluation | 10 | 10 | 10 | 10
Early deaths
Accidental death | – | 1 | – | –
Moribund | 7 | 12 | 15 | 26
Natural deaths | 5 | 7 | 8 | 7
Survivors
Terminal kill | 38 | 30 | 27 | 17
Animals examined microscopically | 60 | 60 | 60 | 60
Twelve-month Interim Evaluation
Alimentary System
Esophagus | (10) | (10) | (10) | (10)
Gallbladder | (8) | (10) | (9) | (9)
Intestine large, cecum | (10) | (10) | (10) | (10)
Intestine large, colon | (10) | (10) | (10) | (10)
Intestine large, rectum | (10) | (10) | (10) | (10)
Intestine small, duodenum | (10) | (10) | (10) | (10)
Intestine small, ileum | (10) | (10) | (10) | (10)
Intestine small, jejunum | (10) | (10) | (10) | (10)
Liver | (10) | (10) | (10) | (10)
Basophilic focus | – | 1 (10%) | – | –
Clear cell focus | 2 (20%) | 2 (20%) | 2 (20%) | –
Mesentery | (0) | (0) | (0) | (1)
Necrosis, fatty | – | – | – | 1 (100%)
Pancreas | (10) | (10) | (10) | (10)
Salivary glands | (10) | (10) | (10) | (10)
Stomach, forestomach | (10) | (10) | (10) | (10)
Stomach, glandular | (10) | (9) | (10) | (10)
Tooth | (1) | (0) | (0) | (0)
Malformation | 1 (100%) | – | – | –
Cardiovascular System
Blood vessel | (10) | (10) | (10) | (10)
Heart | (10) | (10) | (10) | (10)
Cardiomyopathy | – | – | – | 1 (10%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Zona fasciculata, hypertrophy | 3 (30%) | 1 (10%) | – | 1 (10%)
Adrenal medulla | (10) | (10) | (10) | (10)
Islets, pancreatic | (10) | (10) | (10) | (10)
Parathyroid gland | (6) | (7) | (5) | (8)
Pituitary gland | (10) | (10) | (10) | (9)
Thyroid gland | (10) | (10) | (10) | (10)
Genital System
Epididymis | (10) | (10) | (10) | (10)
Preputial gland | (10) | (10) | (10) | (10)
Inflammation, chronic active | 1 (10%) | – | – | –
Prostate | (10) | (10) | (10) | (10)
Seminal vesicle | (10) | (10) | (10) | (10)
Testes | (10) | (10) | (10) | (10)
Hematopoietic System
Bone marrow | (10) | (10) | (10) | (10)
Lymph node, bronchial | (8) | (10) | (10) | (10)
Foreign body | – | 10 (100%) | 10 (100%) | 10 (100%)
Hyperplasia, lymphoid | – | 7 (70%) | 9 (90%) | 10 (100%)
Infiltration cellular, histiocyte | – | 4 (40%) | 4 (40%) | 1 (10%)
Lymph node, mandibular | (5) | (4) | (4) | (4)
Infiltration cellular, histiocyte | – | – | – | 2 (50%)
Lymph node, mediastinal | (4) | (8) | (10) | (10)
Foreign body | – | 1 (13%) | 8 (80%) | 10 (100%)
Hyperplasia, lymphoid | – | 1 (13%) | 4 (40%) | 9 (90%)
Infiltration cellular, histiocyte | – | 1 (13%) | 3 (30%) | 4 (40%)
Lymph node, mesenteric | (10) | (10) | (10) | (10)
Spleen | (10) | (10) | (10) | (10)
Thymus | (10) | (10) | (10) | (10)
Inflammation, chronic active | – | – | – | 1 (10%)
Medulla, hyperplasia, lymphoid | – | 1 (10%) | 1 (10%) | –
Respiratory System
Larynx | (10) | (10) | (10) | (10)
Foreign body | – | 3 (30%) | 5 (50%) | 10 (100%)
Respiratory epithelium, degeneration | – | – | 1 (10%) | –
Respiratory epithelium, hyperplasia | – | 1 (10%) | 4 (40%) | 6 (60%)
Respiratory epithelium, metaplasia, squamous | – | – | 2 (20%) | 3 (30%)
Lung | (10) | (10) | (10) | (10)
Foreign body | – | 10 (100%) | 10 (100%) | 10 (100%)
Infiltration cellular, lymphocyte | – | 10 (100%) | 10 (100%) | 10 (100%)
Inflammation, chronic active | – | 10 (100%) | 10 (100%) | 10 (100%)
Alveolar epithelium, hyperplasia | – | 9 (90%) | 10 (100%) | 10 (100%)
Alveolar epithelium, metaplasia, squamous | – | – | – | 1 (10%)
Alveolus, fibrosis | – | 4 (40%) | 7 (70%) | 10 (100%)
Bronchiole, epithelium, hyperplasia | – | 9 (90%) | 9 (90%) | 9 (90%)
Pleura, fibrosis | – | 5 (50%) | 10 (100%) | 10 (100%)
Pleura, inflammation | – | 7 (70%) | 10 (100%) | 10 (100%)
Nose | (10) | (10) | (10) | (10)
Foreign body | – | 8 (80%) | 10 (100%) | 9 (90%)
Inflammation, acute | – | – | 1 (10%) | –
Respiratory epithelium, accumulation, hyaline droplet | 1 (10%) | – | – | 1 (10%)
Respiratory epithelium, inflammation, chronic active | 1 (10%) | – | – | –
Trachea | (10) | (10) | (10) | (10)
Foreign body | – | – | 2 (20%) | 4 (40%)
Epithelium, hyperplasia | – | – | 1 (10%) | –
Epithelium, metaplasia, squamous | – | 1 (10%) | – | 1 (10%)
Special Senses System
Eye | (10) | (10) | (10) | (10)
Harderian gland | (10) | (10) | (10) | (10)
Hyperplasia | – | – | – | 1 (10%)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Nephropathy | 2 (20%) | 3 (30%) | 4 (40%) | 2 (20%)
Glomerulus, hyalinization | – | – | – | 1 (10%)
Papilla, necrosis | 1 (10%) | – | – | –
Urinary bladder | (10) | (10) | (10) | (10)
Systems Examined at 12 Months with No Lesions Observed
General Body System
Integumentary System
Musculoskeletal System
Nervous System
Two-year Study
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Inflammation, chronic active | 1 (2%) | – | – | –
Gallbladder | (44) | (41) | (38) | (40)
Inflammation, chronic | 2 (5%) | 1 (2%) | – | 2 (5%)
Intestine large, cecum | (46) | (45) | (45) | (47)
Inflammation, chronic active | – | 3 (7%) | – | 1 (2%)
Intestine large, colon | (48) | (45) | (47) | (48)
Lymphoid tissue, hyperplasia | 1 (2%) | – | – | –
Intestine large, rectum | (47) | (42) | (45) | (48)
Intestine small, duodenum | (45) | (45) | (42) | (46)
Intestine small, ileum | (46) | (44) | (43) | (48)
Atrophy | – | 1 (2%) | – | –
Inflammation, chronic active | – | 3 (7%) | – | 1 (2%)
Peyer’s patch, hyperplasia, lymphoid | 2 (4%) | – | – | 2 (4%)
Intestine small, jejunum | (46) | (44) | (42) | (48)
Atrophy | – | 1 (2%) | – | –
Inflammation | 1 (2%) | – | 1 (2%) | 2 (4%)
Mineralization | – | – | – | 1 (2%)
Necrosis | – | – | 1 (2%) | –
Peyer’s patch, hyperplasia, lymphoid | 1 (2%) | – | – | 2 (4%)
Liver | (50) | (50) | (49) | (50)
Angiectasis | 1 (2%) | – | 1 (2%) | –
Basophilic focus | 4 (8%) | 3 (6%) | 2 (4%) | 5 (10%)
Clear cell focus | 14 (28%) | 9 (18%) | 10 (20%) | 6 (12%)
Eosinophilic focus | 4 (8%) | 5 (10%) | 7 (14%) | 7 (14%)
Eosinophilic focus, multiple | – | – | – | 1 (2%)
Fatty change | – | – | 1 (2%) | –
Hepatodiaphragmatic nodule | – | – | – | 1 (2%)
Inflammation, chronic active | 1 (2%) | 1 (2%) | – | 3 (6%)
Mineralization | 1 (2%) | – | – | –
Mixed cell focus | 1 (2%) | 2 (4%) | 3 (6%) | 1 (2%)
Necrosis | 3 (6%) | 2 (4%) | 1 (2%) | 6 (12%)
Pigmentation | – | – | – | 1 (2%)
Syncytial alteration | – | 1 (2%) | 1 (2%) | –
Thrombosis | 1 (2%) | – | – | 1 (2%)
Centrilobular, atrophy | 1 (2%) | – | – | –
Centrilobular, atrophy, chronic | – | 1 (2%) | – | –
Mesentery | (7) | (4) | (4) | (5)
Cyst, squamous | – | – | – | 1 (20%)
Hemorrhage | – | – | 1 (25%) | –
Inflammation, chronic active | – | – | 1 (25%) | –
Necrosis, fatty | 3 (43%) | 2 (50%) | 2 (50%) | 1 (20%)
Thrombosis | 1 (14%) | – | 1 (25%) | –
Artery, inflammation, chronic active | 1 (14%) | – | – | 2 (40%)
Artery, necrosis, chronic active | – | – | – | 1 (20%)
Oral mucosa | (1) | (0) | (0) | (0)
Pharyngeal, inflammation, chronic active | 1 (100%) | – | – | –
Pancreas | (49) | (49) | (49) | (50)
Inflammation | 1 (2%) | – | – | 1 (2%)
Salivary glands | (50) | (50) | (50) | (50)
Artery, inflammation, chronic active | 1 (2%) | – | – | –
Stomach, forestomach | (50) | (50) | (49) | (50)
Hyperkeratosis | – | 2 (4%) | 1 (2%) | 3 (6%)
Hyperplasia, squamous | 1 (2%) | – | – | 3 (6%)
Inflammation, chronic active | 2 (4%) | 4 (8%) | 4 (8%) | 7 (14%)
Mineralization | – | – | 1 (2%) | –
Ulcer | – | – | – | 2 (4%)
Stomach, glandular | (48) | (49) | (49) | (50)
Atrophy | – | 1 (2%) | – | –
Dysplasia, focal | 1 (2%) | – | – | –
Inflammation, chronic active | 2 (4%) | 4 (8%) | – | 1 (2%)
Mineralization | 3 (6%) | 2 (4%) | 1 (2%) | 1 (2%)
Necrosis | 1 (2%) | – | 1 (2%) | –
Thrombosis | – | – | 1 (2%) | –
Artery, inflammation, chronic active | – | 1 (2%) | – | –
Tooth | (14) | (14) | (14) | (6)
Dysplasia | 12 (86%) | 13 (93%) | 12 (86%) | 6 (100%)
Inflammation, chronic active | 11 (79%) | 5 (36%) | 6 (43%) | 3 (50%)
Cardiovascular System
Blood vessel | (50) | (49) | (48) | (44)
Adventitia, inflammation, chronic active | – | – | – | 1 (2%)
Media, inflammation, chronic active | 1 (2%) | – | 1 (2%) | 1 (2%)
Thoracic, thrombosis | – | 1 (2%) | – | –
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 14 (28%) | 13 (26%) | 14 (28%) | 19 (38%)
Necrosis | – | – | 1 (2%) | –
Thrombosis | – | – | 2 (4%) | –
Arteriole, degeneration | – | – | 1 (2%) | –
Artery, inflammation, chronic active | 6 (12%) | 10 (20%) | 8 (16%) | 9 (18%)
Artery, mineralization | – | – | 1 (2%) | –
Atrium, inflammation, acute | – | – | – | 1 (2%)
Epicardium, fibrosis | – | – | – | 1 (2%)
Epicardium, inflammation, chronic active | – | 2 (4%) | 7 (14%) | 16 (32%)
Valve, inflammation, chronic | – | – | 1 (2%) | –
Valve, inflammation, chronic active | – | 1 (2%) | 2 (4%) | –
Valve, thrombosis | – | 1 (2%) | – | –
Endocrine System
Adrenal cortex | (49) | (50) | (49) | (49)
Necrosis | – | – | 1 (2%) | –
Subcapsular, hypertrophy | – | 1 (2%) | – | –
Zona fasciculata, hypertrophy | 26 (53%) | 20 (40%) | 15 (31%) | 8 (16%)
Zona glomerulosa, necrosis | – | – | – | 1 (2%)
Adrenal medulla | (49) | (50) | (46) | (49)
Hyperplasia | 5 (10%) | 8 (16%) | 9 (20%) | 7 (14%)
Necrosis | – | – | 1 (2%) | –
Islets, pancreatic | (49) | (49) | (49) | (50)
Angiectasis | – | – | 1 (2%) | –
Hyperplasia | 4 (8%) | 3 (6%) | – | 2 (4%)
Parathyroid gland | (27) | (32) | (26) | (33)
Pituitary gland | (49) | (49) | (48) | (50)
Pars distalis, cyst | 3 (6%) | 3 (6%) | – | 6 (12%)
Pars distalis, hyperplasia | 4 (8%) | 9 (18%) | 8 (17%) | 3 (6%)
Pars intermedia, hyperplasia | – | 1 (2%) | – | –
Thyroid gland | (49) | (49) | (48) | (49)
Artery, inflammation, chronic active | – | 1 (2%) | – | –
General Body System
Peritoneum | (0) | (0) | (0) | (1)
Genital System
Epididymis | (50) | (50) | (50) | (50)
Inflammation, chronic active | 1 (2%) | – | 1 (2%) | –
Arteriole, inflammation, chronic active | 1 (2%) | 1 (2%) | – | 1 (2%)
Epithelium, hypertrophy | 1 (2%) | – | – | –
Preputial gland | (50) | (50) | (49) | (50)
Ectasia | 12 (24%) | 7 (14%) | 15 (31%) | 18 (36%)
Hyperplasia | 1 (2%) | – | – | –
Inflammation, chronic active | 3 (6%) | 4 (8%) | 4 (8%) | 2 (4%)
Prostate | (49) | (50) | (49) | (50)
Inflammation, chronic active | – | 1 (2%) | 1 (2%) | –
Artery, inflammation, chronic active | 1 (2%) | 1 (2%) | – | –
Seminal vesicle | (49) | (50) | (49) | (50)
Hyperplasia, adenomatous | 1 (2%) | – | – | –
Inflammation, chronic | – | 1 (2%) | – | –
Testes | (49) | (49) | (50) | (50)
Degeneration | 29 (59%) | 28 (57%) | 26 (52%) | 22 (44%)
Mineralization | 1 (2%) | 1 (2%) | – | 1 (2%)
Necrosis | – | 1 (2%) | – | –
Hematopoietic System
Bone marrow | (49) | (50) | (48) | (50)
Hemorrhage | – | – | – | 1 (2%)
Hyperplasia | 10 (20%) | 19 (38%) | 27 (56%) | 33 (66%)
Myelofibrosis | 1 (2%) | – | – | –
Necrosis | 1 (2%) | 1 (2%) | – | 1 (2%)
Thrombosis | – | – | 1 (2%) | 1 (2%)
Lymph node | (2) | (2) | (2) | (2)
Hyperplasia, plasma cell | 1 (50%) | – | – | –
Lymph node, bronchial | (30) | (43) | (47) | (41)
Ectasia | – | 1 (2%) | – | –
Foreign body | – | 34 (79%) | 47 (100%) | 38 (93%)
Hyperplasia, lymphoid | 2 (7%) | 21 (49%) | 26 (55%) | 13 (32%)
Infiltration cellular, histiocyte | – | 2 (5%) | 4 (9%) | 6 (15%)
Lymph node, mandibular | (27) | (26) | (28) | (26)
Foreign body | – | 7 (27%) | 8 (29%) | 16 (62%)
Hyperplasia, lymphoid | 4 (15%) | 8 (31%) | 6 (21%) | 4 (15%)
Infiltration cellular, histiocyte | | 1 (4%) | 4 (14%) | 1 (4%)
Lymph node, mediastinal | (37) | (45) | (48) | (49)
Angiectasis | – | – | 1 (2%) | 1 (2%)
Foreign body | – | 32 (71%) | 42 (88%) | 48 (98%)
Hyperplasia, lymphoid | 2 (5%) | 8 (18%) | 17 (35%) | 34 (69%)
Infiltration cellular, histiocyte | – | 4 (9%) | 13 (27%) | 34 (69%)
Artery, necrosis, fibrinoid | – | – | – | 2 (4%)
Lymph node, mesenteric | (48) | (47) | (47) | (50)
Angiectasis | – | 1 (2%) | | 1 (2%)
Ectasia | – | – | 1 (2%) | –
Fibrosis | 1 (2%) | – | – | –
Hyperplasia, lymphoid | 3 (6%) | – | 1 (2%) | 2 (4%)
Infiltration cellular, histiocyte | – | – | – | 2 (4%)
Infiltration cellular, mixed cell | – | 2 (4%) | – | –
Infiltration cellular, plasma cell | – | 4 (9%) | 1 (2%) | –
Infiltration cellular, polymorphonuclear | – | – | 2 (4%) | –
Inflammation, acute | – | – | 1 (2%) | –
Artery, inflammation, chronic active | – | 1 (2%) | – | –
Spleen | (49) | (50) | (50) | (50)
Angiectasis | – | 1 (2%) | – | 1 (2%)
Hematopoietic cell proliferation | 13 (27%) | 10 (20%) | 10 (20%) | 13 (26%)
Hyperplasia, lymphoid | 4 (8%) | 6 (12%) | 6 (12%) | 3 (6%)
Necrosis | – | – | 1 (2%) | –
Artery, necrosis, fibrinoid | – | – | – | 1 (2%)
Thymus | (41) | (38) | (43) | (39)
Cyst | – | – | 1 (2%) | 1 (3%)
Depletion cellular | 15 (37%) | 14 (37%) | 32 (74%) | 32 (82%)
Thrombosis | – | – | 1 (2%) | –
Medulla, hyperplasia, lymphoid | 2 (5%) | 1 (3%) | 4 (9%) | 2 (5%)
Integumentary System
Mammary gland | (0) | (2) | (4) | (1)
Skin | (50) | (50) | (50) | (50)
Inflammation, chronic active | 5 (10%) | 2 (4%) | 1 (2%) | 3 (6%)
Necrosis | – | 1 (2%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (49) | (50)
Necrosis | – | 1 (2%) | – | –
Femur, fibro-osseous lesion | 2 (4%) | 2 (4%) | 3 (6%) | 2 (4%)
Maxilla, fibro-osseous lesion | | 1 (2%) | – | –
Maxilla, osteomalacia | – | – | – | 1 (2%)
Synovial tissue, inflammation, chronic | – | – | – | 1 (2%)
Skeletal muscle | (2) | (3) | (1) | (1)
Degeneration | 1 (50%) | – | – | –
Metaplasia, cartilaginous | – | – | 1 (100%) | –
Necrosis | – | 1 (33%) | – | –
Artery, inflammation, chronic active | – | 1 (33%) | – | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Hemorrhage | – | 1 (2%) | 1 (2%) | –
Inflammation, multifocal, acute | – | 1 (2%) | – | –
Thrombosis | – | 2 (4%) | 1 (2%) | –
Arteriole, inflammation, chronic active | 1 (2%) | 2 (4%) | – | –
Cerebrum, inflammation, acute | – | 1 (2%) | – | –
Cerebrum, inflammation, chronic | – | – | – | 1 (2%)
Meninges, infiltration cellular, lymphoid | – | 1 (2%) | 1 (2%) | –
Peripheral nerve | (1) | (1) | (0) | (0)
Degeneration | 1 (100%) | – | – | –
Spinal cord | (1) | (2) | (0) | (0)
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Foreign body | – | 15 (30%) | 29 (58%) | 44 (88%)
Inflammation, chronic active | 8 (16%) | 4 (8%) | 7 (14%) | 11 (22%)
Artery, inflammation, chronic active | – | – | – | 1 (2%)
Respiratory epithelium, hyperplasia | 1 (2%) | 3 (6%) | 15 (30%) | 30 (60%)
Respiratory epithelium, inclusion body intracytoplasmic | – | – | – | 1 (2%)
Respiratory epithelium, metaplasia, squamous | – | – | 8 (16%) | 18 (36%)
Respiratory epithelium, necrosis | – | – | – | 1 (2%)
Squamous epithelium, hyperplasia | 2 (4%) | – | 4 (8%) | 13 (26%)
Squamous epithelium, necrosis | – | – | – | 1 (2%)
Lung | (50) | (50) | (50) | (50)
Foreign body | – | 50 (100%) | 50 (100%) | 50 (100%)
Hemorrhage, acute | 1 (2%) | – | – | –
Infiltration cellular, histiocyte | 1 (2%) | – | – | –
Infiltration cellular, lymphocyte | 13 (26%) | 47 (94%) | 48 (96%) | 45 (90%)
Inflammation, focal, chronic | 1 (2%) | – | – | –
Inflammation, chronic active | – | 48 (96%) | 50 (100%) | 50 (100%)
Mineralization | – | 1 (2%) | – | –
Necrosis | – | – | 1 (2%) | –
Pigmentation, focal | 1 (2%) | – | – | –
Proteinosis | – | – | 1 (2%) | –
Thrombosis | 1 (2%) | 1 (2%) | – | –
Alveolar epithelium, hyperplasia | 6 (12%) | 39 (78%) | 45 (90%) | 49 (98%)
Alveolus, fibrosis | – | 12 (24%) | 30 (60%) | 37 (74%)
Alveolus, infiltration cellular, histiocyte | 2 (4%) | – | – | –
Artery, inflammation, chronic active | 1 (2%) | 1 (2%) | – | –
Bronchiole, epithelium, hyperplasia | – | 32 (64%) | 44 (88%) | 44 (88%)
Bronchiole, epithelium, goblet cell, metaplasia | – | – | 1 (2%) | –
Bronchus, epithelium, accumulation, hyaline droplet | – | – | – | 2 (4%)
Bronchus, epithelium, hyperplasia | – | 1 (2%) | 1 (2%) | –
Bronchus, epithelium, metaplasia, squamous | – | – | 1 (2%) | –
Bronchus, epithelium, necrosis | – | – | 1 (2%) | –
Bronchus, epithelium, goblet cell, metaplasia | – | – | – | 3 (6%)
Pleura, fibrosis | – | 36 (72%) | 46 (92%) | 50 (100%)
Pleura, inflammation | 1 (2%) | 40 (80%) | 47 (94%) | 48 (96%)
Nose | (50) | (49) | (49) | (50)
Foreign body | – | 48 (98%) | 48 (98%) | 49 (98%)
Glands, olfactory epithelium, accumulation, hyaline droplet | – | – | – | 1 (2%)
Glands, olfactory epithelium, dilatation | 1 (2%) | – | – | –
Glands, olfactory epithelium, metaplasia, respiratory | 1 (2%) | – | – | –
Nasolacrimal duct, hyperplasia, squamous | – | 1 (2%) | – | –
Nasolacrimal duct, inflammation, acute | – | – | – | 2 (4%)
Nasolacrimal duct, inflammation, chronic active | 1 (2%) | 1 (2%) | 2 (4%) | 3 (6%)
Nasopharyngeal duct, inflammation, chronic active | – | 1 (2%) | – | –
Olfactory epithelium, accumulation, hyaline droplet | 3 (6%) | 2 (4%) | 4 (8%) | 4 (8%)
Olfactory epithelium, atrophy | – | 1 (2%) | 1 (2%) | –
Olfactory epithelium, inflammation, acute | – | – | 1 (2%) | 1 (2%)
Olfactory epithelium, metaplasia, respiratory | 2 (4%) | 4 (8%) | – | –
Olfactory epithelium, necrosis | – | – | – | 1 (2%)
Respiratory epithelium, accumulation, hyaline droplet | 9 (18%) | 7 (14%) | 7 (14%) | 12 (24%)
Respiratory epithelium, erosion, acute | – | – | 1 (2%) | –
Respiratory epithelium, hyperplasia | – | – | – | 2 (4%)
Respiratory epithelium, inflammation, acute | 1 (2%) | 1 (2%) | 3 (6%) | 2 (4%)
Respiratory epithelium, inflammation, chronic active | 3 (6%) | 9 (18%) | 9 (18%) | 6 (12%)
Respiratory epithelium, metaplasia, squamous | – | 2 (4%) | 1 (2%) | 2 (4%)
Respiratory epithelium, necrosis | – | – | – | 2 (4%)
Respiratory epithelium, regeneration | – | – | 1 (2%) | –
Respiratory epithelium, thrombosis | – | – | – | 1 (2%)
Turbinate, inflammation, suppurative | – | – | – | 2 (4%)
Pleura | (0) | (0) | (0) | (2)
Trachea | (49) | (50) | (50) | (50)
Foreign body | – | 3 (6%) | 1 (2%) | 20 (40%)
Inflammation, chronic active | – | 1 (2%) | – | –
Metaplasia, squamous | – | – | 1 (2%) | –
Epithelium, hyperplasia | – | – | 2 (4%) | 5 (10%)
Epithelium, inclusion body intracytoplasmic | – | – | – | 1 (2%)
Epithelium, metaplasia, squamous | – | – | – | 1 (2%)
Glands, cyst | – | 1 (2%) | – | –
Special Senses System
Eye | (48) | (49) | (47) | (50)
Cataract | 5 (10%) | 4 (8%) | 2 (4%) | 2 (4%)
Hemorrhage | – | – | 1 (2%) | –
Retinal detachment | 1 (2%) | – | – | –
Harderian gland | (49) | (50) | (50) | (50)
Hyperplasia | 1 (2%) | – | 2 (4%) | 3 (6%)
Hypertrophy | 2 (4%) | – | 1 (2%) | –
Epithelium, hyperplasia | 1 (2%) | – | – | –
Urinary System
Kidney | (50) | (50) | (49) | (50)
Cyst | 1 (2%) | 1 (2%) | – | –
Hemorrhage | – | – | 1 (2%) | –
Infarct | – | 1 (2%) | 1 (2%) | 1 (2%)
Inflammation, acute | 1 (2%) | – | 1 (2%) | –
Metaplasia, osseous | 1 (2%) | 1 (2%) | 2 (4%) | 1 (2%)
Mineralization | 2 (4%) | – | – | –
Nephropathy | 41 (82%) | 39 (78%) | 38 (78%) | 40 (80%)
Thrombosis | – | 1 (2%) | – | –
Artery, inflammation, chronic active | – | 2 (4%) | – | 1 (2%)
Glomerulus, hyalinization | – | – | 1 (2%) | –
Ureter | (1) | (0) | (0) | (0)
Urinary bladder | (50) | (50) | (48) | (50)
Calculus gross observation | 1 (2%) | – | – | –
Inflammation, chronic active | 1 (2%) | – | 1 (2%) | –
Artery, inflammation, chronic active | – | 2 (4%) | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.