# Appendix B Summary of Lesions in Female Rats in the Two-year Inhalation Study of Antimony Trioxide

Table B-1 Summary of the Incidence of Neoplasms in Female Rats in the Two-year Inhalation Study of Antimony Trioxide^a^

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Disposition Summary
Animals initially in study | 60 | 60 | 60 | 60
Twelve-month interim evaluation | 10 | 10 | 10 | 10
Early deaths
Moribund | 11 | 12 | 20 | 27
Natural deaths | – | – | 2 | 3
Survivors
Died last week of study | – | – | 1 | 1
Terminal kill | 39 | 38 | 27 | 19
Animals examined microscopically | 60 | 60 | 60 | 60
Twelve-month Interim Evaluation
Alimentary System
Esophagus | (10) | (10) | (9) | (10)
Intestine large, cecum | (10) | (10) | (10) | (10)
Intestine large, colon | (10) | (10) | (10) | (10)
Intestine large, rectum | (10) | (10) | (10) | (10)
Intestine small, duodenum | (10) | (10) | (10) | (10)
Intestine small, ileum | (10) | (10) | (10) | (10)
Intestine small, jejunum | (10) | (10) | (10) | (10)
Liver | (10) | (10) | (10) | (10)
Pancreas | (10) | (10) | (10) | (10)
Salivary glands | (10) | (10) | (10) | (10)
Stomach, forestomach | (10) | (10) | (10) | (10)
Squamous cell papilloma | 1 (10%) | – | – | –
Stomach, glandular | (10) | (10) | (10) | (10)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Adrenal medulla | (10) | (10) | (10) | (10)
Islets, pancreatic | (10) | (10) | (10) | (10)
Parathyroid gland | (10) | (8) | (8) | (10)
Pituitary gland | (10) | (10) | (10) | (10)
Pars distalis, adenoma | – | – | – | 1 (10%)
Thyroid gland | (10) | (10) | (10) | (10)
Genital System
Clitoral gland | (10) | (10) | (10) | (10)
Ovary | (10) | (10) | (10) | (10)
Uterus | (10) | (10) | (10) | (10)
Polyp stromal | 1 (10%) | 1 (10%) | 2 (20%) | 1 (10%)
Integumentary System
Mammary gland | (10) | (10) | (10) | (10)
Fibroadenoma | – | – | – | 1 (10%)
Skin | (10) | (10) | (10) | (10)
Respiratory System
Larynx | (10) | (10) | (10) | (10)
Lung | (10) | (10) | (10) | (10)
Alveolar/bronchiolar adenoma | – | – | – | 1 (10%)
Nose | (10) | (10) | (10) | (10)
Trachea | (10) | (10) | (10) | (10)
Systemic Lesions
Multiple organs^b^ | (10) | (10) | (10) | (10)
Lymphoma malignant | 1 (10%) | – | – | –
Systems Examined at 12 Months with No Neoplasms Observed
Cardiovascular System
General Body System
Hematopoietic System
Musculoskeletal System
Nervous System
Special Senses System
Urinary System
Two-year Study
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (50) | (50) | (49) | (50)
Intestine large, colon | (50) | (50) | (50) | (50)
Leiomyoma | – | 1 (2%) | – | –
Intestine large, rectum | (48) | (47) | (50) | (49)
Leiomyosarcoma, metastatic, uterus | – | – | – | 1 (2%)
Intestine small, duodenum | (50) | (50) | (50) | (50)
Intestine small, ileum | (50) | (50) | (49) | (50)
Intestine small, jejunum | (50) | (50) | (49) | (49)
Leiomyoma | 1 (2%) | – | – | –
Leiomyosarcoma | – | 1 (2%) | 1 (2%) | –
Liver | (50) | (50) | (50) | (50)
Hepatocellular adenoma | 1 (2%) | 2 (4%) | – | –
Sarcoma | – | 1 (2%) | – | –
Squamous cell carcinoma, metastatic, uterus | 1 (2%) | – | – | –
Mesentery | (50) | (50) | (50) | (50)
Leiomyosarcoma, metastatic, uterus | – | – | – | 1 (2%)
Sarcoma, metastatic, liver | – | 1 (2%) | – | –
Sarcoma, metastatic, uterus | – | – | 1 (2%) | –
Squamous cell carcinoma, metastatic, uterus | 1 (2%) | – | – | –
Pancreas | (50) | (50) | (50) | (50)
Sarcoma, metastatic, liver | – | 1 (2%) | – | –
Sarcoma, metastatic, uterus | – | – | 1 (2%) | –
Salivary glands | (50) | (50) | (50) | (50)
Adenoma | – | 1 (2%) | – | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Leiomyoma | 1 (2%) | – | – | –
Squamous cell carcinoma | – | – | 1 (2%)
Squamous cell papilloma | – | – | – | 1 (2%)
Stomach, glandular | (50) | (50) | (50) | (50)
Squamous cell carcinoma, metastatic, stomach, forestomach | – | – | 1 (2%) | –
Tooth | (1) | (1) | (0) | (1)
Cardiovascular System
Blood vessel | (49) | (50) | (50) | (49)
Heart | (50) | (50) | (50) | (50)
Schwannoma malignant | – | – | – | 1 (2%)
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Adenoma | – | 1 (2%) | – | –
Adrenal medulla | (49) | (49) | (49) | (50)
Pheochromocytoma benign | – | 2 (4%) | 2 (4%) | 6 (12%)
Pheochromocytoma malignant | – | – | – | 1 (2%)
Islets, pancreatic | (50) | (50) | (50) | (50)
Parathyroid gland | (39) | (41) | (43) | (46)
Adenoma | – | – | 1 (2%) | –
Pituitary gland | (50) | (50) | (50) | (50)
Schwannoma malignant | – | 1 (2%) | – | –
Pars distalis, adenoma | 19 (38%) | 22 (44%) | 19 (38%) | 12 (24%)
Pars distalis, carcinoma | 1 (2%) | – | – | –
Thyroid gland | (50) | (50) | (50) | (50)
Carcinoma | 1 (2%) | – | – | –
C-cell, adenoma | 4 (8%) | 3 (6%) | 5 (10%) | 2 (4%)
C-cell, adenoma, multiple | – | 1 (2%) | – | –
C-cell, carcinoma | 1 (2%) | – | – | –
Follicular cell, adenoma | 1 (2%) | – | 2 (4%) | 2 (4%)
Follicular cell, carcinoma | 1 (2%) | – | 1 (2%) | –
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (50) | (49) | (47) | (49)
Carcinoma | – | 1 (2%) | 1 (2%) | –
Ovary | (50) | (49) | (50) | (50)
Adenoma | 2 (4%) | – | – | 1 (2%)
Cystadenoma | – | – | – | 3 (6%)
Granulosa cell tumor benign | – | 2 (4%) | – | –
Granulosa cell tumor malignant | – | – | – | 1 (2%)
Leiomyosarcoma, metastatic, uterus | – | – | – | 1 (2%)
Luteoma | – | – | – | 1 (2%)
Tubulostromal adenoma | 2 (4%) | – | 1 (2%) | –
Bilateral, cystadenoma | 1 (2%) | – | – | –
Uterus | (50) | (50) | (50) | (50)
Adenocarcinoma | 3 (6%) | – | – | 2 (4%)
Adenoma | – | – | – | 1 (2%)
Fibroma | – | – | – | 1 (2%)
Hemangiosarcoma | 1 (2%) | – | – | –
Leiomyosarcoma | 1 (2%) | – | 1 (2%) | 1 (2%)
Polyp stromal | 2 (4%) | 9 (18%) | 2 (4%) | 4 (8%)
Sarcoma | – | – | 1 (2%) | –
Sarcoma stromal | 1 (2%) | – | – | –
Squamous cell carcinoma, metastatic, uncertain primary site | 1 (2%) | – | – | –
Cervix, carcinoma | – | – | – | 1 (2%)
Endometrium, adenoma | – | – | 1 (2%) | –
Vagina | (0) | (0) | (1) | (0)
Sarcoma, metastatic, uterus | – | – | 1 (100%) | –
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (2) | (3) | (3) | (3)
Iliac, leiomyosarcoma, metastatic, uterus | – | – | – | 1 (33%)
Pancreatic, sarcoma, metastatic, liver | – | 1 (33%) | – | –
Lymph node, bronchial | (35) | (36) | (28) | (41)
Lymph node, mandibular | (42) | (46) | (44) | (48)
Lymph node, mediastinal | (46) | (46) | (46) | (46)
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Hemangioma | – | – | 1 (2%) | 1 (2%)
Spleen | (50) | (50) | (50) | (50)
Thymus | (46) | (41) | (37) | (48)
Thymoma benign | 6 (13%) | 6 (15%) | 6 (16%) | 8 (17%)
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Adenoma | – | 2 (4%) | 2 (4%) | 1 (2%)
Carcinoma | 5 (10%) | 1 (2%) | 4 (8%) | 2 (4%)
Fibroadenoma | 7 (14%) | 4 (8%) | 8 (16%) | 4 (8%)
Fibroma | – | 1 (2%) | – | –
Skin | (50) | (49) | (50) | (50)
Squamous cell carcinoma | – | 1 (2%) | – | –
Subcutaneous tissue, fibroma | 2 (4%) | – | – | –
Subcutaneous tissue, schwannoma malignant | – | – | – | 1 (2%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Mandible, squamous cell carcinoma, metastatic, skin | – | 1 (2%) | – | –
Skeletal muscle | (2) | (1) | (2) | (7)
Leiomyosarcoma, metastatic, uterus | – | – | – | 1 (14%)
Schwannoma malignant, metastatic, skin | – | – | – | 1 (14%)
Nervous System
Brain | (50) | (50) | (50) | (50)
Granular cell tumor benign | 1 (2%) | 1 (2%) | 1 (2%) | –
Granular cell tumor malignant | 1 (2%) | – | – | –
Peripheral nerve | (2) | (1) | (2) | (2)
Spinal cord | (2) | (1) | (2) | (2)
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | – | 2 (4%) | 5 (10%) | 5 (10%)
Alveolar/bronchiolar adenoma, multiple | – | – | 1 (2%) | –
Cystic keratinizing epithelioma | – | – | – | 2 (4%)
Granular cell tumor malignant, metastatic, brain | 1 (2%) | – | – | –
Leiomyosarcoma, metastatic, uterus | – | – | – | 1 (2%)
Schwannoma malignant, metastatic, heart | – | – | – | 1 (2%)
Squamous cell carcinoma | – | – | – | 1 (2%)
Mediastinum | (0) | (0) | (2) | (9)
Nose | (50) | (50) | (50) | (50)
Nerve, granular cell tumor benign | – | – | 1 (2%) | –
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Eye | (49) | (50) | (49) | (49)
Harderian gland | (50) | (50) | (50) | (50)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Urinary bladder | (50) | (50) | (50) | (50)
Leiomyosarcoma, metastatic, uterus | – | – | – | 1 (2%)
Systemic Lesions
None | – | – | – | –
Neoplasm Summary
Total animals with primary neoplasms^c^
Twelve-month interim evaluation | 3 | 1 | 2 | 4
Two-year study | 39 | 41 | 38 | 35
Total primary neoplasms
Twelve-month interim evaluation | 3 | 1 | 2 | 4
Two-year study | 66 | 66 | 68 | 66
Total animals with benign neoplasms
Twelve-month interim evaluation | 2 | 1 | 2 | 4
Two-year study | 33 | 39 | 35 | 33
Total benign neoplasms
Twelve-month interim evaluation | 2 | 1 | 2 | 4
Two-year study | 50 | 60 | 58 | 55
Total animals with malignant neoplasms
Twelve-month interim evaluation | 1
Two-year study | 16 | 6 | 9 | 10
Total malignant neoplasms
Twelve-month interim evaluation | 1 | – | – | –
Two-year study | 16 | 6 | 10 | 11
Total animals with metastatic neoplasms
Two-year study | 2 | 2 | 2 | 3
Total metastatic neoplasms
Two-year study | 4 | 4 | 4 | 9
Total animals with malignant neoplasms of uncertain primary site
Two-year study | 1 | – | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table B-2 Statistical Analysis of Primary Neoplasms in Female Rats in the Two-year Inhalation Study of Antimony Trioxide

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Adrenal Medulla: Benign Pheochromocytoma
Overall rate^a^ | 0/49 (0%) | 2/49 (4%) | 2/49 (4%) | 6/50 (12%)
Adjusted rate^b^ | 0.0% | 4.5% | 4.8% | 15.2%
Terminal rate^c^ | 0/38 (0%) | 1/37 (3%) | 1/27 (4%) | 4/20 (20%)
First incidence (days) | –^e^ | 719 | 698 | 705
Poly-3 test^d^ | P = 0.004 | P = 0.235 | P = 0.221 | P = 0.009
Adrenal Medulla: Benign or Malignant Pheochromocytoma
Overall rate | 0/49 (0%) | 2/49 (4%) | 2/49 (4%) | 7/50 (14%)
Adjusted rate | 0.0% | 4.5% | 4.8% | 17.6%
Terminal rate | 0/38 (0%) | 1/37 (3%) | 1/27 (4%) | 4/20 (20%)
First incidence (days) | – | 719 | 698 | 621
Poly-3 test | P < 0.001 | P = 0.235 | P = 0.221 | P = 0.004
Lung: Alveolar/Bronchiolar Adenoma
Overall rate | 0/50 (0%) | 2/50 (4%) | 6/50 (12%) | 5/50 (10%)
Adjusted rate | 0.0% | 4.4% | 13.8% | 12.4%
Terminal rate | 0/39 (0%) | 2/38 (5%) | 4/28 (14%) | 2/20 (10%)
First incidence (days) | – | 730 (T) | 534 | 534
Poly-3 test | P = 0.029 | P = 0.235 | P = 0.012 | P = 0.021
Lung: Cystic Keratinizing Epithelioma or Squamous Cell Carcinoma
Overall rate | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 7.4%
Terminal rate | 0/39 (0%) | 0/38 (0%) | 0/28 (0%) | 1/20 (5%)
First incidence (days) | – | – | – | 554
Poly-3 test | P = 0.006 | –^f^ | – | P = 0.096
Mammary Gland: Fibroadenoma
Overall rate | 7/50 (14%) | 4/50 (8%) | 8/50 (16%) | 4/50 (8%)
Adjusted rate | 14.9% | 8.7% | 18.1% | 9.7%
Terminal rate | 5/39 (13%) | 3/38 (8%) | 5/28 (18%) | 0/20 (0%)
First incidence (days) | 561 | 589 | 505 | 498
Poly-3 test | P = 0.421N | P = 0.272N | P = 0.450 | P = 0.342N
Mammary Gland: Fibroma, Fibroadenoma, or Adenoma
Overall rate | 7/50 (14%) | 6/50 (12%) | 10/50 (20%) | 5/50 (10%)
Adjusted rate | 14.9% | 12.8% | 22.5% | 12.1%
Terminal rate | 5/39 (13%) | 3/38 (8%) | 6/28 (21%) | 0/20 (0%)
First incidence (days) | 561 | 589 | 505 | 498
Poly-3 test | P = 0.462N | P = 0.503N | P = 0.252 | P = 0.469N
Mammary Gland: Carcinoma
Overall rate | 5/50 (10%) | 1/50 (2%) | 4/50 (8%) | 2/50 (4%)
Adjusted rate | 10.8% | 2.2% | 9.3% | 5.0%
Terminal rate | 3/39 (8%) | 1/38 (3%) | 2/28 (7%) | 0/20 (0%)
First incidence (days) | 635 | 730 (T) | 654 | 618
Poly-3 test | P = 0.429N | P = 0.106N | P = 0.548N | P = 0.284N
Mammary Gland: Adenoma or Carcinoma
Overall rate | 5/50 (10%) | 3/50 (6%) | 5/50 (10%) | 2/50 (4%)
Adjusted rate | 10.8% | 6.5% | 11.6% | 5.0%
Terminal rate | 3/39 (8%) | 2/38 (5%) | 2/28 (7%) | 0/20 (0%)
First incidence (days) | 635 | 589 | 654 | 618
Poly-3 test | P = 0.316N | P = 0.361N | P = 0.583 | P = 0.284N
Mammary Gland: Fibroma, Fibroadenoma, Adenoma, or Carcinoma
Overall rate | 10/50 (20%) | 7/50 (14%) | 12/50 (24%) | 6/50 (12%)
Adjusted rate | 21.3% | 15.0% | 26.8% | 14.4%
Terminal rate | 7/39 (18%) | 4/38 (11%) | 6/28 (21%) | 0/20 (0%)
First incidence (days) | 561 | 589 | 505 | 498
Poly-3 test | P = 0.353N | P = 0.301N | P = 0.352 | P = 0.290N
Ovary: Cystadenoma
Overall rate | 1/50 (2%) | 0/49 (0%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate | 2.2% | 0.0% | 0.0% | 7.6%
Terminal rate | 1/39 (3%) | 0/38 (0%) | 0/28 (0%) | 3/20 (15%)
First incidence (days) | 730 (T) | – | – | 730 (T)
Poly-3 test | P = 0.043 | P = 0.504N | P = 0.515N | P = 0.251
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 19/50 (38%) | 22/50 (44%) | 19/50 (38%) | 12/50 (24%)
Adjusted rate | 39.3% | 45.5% | 41.9% | 27.9%
Terminal rate | 12/39 (31%) | 13/38 (34%) | 10/28 (36%) | 4/20 (20%)
First incidence (days) | 443 | 513 | 534 | 423
Poly-3 test | P = 0.077N | P = 0.343 | P = 0.482 | P = 0.175N
Pituitary Gland (Pars Distalis): Adenoma or Carcinoma
Overall rate | 20/50 (40%) | 22/50 (44%) | 19/50 (38%) | 12/50 (24%)
Adjusted rate | 41.3% | 45.5% | 41.9% | 27.9%
Terminal rate | 12/39 (31%) | 13/38 (34%) | 10/28 (36%) | 4/20 (20%)
First incidence (days) | 443 | 513 | 534 | 423
Poly-3 test | P = 0.061N | P = 0.418 | P = 0.558 | P = 0.129N
Thymus: Benign Thymoma
Overall rate | 6/46 (13%) | 6/41 (15%) | 6/37 (16%) | 8/48 (17%)
Adjusted rate | 14.1% | 16.2% | 19.2% | 21.1%
Terminal rate | 6/36 (17%) | 6/32 (19%) | 5/20 (25%) | 3/19 (16%)
First incidence (days) | 730 (T) | 730 (T) | 534 | 691
Poly-3 test | P = 0.263 | P = 0.523 | P = 0.399 | P = 0.298
Thyroid Gland (C-Cell): Adenoma
Overall rate | 4/50 (8%) | 4/50 (8%) | 5/50 (10%) | 2/50 (4%)
Adjusted rate | 8.7% | 8.7% | 11.5% | 5.1%
Terminal rate | 4/39 (10%) | 2/38 (5%) | 3/28 (11%) | 1/20 (5%)
First incidence (days) | 730 (T) | 610 | 562 | 719
Poly-3 test | P = 0.342N | P = 0.641N | P = 0.462 | P = 0.412N
Thyroid Gland (C-Cell): Adenoma or Carcinoma
Overall rate | 5/50 (10%) | 4/50 (8%) | 5/50 (10%) | 2/50 (4%)
Adjusted rate | 10.9% | 8.7% | 11.5% | 5.1%
Terminal rate | 5/39 (13%) | 2/38 (5%) | 3/28 (11%) | 1/20 (5%)
First incidence (days) | 730 (T) | 610 | 562 | 719
Poly-3 test | P = 0.268N | P = 0.498N | P = 0.592 | P = 0.284N
Thyroid Gland (Follicular Cell): Adenoma or Carcinoma
Overall rate | 2/50 (4%) | 0/50 (0%) | 3/50 (6%) | 2/50 (4%)
Adjusted rate | 4.3% | 0.0% | 7% | 5.1%
Terminal rate | 1/39 (3%) | 0/38 (0%) | 3/28 (11%) | 0/20 (0%)
First incidence (days) | 645 | – | 730 (T) | 719
Poly-3 test | P = 0.354 | P = 0.241N | P = 0.462 | P = 0.634
Uterus: Stromal Polyp
Overall rate | 2/50 (4%) | 9/50 (18%) | 2/50 (4%) | 4/50 (8%)
Adjusted rate | 4.3% | 19.6% | 4.6% | 10.1%
Terminal rate | 1/39 (3%) | 7/38 (18%) | 1/28 (4%) | 2/20 (10%)
First incidence (days) | 561 | 705 | 599 | 691
Poly-3 test | P = 0.534N | P = 0.023 | P = 0.666 | P = 0.265
Uterus: Stromal Polyp or Stromal Sarcoma
Overall rate | 3/50 (6%) | 9/50 (18%) | 2/50 (4%) | 4/50 (8%)
Adjusted rate | 6.4% | 19.6% | 4.6% | 10.1%
Terminal rate | 2/39 (5%) | 7/38 (18%) | 1/28 (4%) | 2/20 (10%)
First incidence (days) | 561 | 705 | 599 | 691
Poly-3 test | P = 0.446N | P = 0.055 | P = 0.535N | P = 0.412
Uterus: Carcinoma
Overall rate | 3/50 (6%) | 0/50 (0%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate | 6.5% | 0.0% | 0.0% | 7.6%
Terminal rate | 3/39 (8%) | 0/38 (0%) | 0/28 (0%) | 2/20 (10%)
First incidence (days) | 730 (T) | – | – | 726
Poly-3 test | P = 0.243 | P = 0.120N | P = 0.133N | P = 0.587
All Organs: Benign Neoplasms
Overall rate | 33/50 (66%) | 39/50 (78%) | 35/50 (70%) | 33/50 (66%)
Adjusted rate | 67.5% | 79.0% | 73.0% | 71.9%
Terminal rate | 25/39 (64%) | 28/38 (74%) | 19/28 (68%) | 14/20 (70%)
First incidence (days) | 443 | 513 | 505 | 423
Poly-3 test | P = 0.527N | P = 0.143 | P = 0.354 | P = 0.401
All Organs: Malignant Neoplasms
Overall rate | 17/50 (34%) | 6/50 (12%) | 9/50 (18%) | 10/50 (20%)
Adjusted rate | 36.2% | 13.0% | 20.4% | 24.1%
Terminal rate | 13/39 (33%) | 5/38 (13%) | 4/28 (14%) | 4/20 (20%)
First incidence (days) | 635 | 519 | 478 | 423
Poly-3 test | P = 0.437N | P = 0.007N | P = 0.073N | P = 0.155N
All Organs: Benign or Malignant Neoplasms
Overall rate | 40/50 (80%) | 41/50 (82%) | 38/50 (76%) | 35/50 (70%)
Adjusted rate | 81.6% | 82.0% | 77.7% | 75.4%
Terminal rate | 31/39 (80%) | 29/38 (76%) | 20/28 (71%) | 15/20 (75%)
First incidence (days) | 443 | 513 | 478 | 423
Poly-3 test | P = 0.230N | P = 0.584 | P = 0.409N | P = 0.303N

(T) = terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal gland, lung, ovary, pituitary gland, thymus, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table B-3 Historical Incidence of Lung Neoplasms in Control Female Wistar Han Rats^a^

Study (Study Start) | Alveolar/Bronchiolar Adenoma | Cystic Keratinizing Epithelioma | Squamous Cell Carcinoma | Cystic Keratinizing Epithelioma or Squamous Cell Carcinoma
Historical Incidence: Inhalation Studies
Antimony trioxide (September 2008) | 0/50 | 0/50 | 0/50 | 0/50
CIMSTAR 3800 (April 2008) | 0/50 | 0/50 | 0/50 | 0/50
Trim VX (July 2009) | 0/50 | 0/50 | 0/50 | 0/50
Total | 0/150 | 0/150 | 0/150 | 0/150
Overall Historical Incidence: All Routes
Total | 0/300 | 0/300 | 0/300 | 0/300

^a^ Data as of November 2014.

Table B-4 Historical Incidence of Pheochromocytoma of the Adrenal Medulla in Control Female Wistar Han Rats^a^

Study (Study Start) | Benign | Malignant | Benign or Malignant
Historical Incidence: Inhalation Studies
Antimony trioxide (September 2008) | 0/49 | 0/49 | 0/49
CIMSTAR 3800 (April 2008) | 1/49 | 1/49 | 2/49
Trim VX (July 2009) | 0/50 | 0/50 | 0/50
Total (%) | 1/148 (0.7%) | 1/148 (0.7%) | 2/148 (1.4%)
Mean ± standard deviation | 0.7% ± 1.2% | 0.7% ± 1.2% | 1.4% ± 2.4%
Range | 0%–2% | 0%–2% | 0%–4%
Overall Historical Incidence: All Routes
Total (%) | 5/297 (1.7%) | 1/297 (0.3%) | 7/297 (2.4%)^b^
Mean ± standard deviation | 1.7% ± 1.5% | 0.3% ± 0.8% | 2.4% ± 2.0%
Range | 0%–4% | 0%–2% | 0%–4%

^a^ Data as of November 2014.

^b^ Includes one incidence of complex pheochromocytoma.

Table B-5 Summary of the Incidence of Nonneoplastic Lesions in Female Rats in the Two-year Inhalation Study of Antimony Trioxide^a^

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Disposition Summary
Animals initially in study | 60 | 60 | 60 | 60
Twelve-month interim evaluation | 10 | 10 | 10 | 10
Early deaths
Moribund | 11 | 12 | 20 | 27
Natural deaths | – | – | 2 | 3
Survivors
Died last week of study | – | – | 1 | 1
Terminal kill | 39 | 38 | 27 | 19
Animals examined microscopically | 60 | 60 | 60 | 60
Twelve-month Interim Evaluation
Alimentary System
Esophagus | (10) | (10) | (9) | (10)
Intestine large, cecum | (10) | (10) | (10) | (10)
Intestine large, colon | (10) | (10) | (10) | (10)
Intestine large, rectum | (10) | (10) | (10) | (10)
Intestine small, duodenum | (10) | (10) | (10) | (10)
Intestine small, ileum | (10) | (10) | (10) | (10)
Intestine small, jejunum | (10) | (10) | (10) | (10)
Liver | (10) | (10) | (10) | (10)
Basophilic focus | 1 (10%) | – | – | –
Hematopoietic cell proliferation | 1 (10%) | – | – | –
Hepatodiaphragmatic nodule | 1 (10%) | – | – | –
Infiltration cellular, histiocyte | – | – | 1 (10%) | –
Pigmentation, hemosiderin | – | – | 1 (10%) | –
Pancreas | (10) | (10) | (10) | (10)
Atrophy | – | – | 1 (10%) | 2 (20%)
Basophilic focus | | 1 (10%) | – | –
Inflammation, chronic active | – | – | 1 (10%) | 1 (10%)
Artery, fibrosis | | 1 (10%) | – | –
Salivary glands | (10) | (10) | (10) | (10)
Stomach, forestomach | (10) | (10) | (10) | (10)
Stomach, glandular | (10) | (10) | (10) | (10)
Cardiovascular System
Blood vessel | (10) | (10) | (10) | (10)
Heart | (10) | (10) | (10) | (10)
Cardiomyopathy | – | 3 (30%) | – | 1 (10%)
Mineralization | 1 (10%) | – | – | –
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Hyperplasia | – | 1 (10%) | 1 (10%) | 1 (10%)
Adrenal medulla | (10) | (10) | (10) | (10)
Islets, pancreatic | (10) | (10) | (10) | (10)
Parathyroid gland | (10) | (8) | (8) | (10)
Pituitary gland | (10) | (10) | (10) | (10)
Pars distalis, hyperplasia | 2 (20%) | 2 (20%) | – | 1 (10%)
Thyroid gland | (10) | (10) | (10) | (10)
C-cell, hyperplasia | – | – | – | 1 (10%)
Genital System
Clitoral gland | (10) | (10) | (10) | (10)
Inflammation, chronic active | 4 (40%) | 3 (30%) | 3 (30%) | 1 (10%)
Ovary | (10) | (10) | (10) | (10)
Cyst | 2 (20%) | 1 (10%) | 4 (40%) | –
Uterus | (10) | (10) | (10) | (10)
Dilatation | – | 1 (10%) | – | –
Endometrial glands, metaplasia, squamous | – | – | 1 (10%) | 1 (10%)
Hematopoietic System
Bone marrow | (10) | (10) | (10) | (10)
Hyperplasia | 1 (10%) | 1 (10%) | 3 (30%) | –
Lymph node, bronchial | (7) | (8) | (9) | (5)
Foreign body | – | 7 (88%) | 9 (100%) | 4 (80%)
Hyperplasia, lymphoid | – | 4 (50%) | 2 (22%) | 1 (20%)
Pigmentation | – | – | – | 1 (20%)
Lymph node, mandibular | (10) | (10) | (10) | (8)
Lymph node, mediastinal | (10) | (9) | (10) | (10)
Foreign body | – | 9 (100%) | 5 (50%) | 6 (60%)
Hyperplasia, lymphoid | – | 8 (89%) | – | 3 (30%)
Pigmentation | 8 (80%) | 8 (89%) | 8 (80%) | 8 (80%)
Lymph node, mesenteric | (10) | (10) | (10) | (10)
Spleen | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | 4 (40%) | 6 (60%) | 6 (60%) | 7 (70%)
Thymus | (10) | (10) | (10) | (10)
Cyst | 1 (10%) | – | 2 (20%) | –
Hyperplasia, squamous | – | 1 (10%) | – | 1 (10%)
Integumentary System
Mammary gland | (10) | (10) | (10) | (10)
Skin | (10) | (10) | (10) | (10)
Cyst, squamous | 1 (10%) | – | – | –
Respiratory System
Larynx | (10) | (10) | (10) | (10)
Foreign body | – | 10 (100%) | 10 (100%) | 10 (100%)
Lung | (10) | (10) | (10) | (10)
Fibrosis | – | 10 (100%) | 10 (100%) | 10 (100%)
Foreign body | – | 10 (100%) | 10 (100%) | 10 (100%)
Hemorrhage | – | – | 1 (10%) | 1 (10%)
Inflammation, chronic active | 2 (20%) | 10 (100%) | 10 (100%) | 10 (100%)
Proteinosis | – | 10 (100%) | 10 (100%) | 10 (100%)
Alveolar epithelium, hyperplasia | – | 10 (100%) | 10 (100%) | 10 (100%)
Alveolus, inflammation, suppurative | – | 1 (10%) | – | 3 (30%)
Bronchiole, epithelium, hyperplasia | – | 1 (10%) | – | 3 (30%)
Perivascular, infiltration cellular, lymphocyte | – | 4 (40%) | 5 (50%) | 3 (30%)
Nose | (10) | (10) | (10) | (10)
Foreign body | – | – | – | 4 (40%)
Metaplasia, mucous | – | – | – | 1 (10%)
Olfactory epithelium, accumulation, hyaline droplet | 2 (20%) | 2 (20%) | 1 (10%) | 2 (20%)
Respiratory epithelium, accumulation, hyaline droplet | – | 1 (10%) | – | 1 (10%)
Respiratory epithelium, hyperplasia | – | 1 (10%) | – | 2 (20%)
Respiratory epithelium, metaplasia, squamous | – | – | – | 1 (10%)
Trachea | (10) | (10) | (10) | (10)
Foreign body | – | 6 (60%) | 10 (100%) | 10 (100%)
Special Senses System
Eye | (10) | (10) | (10) | (10)
Lens, degeneration | – | 1 (10%) | – | –
Retina, atrophy | 1 (10%) | – | 1 (10%) | 1 (10%)
Harderian gland | (10) | (10) | (10) | (10)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Calculus microscopic observation only | – | 1 (10%) | 1 (10%) | –
Nephropathy | – | 2 (20%) | 1 (10%) | 2 (20%)
Cortex, vein, dilatation | – | – | – | 1 (10%)
Urinary bladder | (10) | (10) | (10) | (10)
Systems Examined at 12 Months with No Lesions Observed
General Body System
Musculoskeletal System
Nervous System
Two-year Study
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (50) | (50) | (49) | (50)
Intestine large, colon | (50) | (50) | (50) | (50)
Hemorrhage | – | – | – | 1 (2%)
Necrosis | – | – | – | 1 (2%)
Intestine large, rectum | (48) | (47) | (50) | (49)
Edema | – | 1 (2%) | – | –
Inflammation, chronic active | – | 1 (2%) | – | –
Intestine small, duodenum | (50) | (50) | (50) | (50)
Inflammation, chronic active | – | – | – | 1 (2%)
Intestine small, ileum | (50) | (50) | (49) | (50)
Inflammation, suppurative | – | – | 1 (2%) | –
Intestine small, jejunum | (50) | (50) | (49) | (49)
Liver | (50) | (50) | (50) | (50)
Angiectasis | 3 (6%) | 2 (4%) | 1 (2%) | 2 (4%)
Basophilic focus | 12 (24%) | 7 (14%) | 11 (22%) | 6 (12%)
Clear cell focus | 4 (8%) | 5 (10%) | 1 (2%) | 2 (4%)
Congestion | 2 (4%) | 4 (8%) | 1 (2%) | 1 (2%)
Cyst | 2 (4%) | 4 (8%) | 3 (6%) | 1 (2%)
Degeneration | – | – | 1 (2%) | –
Eosinophilic focus | 3 (6%) | 1 (2%) | 1 (2%) | 1 (2%)
Fatty change | 6 (12%) | 1 (2%) | 1 (2%) | –
Fibrosis | – | – | 4 (8%) | 2 (4%)
Hepatodiaphragmatic nodule | 2 (4%) | 2 (4%) | 4 (8%) | 4 (8%)
Hyperplasia | – | 1 (2%) | – | –
Infiltration cellular, histiocyte | – | 1 (2%) | – | –
Infiltration cellular, lymphocyte | – | – | 1 (2%) | –
Inflammation, chronic active | – | – | 3 (6%) | 4 (8%)
Mixed cell focus | – | 1 (2%) | 1 (2%) | 2 (4%)
Necrosis | – | – | – | 2 (4%)
Pigmentation, hemosiderin | – | 1 (2%) | – | –
Bile duct, hyperplasia | 3 (6%) | 2 (4%) | – | 1 (2%)
Bile duct, hypertrophy | – | – | 1 (2%) | –
Bile duct, inflammation, chronic active | 1 (2%) | – | – | –
Hepatocyte, hypertrophy, focal | – | – | 1 (2%) | –
Serosa, fibrosis | – | 1 (2%) | – | –
Mesentery | (50) | (50) | (50) | (50)
Necrosis | – | – | – | 1 (2%)
Artery, inflammation, chronic active | – | – | – | 6 (12%)
Artery, necrosis | – | – | – | 3 (6%)
Fat, necrosis | 5 (10%) | 3 (6%) | 3 (6%) | 6 (12%)
Pancreas | (50) | (50) | (50) | (50)
Atrophy | 11 (22%) | 14 (28%) | 9 (18%) | 16 (32%)
Basophilic focus | 2 (4%) | – | – | 1 (2%)
Inflammation, chronic active | – | 2 (4%) | 1 (2%) | –
Artery, hemorrhage | – | – | – | 2 (4%)
Artery, inflammation, chronic active | – | – | 3 (6%) | 8 (16%)
Artery, necrosis | – | – | – | 4 (8%)
Artery, thrombosis | – | – | – | 1 (2%)
Salivary glands | (50) | (50) | (50) | (50)
Atrophy | – | 1 (2%) | – | 2 (4%)
Duct, hyperplasia | – | – | – | 1 (2%)
Stomach, forestomach | (50) | (50) | (50) | (50)
Cyst, squamous | 1 (2%) | – | – | –
Fibrosis | – | 1 (2%) | – | –
Hyperplasia, squamous | 4 (8%) | 5 (10%) | 4 (8%) | 6 (12%)
Inflammation, acute | – | 1 (2%) | – | –
Inflammation, chronic active | – | – | – | 1 (2%)
Mineralization | – | – | 1 (2%) | 1 (2%)
Ulcer | 2 (4%) | 1 (2%) | – | –
Stomach, glandular | (50) | (50) | (50) | (50)
Hemorrhage | – | – | 1 (2%) | 1 (2%)
Inflammation, chronic active | – | – | – | 1 (2%)
Mineralization | – | – | – | 1 (2%)
Ulcer | – | – | 1 (2%) | –
Tooth | (1) | (1) | (0) | (1)
Inflammation, chronic active | 1 (100%) | – | – | –
Malformation | – | 1 (100%) | – | 1 (100%)
Cardiovascular System
Blood vessel | (49) | (50) | (50) | (49)
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 29 (58%) | 19 (38%) | 29 (58%) | 29 (58%)
Inflammation, suppurative | – | – | 1 (2%) | –
Valve, fibrosis | – | – | – | 1 (2%)
Valve, inflammation, chronic active | – | – | 1 (2%) | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Accessory adrenal cortical nodule | 1 (2%) | – | – | –
Angiectasis | – | – | – | 1 (2%)
Degeneration | – | – | – | 1 (2%)
Degeneration, cystic | 37 (74%) | 44 (88%) | 39 (78%) | 31 (62%)
Degeneration, fatty | – | – | – | 1 (2%)
Fibrosis | – | 1 (2%) | 1 (2%) | –
Hematopoietic cell proliferation | 1 (2%) | – | 1 (2%) | –
Hyperplasia | 27 (54%) | 23 (46%) | 30 (60%) | 23 (46%)
Hypertrophy | 2 (4%) | 2 (4%) | – | 1 (2%)
Vacuolization cytoplasmic | 1 (2%) | – | – | –
Adrenal medulla | (49) | (49) | (49) | (50)
Atrophy | – | 1 (2%) | – | –
Hyperplasia | – | – | 3 (6%) | 5 (10%)
Islets, pancreatic | (50) | (50) | (50) | (50)
Hyperplasia | 1 (2%) | – | 1 (2%) | –
Parathyroid gland | (39) | (41) | (43) | (46)
Pituitary gland | (50) | (50) | (50) | (50)
Angiectasis | – | – | – | 2 (4%)
Necrosis | – | – | 1 (2%) | –
Vacuolization cytoplasmic | – | 1 (2%) | – | –
Pars distalis, hyperplasia | 22 (44%) | 16 (32%) | 17 (34%) | 21 (42%)
Pars intermedia, hyperplasia | 1 (2%) | 2 (4%) | 2 (4%) | 2 (4%)
Thyroid gland | (50) | (50) | (50) | (50)
C-cell, hyperplasia | 21 (42%) | 16 (32%) | 15 (30%) | 8 (16%)
Follicle, cyst | – | – | – | 1 (2%)
Follicular cell, hyperplasia | 3 (6%) | 3 (6%) | 1 (2%) | –
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (50) | (49) | (47) | (49)
Cyst | – | – | 4 (9%) | –
Fibrosis | – | – | – | 1 (2%)
Inflammation, chronic active | 2 (4%) | 1 (2%) | 2 (4%) | 5 (10%)
Ovary | (50) | (49) | (50) | (50)
Congestion | – | – | 2 (4%) | 5 (10%)
Cyst | 11 (22%) | 10 (20%) | 14 (28%) | 15 (30%)
Fibrosis | – | – | 2 (4%) | 3 (6%)
Hemorrhage | – | 1 (2%) | – | 3 (6%)
Inflammation, chronic active | – | – | – | 1 (2%)
Mineralization | – | – | – | 1 (2%)
Necrosis | – | – | – | 1 (2%)
Thrombosis | – | – | 1 (2%) | 1 (2%)
Granulosa cell, hyperplasia | 1 (2%) | 1 (2%) | 2 (4%) | –
Interstitial cell, hyperplasia | 2 (4%) | 1 (2%) | 1 (2%) | –
Uterus | (50) | (50) | (50) | (50)
Cyst | 1 (2%) | – | – | –
Dilatation | 2 (4%) | 3 (6%) | 1 (2%) | 2 (4%)
Hemorrhage | – | – | – | 1 (2%)
Inflammation, suppurative | 1 (2%) | – | 1 (2%) | 2 (4%)
Inflammation, chronic active | 1 (2%) | 1 (2%) | – | –
Necrosis | 1 (2%) | – | – | –
Thrombosis | – | – | 1 (2%) | –
Endometrial glands, hyperplasia | 2 (4%) | – | 3 (6%) | –
Endometrial glands, metaplasia, squamous | – | 4 (8%) | 2 (4%) | 1 (2%)
Endometrium, cyst | – | – | – | 1 (2%)
Endometrium, hyperplasia | – | 1 (2%) | 2 (4%) | –
Endometrium, hyperplasia, cystic | 9 (18%) | 17 (34%) | 7 (14%) | 16 (32%)
Endometrium, metaplasia, squamous | 1 (2%) | – | – | –
Vagina | (0) | (0) | (1) | (0)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Hemorrhage | – | – | 1 (2%) | –
Hyperplasia | 8 (16%) | 5 (10%) | 11 (22%) | 20 (40%)
Myelofibrosis | – | – | – | 1 (2%)
Lymph node | (2) | (3) | (3) | (3)
Pigmentation | 1 (50%) | 1 (33%) | – | –
Axillary, ectasia | – | – | 1 (33%) | –
Iliac, congestion | – | – | – | 1 (33%)
Iliac, hyperplasia, plasma cell | – | – | 1 (33%) | –
Lumbar, ectasia | – | – | 1 (33%) | –
Lumbar, foreign body | 1 (50%) | – | – | –
Lumbar, hyperplasia | – | 1 (33%) | – | –
Renal, congestion | – | – | 1 (33%) | –
Renal, hemorrhage | – | – | 1 (33%) | –
Thoracic, foreign body | – | – | – | 1 (33%)
Lymph node, bronchial | (35) | (36) | (28) | (41)
Foreign body | – | 35 (97%) | 23 (82%) | 36 (88%)
Hyperplasia, lymphoid | – | 21 (58%) | 9 (32%) | 11 (27%)
Pigmentation | 14 (40%) | 12 (33%) | 8 (29%) | 18 (44%)
Lymph node, mandibular | (42) | (46) | (44) | (48)
Ectasia | – | – | 1 (2%) | –
Foreign body | – | 1 (2%) | – | 5 (10%)
Lymph node, mediastinal | (46) | (46) | (46) | (46)
Congestion | – | – | – | 1 (2%)
Fibrosis | – | 1 (2%) | – | –
Foreign body | – | 27 (59%) | 32 (70%) | 33 (72%)
Hyperplasia, lymphoid | – | 14 (30%) | 10 (22%) | 15 (33%)
Pigmentation | 39 (85%) | 42 (91%) | 41 (89%) | 41 (89%)
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Spleen | (50) | (50) | (50) | (50)
Congestion | – | 1 (2%) | 1 (2%) | –
Depletion cellular | 1 (2%) | – | – | –
Fibrosis | – | 1 (2%) | 1 (2%) | –
Hematopoietic cell proliferation | 44 (88%) | 43 (86%) | 46 (92%) | 48 (96%)
Hemorrhage | – | – | 1 (2%) | 1 (2%)
Pigmentation | – | – | 1 (2%) | 1 (2%)
Artery, inflammation, chronic active | – | – | 1 (2%) | –
Artery, necrosis | – | – | 1 (2%) | 1 (2%)
Lymphoid follicle, atrophy | 1 (2%) | – | – | –
Thymus | (46) | (41) | (37) | (48)
Cyst | – | 1 (2%) | 1 (3%) | 1 (2%)
Depletion cellular | 3 (7%) | 1 (2%) | 2 (5%) | 3 (6%)
Hemorrhage | – | 4 (10%) | 2 (5%) | –
Hyperplasia | – | 1 (2%) | – | –
Inflammation, chronic active | – | – | – | 1 (2%)
Vacuolization cytoplasmic | 1 (2%) | – | – | –
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Cyst | – | – | – | 1 (2%)
Fibrosis | – | – | 1 (2%) | 1 (2%)
Galactocele | 7 (14%) | 9 (18%) | 13 (26%) | 10 (20%)
Granuloma, lipomatous | – | – | – | 2 (4%)
Hyperplasia | 6 (12%) | 3 (6%) | 8 (16%) | 3 (6%)
Infiltration cellular, histiocyte | 1 (2%) | – | – | –
Skin | (50) | (49) | (50) | (50)
Angiectasis | 1 (2%) | – | – | 1 (2%)
Cyst, squamous | – | 4 (8%) | – | 1 (2%)
Fibrosis | 1 (2%) | – | – | –
Hyperplasia | 1 (2%) | – | – | –
Inflammation, suppurative | – | – | – | 1 (2%)
Inflammation, chronic active | 8 (16%) | 5 (10%) | 9 (18%) | 9 (18%)
Ulcer | 2 (4%) | 5 (10%) | 4 (8%) | 8 (16%)
Epidermis, hyperplasia | – | – | – | 1 (2%)
Epidermis, necrosis | – | – | 2 (4%) | –
Subcutaneous tissue, inflammation, chronic active | – | 1 (2%) | – | –
Musculoskeletal System | – | – | – | –
Bone | (50) | (50) | (50) | (50)
Femur, degeneration | – | – | – | 1 (2%)
Femur, hyperostosis | – | – | – | 2 (4%)
Femur, osteomalacia | – | – | – | 1 (2%)
Maxilla, inflammation, chronic active | – | 1 (2%) | 2 (4%) | –
Skeletal muscle | (2) | (1) | (2) | (7)
Atrophy | – | – | – | 1 (14%)
Inflammation, suppurative | – | – | – | 1 (14%)
Inflammation, chronic active | – | – | – | 1 (14%)
Necrosis | – | – | – | 1 (14%)
Nervous System
Brain | (50) | (50) | (50) | (50)
Compression | 10 (20%) | 12 (24%) | 12 (24%) | 5 (10%)
Edema | – | – | 1 (2%) | –
Hemorrhage | – | – | 2 (4%) | 2 (4%)
Infiltration cellular, mixed cell | – | 1 (2%) | – | –
Meninges, hyperplasia | – | – | 1 (2%) | –
Peripheral nerve | (2) | (1) | (2) | (2)
Spinal cord | (2) | (1) | (2) | (2)
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Foreign body | – | 50 (100%) | 50 (100%) | 50 (100%)
Inflammation, chronic active | – | 8 (16%) | – | 3 (6%)
Metaplasia, squamous | – | – | – | 1 (2%)
Arteriole, necrosis | – | – | – | 1 (2%)
Respiratory epithelium, hyperplasia | 5 (10%) | 6 (12%) | 2 (4%) | 3 (6%)
Lung | (50) | (50) | (50) | (50)
Fibrosis | 1 (2%) | 50 (100%) | 50 (100%) | 49 (98%)
Foreign body | – | 50 (100%) | 50 (100%) | 50 (100%)
Hemorrhage | – | 5 (10%) | 3 (6%) | –
Hyperplasia, lymphoid | – | 1 (2%) | – | –
Inflammation, suppurative | 1 (2%) | – | – | –
Inflammation, chronic active | 21 (42%) | 50 (100%) | 50 (100%) | 50 (100%)
Mineralization | 1 (2%) | – | – | –
Proteinosis | – | 50 (100%) | 50 (100%) | 50 (100%)
Thrombosis | – | – | – | 1 (2%)
Alveolar epithelium, hyperplasia | 5 (10%) | 50 (100%) | 49 (98%) | 50 (100%)
Alveolar epithelium, metaplasia, squamous | – | 5 (10%) | 3 (6%) | 1 (2%)
Alveolus, inflammation, suppurative | – | 5 (10%) | 6 (12%) | 5 (10%)
Artery, inflammation, chronic active | – | – | 1 (2%) | 2 (4%)
Artery, necrosis | – | – | – | 2 (4%)
Bronchiole, epithelium, hyperplasia | 6 (12%) | 26 (52%) | 25 (50%) | 27 (54%)
Perivascular, infiltration cellular, lymphocyte | – | 18 (36%) | 11 (22%) | 8 (16%)
Mediastinum | (0) | (0) | (2) | (9)
Artery, inflammation, chronic active | – | – | 2 (100%) | 9 (100%)
Artery, necrosis | – | – | 1 (50%) | 6 (67%)
Nose | (50) | (50) | (50) | (50)
Foreign body | – | 5 (10%) | 26 (52%) | 45 (90%)
Hyperplasia, squamous | – | – | 1 (2%) | –
Inflammation, suppurative | 2 (4%) | 6 (12%) | 5 (10%) | 4 (8%)
Necrosis | – | – | – | 2 (4%)
Glands, respiratory epithelium, hyperplasia | – | – | 1 (2%) | –
Olfactory epithelium, accumulation, hyaline droplet | 9 (18%) | 14 (28%) | 13 (26%) | 13 (26%)
Olfactory epithelium, atrophy | – | – | – | 2 (4%)
Olfactory epithelium, degeneration | – | – | – | 1 (2%)
Olfactory epithelium, metaplasia, respiratory | – | 1 (2%) | – | –
Olfactory epithelium, necrosis | – | – | – | 1 (2%)
Olfactory epithelium, vacuolization cytoplasmic | – | – | 1 (2%) | –
Respiratory epithelium, accumulation, hyaline droplet | – | 2 (4%) | 2 (4%) | 1 (2%)
Respiratory epithelium, degeneration | – | 1 (2%) | – | –
Respiratory epithelium, hyperplasia | 4 (8%) | 6 (12%) | 7 (14%) | 16 (32%)
Respiratory epithelium, metaplasia, squamous | – | 2 (4%) | 3 (6%) | 5 (10%)
Respiratory epithelium, necrosis | 1 (2%) | 1 (2%) | 2 (4%) | 1 (2%)
Respiratory epithelium, regeneration | – | – | 1 (2%) | –
Squamous epithelium, hyperplasia | – | – | – | 1 (2%)
Squamous epithelium, necrosis | – | – | 1 (2%) | 1 (2%)
Trachea | (50) | (50) | (50) | (50)
Fibrosis | – | – | 1 (2%) | 1 (2%)
Foreign body | – | 39 (78%) | 47 (94%) | 49 (98%)
Inflammation, suppurative | – | – | – | 1 (2%)
Metaplasia, squamous | 1 (2%) | – | – | –
Epithelium, hyperplasia | – | – | – | 2 (4%)
Epithelium, metaplasia, squamous | – | – | 1 (2%) | –
Epithelium, regeneration | 1 (2%) | – | 2 (4%) | 1 (2%)
Special Senses System
Eye | (49) | (50) | (49) | (49)
Ciliary body, inflammation, acute | – | – | 1 (2%) | 6 (12%)
Lens, degeneration | – | 2 (4%) | 2 (4%) | –
Posterior chamber, exudate | – | – | 1 (2%) | –
Retina, atrophy | 6 (12%) | 21 (42%) | 18 (37%) | 19 (39%)
Retina, infiltration cellular, polymorphonuclear | – | – | 1 (2%) | –
Harderian gland | (50) | (50) | (50) | (50)
Hyperplasia | 1 (2%) | – | – | –
Urinary System
Kidney | (50) | (50) | (50) | (50)
Cyst | 1 (2%) | 2 (4%) | – | –
Infarct | – | 3 (6%) | 2 (4%) | 1 (2%)
Nephropathy | 16 (32%) | 15 (30%) | 20 (40%) | 24 (48%)
Arteriole, inflammation, chronic active | – | – | – | 1 (2%)
Artery, fibrosis | – | – | – | 1 (2%)
Artery, inflammation, chronic active | – | – | – | 2 (4%)
Artery, necrosis | – | – | 1 (2%) | 2 (4%)
Papilla, necrosis | 1 (2%) | – | – | –
Pelvis, dilatation | 1 (2%) | – | – | 1 (2%)
Pelvis, inflammation, suppurative | – | – | – | 2 (4%)
Pelvis, inflammation, chronic active | 2 (4%) | 3 (6%) | – | 1 (2%)
Pelvis, mineralization | 31 (62%) | 30 (60%) | 24 (48%) | 15 (30%)
Renal tubule, accumulation, hyaline droplet | – | – | 5 (10%) | 11 (22%)
Renal tubule, hyperplasia | 1 (2%) | – | – | 1 (2%)
Renal tubule, infiltration cellular, polymorphonuclear | – | – | 1 (2%) | –
Urinary bladder | (50) | (50) | (50) | (50)
Angiectasis | – | – | – | 1 (2%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.